# Glossary

Affinity: A measurement of the strength of interaction between an epitope and an antibody’s antigen binding site.
Case report: Detailed descriptions of a few patients or clinical cases (frequently, just one sick person) with an unusual disease or complication, uncommon combinations of diseases, an unusual or misleading semiology, cause, or outcome (maybe a surprising recovery). They often are preliminary observations that are later refuted. They cannot estimate disease frequency or risk (e.g., for lack of a valid denominator).
Case series: A collection of subjects (usually, patients) with common characteristics used to describe some clinical, pathophysiological, or operational aspect of a disease, treatment, exposure, or diagnostic procedure. A case series does not include a comparison group and is often based on prevalent cases and on a sample of convenience. Common selection biases and confounding severely limit their power to make causal inferences.
Case-comparison study (case-control study, case referent study): The observational epidemiological study of persons with the disease (or another outcome variable) of interest and a suitable control group of persons without the disease (comparison group, reference group). The potential relationship of a suspected risk factor or an attribute to the disease is examined by comparing the diseased and non-diseased subjects with regard to how frequently the factor or attribute is present (or, if quantitative, the levels of the attribute) in each of the groups (diseased and non-diseased).
Convenience sample: Samples selected by easily employed but basically non-probabilistic (and probably biased) methods. “Man-in-the-street” surveys and a survey of blood pressure among volunteers who drop in at an examination booth in a public place are in this category.
Defining acquired immune deficiency syndrome (AIDS) condition: Any HIV-related illness included in the Centers for Disease Control and Prevention’s (CDC) list of diagnostic criteria for AIDS. AIDS-defining conditions include opportunistic infections and cancers that are life threatening in a person with HIV.
Diagnostic criteria: The specific combination of signs, symptoms, and test results that a clinician uses to identify a person as representing a case of a particular disease or condition.
Enzyme immunoassay: An assay that uses an enzyme-bound antibody to detect antigen. The enzyme catalyzes a color reaction when exposed to substrate.
Exposure variability: A characteristic describing whether epidemiological studies included non-exposed cases or exposed controls. Lack of exposure variability may contribute to observed heterogeneity of study results.
Germinal center: Discrete areas within secondary lymphoid tissues where B-cell maturation and memory development occur.
In situ hybridization: A technique that allows for precise localization of a specific segment of nucleic acid within a histologic section. The underlying basis of in situ hybridization is that nucleic acids, if preserved adequately within a histologic specimen, can be detected through the application of a complementary strand of nucleic acid to which a reporter molecule is attached.
EBV latency patterns: Particular EBV viral gene expression patterns that establish distinct EBV latent infection statuses (latency types III, II, and I).
Latent phase: A phase of the virus life cycle during which the virus is not replicating.
Lytic phase: A phase of the virus life cycle during which the virus replicates within the host cell, releasing a new generation of viruses when the infected cell lyses.
Monoclonal: Pertaining to or designating a group of identical cells or organisms derived from a single cell or organism.
Nude mouse (athymic nude mouse): A type of laboratory mouse that is hairless, lacks a normal thymus gland, and has a defective immune system because of a genetic mutation. Athymic nude mice are often used in cancer research because they do not reject tumor cells, from mice or other species.
Open reading frame: A portion of a DNA molecule that, when translated into amino acids, contains no stop codons.
Optical density: The absorbance of a particular substance at a specified wavelength in an enzyme-linked immunosorbent assay.
Peripheral blood: Blood circulating throughout the body; the primary method for transporting nutrients such as oxygen and carbon dioxide through the body consisting of three primary components: erythrocytes (red blood cells), leukocytes (white blood cells), and thrombocytes (blood platelets).
Polyclonal: Pertaining to or designating a group of cells or organisms derived from several cells.
Titer: A laboratory measurement of the concentration of a substance in a solution (e.g., an antibody titer measures the presence and amount of antibodies in the blood).