# References

Ablashi DV, De-The GB, Easton JM, Liabeuf A, Levine PH, Armstrong GR. 1974. Antibodies to Epstein-Barr virus (EBV) antigens in sera of American Burkitt lymphoma patients. Biomedicine / [publiee pour l'AAICIG]. 21(7):288-293.
Adham M, Kurniawan AN, Muhtadi AI, Roezin A, Hermani B, Gondhowiardjo S, Tan IB, Middeldorp JM. 2012. Nasopharyngeal carcinoma in Indonesia: Epidemiology, incidence, signs, and symptoms at presentation. Chin J Cancer. 31(4):185–196. 10.5732/cjc.011.10328 22313595
Al-Mansour Z, Nelson BP, Evens AM. 2013. Post-transplant lymphoproliferative disease (PTLD): Risk factors, diagnosis, and current treatment strategies. Curr Hematol Malig Rep. 8(3):173–183. 10.1007/s11899-013-0162-5 23737188
Aldred MA, Eng C. 2006. SNP’ing at nasopharyngeal cancer susceptibility: For whom the bell TOLLs. Cancer Biol Ther. 5(10):1292–1293. 10.4161/cbt.5.10.3487 17172806
Alexander FE, Jarrett RF, Lawrence D, Armstrong AA, Freeland J, Gokhale DA, Kane E, Taylor GM, Wright DH, Cartwright RA. 2000. Risk factors for Hodgkin’s disease by Epstein-Barr virus (EBV) status: Prior infection by EBV and other agents. Br J Cancer. 82(5):1117–1121. 10.1054/bjoc.1999.1049 10737396
Alexander FE, Lawrence DJ, Freeland J, Krajewski AS, Angus B, Taylor GM, Jarrett RF. 2003. An epidemiologic study of index and family infectious mononucleosis and adult Hodgkin's disease (HD): evidence for a specific association with EBV+ve HD in young adults. Int J Cancer. 107(2):298-302. 10.1002/ijc.11156
Ambinder RF, Cesarman E. 2007. Clinical and pathological aspects of EBV and KSHV Infection. In: Arvin A, Campadelli-Fiume G, Mocarski E, Moore PS, Roizman B, Whitley R, Yamanishi K, editors. Human Herpesviruses. Cambridge: Cambridge University; p. 885–903. 10.1017/CBO9780511545313.051
American Cancer Society (ACS).2015a. Viruses that can lead to cancer.https://www.cancer.org/cancer/cancercauses/othercarcinogens/infectiousagents/infectiousagentsandcancer/infectious-agents-and-cancer-viruses. [Accessed: June 18, 2015]
American Cancer Society (ACS).2015 b. What are the risk factors for Hodgkin’s Disease? https://www.cancer.org/cancer/hodgkindisease/detailedguide/hodgkin-disease-risk-factors.
Armstrong RW, Armstrong MJ. 1983. Environmental risk factors and nasopharyngeal carcinoma in Selangor, Malaysia: A cross-ethnic perspective. Ecol Dis. 2:185–198.
Arvey A, Tempera I, Tsai K, Chen HS, Tikhmyanova N, Klichinsky M, Leslie C, Lieberman PM. 2012. An atlas of the Epstein-Barr virus transcriptome and epigenome reveals host-virus regulatory interactions. Cell Host Microbe. 12(2):233–245. 10.1016/j.chom.2012.06.008 22901543
Auwaerter PG.2015. Johns Hopkins HIV Guide: Epstein-Barr virus. Johns Hopkins Medicine.https://www.hopkinsguides.com/hopkins/view/Johns_Hopkins_HIV_Guide/545067/all/Epstein_Barr_virus. [Accessed: June 17, 2015]
Balfour HH Jr. 2014. Progress, prospects, and problems in Epstein-Barr virus vaccine development. Curr Opin Virol. 6:1–5. 10.1016/j.coviro.2014.02.005 24632197
Balfour HH Jr, Sifakis F, Sliman JA, Knight JA, Schmeling DO, Thomas W. 2013. Age-specific prevalence of Epstein-Barr virus infection among individuals aged 6-19 years in the United States and factors affecting its acquisition. J Infect Dis. 208(8):1286–1293. 10.1093/infdis/jit321 23868878
Barrionuevo C, Zaharia M, Martinez MT, Taxa L, Misad O, Moscol A, Sarria G, Guerrero I, Casanova L, Flores C et al. 2007. Extranodal NK/T-cell lymphoma, nasal type: study of clinicopathologic and prognosis factors in a series of 78 cases from Peru. Applied immunohistochemistry & molecular morphology: AIMM / official publication of the Society for Applied Immunohistochemistry. 15(1):38-44.
Bernard SM, Cartwright RA, Darwin CM, Richards ID, Roberts B, O’Brien C, Bird CC. 1987. Hodgkin’s disease: Case control epidemiological study in Yorkshire. Br J Cancer. 55(1):85–90. 10.1038/bjc.1987.18 3814482
Berrington de Gonzalez A, Urban MI, Sitas F, Blackburn N, Hale M, Patel M, Ruff P, Sur R, Newton R, Beral V. 2006. Antibodies against six human herpesviruses in relation to seven cancers in black South Africans: A case control study. Infect Agent Cancer. 1:2. 10.1186/1750-9378-1-2 17150131
Bialas M, Sinczak A, Choinska-Stefanska A, Zygulska A. 2002. EBV-positive lymphoepithelial carcinoma of salivary gland in a woman of a non-endemic area--a case report. Polish journal of pathology: official journal of the Polish Society of Pathologists. 53(4):235-238.
Borza CM, Hutt-Fletcher LM. 2002. Alternate replication in B cells and epithelial cells switches tropism of Epstein-Barr virus. Nat Med. 8(6):594–599. 10.1038/nm0602-594 12042810
Boysen T, Friborg J, Stribolt K, Hamilton-Dutoit S, Goertz S, Wohlfahrt J, Melbye M.2011. Epstein-Barr virus-associated gastric carcinoma among patients with pernicious anemia. Int J Cancer. 129(11):2756-2760. 10.1002/ijc.25925
Burke AP, Yen TS, Shekitka KM, Sobin LH. 1990. Lymphoepithelial carcinoma of the stomach with Epstein-Barr virus demonstrated by polymerase chain reaction. Mod Pathol . 3(3):377–380.
Cancer Genome Atlas Research Network. 2014. Comprehensive molecular characterization of gastric adenocarcinoma. Nature. 513(7517):202–209. 10.1038/nature13480 25079317
Carbone A, Gloghini A, Dotti G. 2008. EBV-associated lymphoproliferative disorders: Classification and treatment. Oncologist. 13(5):577–585. 10.1634/theoncologist.2008-0036 18515742
Carpenter LM, Newton R, Casabonne D, Ziegler J, Mbulaiteye S, Mbidde E, Wabinga H, Jaffe H, Beral V. 2008. Antibodies against malaria and Epstein-Barr virus in childhood Burkitt lymphoma: a case-control study in Uganda. Int J Cancer. 122(6):1319-1323. 10.1002/ijc.23254
Carter CD, Brown TM Jr, Herbert JT, Heath CW Jr. 1977. Cancer incidence following infectious mononucleosis. Am J Epidemiol. 105(1):30–36. 10.1093/oxfordjournals.aje.a112352 831462
Cavdar AO, Yavuz G, Babacan E, Gozdasoglu S, Unal E, Ertem U, Pamir A, Yucesan S, Gokcora H, Uluoglu O, et al. 1994. Burkitt’s lymphoma in Turkish children: Clinical, viral [EBV] and molecular studies. Leuk Lymphoma. 14(3-4):323–330. 10.3109/10428199409049685 7950922
Centers for Disease Control and Prevention (CDC).2011. List of vaccines used in United States. Atlanta, GA: Centers for Disease Control and Prevention.https://www.cdc.gov/vaccines/vpd-vac/vaccines-list.htm. [Accessed: June 18, 2015]
Centers for Disease Control and Prevention (CDC).2014a. About Epstein-Barr virus (EBV). Atlanta, GA: Centers for Disease Control and Prevention.https://www.cdc.gov/epstein-barr/about-ebv.html. [Accessed: June 18, 2015]
Centers for Disease Control and Prevention (CDC).2014b. About infectious mononucleosis. Atlanta, GA: Centers for Disease Control and Prevention.https://www.cdc.gov/epstein-barr/about-mono.html. [Accessed: June 18, 2015]
Chan CK, Mueller N, Evans A, Harris NL, Comstock GW, Jellum E, Magnus K, Orentreich N, Polk BF, Vogelman J. 1991. Epstein-Barr virus antibody patterns preceding the diagnosis of nasopharyngeal carcinoma. Cancer Causes Control. 2(2):125–131. 1651778
Chan JKC, Bray F, McCarron P. 2005. Nasopharyngeal carcinoma. In: Barnes EL, Eveson JW, Reichart P, Sidransky D, editors. World Health Organization Classification of Tumours – Pathology and Genetics of Head and Neck Tumours. Lyon, France: International Agency for Research on Cancer; p. 85–97.
Chan WY, Chan EK, Chow JH. 2001. Epstein-Barr virus-associated gastric lymphomas are distinct from mucosa-associated lymphoid tissue-type lymphomas: genetic abnormalities of p53 gene. Diagnostic molecular pathology: the American journal of surgical pathology, part B. 10(3):153-160. 10.1097/00019606-200109000-00002
Chang ET, Adami HO. 2006. The enigmatic epidemiology of nasopharyngeal carcinoma. Cancer Epidemiol Biomarkers Prev. 15(10):1765–1777. 10.1158/1055-9965.EPI-06-0353 17035381
Chen CJ, Wang YF, Shieh T, Chen JY, Liu MY. 1988. Multifactorial etiology of nasopharngeal carcinoma. Epstein-Barr virus, familial tendency and environmental co-factors. In: Wolf GT, Carey TE, editors. Head and Neck Oncology Research. Amsterdam: Kugler Publications; p. 469–476.
Chen JY, Chen CJ, Liu MY, Cho SM, Hsu MM, Lynn TC, Shieh T, Tu SM, Lee HH, Kuo SL, et al. 1987. Antibodies to Epstein-Barr virus-specific DNase in patients with nasopharyngeal carcinoma and control groups. J Med Virol. 23(1):11–21. 10.1002/jmv.1890230103 2824675
Chen XZ, Castro FA, Hu J-K, Brenner H. 2015. Epstein-Barr virus infection and gastric cancer: A systematic review. Medicine (Baltimore). 94(20):e792. 10.1097/MD.0000000000000792 25997049
Chesnokova LS, Hutt-Fletcher LM. 2011. Fusion of Epstein-Barr virus with epithelial cells can be triggered by alphavbeta5 in addition to alphavbeta6 and alphavbeta8, and integrin binding triggers a conformational change in glycoproteins gHgL. J Virol. 85(24):13214–13223. 10.1128/JVI.05580-11 21957301
Chien YC, Chen JY, Liu MY, Yang HI, Hsu MM, Chen CJ, Yang CS. 2001. Serologic markers of Epstein-Barr virus infection and nasopharyngeal carcinoma in Taiwanese men. N Engl J Med. 345(26):1877–1882. 10.1056/NEJMoa011610 11756578
Chin YM, Mushiroda T, Takahashi A, Kubo M, Krishnan G, Yap LF, Teo SH, Lim PVH, Yap YY, Pua KC, et al. 2015. HLA-A SNPs and amino acid variants are associated with nasopharyngeal carcinoma in Malaysian Chinese. Int J Cancer. 136(3):678–687. 24947555
Chow KU, Mitrou PS, Geduldig K, Helm EB, Hoelzer D, Brodt HR. 2001. Changing incidence and survival in patients with aids-related non-Hodgkin’s lymphomas in the era of highly active antiretroviral therapy (HAART). Leuk Lymphoma. 41(1-2):105–116. 10.3109/10428190109057959 11342362
Cocco M, Bellan C, Tussiwand R, Corti D, Traggiai E, Lazzi S, Mannucci S, Bronz L, Palummo N, Ginanneschi C, et al. 2008. CD34+ cord blood cell-transplanted Rag2-/- gamma(c)-/- mice as a model for Epstein-Barr virus infection. Am J Pathol. 173(5):1369–1378. 10.2353/ajpath.2008.071186 18845836
Cohen JI. 2009. Optimal treatment for chronic active Epstein-Barr virus disease. Pediatr Transplant. 13(4):393–396. 10.1111/j.1399-3046.2008.01095.x 19032417
Cohen JI. 2015. Epstein-barr virus vaccines. Clin Transl Immunology. 4(1):e32. 10.1038/cti.2014.27 25671130
Condon LM, Cederberg LE, Rabinovitch MD, Liebo RV, Go JC, Delaney AS, Schmeling DO, Thomas W, Balfour HH Jr. 2014. Age-specific prevalence of Epstein-Barr virus infection among Minnesota children: Effects of race/ethnicity and family environment. Clin Infect Dis. 59(4):501–508. 10.1093/cid/ciu342 24820696
Connelly RR, Christine BW. 1974. A cohort study of cancer following infectious mononucleosis. Cancer Res. 34(5):1172–1178. 4842360
Crawford DH.2001. Biology and disease associations of Epstein-Barr virus. Philos Trans R Soc Lond B Biol Sc. 356(1408):461-473. 10.1098/rstb.2000.0783
Crew KD, Neugut AI. 2006. Epidemiology of gastric cancer. World J Gastroenterol. 12(3):354–362. 10.3748/wjg.v12.i3.354 16489633
Daud II, Coleman CB, Smith NA, Ogolla S, Simbiri K, Bukusi EA, Ng’ang’a ZW, Sumba PO, Vulule J, Ploutz-Snyder R, et al. 2015. Breast milk as a potential source of Epstein-Barr virus transmission among infants living in a malaria-endemic region of Kenya. J Infect Dis. 212(11):1735–1742. 10.1093/infdis/jiv290 25985902
de Aquino PF, Carvalho PC, da Gama Fischer JS, de Souza AQ, Viana JS, Chalub SR, de Souza AD, Carvalho MG.2012. Epstein-Barr virus DNA associated with gastric adenocarcinoma and adjacent non-cancerous mucosa in patients from Manaus, Brazil. Genetics and molecular research: GMR. 11(4):4442-4446. 10.4238/2012.October.15.3
de Thé G, Lavoué ME, Muenz L. 1978. Differences in EBV antibody titres of patients with nasopharngeal carcinoma originating from high, intermediate and low incidence areas. IARC Sci Publ. 20:471–481. 215529
Dinand V, Dawar R, Arya LS, Unni R, Mohanty B, Singh R. 2007. Hodgkin’s lymphoma in Indian children: Prevalence and significance of Epstein-Barr virus detection in Hodgkin’s and Reed-Sternberg cells. Eur J Cancer. 43(1):161–168. 10.1016/j.ejca.2006.08.036 17113770
Dowd JB, Palermo T, Brite J, McDade TW, Aiello A. 2013. Seroprevalence of Epstein-Barr virus infection in U.S. children ages 6-19, 2003-2010. PLoS One. 8(5):e64921. 10.1371/journal.pone.0064921 23717674
Epstein MA, Achong BG, Barr YM. 1964. Virus particles in cultured lymphoblasts from Burkitt’s lymphoma. Lancet. 283(7335):702–703. 10.1016/S0140-6736(64)91524-7 14107961
Evans AS, Gutensohn NM. 1984. A population-based case-control study of EBV and other viral antibodies among persons with Hodgkin's disease and their siblings. Int J Cancer. 34(2):149-157. 10.1002/ijc.2910340203
Ferlay J, Soerjomataram I, Dikshit R, Eser S, Mathers C, Rebelo M, Parkin DM, Forman D, Bray F. 2015. Cancer incidence and mortality worldwide: sources, methods and major patterns in GLOBOCAN 2012. Int J Cancer. 136(5):E359-386. 10.1002/ijc.29210
Flavell KJ, Murray PG. 2000. Hodgkin's disease and the Epstein-Barr virus. Molecular pathology: MP. 53(5):262-269. 10.1136/mp.53.5.262
Gallagher A, Armstrong AA, MacKenzie J, Shield L, Khan G, Lake A, Proctor S, Taylor P, Clements GB, Jarrett RF. 1999. Detection of Epstein-Barr virus (EBV) genomes in the serum of patients with EBV-associated Hodgkin's disease. Int J Cancer. 84(4):442-448.
Garfin PM, Twist CJ, Talavera F, Conrad ME, Shapiro MD.2015. Posttransplant Lymphoproliferative Disease. Medscape.http://emedicine.medscape.com/article/431364-overview. [Accessed: June 17, 2015]
Geser A, de The G, Lenoir G, Day NE, Williams EH. 1982. Final case reporting from the Ugandan prospective study of the relationship between EBV and Burkitt's lymphoma. Int J Cancer. 29(4):397-400.
Geser A, Brubaker G, Draper CC. 1989. Effect of a malaria suppression program on the incidence of African Burkitt’s lymphoma. Am J Epidemiol. 129(4):740–752. 10.1093/oxfordjournals.aje.a115189 2923122
Geser A, Charnay N, Day NE, de Thé G, Ho HC. 1978. Environmental factors in the etiology of nasopharyngeal carcinoma: Report on a case-control study in Hong Kong. IARC Sci Publ. (20):213–229. 730191
Glaser SL, Keegan TH, Clarke CA, Trinh M, Dorfman RF, Mann RB, DiGiuseppe JA, Ambinder RF. 2005. Exposure to childhood infections and risk of Epstein-Barr virus--defined Hodgkin's lymphoma in women. Int J Cancer. 115(4):599-605. 10.1002/ijc.20787
Gloghini A, Dolcetti R, Carbone A. 2013. Lymphomas occurring specifically in HIV-infected patients: From pathogenesis to pathology. Semin Cancer Biol. 23(6):457–467. 10.1016/j.semcancer.2013.08.004 23999127
Gotleib-Stematsky T, Ramot B, Vonsover B, Aghai E, Kende G, Ninio M, Modan M. 1976. Antibodies to Epstein-Barr viral capsid and early antigens associated with Burkitt’s lymphoma and lymphoblastic lymphosarcoma in Israel. J Natl Cancer Inst. 56(4):721–723. 10.1093/jnci/56.4.721 233958
Gotlieb-Stematsky T, Vonsover A, Ramot B, Zaizov R, Nordan U, Aghal E, Kende G, Modan M. 1975. Antibodies to Epstein-Barr virus in patients with Hodgkin’s disease and leukemia. Cancer. 36(5):1640–1645. 10.1002/1097-0142(197511)36:5<1640::AID-CNCR2820360517>3.0.CO;2-V 172216
Grulich AE, Vajdic CM, Cozen W. 2007 a. Altered immunity as a risk factor for non-Hodgkin lymphoma. Cancer Epidemiol Biomarkers Prev. 16(3):405–408. 10.1158/1055-9965.EPI-06-1070 17337643
Grulich AE, van Leeuwen MT, Falster MO, Vajdic CM. 2007 b. Incidence of cancers in people with HIV/AIDS compared with immunosuppressed transplant recipients: A meta-analysis. Lancet. 370(9581):59–67. 10.1016/S0140-6736(07)61050-2 17617273
Grywalska E, Rolinski J. 2015. Epstein-Barr virus-associated lymphomas. Semin Oncol. 42(2):291–303. 10.1053/j.seminoncol.2014.12.030 25843733
Gulley ML. 2015. Genomic assays for Epstein-Barr virus-positive gastric adenocarcinoma. Exp Mol Med. 47:e134. 10.1038/emm.2014.93 25613731
Gulley ML, Tang W. 2010. Using Epstein-Barr viral load assays to diagnose, monitor, and prevent posttransplant lymphoproliferative disorder. Clin Microbiol Rev. 23(2):350–366. 10.1128/CMR.00006-09 20375356
Gutensohn N, Cole P. 1981. Childhood social environment and Hodgkin’s disease. N Engl J Med. 304(3):135–140. 10.1056/NEJM198101153040302 6255329
Gutensohn NM. 1982. Social class and age at diagnosis of Hodgkin’s disease: New epidemiologic evidence for the “two-disease hypothesis”. Cancer Treat Rep. 66(4):689–695. 7074638
Hauke R, Smir B, Greiner T, Bierman P, Tarantolo S, Anderson J, Shaw B, Armitage J. 2001. Clinical and pathological features of posttransplant lymphoproliferative disorders: influence on survival and response to treatment. Annals of oncology: official journal of the European Society for Medical Oncology / ESMO. 12(6):831-834. 10.1023/A:1011131700811
He YJ, Jia XS, Hasui K, Wang EH, He AG. 2007. [Nasal and pharyngeal non-Hodgkin lymphomas and their relationship with Epstein-Barr virus: a report of 158 cases]. Zhonghua bing li xue za zhi Chinese journal of pathology. 36(2):94-97.
Henderson BE, Dworsky R, Pike MC, Baptista J, Menck H, Preston-Martin S, Mack T. 1979. Risk factors for nodular sclerosis and other types of Hodgkin’s disease. Cancer Res. 39(11):4507–4511. 498082
Henderson BE, Louie E. 1978. Discussion of risk factors for nasopharyngeal carcinoma. IARC Sci Publ. (20):251–260. 730193
Henle G, Henle W, Clifford P, Diehl V, Kafuko GW, Kirya BG, Klein G, Morrow RH, Munube GM, Pike P, et al. 1969. Antibodies to Epstein-Barr virus in Burkitt’s lymphoma and control groups. J Natl Cancer Inst. 43(5):1147–1157. 5353242
Henle G, Henle W, Klein G, Gunven P, Clifford P, Morrow RH, Ziegler JL. 1971. Antibodies to early Epstein-Barr virus-induced antigens in Burkitt’s lymphoma. J Natl Cancer Inst. 46(4):861–871. 4324816
Hildesheim A, Apple RJ, Chen CJ, Wang SS, Cheng YJ, Klitz W, Mack SJ, Chen IH, Hsu MM, Yang CS, et al. 2002. Association of HLA class I and II alleles and extended haplotypes with nasopharyngeal carcinoma in Taiwan. J Natl Cancer Inst. 94(23):1780–1789. 10.1093/jnci/94.23.1780 12464650
Hilgers F, Hilgers J. 1976. An immunofluorescence technique with counterstain on fixed cells for the detection of antibodies to human herpesviruses; antibody patterns in patients with Hodgkin’s disease and nasopharyngeal carcinoma. Intervirology. 7(6):309–327. 10.1159/000149972 67099
Hill AB. 1965. The environment and disease: Association or causation? Proc R Soc Med. 58:295–300. 10.1177/003591576505800503 14283879
Hirshaut Y, Cohen MH, Stevens DA. 1973. Epstein-Barr-virus antibodies in American and African Burkitt’s lymphoma. Lancet. 302(7821):114–116. 10.1016/S0140-6736(73)93061-4 4124041
Hjalgrim H, Askling J, Sorensen P, Madsen M, Rosdahl N, Storm HH, Hamilton-Dutoit S, Eriksen LS, Frisch M, Ekbom A, et al. 2000. Risk of Hodgkin’s disease and other cancers after infectious mononucleosis. J Natl Cancer Inst. 92(18):1522–1528. 10.1093/jnci/92.18.1522 10995808
Hjalgrim H, Smedby KE, Rostgaard K, Molin D, Hamilton-Dutoit S, Chang ET, Ralfkiaer E, Sundstrom C, Adami HO, Glimelius B, et al. 2007. Infectious mononucleosis, childhood social environment, and risk of Hodgkin lymphoma. Cancer Res. 67(5):2382–2388. 10.1158/0008-5472.CAN-06-3566 17332371
Imai S, Nishikawa J, Takada K. 1998. Cell-to-cell contact as an efficient mode of Epstein-Barr virus infection of diverse human epithelial cells. J Virol. 72(5):4371–4378. 10.1128/JVI.72.5.4371-4378.1998 9557727
International Agency for Research on Cancer (IARC).1997a. Epstein-Barr virus. In: Epstein-Barr Virus and Kaposi's Sarcoma Herpesvirus/Human Herpesvirus 8. Lyon, France: International Agency for Research on Cancer. p. 47-373. https://monographs.iarc.fr/ENG/Monographs/vol370/index.php.
International Agency for Research on Cancer (IARC). 1997 b. Epstein-Barr Virus and Kaposi’s Sarcoma Herpesvirus/Human Herpesvirus 8. Vol. 70. Lyon, France: IARC Working Group on the Evaluation of Carcinogenic Risks to Humans.
International Agency for Research on Cancer (IARC). 2012. Biological Agents. Lyon, France: International Agency for Research on Cancer; Epstein-Barr virus; p. 49–92.
Ito Y, Kawanishi M, Harayama T, Takabayashi S. 1981. Combined effect of the extracts from Croton tiglium, Euphorbia lathyris or Euphorbia tirucalli and n-butyrate on Epstein-Barr virus expression in human lymphoblastoid P3HR-1 and Raji cells. Cancer Lett. 12(3):175–180. 10.1016/0304-3835(81)90066-5 6266651
Jarrett RF. 2003. Risk factors for Hodgkin’s lymphoma by EBV status and significance of detection of EBV genomes in serum of patients with EBV-associated Hodgkin’s lymphoma. Leuk Lymphoma. 44 Suppl 3:S27–S32. 10.1080/10428190310001623801 15202522
Ji MF, Wang DK, Yu YL, Guo YQ, Liang JS, Cheng WM, Zong YS, Chan KH, Ng SP, Wei WI, et al. 2007. Sustained elevation of Epstein-Barr virus antibody levels preceding clinical onset of nasopharyngeal carcinoma. Br J Cancer. 96(4):623–630. 10.1038/sj.bjc.6603609 17285127
Jimenez S. 2015. Epstein-Barr virus-associated post-transplantation lymphoproliferative disorder: Potential treatments and implications for nursing practice. Clin J Oncol Nurs. 19(1):94–98. 10.1188/15.CJON.94-98 25689655
Kanemitsu N, Isobe Y, Masuda A, Momose S, Higashi M, Tamaru J, Sugimoto K, Komatsu N. 2012. Expression of Epstein-Barr virus-encoded proteins in extranodal NK/T-cell Lymphoma, nasal type (ENKL): Differences in biologic and clinical behaviors of LMP1-positive and -negative ENKL. Clin Cancer Res. 18(8):2164–2172. 10.1158/1078-0432.CCR-11-2395 22371452
Kennedy G, Komano J, Sugden B. 2003. Epstein-Barr virus provides a survival factor to Burkitt’s lymphomas. Proc Natl Acad Sci USA. 100(24):14269–14274. 10.1073/pnas.2336099100 14603034
Kim Y, Shin A, Gwack J, Ko KP, Kim CS, Park SK, Hong YC, Kang D, Yoo KY. 2009. Epstein-Barr virus antibody level and gastric cancer risk in Korea: A nested case-control study. Br J Cancer. 101(3):526–529. 10.1038/sj.bjc.6605146 19550421
Klein G, Geering G, Old LJ, Henle G, Henle W, Clifford P. 1970. Comparison of the anti-EBV titer and the EBV-associated membrane reactive and precipitating antibody levels in the sera of Burkitt lymphoma and nasopharyngeal carcinoma patients and controls. Int J Cancer. 5(2):185-194.
Koshiol J, Qiao YL, Mark SD, Dawsey SM, Abnet CC, Kamangar F, Lennette ET, Dong ZW, Taylor PR. 2007. Epstein-Barr virus serology and gastric cancer incidence and survival. Br J Cancer. 97(11):1567–1569. 10.1038/sj.bjc.6604063 17987041
Kvale G, Hoiby EA, Pedersen E. 1979. Hodgkin's disease in patients with previous infectious mononucleosis. Int J Cancer. 23(5):593-597. 10.1002/ijc.2910230502
Kwong J, Lo KW, To KF, Teo PM, Johnson PJ, Huang DP. 2002. Promoter hypermethylation of multiple genes in nasopharyngeal carcinoma. Clin Cancer Res. 8(1):131–137. 11801549
Lange B, Arbeter A, Hewetson J, Henle W. 1978. Longitudinal study of Epstein-Barr virus antibody titers and excretion in pediatric patients with Hodgkin's disease. Int J Cancer. 22(5):521-527. 10.1002/ijc.2910220503
Lanier AP, Henle W, Bender TR, Henle G, Talbot ML. 1980. Epstein-Barr virus-specific antibody titers in seven Alaskan natives before and after diagnosis of nasopharyngeal carcinoma. Int J Cancer. 26(2):133-137. 10.1002/ijc.2910260203
Lee HP, Gourley L, Duffy SW, Esteve J, Lee J, Day NE. 1994. Preserved foods and nasopharyngeal carcinoma: a case-control study among Singapore Chinese. Int J Cancer. 59(5):585-590. 10.1002/ijc.2910590502
Lee J, Suh C, Park YH, Ko YH, Bang SM, Lee JH, Lee DH, Huh J, Oh SY, Kwon HC, et al. 2006. Extranodal natural killer T-cell lymphoma, nasal-type: A prognostic model from a retrospective multicenter study. J Clin Oncol. 24(4):612–618. 10.1200/JCO.2005.04.1384 16380410
Lee JT, Ko CY. 2005. Has survival improved for nasopharyngeal carcinoma in the United States? Otolaryngol Head Neck Surg. 132(2):303–308. 10.1016/j.otohns.2004.09.018 15692545
Lehtinen T, Lumio J, Dillner J, Hakama M, Knekt P, Lehtinen M, Teppo L, Leinikki P. 1993. Increased risk of malignant lymphoma indicated by elevated Epstein-Barr virus antibodies—a prospective study. Cancer Causes Control. 4(3):187–193. 8391336
Lei KI, Chan LY, Chan WY, Johnson PJ, Lo YM. 2000. Quantitative analysis of circulating cell-free Epstein-Barr virus (EBV) DNA levels in patients with EBV-associated lymphoid malignancies. Br J Haematol. 111(1):239–246. 11091207
Lennette ET, Rymo L, Yadav M, Masucci G, Merk K, Timar L, Klein G. 1993. Disease-related differences in antibody patterns against EBV-encoded nuclear antigens EBNA 1, EBNA 2 and EBNA 6. Eur J Cancer. 29(11):1584–1589. 10.1016/0959-8049(93)90299-U 8217366
Lennette ET, Winberg G, Yadav M, Enblad G, Klein G. 1995. Antibodies to LMP2A/2B in EBV-carrying malignancies. Eur J Cancer. 31(11):1875–1878. 10.1016/0959-8049(95)00354-L 8541116
Leung SY, Chung LP, Yuen ST, Ho CM, Wong MP, Chan SY. 1995. Lymphoepithelial carcinoma of the salivary gland: In situ detection of Epstein-Barr virus. J Clin Pathol. 48(11):1022–1027. 10.1136/jcp.48.11.1022 8543624
Levine PH, O’Conor GT, Bernard CW. 1972. Antibodies to Epstein-Barr virus (EBV) in American patients with Burkitt’s lymphoma. Cancer. 30(3):610–615. 10.1002/1097-0142(197209)30:3<610::AID-CNCR2820300303>3.0.CO;2-A 4342405
Levine PH, Stemmermann G, Lennette ET, Hildesheim A, Shibata D, Nomura A. 1995. Elevated antibody titers to Epstein-Barr virus prior to the diagnosis of Epstein-Barr-virus-associated gastric adenocarcinoma. Int J Cancer. 60(5):642-644. 10.1002/ijc.2910600513
Lim WH, Russ GR, Coates PT. 2006. Review of Epstein-Barr virus and post-transplant lymphoproliferative disorder post-solid organ transplantation. Nephrology (Carlton). 11(4):355–366. 10.1111/j.1440-1797.2006.00596.x 16889577
Lin JC, Smith MC, Pagano JS. 1982. Effects of 12-O-tetradecanoyl-phorbol-13-acetate on cell proliferation and Epstein-Barr virus DNA replication. Virology. 117(1):186–194. 10.1016/0042-6822(82)90518-9 6278735
Linabery AM, Erhardt EB, Fonstad RK, Ambinder RF, Bunin GR, Ross JA, Spector LG, Grufferman S. 2014. Infectious, autoimmune and allergic diseases and risk of Hodgkin lymphoma in children and adolescents: a Children's Oncology Group study. Int J Cancer. 135(6):1454-1469. 10.1002/ijc.28785
Liu P, Fang X, Feng Z, Guo YM, Peng RJ, Liu T, Huang Z, Feng Y, Sun X, Xiong Z, et al. 2011. Direct sequencing and characterization of a clinical isolate of Epstein-Barr virus from nasopharyngeal carcinoma tissue by using next-generation sequencing technology. J Virol. 85(21):11291–11299. 10.1128/JVI.00823-11 21880770
Lo YM, Chan WY, Ng EK, Chan LY, Lai PB, Tam JS, Chung SC. 2001. Circulating Epstein-Barr virus DNA in the serum of patients with gastric carcinoma. Clin Cancer Res. 7(7):1856–1859. 11448896
Lombardi L, Newcomb EW, Dalla-Favera R. 1987. Pathogenesis of Burkitt lymphoma: Expression of an activated c-myc oncogene causes the tumorigenic conversion of EBV-infected human B lymphoblasts. Cell. 49(2):161–170. 10.1016/0092-8674(87)90556-3 3032447
Lu J, Murakami M, Verma SC, Cai QL, Haldar S, Kaul R, Wasik MA, Middeldorp J, Robertson ES. 2011. Epstein-Barr Virus nuclear antigen 1 (EBNA1) confers resistance to apoptosis in EBV-positive B-lymphoma cells through up-regulation of survivin. Virology. 410(1):64–75. 10.1016/j.virol.2010.10.029 21093004
Lung ML, Cheung AK, Ko JM, Lung HL, Cheng Y, Dai W. 2014. The interplay of host genetic factors and Epstein-Barr virus in the development of nasopharyngeal carcinoma. Chin J Cancer. 33(11):556–568. 10.5732/cjc.014.10170 25367335
Ma SD, Hegde S, Young KH, Sullivan R, Rajesh D, Zhou Y, Jankowska-Gan E, Burlingham WJ, Sun X, Gulley ML, et al. 2011. A new model of Epstein-Barr virus infection reveals an important role for early lytic viral protein expression in the development of lymphomas. J Virol. 85(1):165–177. 10.1128/JVI.01512-10 20980506
MacMahon B. 1966. Epidemiology of Hodgkin’s disease. Cancer Res. 26(6):1189–1201. 5329907
Maia DM, Peace-Brewer AL. 2000. Chronic, active Epstein-Barr virus infection. Curr Opin Hematol. 7(1):59–63. 10.1097/00062752-200001000-00011 10608506
Marquitz AR, Mathur A, Shair KH, Raab-Traub N. 2012. Infection of Epstein-Barr virus in a gastric carcinoma cell line induces anchorage independence and global changes in gene expression. Proc Natl Acad Sci USA. 109(24). 10.1073/pnas.1202910109 22647604
Merk K, Lennette E, Holm G, Johansson B, Masucci G, Grimfors G, Klein G, Bjorkholm M. 1995. Antibodies to Epstein-Barr virus in relation to clinical characteristics of untreated patients with Hodgkin’s Disease. Cancer Research Therapy and Control. 4:223–229.
Mesri EA, Feitelson MA, Munger K. 2014. Human viral oncogenesis: A cancer hallmarks analysis. Cell Host Microbe. 15(3):266–282. 10.1016/j.chom.2014.02.011 24629334
Miller RW, Beebe GW. 1973. Infectious mononucleosis and the empirical risk of cancer. J Natl Cancer Inst. 50(2):315–321. 10.1093/jnci/50.2.315 4702109
Mochanko K, Fejes M, Breazavscek DM, Suarez A, Bachmann AE. 1979. The relation between Epstein-Barr virus antibodies and clinical symptomatology and immunodeficiency in patients with Hodgkin’s disease. Cancer. 44(6):2065–2070. 10.1002/1097-0142(197912)44:6<2065::AID-CNCR2820440617>3.0.CO;2-G 228834
Mohamed G, Vrzalikova K, Cader FZ, Vockerodt M, Nagy E, Flodr P, Yap LF, Diepstra A, Kluin PM, Rosati S, et al. 2014. Epstein-Barr virus, the germinal centre and the development of Hodgkin’s lymphoma. J Gen Virol. 95(9):1861–1869. 10.1099/vir.0.066712-0 24893782
Moore PS, Chang Y. 2014. The conundrum of causality in tumor virology: The cases of KSHV and MCV. Semin Cancer Biol. 26:4–12. 10.1016/j.semcancer.2013.11.001 24304907
Moore PS, Chang YA. 2010. Why do viruses cause cancer? Highlights of the first century of human tumour virology. Nat Rev Cancer. 10(12):878–889. 10.1038/nrc2961 21102637
Moormann AM, Heller KN, Chelimo K, Embury P, Ploutz-Snyder R, Otieno JA, Oduor M, Munz C, Rochford R. 2009. Children with endemic Burkitt lymphoma are deficient in EBNA1-specific IFN-gamma T cell responses. Int J Cancer. 124(7):1721-1726. 10.1002/ijc.24014
Morrow RH Jr. 1985. Epidemiological evidence for the role of falciparum malaria in the pathogenesis of Burkitt’s lymphoma. In: Lenoir G, O’Conor G, Olweny CLM, editors. Burkitt’s Lymphoma: A Human Cancer Model. Lyon, France: International Agency for Research on Cancer; p. 177–186.
Mosier DE, Gulizia RJ, Baird SM, Spector S, Spector D, Kipps TJ, Fox RI, Carson DA, Cooper N, Richman DD, et al. 1989. Studies of HIV infection and the development of Epstein-Barr virus-related B cell lymphomas following transfer of human lymphocytes to mice with severe combined immunodeficiency. Curr Top Microbiol Immunol. 152:195–199. 10.1007/978-3-642-74974-2_23 2553338
Moumad K, Lascorz J, Bevier M, Khyatti M, Ennaji MM, Benider A, Huhn S, Lu S, Chouchane L, Corbex M, et al. 2013. Genetic polymorphisms in host innate immune sensor genes and the risk of nasopharyngeal carcinoma in North Africa. G3 (Bethesda). 3(6):971–977. 10.1534/g3.112.005371 23576520
Mueller N, Evans A, Harris NL, Comstock GW, Jellum E, Magnus K, Orentreich N, Polk BF, Vogelman J. 1989. Hodgkin’s disease and Epstein-Barr virus. Altered antibody pattern before diagnosis. N Engl J Med. 320(11):689–695. 10.1056/NEJM198903163201103 2537928
Mulama DH, Bailey JA, Foley J, Chelimo K, Ouma C, Jura WG, Otieno J, Vulule J, Moormann AM. 2014. Sickle cell trait is not associated with endemic Burkitt lymphoma: an ethnicity and malaria endemicity-matched case-control study suggests factors controlling EBV may serve as a predictive biomarker for this pediatric cancer. Int J Cancer. 134(3):645-653. 10.1002/ijc.28378
Munoz N, Davidson RJ, Witthoff B, Ericsson JE.de The G. 1978. Infectious mononucleosis and Hodgkin's disease. Int J Cancer. 22(1):10-13. 10.1002/ijc.2910220104
Murphy G, Pfeiffer R, Camargo MC, Rabkin CS. 2009. Meta-analysis shows that prevalence of Epstein-Barr virus-positive gastric cancer differs based on sex and anatomic location. Gastroenterology. 137(3):824–833. 10.1053/j.gastro.2009.05.001 19445939
Musacchio JG, Carvalho Mda G, Morais JC, Silva NH, Scheliga A, Romano S, Spector N. 2006. Detection of free circulating Epstein-Barr virus DNA in plasma of patients with Hodgkin’s disease. Sao Paulo Med J. 124(3):154–157. 17119693
Mutalima N, Molyneux E, Jaffe H, Kamiza S, Borgstein E, Mkandawire N, Liomba G, Batumba M, Lagos D, Gratrix F, et al. 2008. Associations between Burkitt lymphoma among children in Malawi and infection with HIV, EBV and malaria: Results from a case-control study. PLoS One. 3(6):e2505. 10.1371/journal.pone.0002505 18560562
National Toxicology Program (NTP).2015. Handbook for preparing the Report on Carcinogens monographs. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health.https://ntp.niehs.nih.gov/ntp/roc/handbook/roc_handbook_508.pdf.
National Toxicology Program (NTP). 2016. Report on Carcinogens monograph on Human Immunodeficiency Virus type 1. Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institute of Environmental Health Sciences, National Toxicology Program.
Newton R, Carpenter L, Casabonne D, Beral V, Babiker A, Darbyshire J, Weller I, Weiss R, Kwan A, Bourboulia D, et al. 2006. A prospective study of Kaposi’s sarcoma-associated herpesvirus and Epstein-Barr virus in adults with human immunodeficiency virus-1. Br J Cancer. 94(10):1504–1509. 10.1038/sj.bjc.6603100 16705315
Niedobitek G, Agathanggelou A, Rowe M, Jones EL, Jones DB, Turyaguma P, Oryema J, Wright DH, Young LS. 1995. Heterogeneous expression of Epstein-Barr virus latent proteins in endemic Burkitt’s lymphoma. Blood. 86(2):659–665. 10.1182/blood.V86.2.659.bloodjournal862659 7605996
Ning JP, Yu MC, Wang QS, Henderson BE. 1990. Consumption of salted fish and other risk factors for nasopharyngeal carcinoma (NPC) in Tianjin, a low-risk region for NPC in the People’s Republic of China. J Natl Cancer Inst. 82(4):291–296. 10.1093/jnci/82.4.291 2299678
Nkrumah F, Henle W, Henle G, Herberman R, Perkins V, Depue R. 1976. Burkitt’s lymphoma: Its clinical course in relation to immunologic reactivities to Epstein-Barr virus and tumor-related antigens. J Natl Cancer Inst. 57(5):1051–1056. 10.1093/jnci/57.5.1051 187787
Nong LG, Luo B, Zhang L, Nong HB. 2009. Interleukin-18 gene promoter polymorphism and the risk of nasopharyngeal carcinoma in a Chinese population. DNA Cell Biol. 28(10):507–513. 10.1089/dna.2009.0912 19622039
Pathmanathan R, Prasad U, Sadler R, Flynn K, Raab-Traub N. 1995. Clonal proliferations of cells infected with Epstein-Barr virus in preinvasive lesions related to nasopharyngeal carcinoma. N Engl J Med. 333(11):693–698. 10.1056/NEJM199509143331103 7637746
Pearson GR, Weiland LH, Neel HB 3rd, Taylor W, Earle J, Mulroney SE, Goepfert H, Lanier A, Talvot ML, Pilch B, et al. 1983. Application of Epstein-Barr virus (EBV) serology to the diagnosis of North American nasopharyngeal carcinoma. Cancer. 51(2):260–268. 10.1002/1097-0142(19830115)51:2<260::AID-CNCR2820510216>3.0.CO;2-# 6295597
Pietersma F, Piriou E, van Baarle D. 2008. Immune surveillance of EBV-infected B cells and the development of non-Hodgkin lymphomas in immunocompromised patients. Leuk Lymphoma. 49(6):1028–1041. 10.1080/10428190801911662 18452077
Poirier S, Bouvier G, Malaveille C, Ohshima H, Shao YM, Hubert A, Zeng Y, de The G, Bartsch H. 1989. Volatile nitrosamine levels and genotoxicity of food samples from high-risk areas for nasopharyngeal carcinoma before and after nitrosation. Int J Cancer. 44(6):1088-1094.
Ponce RA, Gelzleichter T, Haggerty HG, Heidel S, Holdren MS, Lebrec H, Mellon RD, Pallardy M. 2014. Immunomodulation and lymphoma in humans. J Immunotoxicol. 11(1):1–12. 10.3109/1547691X.2013.798388 23746314
Pope JH, Horne MK, Scott W. 1968. Transformation of foetal human keukocytes in vitro by filtrates of a human leukaemic cell line containing herpes-like virus. Int J Cancer. 3(6):857-866.
Raab-Traub N. 2002. Epstein-Barr virus in the pathogenesis of NPC. Semin Cancer Biol. 12(6):431–441. 10.1016/S1044579X0200086X 12450729
Raab-Traub N, Rajadurai P, Flynn K, Lanier AP. 1991. Epstein-Barr virus infection in carcinoma of the salivary gland. J Virol. 65(12):7032–7036. 10.1128/jvi.65.12.7032-7036.1991 1658395
Robbiani DF, Deroubaix S, Feldhahn N, Oleveira TY, Callen E, Wang Q, Jankovic M, Silva IT, Rommel PC, Bosque D, et al. 2015. Plasmodium infection promotes genomic instability and AID-dependent B cell lymphoma. Cell. 162(4):727–737. 10.1016/j.cell.2015.07.019 26276629
Rocchi G, Tosato G, Papa G, Ragona G. 1975. Antibodies to Epstein-Barr virus-associated nuclear antigen and to other viral and non-viral antigens in Hodgkin's disease. Int J Cancer. 16(2):323-328. 10.1002/ijc.2910160216
Rosdahl N, Larsen SO, Clemmesen J. 1974. Hodgkin’s disease in patients with previous infectious mononucleosis: 30 years’ experience. BMJ. 2(5913):253–256. 10.1136/bmj.2.5913.253 4406463
Rothman KJ, Greenland S. 2005. Causation and causal inference in epidemiology. Am J Public Health. 95:S144–S150. 10.2105/AJPH.2004.059204 16030331
Rowe M, Young LS, Crocker J, Stokes H, Henderson S, Rickinson AB. 1991. Epstein-Barr virus (EBV)-associated lymphoproliferative disease in the SCID mouse model: Implications for the pathogenesis of EBV-positive lymphomas in man. J Exp Med. 173(1):147–158. 10.1084/jem.173.1.147 1845872
Saku T, Cheng J, Jen KY, Tokunaga M, Li J, Zhang W, Liu A, Wu L, Lu Y, Zhou Z, et al. 2003. Epstein-Barr virus infected lymphoepithelial carcinomas of the salivary gland in the Russia-Asia area: A clinicopathologic study of 160 cases. Arkh Patol. 65(2):35–39. 15357246
Saqui-Salces M, Martinez-Benitez B, Gamboa-Dominguez A. 2006. EBV+ lymphoepithelial carcinoma of the parotid gland in Mexican Mestizo patients with chronic autoimmune diseases. Pathology oncology research: POR. 12(1):41-45. PAOR.2006.12.1.0041
SEER.2015. SEER Stat Fact Sheets: Hodgkin Lymphoma. Surveillance, Epidemiology, and End Results Program.https://seer.cancer.gov/statfacts/html/hodg.html.
Serraino D, Franceschi S, Talamini R, Barra S, Negri E, Carbone A, La Vecchia C. 1991. Socio-economic indicators, infectious diseases and Hodgkin's disease. Int J Cancer. 47(3):352-357. 10.1002/ijc.2910470307
Shao YM, Poirier S, Ohshima H, Malaveille C, Zeng Y, de The G, Bartsch H. 1988. Epstein-Barr virus activation in Raji cells by extracts of preserved food from high risk areas for nasopharyngeal carcinoma. Carcinogenesis. 9(8):1455–1457. 10.1093/carcin/9.8.1455 2841048
Shibata D, Weiss LM. 1992. Epstein-Barr virus-associated gastric adenocarcinoma. Am J Pathol. 140(4):769–774. 1314023
Shinkura R, Yamamoto N, Koriyama C, Shinmura Y, Eizuru Y, Tokunaga M. 2000. Epstein-Barr virus-specific antibodies in Epstein-Barr virus-positive and -negative gastric carcinoma cases in Japan. J Med Virol. 60(4):411–416. 10.1002/(SICI)1096-9071(200004)60:4<411::AID-JMV8>3.0.CO;2-8 10686024
Shope T, Dechairo D, Miller G. 1973. Malignant lymphoma in cottontop marmosets after inoculation with Epstein-Barr virus. Proc Natl Acad Sci USA. 70(9):2487–2491. 10.1073/pnas.70.9.2487 4354852
Shope TC, Khalifa AS, Smith ST, Cushing B. 1982. Epstein-Barr virus antibody in childhood Hodgkin’s disease. Am J Dis Child. 136(8):701–703. 10.1001/archpedi.1982.03970440045012 6285693
Skalsky RL, Cullen BR. 2015. EBV noncoding RNAs. Curr Top Microbiol Immunol. 2(391):181–217. 26428375
Sousa H, Pinto-Correia AL, Medeiros R, Dinis-Ribeiro M. 2008. Epstein-Barr virus is associated with gastric carcinoma: The question is what is the significance?. World J Gastroenterol. 14(27):4347–4351. 10.3748/wjg.14.4347 18666324
Sriamporn S, Vatanasapt V, Pisani P, Yongchaiyudha S, Rungpitarangsri V. 1992. Environmental risk factors for nasopharyngeal carcinoma: A case-control study in northeastern Thailand. Cancer Epidemiol Biomarkers Prev. 1(5):345–348. 1305465
Stefan DC, Wessels G, Poole J, Wainwright L, Stones D, Johnston WT, Newton R. 2011. Infection with human immunodeficiency virus-1 (HIV) among children with cancer in South Africa. Pediatr Blood Cancer. 56(1):77–79. 10.1002/pbc.22672 21110416
Stein H, Delsol G, Pileri SA, Weiss LM, Poppema S, Jaffe ES. 2008. Classical Hodgkin Lymphoma, Introduction. In: Swerdlow SH, Campo E, Harris NL, et al., editors. WHO Classification of Tumours of Haematopoietic and Lymphoid Tissues. Lyon, France: IARC Press; p. 326.
Suwiwat S, Pradutkanchana J, Ishida T, Mitarnun W. 2007. Quantitative analysis of cell-free Epstein-Barr virus DNA in the plasma of patients with peripheral T-cell and NK-cell lymphomas and peripheral T-cell proliferative diseases. Journal of clinical virology: the official publication of the Pan American Society for Clinical Virology. 40(4):277-283. 10.1016/j.jcv.2007.08.013
Taylor AL, Marcus R, Bradley JA. 2005. Post-transplant lymphoproliferative disorders (PTLD) after solid organ transplantation. Crit Rev Oncol Hematol. 56(1):155–167. 10.1016/j.critrevonc.2005.03.015 15979320
Thomas R, Macsween KF, McAulay K, Clutterbuck D, Anderson R, Reid S, Higgins CD, Swerdlow AJ, Harrison N, Williams H, et al. 2006. Evidence of shared Epstein-Barr viral isolates between sexual partners, and low level EBV in genital secretions. J Med Virol. 78(9):1204–1209. 10.1002/jmv.20682 16847960
Thompson MP, Kurzrock R. 2004. Epstein-Barr virus and cancer. Clin Cancer Res. 10(3):803–821. 10.1158/1078-0432.CCR-0670-3 14871955
Thorley-Lawson DA, Gross A. 2004. Pesistence of the Epstein-Barr virus and the origins of associated lymphomas. N Engl J Med. 350:1328–1337. 10.1056/NEJMra032015 15044644
Tiwawech D, Srivatanakul P, Karalak A, Ishida T. 2008. Association between EBNA2 and LMP1 subtypes of Epstein-Barr virus and nasopharyngeal carcinoma in Thais. Journal of clinical virology: the official publication of the Pan American Society for Clinical Virology. 42(1):1-6. 10.1016/j.jcv.2007.11.011
Torgbor C, Awuah P, Deitsch K, Kalantari P, Duca KA, Thorley-Lawson DA. 2014. A multifactorial role for P. falciparum malaria in endemic Burkitt’s lymphoma pathogenesis. PLoS Pathog. 10(5):e1004170. 10.1371/journal.ppat.1004170 24874410
Tsai CC, Chen CL, Hsu HC. 1996. Expression of Epstein-Barr virus in carcinomas of major salivary glands: A strong association with lymphoepithelioma-like carcinoma. Hum Pathol. 27(3):258–262. 10.1016/S0046-8177(96)90066-0 8600040
Tsang CM, Deng W, Yip YL, Zeng MS, Lo KW, Tsao SW. 2014. Epstein-Barr virus infection and persistence in nasopharyngeal epithelial cells. Chin J Cancer. 33(11):549–555. 25223910
Tsang WYW, Chan JKC. 2005. Lymphoepithelial carcinoma. In: Barnes EL, Eveson JW, Reichart P, Sidransky D, editors. World Health Organization Classification of Tumours – Pathology and Genetics of Head and Neck Tumours. Lyon, France: International Agency for Research on Cancer; p. 85–97.
Tsao SW, Tsang CM, To KF, Lo KW. 2015. The role of Epstein-Barr virus in epithelial malignancies. J Pathol. 235(2):323–333. 10.1002/path.4448 25251730
Tugizov SM, Berline JW, Palefsky JM. 2003. Epstein-Barr virus infection of polarized tongue and nasopharyngeal epithelial cells. Nat Med. 9(3):307–314. 10.1038/nm830 12592401
U.S. Food and Drug Administration (FDA).2015. Complete list of vaccines licensed for immunization and distribution in the US. U.S. Food and Drug Administration.https://www.fda.gov/BiologicsBloodVaccines/Vaccines/ApprovedProducts/ucm093833.htm. [Accessed: June 18, 2015]
Vegso G, Hajdu M, Sebestyen A. 2011. Lymphoproliferative disorders after solid organ transplantation-classification, incidence, risk factors, early detection and treatment options. Pathol Oncol Res. 17(3):443–454. 21193979
Vetsika EK, Callan M. 2004. Infectious mononucleosis and Epstein-Barr virus. Expert Rev Mol Med. 6(23):1–16. 10.1017/S1462399404008440 15541197
Wang CP, Chang YL, Ko JY, Lou PJ, Yeh CF, Sheen TS. 2004. Lymphoepithelial carcinoma versus large cell undifferentiated carcinoma of the major salivary glands. Cancer. 101(9):2020–2027. 10.1002/cncr.20614 15389474
Wei YS, Lan Y, Zhang L, Wang JC. 2010. Association of the interleukin-2 polymorphisms with interleukin-2 serum levels and risk of nasopharyngeal carcinoma. DNA Cell Biol. 29(7):363–368. 10.1089/dna.2010.1019 20438365
Weiss LM. 2000. Epstein-Barr virus and Hodgkin’s disease. Curr Oncol Rep. 2(2):199–204. 10.1007/s11912-000-0094-9 11122844
Wikipedia.2015. Epstein-Barr virus. Wikipedia.https://en.wikipedia.org/wiki/Epstein%E2%80%93Barr_virus. [Accessed: August 27, 2015]
Wutzler P, Farber I, Sprossig M, Sauerbrei A, Wutke K, Hoche D, Rudiger KD, Wockel W, Scheibner K. 1983. Antibodies against herpesviruses in patients with Hodgkin’s disease. Arch Geschwulstforsch. 53(5):417–422. 6316868
Yau TO, Tang CM, Yu J. 2014. Epigenetic dysregulation in Epstein-Barr virus-associated gastric carcinoma: Disease and treatments. World journal of gastroenterology. World J Gastroenterol. 20(21):6448–6456. 10.3748/wjg.v20.i21.6448 24914366
Young LS, Rickinson AB. 2004. Epstein-Barr virus: 40 years on. Nat Rev Cancer. 4(10):757–768. 10.1038/nrc1452 15510157
Yu MC, Ho JH, Lai SH, Henderson BE. 1986. Cantonese-style salted fish as a cause of nasopharyngeal carcinoma: Report of a case-control study in Hong Kong. Cancer Res. 46(2):956–961. 3940655
Yu MC, Huang TB, Henderson BE. 1989. Diet and nasopharyngeal carcinoma: a case-control study in Guangzhou, China. Int J Cancer. 43(6):1077-1082.
Yu MC, Mo CC, Chong WX, Yeh FS, Henderson BE. 1988. Preserved foods and nasopharyngeal carcinoma: A case-control study in Guangxi, China. Cancer Res. 48(7):1954–1959. 3349469
Yu MC, Yuan JM. 2002. Epidemiology of nasopharyngeal carcinoma. Semin Cancer Biol. 12(6):421–429. 10.1016/S1044579X02000858 12450728
Zhan KY, Nicolli EA, Khaja SF, Day TA. 2016. Lymphoepithelial carcinoma of the major salivary glands: Predictors of survival in a non-endemic region. Oral Oncol. 52:24–29. 10.1016/j.oraloncology.2015.10.019 26547125
Zhao M, Cai H, Li X, Zheng H, Yang X, Fang W, Zhang L, Wei G, Li M, Yao K, et al. 2012. Further evidence for the existence of major susceptibility of nasopharyngeal carcinoma in the region near HLA-A locus in Southern Chinese. J Transl Med. 10:57. 10.1186/1479-5876-10-57 22440091
Zheng X, Yan L, Nilsson B, Eklund G, Drettner B. 1994 a. Epstein-Barr virus infection, salted fish and nasopharyngeal carcinoma. A case-control study in southern China. Acta Oncol. 33(8):867–872. 10.3109/02841869409098448 7818917
Zheng YM, Tuppin P, Hubert A, Jeannel D, Pan YJ, Zeng Y.de The G. 1994b. Environmental and dietary risk factors for nasopharyngeal carcinoma: A case-control study in Zangwu County, Guangxi, China. Br J Cancer. 69(3):508-514. 10.1038/bjc.1994.92
zur Hausen H. 1994. Molecular pathogenesis of cancer of the cervix and its causation by specific human papillomavirus types. Curr Top Microbiol Immunol. 186:131–156. 10.1007/978-3-642-78487-3_8 8205839
zur Hausen H. 2001. Oncogenic DNA viruses. Oncogene. 20(54):7820–7823. 10.1038/sj.onc.1204958 11753664
zur Hausen H, de Villiers EM. 2014. Cancer “causation” by infections—individual contributions and synergistic networks. Semin Oncol. 41(6):860–875. 10.1053/j.seminoncol.2014.10.003 25499643