# Appendix A Literature Search Strategy

The objective of the literature search approach is to identify published literature that is relevant for evaluating the potential carcinogenicity of the Epstein-Barr Virus (EBV). As discussed in the Viruses Concept Document (https://ntp.niehs.nih.gov/ntp/roc/concept_docs/2014/virusesconcept_508.pdf), the monograph relies on the IARC monograph and studies published since the monograph (new studies). The literature search strategy was used to identify new human cancer studies and recent reviews of mechanistic data.

## A.1 General Approach

Database searching encompasses selecting databases and search terms and conducting the searches. Searches of several citation databases are generally conducted using search terms for the individual viruses of interest, combined with search terms for cancer and/or specific topics, including epidemiological and mechanistic studies. A critical step in the process involves consultation with an information specialist to develop relevant search terms. These terms are used to search bibliographic databases. IARC used literature found by searching PubMed for EBV through 12/2008, so PubMed, Web of Science and Scopus were searched for new information about EBV from >2008 to August 2015. Table A-1 highlights the general concepts searched with selected example terms. To review all the terms used, please refer to the full search strings below.

Table A-1 Major Topics Searched

Topics | Example Terms
Epstein-Barr virus *NOT post-transplant | Epstein-Barr virus infections (MeSH), EBV infection, herpes virus 4, herpesvirus 4, human (MeSH)
General cancer Relevant cancers | Neoplasms (MeSH), tumor(s), leukemia, cancer Gastric cancers, stomach neoplasms (MeSH), parotid, salivary gland neoplasms (MeSH), lymphoepithelial, LELC
Study types Epidemiology terms | Case control, ecological studies, follow-up study cohort, epidemiologic studies (MeSH), epidemiology (Subheading)

The large and complex body of literature for EBV was searched using narrowing terms for the relevant major topics within the bibliographic databases. The results were then processed in EndNote to remove duplicates and conduct a first level of screening, before being transferred to DistillerSR for additional screening.

Figure A-1

Literature Processing Flow

The bibliographic database search results (2,632) were processed in EndNote then imported into DistillerSR for first and second tier screening. Relevant studies found through the citations of review articles and other secondary searched were also included. Tagging in DistillerSR categorized the useful articles into Human Epidemiologic literature (245) or Mechanistic literature (335).

## A.2 Search Strings for EBV Searches

### A.2.1 Cancer and Epidemiology

#### A.2.1.1 PubMed: 2009–2015

(Epstein-Barr virus infections[mh] OR “epstein-barr virus nuclear antigens”[mh] OR “epstein-barr”[tiab] OR EBV[tiab] OR (EBV*[tiab] NOT “epstein-barr”[tiab]) OR EBVaGC[tiab] OR Herpesvirus 4, human[mh] OR “Herpes virus 4”[tiab] OR HHV-4[tiab] OR HHV4[tiab] OR “EBV infection” OR EBV-infected OR “EBV-associated” OR “Ebv-encoded” OR “EBV-driven” OR “EBV-positive”) NOT (Posttransplant OR post-transplant OR transplant*[tiab])

AND

Neoplasms[mh] OR neoplas*[tiab] OR tumor[tiab] OR tumors[tiab] OR tumorigenesis[tiab] OR tumour*[tiab] OR cancer*[tiab] OR carcinogen*[tiab] OR lesion*[tiab] OR adenoma*[tiab] OR adenosarcoma*[tiab] OR leiomyo*[tiab] OR leukemia*[tiab] OR lymphoma*[tiab] OR lymphangio*[tiab] OR sarcoma*[tiab] OR carcinoma*[tiab] OR adenocarcinoma*[tiab] OR oncogen*[tiab]

AND

Epidemiologic studies[mh] OR epidemiology[sh] OR case-control[tiab] OR case reports[ptyp] OR clinical trial[ptyp] OR cohort[tiab] OR comparative study[ptyp] OR cross-sectional[tiab] OR evaluation studies[ptyp] OR “follow-up study”[tiab] OR longitudinal[tiab] OR meta-analysis[tiab] OR meta-analysis[ptyp] OR multicenter study[ptyp] OR observational-study[tiab] OR prospective[tiab] OR randomized controlled trial[tiab] OR retrospective[tiab] OR individual*[tiab] OR man[tiab] OR men[tiab] OR patient*[tiab] OR subject*[tiab] OR woman[tiab] OR women[tiab] OR cases[mh]

#### A.2.1.2 Web of Science and Scopus: 2009–2015

(“epstein-barr” OR EBV* OR EBVaGC OR “Herpes virus 4” OR HHV-4 OR HHV4 OR EBV-infected OR EBV-infection OR EBV-associated OR EBV-encoded OR EBV-driven OR EBV-positive) NOT (Posttransplant OR post-transplant OR transplant*)

AND

neoplas* OR tumor* OR tumour* OR cancer* OR carcinogen* OR lesion* OR adenoma* OR adenosarcoma* OR leiomyo* OR leukemia* OR lymphoma* OR lymphangio* OR sarcoma* OR carcinoma* OR adenocarcinoma* OR oncogen*

AND

Epidemiologic* OR case-control OR “case report” OR “case reports” OR “clinical trial” OR cohort OR “comparative study” OR cross-sectional OR “evaluation studies” OR “follow-up study” OR longitudinal OR meta-analysis OR multicenter study OR observational-study OR prospective OR “randomized controlled trial” OR retrospective OR individual* OR man OR men OR patient* OR subject* OR woman OR women

### A.2.2 Relevant Cancers

#### A.2.2.1 PubMed: 2009–2015

A. (Epstein-Barr virus infections[mh] OR “epstein-barr virus nuclear antigens”[mh] OR “epstein-barr”[tiab] OR EBV[tiab] OR (EBV*[tiab] NOT “epstein-barr”[tiab]) OR EBVaGC[tiab] OR Herpesvirus 4, human[mh] OR “Herpes virus 4”[tiab] OR HHV-4[tiab] OR HHV4[tiab] OR “EBV infection” OR EBV-infected OR “EBV-associated” OR “Ebv-encoded” OR “EBV-driven” OR “EBV-positive”) NOT (Posttransplant OR post-transplant OR transplant*[tiab])

AND

Stomach neoplasms[mh] OR ((gastric OR stomach) AND (adenocarcinoma* OR adenoma*[tiab] OR adenosarcoma*[tiab] OR cancer*[tiab] OR carcinogen* OR carcinoma* OR lesion*[tiab] OR lymphoid[tiab] OR lymphoma*[tiab] OR lymphoepithel*[tiab] OR neoplas* OR tumor[tiab] OR tumors[tiab] OR tumorigenesis OR tumour*))OR stomach/virology[mh] OR ((stomach OR gastric) AND (epithelial*[tiab] OR epithelial cells/virology[mh])) OR (gammaherpesvirus-68[tiab] OR gammaHV-68[tiab]) AND (stomach[tiab] OR intestin*[tiab] OR gastric[tiab] OR gut[tiab])

B. (Epstein-Barr virus infections[mh] OR “epstein-barr virus nuclear antigens”[mh] OR “epstein-barr”[tiab] OR EBV[tiab] OR (EBV*[tiab] NOT “epstein-barr”[tiab]) OR EBVaGC[tiab] OR Herpesvirus 4, human[mh] OR “Herpes virus 4”[tiab] OR HHV-4[tiab] OR HHV4[tiab] OR “EBV infection” OR EBV-infected OR “EBV-associated” OR “Ebv-encoded” OR “EBV-driven” OR “EBV-positive”) NOT (Posttransplant OR post-transplant OR transplant*[tiab])

AND

Salivary gland neoplasms[mh] OR salivary glands[mh] OR salivary-gland*[tiab] OR parotid[tiab] OR sublingual[tiab] OR submandibular[tiab] OR salivary-duct*[tiab] OR “von Ebner”[tiab] AND (Lymphoproliferative OR lymphoepithel* OR LEC OR LELC)

C. (Epstein-Barr virus infections[mh] OR “epstein-barr virus nuclear antigens”[mh] OR “epstein-barr”[tiab] OR EBV[tiab] OR (EBV*[tiab] NOT “epstein-barr”[tiab]) OR EBVaGC[tiab] OR Herpesvirus 4, human[mh] OR “Herpes virus 4”[tiab] OR HHV-4[tiab] OR HHV4[tiab] OR “EBV infection” OR EBV-infected OR “EBV-associated” OR “Ebv-encoded” OR “EBV-driven” OR “EBV-positive”) NOT (Posttransplant OR post-transplant OR transplant*[tiab])

AND

lymphoepithel*[tiab] OR LEC[tiab] OR LELC[tiab]

#### A.2.2.2 Web of Science and Scopus: 2009–2015

A. (“epstein-barr” OR EBV* OR EBVaGC OR “Herpes virus 4” OR HHV-4 OR HHV4 OR EBV-infected OR EBV-infection OR EBV-associated OR EBV-encoded OR EBV-driven OR EBV-positive) NOT (Posttransplant OR post-transplant OR transplant*)

AND

((gastric OR gut OR intestin* OR stomach) AND (adenocarcinoma* OR cancer* OR carcinogen* OR carcinoma* OR neoplas* OR tumor* OR tumour*)) OR ((gammaherpesvirus-68 OR gammaHV-68) AND (stomach OR intestin* OR gastric OR gut)

B. (“epstein-barr” OR EBV* OR EBVaGC OR “Herpes virus 4” OR HHV-4 OR HHV4 OR EBV-infected OR EBV-infection OR EBV-associated OR EBV-encoded OR EBV-driven OR EBV-positive) NOT (Posttransplant OR post-transplant OR transplant*)

AND

“Salivary gland” OR “salivary glands” OR parotid OR sublingual OR submandibular OR “salivary duct” OR “salivary ducts” OR “von Ebner” AND (Lymphoproliferative OR lymphoepithel* OR LEC OR LELC)

C. (“epstein-barr” OR EBV* OR EBVaGC OR “Herpes virus 4” OR HHV-4 OR HHV4 OR EBV-infected OR EBV-infection OR EBV-associated OR EBV-encoded OR EBV-driven OR EBV-positive) NOT (Posttransplant OR post-transplant OR transplant*)

AND

lymphoepithel* OR LEC OR LELC