# 7 Overall Cancer Evaluation and NTP Listing Recommendation

This section brings forward and integrates the evaluations of the human, animal, and mechanistic and other relevant data, applies the RoC listing criteria, and reaches an NTP listing recommendation.

## NTP Listing Recommendation

“Cobalt and cobalt compounds that release cobalt ions in vivo” are reasonably anticipated to be human carcinogens based on sufficient evidence from studies in experimental animals and supporting mechanistic data. Mechanistic data indicate that the release of cobalt ions in vivo (whether from soluble or poorly water-soluble compounds and particles) is a key event for cobalt-induced carcinogenicity.

Mechanistic data (discussed in Section 6) formed the basis for the approach for grouping cobalt and cobalt compounds that release cobalt ions in vivo as a class (Section 7.1). The scientific data supporting the conclusion of sufficient evidence of cobalt and cobalt compounds that release cobalt ions in vivo from studies in experimental animals is discussed in Section 7.2, and the conclusions from the cancer studies in human studies is briefly summarized in Section 7.3.

## 7.1 Cobalt and Cobalt Compounds That Release Cobalt Ion In Vivo as a Class

Chemical grouping describes a general approach for considering more than one chemical at the same time for hazard assessment or regulatory purposes. Chemicals whose physicochemical and/or toxicological properties are likely to be similar or follow a consistent pattern, usually as a result of structural similarity, may be considered as a group, or category of substances (ECHA 2009; OECD 2014). One of the primary advantages of grouping is that every chemical within the group does not necessarily require testing for every endpoint. Where scientifically justifiable, chemicals and endpoints that have been tested can be used to fill in the data gaps for the untested chemicals and endpoints. Obviously, only a limited number of cobalt compounds have been tested for one or more of the endpoints evaluated in this monograph. Therefore, a group approach is proposed, and the following sections are based on data reviewed in the previous sections of this document that are relevant to the proposed group listing.

Mechanistic data informed the approach for grouping cobalt and cobalt compounds that release cobalt ions in vivo as a class. The key events involve cellular uptake of cobalt, intracellular release of cobalt ions from particles, intracellular concentrations and distribution, immediate and downstream molecular effects (discussed below and illustrated in Figure 6-1), and tumor formation. Thus, physicochemical properties, toxicokinetics, mechanistic data and other relevant data were used to identify and compare the chemical and biological properties and events that were relevant to cobalt-induced carcinogenicity to determine if a group listing for cobalt and cobalt compounds that release cobalt ions in vivo was warranted. These endpoints are compared for several cobalt compounds in Section 7.1.4 and Table 7-1 and discussed in more detail in the sections below.

Table 7-1 Comparison of Chemical and Biological Properties of Cobalt Metal and Cobalt Compounds

Endpoint | Soluble Cobalt Salts | Cobalt Metal | Poorly Soluble Cobalt Compounds
Endpoint | CoCl_2_ and/or CoSO_4_ | Particles | CoO and/or Co_3_O_4_
Bioaccessibility
Lysosomal fluid | + | + | +^a^
Gastric fluid | + | + | +^b^
Cellular uptake | + | + | +^c^
Cytotoxicity | + | + | +^c^
ROS | +^d^ | + | +^e^
HIF-1α stabilization | + | + | +^f^
DNA repair inhibition | +^d^ | + | ND
Genotoxicity in vitro | + | + | +^g^
Genotoxicity in vivo | +^d^ | − | ND
Animal carcinogenicity | +^h^ | + | +^i^

ND = No data, + = positive, − = negative.

^a^ CoO = 92.4% (Stopford et al. 2003); Co_3_O_4_ = 50% by release of cobalt ions into RPMI 1640 culture medium in the presence of canine alveolar macrophages after 2 weeks of culture (Kreyling et al. 1990).

^b^ CoO = 100% (Stopford et al. 2003); Co_3_O_4_ = ND.

^c^ CoO = + (Smith et al. 2014); Co_3_O_4_ = + (Ortega et al. 2014).

^d^ CoCl_2_ = +; CoSO_4_ = ND.

^e^ CoO = + (Chattopadhyay et al. 2015); Co_3_O_4_ = + (Alarifi et al. 2013).

^f^ CoO = ND; Co_3_O_4_ = + (Ortega et al. 2014).

^g^ CoO = ± for chromosomal aberrations (Horie et al. 2012); Co_3_O_4_ = + for DNA damage (Alarifi et al. 2013; Kain et al. 2012).

^h^ CoCl_2_ = + by local injection; CoSO_4_ = + by inhalation.

^i^ CoO = + by intratracheal, intraperitoneal, and subcutaneous injection; Co_3_O_4_ = ND.

- Physicochemical properties and toxicokinetics (Section 7.1.1)
- Overview of the major modes of action (7.1.2)
- Toxicological effects related to a common functional group (i.e., the cobalt ion) (Section 7.1.3)
- Overall synthesis (Section 7.1.4).

### 7.1.1 Physicochemical Properties and Toxicokinetics

Physicochemical properties and toxicokinetic data for cobalt metal and various cobalt compounds were presented in Sections 1 and 3. Solubility, particle size, bioavailability, and cellular uptake and retention affect toxicity. These data show the following general rank order for aqueous solubility: cobalt(II) salts > cobalt metal > cobalt oxides. Bioaccessibility, defined as the availability of a metal for absorption when dissolved in artificial body fluids, is often used as an in vitro surrogate for bioavailability testing (Stopford et al. 2003). Bioaccessibility measurements showed the same general rank order as aqueous solubility at near neutral pH but, in acidic solutions associated with lysosomes (pH 4.5) or gastric fluid (pH 1.5), bioaccessibility was 100% or near 100% for cobalt metal and several cobalt compounds tested including water-soluble and several poorly soluble compounds indicating that they release cobalt ions in solution (see Table 1-1). Although very low values (≤2%) for bioavailability in artificial gastric and lysosomal fluids have been reported for the sulfide and mixed (II, III) oxide and intermediate values (14% to 55%) for stearate and oxalate under the same test conditions, other, more informative (e.g., physiologically relevant) test conditions in the presence of lung cells (Section 1.2.2) have found higher bioavailability values for cobalt(II, III) oxide (i.e., Co_3_O_4_) in culture media with alveolar macrophages and other studies have reported its uptake by lung cells, which suggests that Co_3_O_4_ would release ions in vivo.

As discussed in Section 3, a number of factors affect cobalt absorption. This is reflected by the fact that absorption of cobalt compounds following oral exposure varies widely but soluble forms are better absorbed than insoluble forms. Inhalation studies also indicate better absorption and shorter retention in the respiratory tract of soluble forms compared to insoluble forms. Thus, cobalt particles with low solubility (e.g., cobalt oxides) are retained in the lungs for long periods and represent a continuing source of exposure. Although cobalt metal has low aqueous solubility, NTP’s chronic inhalation study showed that lung clearance in rats and mice was similar to that observed for soluble cobalt sulfate heptahydrate. Cobalt concentrations and tissue burdens increased with increasing exposure concentrations in all tissues examined, indicating systemic exposure; however, normalized tissue burdens increased only in the liver.

Although soluble cobalt compounds are better absorbed, cellular uptake mechanisms for particles also are important (see Section 6.1). Thus, cellular uptake of poorly soluble cobalt particles via endocytosis/phagocytosis can result in intracellular dissolution within the lysosomes and release of cobalt ions. In vitro studies of cobalt metal and cobalt oxide particles generally show that intracellular cobalt ion release is responsible for toxicity as opposed to extracellular dissolution. These studies demonstrated that direct particle contact with the cultured cells was required for cellular uptake and intracellular ion release and toxicity, while cells that were exposed only to extracellular ions dissolved from the particles were not affected. In contrast, cobalt ions readily form complexes with proteins and low molecular weight components and must first saturate binding sites in the extracellular milieu and on cell surfaces before entering the cell via metal ion transport systems. Solubility, particle size, and particle surface area also affect elimination from the body. Elimination of cobalt particles and ions is multiphasic with fast, intermediate, and slow phases; however, soluble compounds are cleared faster with a smaller fraction of the dose retained long term.

### 7.1.2 Mechanistic and Other Relevant Data

Although the mechanisms of cobalt-induced carcinogenicity are not completely understood, three biologically plausible modes-of-action have been identified and were reviewed in Section 6. These include (1) genotoxicity and inhibition of DNA repair, (2) ROS and oxidative damage, and (3) stabilization of HIF-1α. Cobalt ions can replace zinc ions in the zinc finger domains of DNA repair proteins, thus altering their catalytic activity, and in vitro assays consistently show genotoxic effects (primarily clastogenic) in mammalian cells exposed to a wide range of cobalt compounds. Cobalt is a redox-active transition metal and in vitro studies show that cobalt particles and ions can induce ROS in mammalian cells with cobalt metal and cobalt oxide particles having a greater effect than ions. Evidence of oxidative stress and oxidative damage also were shown in in vivo studies. Finally, HIF-1α stabilization is well established for cobalt. Although most studies used cobalt chloride to promote a hypoxia-like state, cobalt metal nanoparticles were also shown to have this effect. HIF-1α plays a central role in the transcriptional regulation of more than 100 hypoxia-responsive genes and is a major regulator of the adaptation of cancer cells to hypoxia. Although there were some differences in the degree of toxicity or biological response among cobalt metal particles, cobalt oxide particles, and cobalt ions the modes of action are relevant for all of these cobalt forms.

### 7.1.3 Toxicological Effects and Key Events

In vivo studies in humans and experimental animals consistently show that cobalt and cobalt compounds induce a similar spectrum of inflammatory, fibrotic, and proliferative lesions in the upper respiratory tract. Toxicological effects of cobalt are attributed primarily to the cobalt ion; however, in vitro studies indicate that direct toxic effects of cobalt particles also contribute. Relevant toxic effects reviewed in this document include carcinogenicity in humans and experimental animals, genetic and related effects (in vitro and in vivo), oxidative stress (in vitro and in vivo), and cytotoxicity (in vitro). Although not completely understood, cellular uptake mechanisms and intracellular release of cobalt ions and their distribution are important factors.

Cobalt metal and cobalt compounds exhibited similar carcinogenic effects in animals and similar genotoxic and cytotoxic effects in vitro. Inhalation studies with cobalt sulfate or cobalt metal primarily induced lung tumors (although tumors distal to the lung were found for cobalt metal) while injection-site tumors were induced following subcutaneous, intraperitoneal, intramuscular, or intratracheal administration of various cobalt particles and compounds. In vitro assays show that cobalt metal and cobalt compounds induce genetic damage and inhibit DNA repair. In vivo genotoxicity data were mostly conducted with cobalt chloride and were positive for aneuploidy, micronucleus formation, and chromosomal aberrations; cobalt acetate caused DNA damage in the lung and several other tissues. In vitro cytotoxicity assays were consistent in reporting dose-related effects for cobalt metal particles, cobalt oxide particles, and cobalt ions. In general, metallic cobalt particles induced cytotoxicity, ROS formation, genotoxicity, and carcinogenicity to a greater extent than cobalt ions while cobalt oxide particles with low solubility were less cytotoxic than cobalt ions but induced higher levels of ROS (see Table 6-1). Many studies (both in vitro and in vivo) have reported evidence that cobalt induces oxidative stress, particularly when complexed with endogenous chelators such as glutathione or anserine. In addition, mutations in lung tumors induced by cobalt sulfate or cobalt metal included G to T transversions that are characteristic of oxidative damage.

### 7.1.4 Overall Synthesis

Several biological endpoints were identified from physicochemical, toxicological, and mechanistic data for cobalt metal, cobalt chloride, cobalt sulfate, and cobalt oxides (CoO and Co_3_O_4_). These cobalt forms were the most studied and included both soluble and poorly soluble forms (see Table 7-1 for synthesis of available information). Data for two cobalt oxides, CoO and Co_3_O_4_, were combined because both are poorly water-soluble, but are bioavailable (under more informative, physiologically relevant, test conditions in the presence of lung cells; see Sections 1.2.2 and 7.1.1) since they enter cells by endocytosis and release Co ions in the lysosomes, and induced similar biological effects (e.g., genotoxicity and cytotoxicity). Although data was not available for all endpoints for each oxide, overall the mechanistic data support the inclusion of both oxides in the class of cobalt compounds that release ions in vivo.

Symbols (i.e., −, +) in Table 7-1 are used to indicate the overall evaluation for the various endpoints and cobalt forms. These data provide justification for the proposed group approach and are consistent with the OECD (2014) and ECHA (2009) guidelines for chemical grouping. Thus, biological properties of cobalt compounds that are not included in this table may be inferred by comparing with an analogous cobalt compound within the table.

## 7.2 Evidence of Carcinogenicity from Studies in Experimental Animals

There is sufficient evidence for the carcinogenicity of cobalt and cobalt compounds that release cobalt ions in vivo (collectively referred to as cobalt) in experimental animals based on increased incidence of malignant and/or a combination of malignant and benign neoplasms at several tissue sites in rats and mice by different routes of exposure. Inhalation exposure to cobalt caused dose-related increases in the incidence of lung neoplasms (mainly alveolar/bronchiolar adenoma and carcinoma) in male and female mice and rats, adrenal gland (benign and malignant pheochromocytoma) in male and female rats, hematopoietic system (mononuclear-cell leukemia) in female rats, and pancreas (islet-cell adenoma or carcinoma combined) in male rats. (Evidence is insufficient to differentiate between a direct and indirect cause of adrenal gland neoplasms from cobalt exposure.) Tumors of the pancreas (islet-cell carcinoma) in female rats and kidney (adenoma or carcinoma combined) in male rats may have been related to exposure to cobalt metal. The increased tissue levels of cobalt reported in treated animals support the likelihood that the tumors (e.g., mononuclear-cell leukemia and pancreatic cancers) observed distal from the site of exposure resulted from systemic exposure to cobalt. Injection-site tumors (such as sarcoma, histiocytoma, rhabdomyofibrosarcoma, or fibrosarcoma) were observed in rats exposed to different forms of cobalt by parenteral administration (such as intramuscular, subcutaneous, intraperitoneal injection).

Both lung and injection-site tumors were induced in rodents by different forms of cobalt, including cobalt metal, and soluble (e.g., cobalt sulfate or cobalt chloride) and poorly soluble cobalt compounds (cobalt(II) oxide). Data are summarized in Table 7-2. A comparison of the inhalation studies conducted by NTP of cobalt metal and cobalt sulfate suggests that cobalt metal was more toxic and carcinogenic at a similar cobalt concentration as evidenced by the incidence and spectrum of lung neoplasms and the extent of systemic lesions. This is consistent with mechanistic studies showing that cobalt metal has a greater effect on ROS than cobalt ions.

Table 7-2 Carcinogenic Effects of Cobalt Metal and Cobalt Compounds in Experimental Animals

Animal Neoplasms | Soluble Cobalt Salts | | Cobalt Metal | Poorly Soluble Cobalt Compounds
Animal Neoplasms | CoCl_2_ | CoSO_4_ | Particles | CoO
Lung | ND | + | + | +
Adrenal gland | ND | + | + | ND
Pancreatic islet cell | ND | − | + | ND
Mononuclear cell leukemia | ND | − | + | ND
Kidney | ND | − | ± | ND
Injection site sarcomas | + | ND | + | +

ND = no data; + = positive; − = negative; ± = equivocal.

## 7.3 Evidence of Carcinogenicity from Studies in Humans

There is inadequate evidence from studies in humans to evaluate the association between exposure to cobalt and cobalt compounds that release cobalt ions in vivo and cancer. The data relevant to the evaluation were from studies of five independent cohorts of workers in various industries that focused on lung cancer and two case-population case-control studies (see Section 3) Although almost all the cohort studies reported approximately a doubling of the risk of lung cancer from exposure to various cobalt compounds, it is unclear that the excess risks were due to exposure specifically to cobalt, because of potential confounding from exposure to known lung carcinogens or other limitations (such as concerns about unexposed groups) which complicate the interpretation of the results. In addition, the studies had limited sensitivity to detect a true risk because of small number of cases, crude exposure assessment, or concern about healthy worker related effects.

Increased risks of esophageal cancer were found in the two population-based case-control studies; however, cobalt exposure was assessed in a single sample of toenail clippings taken at or several months after diagnosis of esophageal cancer. Based on data on reproducibility of measurements of metals in toenails, cobalt has low to intermediate within-person reliability, suggesting that a single sample is less than ideal. Measurements of nail cobalt reflect integrated exposures that occurred 12 to 18 months prior to clipping, raising the question about whether cobalt levels taken in toenails close to, and in many cases after cancer diagnosis, reflect the relevant period of exposure for long latency cancer.