# 6 Mechanistic and Other Relevant Effects

Cobalt particles and ions induce similar biological effects in vivo (e.g., respiratory and inflammatory responses in both experimental animals and humans and carcinogenic effects in experimental animals) and in vitro (e.g., cytotoxicity, genotoxicity, and at high concentrations, necrosis with an inflammatory response). This section discusses the relative role of cobalt particles and ions in cobalt toxicity (Section 6.1), several proposed modes of action for cobalt carcinogenicity (Section 6.2), other biological responses (Section 6.3), and a synthesis (Section 6.4). Although the mechanism(s) of action for the reported cobalt-induced carcinogenic effects are not completely understood, the experimental support for several possible modes of action, including genotoxicity, is reviewed below. Studies on genotoxicity and cell transformation of cobalt and cobalt compounds are reviewed in Appendix E.

## 6.1 Cobalt Particles and Cobalt Ions

Studies with toxic metals in general, and cobalt specifically, show that solubility and particle size can play an important role in metal-induced toxicity, genotoxicity, and carcinogenicity (Smith et al. 2014). The main cobalt compounds studied for toxicological effects (including both micro- and nanoparticles) are metallic cobalt (Co(0)), cobalt(II) oxide (CoO), cobalt(II, III) oxide (Co_3_O_4_), and various cobalt(II) salts (e.g., cobalt sulfate, cobalt chloride) (Beyersmann and Hartwig 2008; Lison 2015; Ortega et al. 2014; Sabbioni et al. 2014b; Smith et al. 2014). Many cobalt(II) salts are readily soluble in water and biological fluids (see Section 1).

Several in vitro studies that specifically compared the cellular uptake and/or molecular and cellular effects (e.g., cytotoxicity, genetic toxicity, reactive oxygen species [ROS] production) of cobalt ions and particles (i.e., cobalt metal nanoparticles or cobalt(II) oxide micro or nanoparticles are shown in Table 6-1. In vitro studies generally show that cobalt nanoparticles are more toxic than cobalt microparticles due to increased surface reactivity resulting from a higher surface area/volume ratio (Mo et al. 2008; Peters et al. 2007; Simonsen et al. 2012; Zhang et al. 2000). In addition, relatively soluble cobalt particles (e.g., cobalt metal) are generally more cytotoxic and genotoxic than cobalt ions (Peters et al. 2007; Ponti et al. 2009; Sabbioni et al. 2014b) and cobalt ions are generally more cytotoxic than cobalt particles with low solubility (e.g., cobalt oxides) (Table 6-1) (Ortega et al. 2014; Papis et al. 2009; Smith et al. 2014). NTP (2009) previously reviewed cobalt-tungsten carbide powders and hard-metals and reported that cobalt-tungsten carbide particles were more cytotoxic and/or genotoxic than cobalt powder when tested in vivo (rat lung) or in vitro in mammalian cells. The greater toxicity of cobalt-tungsten carbide was attributed to a synergistic effect between the particles of cobalt and tungsten carbide that resulted in enhanced production of ROS. Synergistic toxicity in vitro was also reported for cobalt with zinc (Bresson et al. 2013) and cobalt with nickel (Patel et al. 2012) but not with chromium (Allen et al. 1997).

Table 6-1 In Vitro Mechanistic Data Comparing Effects of Cobalt Nanoparticles, Microparticles, and Ions

Reference | Cobalt Form (Size, nm) and Cell Types | Cytotoxicity | Genotoxicity^a^ | ROS | Cellular Uptake
Sabbioni et al. (1994a; 1994b) | Co NP (3.4) Co MP (2,200) CoCl_2_ Balb/3T3 mouse fibroblasts | IC50 μg/mL Time Co MP Co NP Co^2+^ 4 h 12 19.5 47 12 h 10 10 22 24 h 11 10 10 48 h 10 9.9 10 | Relative amount of Co incorporated into the DNA was Co MP > Co NP > cobalt ions. Cell transformation: Co MP > Co NP; negative for Co^2+^ | Dose-dependent increase in ROS production by Co NP > Co MP; Co^2+^ did not induce significant increase. All forms induced lipid peroxidation: Co NP > Co MP > Co^2+^ | Co uptake was dose dependent but significantly higher for NP and MP than for cobalt ions. Maximum uptake at 4 hours post-exposure.
Ortega et al. (2014) | Co_3_O_4_ MP (100–400) CoCl_2_ BEAS-2B human lung | Co_3_O_4_ CoCl_2_ IC25 μg/mL 50 2.9 IC50 170 4.4 IC75 600 6.5 | No data | No data | Co_3_O_4_ particles entered cells via endocytosis and released cobalt ions within lysosomes over long periods of time and were responsible for toxicity.
Smith et al. (2014) | CoO MP (270–3,560) CoCl_2_ WTHBF-6 human lung fibroblasts | Both forms induced concentration-dependent increase in cytotoxicity; however, similar levels of cytotoxicity at intracellular cobalt levels <1,000 μM while cobalt ions were more cytotoxic than particulate Co at higher levels. | Chromosome aberrations (similar effect for particulate and soluble forms). | No data | Both particulate and soluble Co induced a concentration-dependent increase in intracellular cobalt ion levels. Particle-cell contact was required for uptake of CoO.
Alarifi et al. (2013) | Co_3_O_4_ NP (21) CoCl_2_ HepG2 human hepatocarcinoma cells | Both forms induced concentration-dependent increase in cytotoxicity, but particulate Co was more cytotoxic than soluble Co. | DNA damage (comet assay, NP were more potent than soluble form) | Particles induced ROS and oxidative stress. Effects were lower for cobalt ions. | No data
Horie et al. (2012) | CoO NP (>10) CoCl_2_ HaCaT human keratinocytes A549 human lung carcinoma cells | Both forms induced similar concentration-dependent increase in cytotoxicity in both cell types. | No data | No increase in intracellular ROS in cells treated with cobalt ions or particles. | No data
Papis et al. (2009) | Co_3_O_4_ NP (45) CoCl_2_ HepG2 and ECV-304 human cell lines | Both forms induced concentration-dependent increase in cytotoxicity, but cobalt ions were more toxic. HepG2 cells not as sensitive as ECV-304 cells. | No data | Particles but not ions induced dose-dependent increase in ROS production in both cell lines. HepG2 cells less sensitive. | No data
Limbach et al. (2007) | Co_3_O_4_ NP (20–75) Co_3_O_4_/silica NP Cobalt salt A549 human lung adenocarcinoma epithelial cells | No data | No data | Release of ROS was up to 8 times higher for particles than cobalt ions. | No data
Nyga et al. (2015) | CoNP (2–60) CoCl_2_ U937 human monocytic cell line, peripheral blood mononuclear cells, and alveolar macrophages | NPs induced a concentration-dependent reduction in all three monocytic cell lines (prevented by co-incubation with ascorbic acid). CoCl_2_ at comparable concentrations (50–350 μM) was not cytotoxic. | No data | NPs induced ROS in a concentration-dependent manner in all cell lines (prevented by both ascorbic acid and glutathione). CoCl_2_ did not significantly increase ROS. | No data
Annangi et al. (2014) | CoNP (30.7 ± 20.2) Ogg1+/+ and Ogg1−/− mouse embryo fibroblasts (MEF) | NPs induced dose-dependent cytotoxicity in wild-type and knockout MEF cells (more toxic to knockout cells). | Sub-toxic doses for 12 weeks induced cell transformation (knockout cells were more sensitive). | Acute and subchronic exposure induced ROS. Greater toxicity in knockout cells attributed to increased sensitivity to oxidative damage. | Dose-dependent increase in cellular uptake of CoNPs in wild-type and knockout cells.
Horev-Azaria et al. (2011) | Co NP (10–50) CoCl_2_ A549, NCIH441, Caco-2, HepG2 (human lung, colorectal, liver); MDCK (dog kidney); murine dendritic cells | NPs and ions induced dose-dependent cytotoxicity. NPs were generally more toxic. Ion sensitivity: A549 > MDCK > NCIH441 > Caco-2 > HepG2 > DC; NP sensitivity: A549 = MDCK = NCIH441 = Caco-2 > DC > HepG2. Toxicity of NP aggregates attributed to extracellular cobalt ion dissolution (34%–44% at 48 and 72 hrs). | No data | No data | No data
Ponti et al. (2009) | Co NP (20–500) CoCl_2_ Balb/3T3 mouse fibroblasts | Dose-dependent cytotoxicity for both forms (higher for particles at 2 and 24 h but overlapping at 72 h). | Co NP induced DNA damage, MN, and cell transformation; CoCl_2_ induced DNA damage only. | No data | No data
Kwon et al. (2009) | Co NP (30) CoSO_4_ RAW 264.7 murine macrophages | NPs and ions induced dose-dependent cytotoxicity. | No data | No data | NP toxicity likely resulted from cellular uptake rather than extracellular dissolution.
Colognato et al. (2008) | Co NP (100–500) CoCl_2_ Human peripheral blood leukocytes | Co NP and cobalt ions induced dose-related cytotoxic effects (decrease in the cytokinesis-block proliferation index (CBPI). CBPI was slightly higher for ions at 10^−5^ M but similar toxicity at >2 × 10^−5^ M | Cobalt ions induced clear trend in increase of MN frequency while Co NP were less effective; MN response varied with donor. DNA damage with NP only (comet assay, short incubation time). No MN observed at non-cytotoxic concentrations. | No data | NP readily taken up by cells. Cells exposed to cobalt ions showed only slight or no change in intracellular cobalt compared to baseline levels.
Peters et al. (2007) | Co NP (28) CoCl_2_ Human dermal microvascular endothelial cells | Concentration-dependent effect (greater effect for NP than ions) | No data | Co NP induced strong concentration-dependent increase in ROS, cobalt ions induced less ROS and was concentration independent. | NP readily taken up by cells and stored in vacuoles. Pro-inflammatory activation after exposure to Co NP was attributed to intercellular release of cobalt ions.

MP = microparticles (diameter > 100 nm), NP = nanoparticles (diameter < 100 nm).

^a^ Genotoxicity also includes data for related effects (e.g., cell transformation assay) that do not necessarily measure a specific genotoxic endpoint.

Ortega et al. (2014) reported that although cobalt ions were more cytotoxic than poorly soluble Co_3_O_4_ particles, human lung cells exposed to the IC_25_ (inhibitory concentration at which the ATP content was reduced by 25% compared to non-exposed cells) of cobalt chloride (2.9 μg/mL) or Co_3_O_4_ (50 μg/mL) had similar intracellular concentrations of solubilized cobalt (6.5 fg/cell for Co_3_O_4_ compared to 5.4 fg/cell for cobalt chloride) (Figure 6-1). Smith et al. (2014) also reported that at intracellular cobalt concentrations less than 1,000 μM, the cytotoxic effects of cobalt chloride and CoO to human lung fibroblasts were similar while cobalt chloride was more cytotoxic than CoO at intracellular concentrations greater than 1,000 μM. Horie et al. (2012) studied a variety of metal oxide nanoparticles and concluded that cellular influences (cell viability and oxidative stress) of metal oxide nanoparticles were most dependent on metal ion release (i.e., effects were greater for soluble particles compared to insoluble particles). In addition, Auffan et al. (2009) reported that chemically stable nanoparticles did not have significant cellular toxicity while nanoparticles that could be oxidized, reduced, or dissolved were cytotoxic and genotoxic. Thus, the available data indicate that intracellular cobalt ions are the primary toxic form, and it is likely that the mode of action for systemic toxicity is related to cobalt ions (Ortega et al. 2014; Paustenbach et al. 2013; Simonsen et al. 2012; Smith et al. 2014).

Figure 6-1

Cellular Uptake of Cobalt Particles and Ions

Source: Ortega et al. (2014).

Because of similar physical/chemical properties, cobalt ions compete with essential divalent metal ions (e.g., calcium, copper, zinc, iron, manganese, and magnesium) for absorption, specific receptor activation, and ion channel transport (Paustenbach et al. 2013). For example, cobalt absorption is increased in humans and animals with iron deficiency suggesting that these metals share a common uptake mechanism (Thomson et al. 1971). Further, cobalt ions have the same size and charge as zinc ions; therefore, both ions bind to the same types of ligands (e.g., oxygen, nitrogen, and sulfur groups of biomolecules) (Beyersmann and Hartwig 2008). The bioavailability of cobalt ions in vivo is limited because of extensive binding (90% to 95%) to serum proteins (e.g., albumin, α_2_-macroglobulin) (Paustenbach et al. 2013; Simonsen et al. 2012). Thus, the concentration of free, ionized cobalt in serum is about 5% to 12% of the total cobalt concentration (Simonsen et al. 2012). However, Heath et al. (1969) demonstrated that myoblasts exposed to cobalt-bound protein complexes (primarily globulin and albumin), but not to cobalt chloride, developed cytological alterations (e.g., enlarged hyperchromatic nucleoli, chromocenters, and nuclei) in actively growing cultures that were similar to those seen in pre-malignant myoblasts in vivo. In contrast, myoblasts exposed to cobalt chloride were either killed or showed no cytological abnormalities when exposed to sublethal concentrations.

Differences in toxicity reported for cobalt particles and ions may be partially explained by differences in cellular uptake mechanisms (see Figure 6-1). Cobalt ions first saturate binding sites in the extracellular milieu and on cell surfaces and, after saturation, are actively transported inside the cell via metal ion transport systems such as calcium channels or divalent metal ion transporters (Garrick et al. 2003; Sabbioni et al. 2014b; Simonsen et al. 2012; Smith et al. 2014). However, current knowledge of the molecular mechanisms of cobalt ion-specific transporters is very limited (Guskov and Eshaghi 2012). In contrast, particulate cobalt is transported into cells by phagocytosis/endocytosis. However, nanoparticles are not as readily phagocytized by alveolar macrophages as larger particles and also may enter the systemic circulation by penetrating through the alveolar membrane (Mo et al. 2008).

Studies with low-solubility cobalt oxide (CoO or Co_3_O_4_) particles show that these particles readily enter cells through endocytosis via a clathrin-mediated pathway (called a Trojan-horse type mechanism) and are partially solubilized in the low pH environment within the lysosomes (Limbach et al. 2007; Ortega et al. 2014; Papis et al. 2009; Smith et al. 2014). Although the intracellular solubilized cobalt content was small compared to the intracellular particulate content, the data suggest that the solubilized fraction was responsible for the overall toxicity to human lung cells (Ortega et al. 2014; Smith et al. 2014).

Endocytosis of Co_3_O_4_ particles was a more efficient uptake pathway compared to the specific transport or ionic pumps involved with uptake of cobalt ions (Ortega et al. 2014). These studies also demonstrated that concentrations of extracellular solubilized cobalt were too low to induce cytotoxicity and that particle-to-cell contact was necessary to generate high intracellular cobalt levels. Further, cobalt particles taken up by lung cells can lead to long-term intracellular release of toxic metal ions. Similarly, cobalt metal nanoparticles are internalized by phagocytosis and endocytosis and spread rapidly to the cytoplasm, cellular organelles, and nucleus where they release cobalt ions (Ponti et al. 2009; Sabbioni et al. 2014b). However, one study reported that the toxic effects of aggregated cobalt metal nanoparticles in vitro were attributed to extracellular release of cobalt ions from particle dissolution (Horev-Azaria et al. 2011) while another study reported that extracellular release of cobalt ions had no effect on cell viability (Nyga et al. 2015).

Sabbioni et al. (2014b) also reported that the intracellular distribution of cobalt in Balb/3T3 cells was different following exposure to cobalt nanoparticles compared to cobalt ions. Cells exposed to cobalt nanoparticles had a higher nuclear fraction and a lower cytoplasmic fraction than cells exposed to cobalt ions. The amount of cobalt bound to DNA was significantly greater in cells exposed to cobalt microparticles than nanoparticles but was the lowest in cells exposed to cobalt ions (tested concentrations were 10 and 100 μM for 4 hours). Intracellular distribution studies in primary rhabdomyosarcoma induced by intramuscular injection of metallic cobalt also reported that most of the total cellular content of cobalt was associated with the nuclear fraction and was bound by components of the nucleoplasm, chromatin, and nucleoli (Heath and Webb 1967; Webb et al. 1972).

The in vivo toxicity and carcinogenicity of soluble cobalt sulfate heptahydrate and cobalt metal particles from the NTP (1998; 2014d) bioassays were recently compared (Behl et al. 2015). The findings supported the possibility of a common underlying mechanism of cobalt toxicity irrespective of the form of cobalt exposure based on the following: (1) common sites of carcinogenicity (lung and adrenal gland) and a similar spectrum of nonneoplastic, inflammatory, fibrotic and proliferative lesions in the upper respiratory tract following subchronic and chronic exposure; (2) similar mutation spectrum in the K-ras oncogene in lung tumors; (3) toxicity in common extra-pulmonary sites; and (4) similar clinical findings. Possible explanations for the reported differences between cobalt particles and ions may involve a synergistic effect between the particles and the transition metal on reactive oxygen species (ROS) release and/or differences in intracellular cobalt accumulation and distribution (Peters et al. 2007; Sabbioni et al. 2014b; Smith et al. 2014).

## 6.2 Proposed Modes of Action of Cobalt Carcinogenicity

Similar cytotoxic, genotoxic, and carcinogenic effects have been described for soluble and particulate forms of cobalt. Three major mechanisms have been identified that are applicable for the majority of carcinogenic metal compounds (Angelé-Martínez et al. 2014; Beyersmann and Hartwig 2008; Koedrith and Seo 2011). These include (1) oxidative stress, (2) DNA repair modulation, and (3) disturbances of signal transduction pathways that affect cell growth and differentiation. Modes of action most likely involved in cobalt-induced carcinogenesis are consistent with these general mechanisms and include: (1) genotoxicity and inhibition of DNA repair, (2) induction of reactive oxygen species (ROS) and oxidative damage, and (3) induction of hypoxia-like responses by activating hypoxia-inducible factors (HIFs) (see Figure 6-2) (De Boeck et al. 2003a; Green et al. 2013; Lison et al. 2001; Magaye et al. 2012; Simonsen et al. 2011; Simonsen et al. 2012; Smith et al. 2014).

Figure 6-2

Proposed Modes of Action of Cobalt Carcinogenicity

Adapted from Beyersmann and Hartwig (2008) and De Boeck et al. (2003a).

In addition to HIFs, signaling pathways, receptors, and transcription factors that are potentially relevant to carcinogenesis and are affected by cobalt include MAPKs, AP-1, P13K/Akt, and NF-κB (Davidson et al. 2015; Lee et al. 2012; Leonard et al. 2004; Matés et al. 2010; Valko et al. 2006). Dysregulation of these signaling pathways alters expression of genes that mediate cell growth, proliferation, differentiation, inflammation, invasion, angiogenesis, metastasis, apoptosis, and transformation and have been implicated in a variety of cancers (Davidson et al. 2015). In addition, there is some evidence that cobalt may also has epigenetic effects such as histone modifications that can lead to altered gene expression (e.g., tumor suppressor gene silencing and oncogene activation) and genomic instability; however, epigenetic effects of cobalt have not been as extensively studied as some other carcinogenic metals and are not further reviewed (Broberg et al. 2015; Davidson et al. 2015; Li et al. 2009). The experimental evidence for the proposed modes of action is briefly reviewed below.

### 6.2.1 Genotoxicity, Inhibition of DNA Repair, and Related Key Events

This section addresses genotoxicity and related biological adverse effects or key events (e.g., cell transformation, cell-cycle arrest) that are possibly relevant to the mode of action of cobalt-induced carcinogenicity. Genotoxicity (e.g., DNA reactivity, mutagenicity, chromosomal damage, enzyme-mediated effects on DNA damage or repair) are well recognized as key events associated with carcinogenesis (Guyton et al. 2009).

#### Overview of Genotoxicity Findings

The genotoxic and related effects for cobalt metal and soluble and insoluble cobalt compounds are reviewed in Appendix E and briefly summarized here (see Table 6-2). Increases in DNA strand breaks, sister chromatid exchange, micronuclei, aneuploidy, chromosomal aberrations, and DNA-protein crosslinks were reported in mammalian cells in vitro following exposure to cobalt and cobalt compounds. These data provide evidence that cobalt mainly causes clastogenic effects and DNA damage. Cobalt compounds were mostly non-mutagenic in bacterial assays and mutagenicity data in mammalian cells were conflicting. The positive genotoxic effects were reported for a variety of cobalt compounds, including water-soluble salts (chloride, sulfate, nitrate), poorly water-soluble cobalt compounds (oxide, sulfide, metal, nanoparticles) and a water-soluble organic cobalt compound (acetate). Although the number of available in vivo studies was limited, they indicated that cobalt chloride induced genotoxic effects including aneuploidy in the bone marrow and testes of male hamsters and chromosomal damage and micronucleus formation in mouse bone marrow; cobalt acetate caused oxidative DNA damage in rat kidney, liver, and lung (Kasprzak et al. 1994). Dose-dependent responses were reported in some of these studies, supporting the evidence for some types of genotoxicity in vivo.

Table 6-2 Summary Assessment of Genotoxicity and Related Effects for Cobalt Compounds^a^

Endpoint (Test System) | Cobalt Chloride | | Cobalt Sulfate | Cobalt Nitrate | Cobalt(II) Oxide | Cobalt(II, III) Oxide | Cobalt Acetate | | Cobalt Metal | | Cobalt Sulfide | Cobalt Nanoparticles
Endpoint (Test System) | In Vitro ^b^ | In Vivo | In Vitro ^b^ | In Vitro ^c^ | In Vitro ^c^ | In Vitro ^c^ | In Vitro ^c^ | In Vivo | In Vitro ^b^ | In Vivo | In Vitro ^c^ | In Vitro ^c^
Mutation
Mutation (prokaryotes) | (−) | | (−) | | | | | | (−)
Mutation (eukaryotes) | ± | | | + | | | | | | | ± | −
Chromosomal damage/cytogenetic effects
Chromosomal aberrations | + | + | + | − | ± | | −
Micronucleus induction | ± | + | | | | | | | + | −
Recombination | + | | | + | | | | | | | | +
Gene conversion | (+)
Aneuploidy | + | + | +
Sister chromatid exchange | +
DNA damage and repair
DNA damage/ strand breaks or bases | + | | + | + | | + | | + | + | | + | +
DNA repair inhibition | + | | | | | | + | | +
Binding/cross-links
DNA-protein crosslinks | + | | + | | | | | | + | | | +
DNA-protein binding inhibition | + | | | +

Sources: IARC (2006) review and additional primary references as described in tables and text.

+ = positive; (+) = mostly positive evidence; ± = mixed results; (−) = mostly negative evidence; − = negative.

^a^ No column is included for in vivo results if none were identified.

^b^ Results shown are for −S9; test +S9 was negative.

^c^ Results shown are for −S9; not tested with the addition of metabolic activation (S9).

Some recent in vitro studies are consistent with the earlier data and show that cobalt ions and particles induce genotoxic effects in human and animal cells, but the studies also compared effects and relative potency of cobalt ions and particles (Table 6-1) (Alarifi et al. 2013; Colognato et al. 2008; Patel et al. 2012; Ponti et al. 2009; Smith et al. 2014). Smith et al. (2014) compared the effect of CoO particles with cobalt chloride and reported similar genotoxic effects (primarily chromatid lesions); however, particle-to-cell contact was required to induce genotoxicity from CoO. Soluble cobalt also induced cell-cycle arrest at a much lower intracellular cobalt concentration than CoO. Alarifi et al. (2013) compared Co_3_O_4_ nanoparticles and cobalt chloride and reported that both forms caused DNA damage in human HepG2 cells, but the nanoparticles were more potent. Two studies investigated the genetic effects of metallic cobalt nanoparticles in Balb/3T3 mouse fibroblast (Patel et al. 2012) and human leukocytes (Colognato et al. 2008). Cobalt nanoparticles induced DNA strand breaks, micronuclei, and cell transformation in mouse fibroblasts and DNA damage in human leukocytes. Cobalt ions had no effect in human leukocytes but induced DNA damage in mouse fibroblasts. Ponti et al. (2009) reported that cobalt chloride induced double-strand breaks in human lung epithelial cells and that the effects were increased with co-exposure to nickel chloride.

Potential molecular mechanisms for cobalt-induced genotoxicity (primarily clastogenic effects) include (1) a direct effect of cobalt(II) ions to induce oxidative damage to DNA through a Fenton-like mechanism (see Section 6.2.2), and (2) an indirect effect of cobalt(II) ions to inhibit repair of DNA damage caused by endogenous events or induced by other agents (IARC 2006; Lison 2015). These mechanisms are discussed below.

#### Inhibition of DNA Repair

Evidence for cobalt-induced inhibition of DNA repair comes from several studies that show exposure to cobalt enhances the genotoxic effects of some mutagens and that cobalt modifies the catalytic activity of DNA repair proteins (Beyersmann and Hartwig 1992; 2008; IARC 2006). It is thought that interaction with DNA repair proteins, transcription factors, and tumor suppressors may be more relevant for metal-mediated carcinogenesis than direct binding to DNA (Beyersmann and Hartwig 2008; Koedrith and Seo 2011). Possible mechanisms include substitution of cobalt ions for zinc ions resulting in proteins with modified catalytic activity (e.g., p53 tumor suppressor protein and zinc finger domains of DNA repair proteins) or substitution of cobalt for magnesium in DNA polymerases or topoisomerases (Asmuss et al. 2000; Baldwin et al. 2004; Beyersmann and Hartwig 2008; Hartwig 1998; Hartwig et al. 1991; Kasten et al. 1997; Kopera et al. 2004; Witkiewicz-Kucharczyk and Bal 2006). The DNA binding capacity of p53 protein can be modulated by cobalt(II) ions (Adámik et al. 2015; Lee et al. 2001; Méplan et al. 2000; Paleček et al. 1999). In addition to cell-cycle arrest and apoptosis, p53 and its downstream genes also regulate DNA excision repair pathways, including repair of oxidative damage (Smith and Seo 2002). Kasten et al. (1997) reported that non-cytotoxic doses of cobalt enhanced DNA damage caused by ultraviolet radiation in human fibroblasts by inhibiting both the incision and polymerization steps of nucleotide excision repair. Kopera et al. (2004) and Asmuss et al. (2000) showed that cobalt reduced the DNA-binding ability of xeroderma pigmentosum group A (XPA) protein (a zinc finger protein involved in nucleotide excision repair). Further, poly(ADP-ribose)polymerase (PARP), a DNA strand break repair protein also was inhibited by cobalt (Hartwig et al. 2002). Unrepaired genotoxicity can contribute to accumulation of critical mutations and dysregulation of cell growth and proliferation that can lead to cancer.

#### Key Events

In addition to DNA and chromosome damage and inhibition of DNA repair, cobalt also causes other effects that can contribute to malignant transformation, genomic instability, and survival of damaged cells. There is some evidence that cobalt decreases the cell’s resistance to apoptosis (i.e., avoidance of cell death). Green et al. (2013) reported that normal human cell lines (IMR90 fibroblasts and primary bronchial epithelial cells) and a lung cancer cell line (H460) treated with cobalt had several times higher accumulation, less efficient activation of p53, and a delayed and weaker caspase activation compared to cells treated with nickel. This facilitates cell survival and proliferation of damaged cells (e.g., such as cells with cobalt-induced chromosomal damage).

Cell transformation assays measure induction of phenotypic alterations characteristic of tumorigenic cells, which could be caused by genotoxic or non-genotoxic mechanisms. Overall, the available studies provide strong evidence that different forms of cobalt can induce cellular transformation; however, cobalt particles were generally more effective than cobalt ions. Some studies suggested that cell transformation was related in part to ROS production or decreases in DNA repair of oxidative DNA damage, which can lead to genotoxicity and these studies are briefly reviewed here.

Cobalt metal particles, water-soluble cobalt compounds (cobalt chloride, cobalt sulfate, cobalt acetate), and water-insoluble cobalt compounds (cobalt sulfides) induced cell transformation in different types of rodent cells (C3H10T1/2 mouse fibroblasts, Syrian hamster embryo cells (SHE), or BALB/3T3 cells) (Abbracchio et al. 1982; Annangi et al. 2014; Casto et al. 1979; Costa et al. 1982; Doran et al. 1998; Kerckaert et al. 1996; Ponti et al. 2009; Sabbioni et al. 2014a; Sighinolfi et al. 2014). A few studies of either cobalt chloride (Ponti et al. 2009; Sabbioni et al. 2014a) or cobalt metal (Doran et al. 1998) were negative, which could be due to differences in experimental conditions such as the types of cells, because positive findings were found for the same cobalt forms using other experimental conditions. Sabbioni et al. (2014a) reported that Type III foci in Balb/3TC cells induced by cobalt nanoparticles and microparticles were inhibited by ascorbic acid and suggested that the response was dependent on ROS production and lipid peroxidation. Another study found that mouse fibroblast cells without a DNA base-pair excision gene (8-oxoguanine glycosylate, Ogg1^-/-^) were more sensitive to cobalt nanoparticle-induced cellular transformation (after 12 weeks of exposure to sub-toxic doses) compared to wild type cells (Ogg1^+/+^) (Annangi et al. 2014). Ogg is involved in the repair of 8-oxoguanine and thus, this study supports the role of oxidative DNA damage in cobalt carcinogencitiy. Oxidative stress is discussed in more detail in the following section.

### 6.2.2 Oxidative Stress and Damage

Reactive oxygen species (ROS) and reactive nitrogen species (RNS) induce oxidative and nitrative stress and are recognized as key contributors to carcinogenesis (Matés et al. 2010). Redox-active transition metals (e.g., iron, zinc, copper, chromium, cobalt, nickel, manganese) have been shown to produce oxidative stress through redox reactions in vivo and in mammalian cells in vitro (Beyersmann and Hartwig 2008; Jomova and Valko 2011; Kasprzak 2002; Koedrith and Seo 2011; Valko et al. 2005; Valko et al. 2006). Oxidative stress has been demonstrated to be one of the principal injury mechanisms through which metal and metal oxide nanoparticles induce adverse health effects (Zhang et al. 2012a). In addition, cobalt nanoparticles that are translocated from the lungs to the blood may directly or indirectly activate peripheral blood neutrophils to release ROS, RNS, and pro-inflammatory cytokines (e.g., IL-1, IL-6, IL-12, MIP-2, and TNF-α) (Mo et al. 2008). Excessive or inappropriate neutrophil activation is recognized as a potential cause of tissue damage. Increased formation of reactive ROS/RNS can overwhelm body antioxidant defenses leading to oxidative stress and damage to lipids, proteins, and DNA (Jomova and Valko 2011; Petit et al. 2005; Romero et al. 2014; Valko et al. 2005).

#### Mechanisms of ROS

Direct interactions between cobalt metal or ions and oxygen or lipids can generate ROS. High concentrations (10 mg/mL) of aqueous suspensions of Co(0) metal particles can react with dissolved oxygen to generate hydrogen peroxide and hydroxyl radicals in the presence of superoxide dismutase (SOD) as illustrated below in Figure 6-3 (reactions 1–3) (Jomova and Valko 2011; Lee et al. 2012; Leonard et al. 1998). The hydroxyl radical was not generated when catalase, a hydrogen peroxide scavenger, was added. Cobalt(II) ions alone did not generate significant amounts of hydroxyl radicals from hydrogen peroxide except when bound to certain endogenous chelators such as glutathione and anserine (Figure 6-3, reaction 4) (Leonard et al. 1998; Mao et al. 1996; Shi et al. 1993). Glutathione and anserine normally function as antioxidants; however, these data suggest that a cobalt(II)-mediated switch to pro-oxidants may occur and cause cellular damage (Valko et al. 2005). Cobalt(II) ions also are capable of reacting with lipid hydroperoxides to generate free radicals in the presence of proper chelating agents (Shi et al. 1993). Hydroxyl radicals and lipid hydroperoxide-derived free radicals are considered important intermediates in oxidative stress-induced genetic damage and as mediators of tumor initiation and promotion (Barrera 2012; Shi et al. 1993; Vaca et al. 1988). Thus, under certain conditions, both cobalt metal and cobalt ions are capable of generating ROS through Fenton-like reactions (reactions 3 and 4) with the potential to increase oxidative stress and cellular injury through DNA damage, protein modification, induction of oncogene expression, and nuclear transcription factor activation.

Figure 6-3

ROS Generation by Cobalt Metal or Ion Interaction with Oxygen or Lipids

#### Evidence for Cobalt-induced Oxidative Stress

Petit et al. (2005) reported that cobalt ions induced time- and dose-dependent protein oxidation in human U937 macrophages that was inhibited by glutathione. In addition to generating DNA damage, ROS also activate stress-response genes and redox-sensitive transcription factors (e.g., NF-κB, AP1, p53, Nrf2) (Beyersmann and Hartwig 2008; Klaunig et al. 2010; Valko et al. 2005; Valko et al. 2006). Although high levels of ROS may lead to apoptosis or necrosis, low or transient increases in ROS may lead to increased cell proliferation through altered growth factor and oncogene expression (Klaunig et al. 2010). Dysregulation of stress response and redox-sensitive transcription factors have been linked to carcinogenesis because of their role in regulating DNA repair, inflammation, cell proliferation, differentiation, angiogenesis, and apoptosis. Thus, depending on the dose and the extent and timing of interference, ROS may initiate tumor development by mutagenesis and/or promote tumor growth by dysregulation of cell growth and proliferation (Beyersmann and Hartwig 2008; Davidson et al. 2015; Klaunig et al. 2010; Valko et al. 2005; Valko et al. 2006).

Both cobalt ions and cobalt metal can catalyze the formation of ROS in vivo and in vitro (Alarifi et al. 2013; Annangi et al. 2014; Chattopadhyay et al. 2015; Dick et al. 2003; Hanna et al. 1992; Kadiiska et al. 1989; Kawanishi et al. 1989; 1994; Kotake-Nara and Saida 2007; Lewis et al. 1991; 1992; Limbach et al. 2007; Moorhouse et al. 1985; Papis et al. 2009; Patel et al. 2012; Peters et al. 2007; Pourahmad et al. 2003; Qiao et al. 2009; Scharf et al. 2014; Zou et al. 2001). Cobalt sulfate heptahydrate and cobalt(II) acetate (PubChem 2015) were strongly active in the antioxidant response element signaling pathway (Nrf2/ARE assay) in human hepatocellular carcinoma (HepG2) cells (Shukla et al. 2012). Cobalt chloride-induced apoptosis in rat pheochromocytoma (PC12) cells was attributed to ROS formation (Pulido and Parrish 2003; Zou et al. 2001). Treatment with antioxidants suppressed ROS formation and blocked apoptosis. Annangi et al. (2014) reported that oxidative stress exacerbated the acquisition of a cancer-like phenotype as indicated by greater sensitivity of Ogg knockout mouse embryonic fibroblasts compared to wild-type cells. Scharf et al. (2014) conducted a proteomic analysis of periprosthetic tissues collected from joint replacement patients during surgery and reported that cobalt ions induced oxidative damage to proteins involved in the cellular redox system, metabolism, molecular transport, cellular motility, cell signaling, and organelle function. Dick et al. (2003) reported evidence for a role of ROS in the toxic and inflammatory effects in rat lung following intratracheal instillation of Co_3_O_4_, and Lewis et al. (1991; 1992) reported evidence of oxidative stress in hamster lung following exposure to cobalt ions in vivo and in vitro. Evidence of oxidative stress included decreased levels of reduced glutathione, increased levels of oxidized glutathione, and increased activity of the pentose phosphate pathway. Simultaneous incubation with hydrogen peroxide potentiated cobalt-induced increases in levels of oxidized glutathione and pentose phosphate pathway activity. Although the data suggested that oxidation of glutathione occurred as an early event in cobalt-induced lung toxicity, the data did not indicate that glutathione oxidation related directly to the observed toxicity. Thus, oxidative effects that occur at sites other than the glutathione system might mediate cobalt toxicity.

#### Oxidative Stress and DNA Damage

As mentioned above, one of the likely mechanisms for cobalt particles and ions to induce genetic damage is through ROS and oxidative stress. Several types of DNA damage are associated with ROS including single- and double-strand breaks, base modifications, deoxyribose modification, and DNA cross-linking (Klaunig et al. 2010). If not repaired prior to DNA replication, DNA damage can lead to cell death, mutations, replication errors, and genomic instability. Kasprzak et al. (1994) reported oxidative damage to DNA in the liver, kidney, and lung of rats injected with cobalt ions.

Two studies, using different cobalt forms, evaluated K-ras mutations (Figure 6-4) in cobalt-induced lung neoplasms of B6C3F_1_ mice (cobalt metal and cobalt sulfate heptahydrate) or F344/NTac rats (cobalt metal only). Rodents were exposed by inhalation (Hong et al. 2015; NTP 1998; 2014a). Both studies found a higher frequency of G to T transversions in codon 12 of the K-ras gene in cobalt-induced neoplasms compared to spontaneous lung neoplasms from historical control or other laboratory control rodents. In contrast, the predominant type of K-ras mutation observed in spontaneous lung tumors from historical control mice was G to A transitions. No K-ras mutations were observed in spontaneous lung tumors in the concurrent or historical control rats. K-ras G to T transversion mutations are associated with the production of 8-hydroxydeoxyguanosine, an oxidative DNA lesion that is formed when ROS reacts with deoxyguanosine (Itsara et al. 2014; Klaunig et al. 2010). This is also consistent with the mutation pattern observed in bacteria (i.e., results were correlated with ability of the tester strain to detect mutational events at G:C base pairs) (Hong et al. 2015) G to T transversions are also the most common type of mutation observed in human lung tumors in the p53 gene (Harty et al. 1996). These studies suggest that oxidative DNA damage may play a role in cobalt-mediated lung tumorigenicity.

Figure 6-4

K-ras Mutations in Lung Tumors from Cobalt-exposed and Non-exposed Rodents

HC = historical control; M = mouse; R = rat.

Frequency of K-ras mutations from lung tumors in mice or rats exposed to cobalt metal or cobalt sulfate and spontaneous tumors. Total K-ras is the incidences of any K-ras mutation detected in all samples and includes mutations in codon 12, 13, and 61. G to T and G to A is the frequency of these specific mutations occurring in codon 12 only. i.e., the total number of K-ras mutations in codon 12 is the denominator.

Sources: Hong et al. (2015); NTP (1998; 2014a).

One argument against the oxidative-stress hypothesis of metal-induced carcinogenesis is that high, cytotoxic doses of metals (e.g., mM range) are often required to induce oxidative damage while much lower doses induce tumors (Beyersmann and Hartwig 2008; Paustenbach et al. 2013). However, as mentioned above, G to T transversions in mouse and rat lung tumors induced by cobalt sulfate and/or cobalt metal are characteristic of oxidative damage. Further, sub-toxic doses of cobalt nanoparticles induced oxidative stress and cell transformation in mouse embryo fibroblasts (Annangi et al. 2014; Sighinolfi et al. 2014) and oxidative stress and DNA damage in human lung epithelial (A549) cells (Wan et al. 2012). It has been suggested that oxidative stress is not the sole cause of cobalt-induced carcinogenicity but may contribute in a potentiating manner (Beyersmann and Hartwig 2008).

### 6.2.3 HIF Stabilization and Hypoxia Mimicry

Oxygen homeostasis in mammals is tightly regulated in order to provide sufficient oxygen levels to body tissues and cells while minimizing production of ROS (Bracken et al. 2003). HIFs are heterodimers composed of a labile α subunit and a stable β subunit and are the primary transcriptional regulators that mediate the cellular response to hypoxia (Befani et al. 2013; Davidson et al. 2015; Forooghian et al. 2007; Galanis et al. 2008; Salnikow et al. 2004; Zhang et al. 2014). The α subunit is post-translationally regulated by oxygen and is rarely detectable at normal oxygen tension, while the β subunit, also known as aryl hydrocarbon receptor nuclear translocator (ARNT), is constitutively expressed. There are three known isoforms of the α subunit (HIF-1α, HIF-2α, and HIF-3α) in humans and mammals; however, the HIF-1α subunit is the most widely studied (Bracken et al. 2003; Forooghian et al. 2007; Wolff et al. 2013; Zhang et al. 2014). HIF-1α and HIF-2α share significant structural homology and function and are expressed in multiple tissues and cell types in response to hypoxia (Befani et al. 2013). Less is known about HIF-3α; however, it is a transcriptional target of HIF-1α (Tanaka et al. 2009). Most studies with cobalt investigated its effects on HIF-1α; however, Befani et al. (2013) reported that cobalt stimulated HIF-1-dependent gene expression in two human liver cancer cell lines but inhibited HIF-2-dependent gene expression. Therefore, the following discussion is limited to HIF-1α.

#### Cobalt-induced HIF Stabilization

HIF-1 overexpression and enhanced transcriptional activity are linked to cancer initiation and progression. There is strong experimental support that cobalt is a potent inducer of HIF-1α activation. Cobalt metal particles, cobalt chloride, and cobalt sulfate heptahydrate promote a hypoxia-like state in vivo and in vitro, even with normal molecular oxygen pressure, by stabilizing HIF-1α (Beyersmann and Hartwig 2008; Galán-Cobo et al. 2013; Galanis et al. 2009; Gao et al. 2013; Maxwell and Salnikow 2004; Nyga et al. 2015; Qiao et al. 2009; Saini et al. 2010a; Saini et al. 2010b; Xia et al. 2009). Further, Wang and Semenza (1995) demonstrated that HIF-1 induction either from hypoxia or cobalt chloride treatment was indistinguishable with respect to DNA binding specificity and contacts with target DNA sequences.

Evidence for cobalt-induced HIF-1 stabilization has been demonstrated in several human cell lines, including cancer cell lines (Ardyanto et al. 2008; Fu et al. 2009; Wang and Semenza 1995). Cobalt chloride-induced hypoxia also increased the invasiveness of one primary breast cancer cell line (Fu et al. 2009). Human A549 lung adenocarcinoma cells exposed to cobalt chloride overexpressed Cap43, a hypoxia-regulated gene (Salnikow et al. 2000). Increased expression of Cap43 was reported in tumors and serum of lung cancer patients compared to adjacent normal tissues and may be predictive of tumor angiogenesis and poor prognosis (Azuma et al. 2012; Wang et al. 2012). Permenter et al. (2013) investigated gene expression and intracellular protein abundance in two rat liver cell lines exposed to cobalt chloride. Many genes, proteins, and pathways were modulated, which were mainly due to induction of a hypoxia-like response and oxidative stress. These data were consistent with gene expression profiling in hypoxia signaling in human hepatocellular carcinoma (Hep3B) cells exposed to cobalt chloride (Vengellur et al. 2005). Cobalt nanoparticles and ions also induced a time-dependent increase in HIF-target genes and expression of proinflammatory cytokines in the U937 human monocytic cell line (Nyga et al. 2015).

Under normal oxygen conditions, the iron-containing oxygen-sensing enzymes (prolyl hydroxylases) and an asparagine hydroxylase that hydroxylate specific proline or asparagine residues in the HIF-1α subunits (Maxwell and Salnikow 2004). Hydroxylated HIF-1α binds to a multiprotein complex that contains the von Hippel-Lindau (VHL) tumor suppressor. VHL acts as part of a ubiquitin ligase complex resulting in rapid ubiquitination and proteolysis of HIF-1α. Under hypoxic conditions, HIF-1α subunits are not hydroxylated, and consequently the protein is stabilized and translocates to the nucleus where it binds with a HIF-1β subunit. The response to hypoxia includes increased red blood cell production, blood vessel growth and increased blood supply to tissues, and increased anaerobic metabolism. Cobalt affects the function of several genes and enzymes responsible for posttranslational modification of HIF-1α such as prolyl hydroxylases and VHL (Davidson et al. 2015). Possible mechanisms by which cobalt ions activate HIF-1 include replacing iron in the regulatory prolyl hydroxylases or depleting intracellular ascorbate (a cofactor for prolyl hydroxylase activity), thus, deactivating these enzymes (Davidson et al. 2015; Maxwell and Salnikow 2004; Qiao et al. 2009; Salnikow et al. 2004). Kang et al. (2006) reported that metal-induced (cobalt or nickel) HIF-1α stabilization was reversed in human lung carcinoma A549 cells when the cells were treated simultaneously with iron and metal ions. Oxidative stress does not appear to be a primary mechanism of cobalt-induced HIF activation. Salnikow et al. (2000) found that while cobalt and nickel produced oxidative stress in A549 cells, activation of HIF-1-dependent genes was independent of ROS formation. Although the mitochondria are a main target of cobalt toxicity and generate ROS that trigger hypoxia-induced transcription, cobalt activates hypoxia-induced transcription via a mitochondria-independent mechanism (Chandel et al. 1998; Karovic et al. 2007). In a study with rat hepatocytes, lysosomes were shown to be the source of ROS formation with redox transition metals (including cobalt), while the mitochondria were the source of ROS formation for non-redox or poor redox cycling transition metals (Pourahmad et al. 2003). Nyga et al. (2015) also reported evidence that HIF-1α stabilization in human macrophages treated with cobalt metal nanoparticles or cobalt ions occurred via an ROS-independent pathway.

#### Hypoxia Mimicry

HIF-1α is present in almost all human and animal cells and its activation has a central role in the transcriptional regulation of more than 100 hypoxia-responsive genes (including genes encoding for multiple angiogenic growth factors (e.g., VEGF), erythropoietin synthesis, endothelin, glucose transporters, inflammatory factors, and regulation of apoptosis and cell proliferation) that allow for cell survival at low oxygen pressure (Beyersmann and Hartwig 2008; Gao et al. 2013; Greim et al. 2009; Saini et al. 2010a; Saini et al. 2010b; Simonsen et al. 2012; Wang and Semenza 1995). The evidence suggests that HIF-1α is a major regulator of the adaptation of cancer cells to hypoxia and may contribute to tumor development and progression by decreasing both repair and removal of mutated cells, selecting for cells with genetic instability, reducing p53 transcriptional activity, evading growth arrest checkpoints, and inducing apoptosis resistance (Ardyanto et al. 2008; Greim et al. 2009; Hammond and Giaccia 2005; Lee et al. 2001; Maxwell and Salnikow 2004).

HIF-1α overexpression, stabilization, and transcriptional activation is found in more than 70% of human cancers (e.g., breast, ovarian, cervical, prostate, brain, lung, head and neck) and is associated with poor clinical outcomes (Cheng et al. 2013; Galanis et al. 2009; Galanis et al. 2008; Maxwell and Salnikow 2004; Paul et al. 2004). Greim et al. (2009) also identified hypoxia and HIF activation as a relevant mechanism for pheochromocytoma in rats. Further evidence for a role of HIF-1 in cancer is as follows: (1) enhanced glycolytic and angiogenic activities are hallmarks of many tumors and are consequences of HIF-1 activation, (2) immunolabelling for HIF-1α subunits confirms there is a common activation in solid tumors, (3) genetic studies comparing tumor growth with and without HIF-1 have generally shown that tumors without specific HIF subunits have decreased vascularization and growth, (4) a number of pathways implicated in cancer progression increase activation of the HIF-1 pathway in normoxia and hypoxia, and (5) as described above, the VHL tumor suppressor protein is required to regulate HIF-1 (Maxwell and Salnikow 2004). VHL loss of function results in constitutive HIF activation and an increased risk of developing cancer and is evident in people with VHL disease. VHL disease is a hereditary cancer syndrome that is caused by inactivation of the VHL protein (Ben-Skowronek and Kozaczuk 2015). This disease is characterized by the development of multiple vascular tumors including pheochromocytomas, pancreatic islet cell tumors, renal cell tumors, retinal and central nervous system hemangioblastomas, and others. Loss of the VHL protein results in elevated levels of HIF and leads to increased production of VEGF, platelet-derived growth factor (PDGF), transforming growth factor α (TGF-α) and other hypoxia-responsive transcripts that promote cell growth and angiogenesis. HIF also contributes to overproduction of tyrosine hydroxylase and catecholamines in pheochromocytomas.

## 6.3 Other Biological Effects

In addition to the biological effects discussed in Section 6.2 and illustrated in Figure 6-2, different forms of cobalt ions induce similar biological effects that may or may not be related to carcinogenicity. The effects of chronic exposure to cobalt and cobalt compounds on the respiratory system in humans and experimental animals are well documented (ATSDR 2004; IARC 1991; 2006). Effects include a spectrum of inflammatory and proliferative changes including respiratory irritation, diminished pulmonary function, asthma, alveolar epithelial hyperplasia and metaplasia, squamous metaplasia, and interstitial fibrosis. Respiratory effects have been observed in workers employed in cobalt refineries, hard-metal workers, diamond polishers, and ceramic dish painters.

Potential mechanisms for these endpoints might be some of the modes of action discussed in Section 6.2 as well as other cobalt-related biological responses. Oxidative damage and inflammatory events are characteristics of fibrosing alveolitis (hard-metal lung disease) and lung cancer and there is some evidence that lung fibrosis is a risk factor for lung cancer (IARC 2006). Lung injury may be due in part to cobalt-induced apoptosis which is primarily mediated via loss of mitochondrial membrane potential and release of cytochrome c and apoptosis-inducing factor (AIF) (Araya et al. 2002; Battaglia et al. 2009; Karovic et al. 2007; Pulido and Parrish 2003). Cobalt also competes with essential divalent metal ions (e.g., calcium, copper, zinc, iron, manganese, and magnesium) for absorption, specific receptor activation, and ion channel transport (Paustenbach et al. 2013) and interferes with a number of iron-containing proteins such as the iron regulatory protein 1 (IRP1)/iron response element (IRE) system and various iron-sulfur cluster proteins that are important for maintaining iron homeostasis, energy production, metabolism, gene expression, DNA/RNA processing and repair, and defense against oxidative stress (Davidson et al. 2015; Lee et al. 2006; Sheftel et al. 2010). Thus, disruption of iron homeostasis could potentially lead to numerous adverse health effects, including cancer.

## 6.4 Synthesis

Cobalt metal and several cobalt compounds induce similar carcinogenic effects in experimental animals. The mechanisms of cobalt-induced neoplasms are not completely understood but the available data provide strong support that intracellular cobalt ions are the principal toxic entity. Cobalt ions are actively transported inside the cell via metal ion transport systems while cobalt particles with low solubility are readily taken up by cells via endocytosis. Once inside the cell, cobalt particles are partially solubilized at the low pH within lysosomes and release cobalt ions that can react with various cytoplasmic and nuclear proteins and lipids and possibly DNA. Mechanistic data provide strong support that inhibition of DNA repair, oxidative stress, and activation of HIF-1α likely contribute to cobalt-induced neoplastic development and progression. All of these mechanisms are relevant to humans.