# 5 Studies of Cancer in Experimental Animals

This section reviews and assesses the evidence from carcinogenicity studies in experimental animals exposed to cobalt and cobalt compounds that release cobalt ions in vivo (hereinafter referred to as cobalt). Cancer and co-carcinogen studies in experimental animals were identified using methods described in the protocol and literature search strategy document (https://ntp.niehs.nih.gov/go/730697). In all, 23 publications (16 carcinogenicity and 9 co-carcinogenicity studies) were identified that met the following inclusion criteria: reported on the presence or absence of neoplastic and related non-neoplastic lesion, had concurrent or historical control group, and had an observational duration of 12 months or greater for rats and mice or were co-carcinogen exposure studies (initiation/promotion and other co-carcinogen studies that isolate the effect of cobalt compound exposures). Some of these publications overlap since some co-carcinogenicity studies had a cobalt exposure alone group and a corresponding control as part of their design. Several studies were excluded from the review because they did not have concurrent controls or controls from a closely related study. These included Hopps et al. (1954), Delahant (1955), Gilman (1962), Nowak (1966), and Gunn et al. (1967). Studies of cobalt alloys cobalt composites, cobalt compounds containing other metals, and radioactive cobalt in experimental animals were not considered to be informative because of potential confounding by other carcinogens. The cobalt alloys that were tested in experimental animals also contained other metals shown to be carcinogenic in experiments such as nickel and chromium and thus it would not be possible to separate any effects due to cobalt from those due to the other metals [see ((See IARC 2006 for a review of studies of cobalt alloys.) for a review of studies of cobalt alloys].

This section is organized by the type of study, i.e., carcinogenicity (Section 5.1) and co-carcinogenicity (Section 5.2). For each of these study types, the monograph provides an overview of the available studies, assesses their quality, discusses the findings, and identifies potential treatment-related cancer sites (carcinogenicity studies only). The co-carcinogen studies are only briefly discussed because they do not contribute substantially to the evaluation of potential carcinogenicity. Section 5.3 provides a synthesis of the findings for the different types of cobalt compounds across the cancer sites. The level of evidence conclusion for the carcinogenicity of cobalt compounds that release cobalt ions in vivo as a class from studies in experimental animals is provided in Section 7, which provides the rationale for evaluating them as a class.

## 5.1 Carcinogenicity Studies

### 5.1.1 Overview of the Studies

Different forms of cobalt were tested in 16 carcinogenicity studies: cobalt metal or cobalt nanoparticles (6 studies); two soluble cobalt salts, cobalt sulfate heptahydrate (2 studies) and cobalt chloride (1 study); and two poorly soluble cobalt compounds, cobalt(II) oxide (6 studies) and cobalt sulfide (1 study); (see Table 5-1). Most carcinogenicity studies were conducted in rats, with three studies in mice, and one study in hamsters. Routes of administration included either administration through the respiratory tract (inhalation or intratracheal instillation) or by local injection (subcutaneous, intramuscular, intraperitoneal, intrapleural, or intrarenal). Three publications that did not have concurrent controls for all or part of their series of studies were included in the evaluation because the authors either reported non-concurrent controls from other parts of their series of studies (Heath 1956; Shabaan et al. 1977) or authors reported non-concurrent controls from a previous study in the same laboratory (Heath and Daniel 1962).

Table 5-1 Overview of Cancer Studies in Experimental Animals Reviewed

Strain (Sex) | Substance | Route | Exposure Period/ Study Duration | Reference
Cobalt metal
Rat F344/NTac (M&F) | Cobalt metal | Inhalation | 2 yr/2 yr | NTP (2014d)
Mouse B6C3F_1_ (M&F) | Cobalt metal | Inhalation | 2 yr/2 yr | NTP (2014d)
Rat Sprague-Dawley (M) | Cobalt metal [nano] and | IM inj. | Single dose/1 yr | Hansen et al. (2006)
| Cobalt metal [bulk]^a^ | SC inj.
Rat Sprague-Dawley (F) | Cobalt metal | Intrarenal inj. | Single dose/1 yr | Jasmin and Riopelle (1976)
Rat Hooded (F) | Cobalt metal | Intrapleural inj. | Single dose/2.3 yr | Heath and Daniel (1962)
Rat Hooded (M&F) | Cobalt metal | IM inj. | Single dose/lifespan | Heath (1956)
Soluble cobalt compounds
Rat F344/N (M&F) | Cobalt sulfate heptahydrate | Inhalation | 2 yr/2 yr | NTP (1998)
Mouse B6C3F_1_ (M&F) | Cobalt sulfate heptahydrate | Inhalation | 2 yr/2 yr | NTP (1998)
Rat Wistar (M) | Cobalt chloride | SC inj. | 8–12 mo/8–12 mo | Shabaan et al. (1977)
Poorly soluble cobalt compounds
Rat Sprague-Dawley (M&F) | Cobalt(II) oxide | Intratracheal instill. | 1.5 yr/lifespan | Steinhoff and Mohr (1991)
Rat Sprague-Dawley (M&F) | Cobalt(II) oxide | IP inj. | 6 mo/lifespan | Steinhoff and Mohr (1991)
Rat Sprague-Dawley (M) | Cobalt(II) oxide | SC inj. | 730 day/lifespan | Steinhoff and Mohr (1991)
Rat Wistar (M&F) | Cobalt(II)oxide | IM inj. | Single dose/1.3 yr | Gilman and Ruckerbauer (1962)
Mouse Swiss (F) | Cobalt(II) oxide | IM inj. | Single dose/2 yr | Gilman and Ruckerbauer (1962)
Hamster Syrian Golden (M) | Cobalt(II) oxide | Inhalation | Lifespan/lifespan | Wehner et al. (1977)
Rat Sprague-Dawley (F) | Cobalt sulfide | Intrarenal inj. | Single dose/1 yr | Jasmin and Riopelle (1976)

M = male, F = female, instill. = instillation, inj. = injection, IP = intraperitoneal, IM = intramuscular, SC = subcutaneous, wk = week, yr = year.

^a^ Both cobalt compounds tested in the same animal.

### 5.1.2 Study Quality Assessment

Each of these primary studies was systematically evaluated for its ability to inform the cancer hazard evaluation using a series of signaling questions related to the following study performance elements: population, exposure conditions, outcome assessment, potential confounding, and statistics and reporting (see Protocol for Preparing the RoC Monograph on Cobalt (NTP 2014b)). An overview of the quality evaluations for the carcinogenicity studies is shown in Table 5-2 and discussed below. Details of each study assessment and quality criteria on a study-by-study basis are reported in Appendix D.

Table 5-2 Overview of Experimental Animal Carcinogenicity Study Quality Evaluations

Study | Quality | | | | | | | | | | Sensitivity | | | Overall Utility
Study | | Controls | Historical Data | Ran-dom-ization | Purity | Dosing | Treatment-related Survival | Pathology | Confounding | Reporting & Analysis | Animal Model | Stat Power | Duration | Overall Utility
NTP (2014d) R | Cobalt metal | +++ | Yes | +++ | +++ | +++ | ++ | +++ | +++ | +++ | +++ | +++ | +++ | High
NTP (2014d) M | Cobalt metal | +++ | Yes | +++ | +++ | +++ | ++ | +++ | +++ | +++ | +++ | +++ | +++ | High
Hansen et al. (2006) ^a^ | Cobalt metal and nano | +++ | No | NR | NR | ++ | +++ | +++ | ++ | ++ | ++ | + | + | Moderate
Jasmin and Riopelle (1976) ^a^ | Cobalt metal and sulfide | +++ | No | NR | ++ | + | NR | ++ | ++ | ++ | ++ | ++ | + | Low
Heath and Daniel (1962) | Cobalt metal | + | Yes^b^ | NR | ++ | + | NR | ++ | ++ | + | ++ | + | +++ | Low
Heath (1956) | Cobalt metal | ++ | Yes^b^ | NR | ++ | + | NR | ++ | ++ | + | ++ | + | +++ | Low
NTP (1998) R | Cobalt sulfate | +++ | Yes | +++ | +++ | +++ | +++ | +++ | +++ | +++ | +++ | +++ | +++ | High
NTP (1998) M | Cobalt sulfate | +++ | Yes | +++ | +++ | +++ | +++ | +++ | +++ | +++ | +++ | +++ | +++ | High
Shabaan et al. (1977) | Cobalt chloride | ++ | Yes^b^ | NR | NR | + | ++ | + | + | + | ++ | ++ | + | Low
Steinhoff and Mohr (1991)- (intratracheal) | Cobalt(II) oxide | +++ | No | NR | ++ | ++ | ++ | ++ | ++ | ++ | +++ | +++ | +++ | Moderate
Steinhoff and Mohr (1991) - (IP) | Cobalt(II) oxide | +++ | No | NR | ++ | + | NR | ++ | ++ | ++ | +++ | + | +++ | Moderate
Steinhoff and Mohr (1991) - (SC) | Cobalt(II) oxide | +++ | No | NR | ++ | ++ | NR | ++ | ++ | ++ | ++ | + | +++ | Moderate
Gilman and Ruckerbauer (1962) R | Cobalt(II) oxide | +++ | No | NR | + | + | ++ | ++ | + | + | +++ | + | ++ | Low
Gilman and Ruckerbauer (1962) M | Cobalt(II) oxide | +++ | No | NR | + | + | ++ | ++ | + | ++ | ++ | ++ | +++ | Low
Wehner et al. (1977) | Cobalt(II) oxide | +++ | No | NR | ++ | ++ | +++ | +++ | ++ | + | ++ | + | +++ | Moderate

+ ++ = high quality/little to no concerns, ++ = moderate quality/moderate concerns, + = low quality/high concerns, 0 = inadequate, NR = not reported; M = mice; R = rats.

^a^ Includes test results for two forms of cobalt, so considered two studies.

^b^ Limited number of controls (less than 15) from an earlier study.

No critical concerns for biases were identified in any of the 16 carcinogenicity studies and they were all considered to have some utility for the cancer hazard evaluation. The four NTP inhalation studies (cobalt metal and cobalt sulfate in rats and mice) were considered to be the most informative (high utility) because they used a sufficient number of experimental animals of both sexes for a near lifetime exposure duration and tested three dose levels along with an untreated control. Two inhalation/intratracheal instillation studies of exposure to cobalt(II) oxide (Steinhoff and Mohr 1991; Wehner et al. 1977) and three injection studies of cobalt metal or cobalt sulfide in two publications (Hansen et al. 2006; Steinhoff and Mohr 1991) were considered to have moderate utility. In general, most of the limitations of the studies were related to low sensitivity of the study to detect an effect, e.g., due to the use of a single dose, short study duration, or small numbers of animals. In the remaining seven injection studies (Gilman and Ruckerbauer 1962; Heath 1956; Heath and Daniel 1962; Jasmin and Riopelle 1976; Shabaan et al. 1977), there were major concerns for several potential biases; thus, these studies were considered to have lower utility. Most of these studies had low sensitivity or incomplete necropsies. Poor reporting of methods and results was also a common problem, and in some studies, there were concerns about potential confounding. Historical controls from a related study by the same authors were used in lieu of concurrent controls in one study (Heath and Daniel 1962). Overall, the major limitations in the studies with low and moderate utility were primarily (but not exclusively) due to low sensitivity and for these cases there is little concern that these limitations would decrease confidence in a positive finding.

### 5.1.3 Assessment of Neoplastic Findings from Carcinogenicity Studies

Discussions of the findings from the 16 carcinogenicity studies grouped by site of tumor development are reported below and in Table 5-3, Table 5-4, and Table 5-5. The main neoplasm locations were the lung in inhalation and intratracheal studies (six studies) and injection sites in studies using various routes of injection (subcutaneous, intramuscular, intraperitoneal, intrapleural, and intrarenal). In addition, in some inhalation studies, some tumors were observed in sites distal from the site of administration. Findings for cobalt compounds across organ sites are discussed in Section 5.3.

Table 5-3 Lung Neoplasms and Non-neoplastic Lesions in Experimental Animals Exposed to Cobalt Compounds

Reference & Year, Animal, Study Duration | Substance, Purity, Size | Dosing Regimen | Dose Levels | # Animals at Sacrifice | Tumor Incidence (n/N^+^) (%) | Comments
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Multiple alveolar/bronchiolar carcinoma | | | Survival in exposed groups was similar to controls. Strengths: A well-designed study in all factors such as long observation period, sufficient dose levels, adequate number of animals. Limitations: Decreases in body weight in mid and high dose rats. Other comments: Historical controls were limited (100 rats). Significantly increased non-neoplastic lesions: Alveolar epithelium hyperplasia (pre-neoplastic) - all dose levels Bronchiolar hyperplasia (pre-neoplastic) - all dose levels
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 0 mg/m^3^ | 17 | 0/50 (0%)
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 1.25 mg/m^3^ | 20 | 6/50 (12%)*
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 2.5 mg/m^3^ | 16 | 14/50 (28%)**
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 5 mg/m^3^ | 16 | 30/50 (60%)**
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Alveolar/bronchiolar carcinoma^a^
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 0 mg/m^3^ | 17 | 0/50 (0%)
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 1.25 mg/m^3^ | 20 | 16/50 (38%)***
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 2.5 mg/m^3^ | 16 | 34/50 (77%)***
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 5 mg/m^3^ | 16 | 36/50 (81%)***
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Trend-test p value: 0.001
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Multiple alveolar/bronchiolar adenoma
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 0 mg/m^3^ | 17 | 1/50 (2%)
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 1.25 mg/m^3^ | 20 | 3/50 (6%)
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 2.5 mg/m^3^ | 16 | 2/50 (4%)
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 5 mg/m^3^ | 16 | 6/50 (12%)
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Alveolar/bronchiolar adenoma^a^
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 0 mg/m^3^ | 17 | 2/50 (5%)
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 1.25 mg/m^3^ | 20 | 10/50 (24%)*
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 2.5 mg/m^3^ | 16 | 10/50 (23%)*
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 5 mg/m^3^ | 16 | 14/50 (33%)***
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Trend-test p value: 0.011
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Alveolar/bronchiolar carcinoma or adenoma combined^a^
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 0 mg/m^3^ | 17 | 2/50 (5%)
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 1.25 mg/m^3^ | 20 | 25/50 (58%)***
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 2.5 mg/m^3^ | 16 | 39/50 (85%)***
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 5 mg/m^3^ | 16 | 44/50 (94%)***
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Trend-test p value: 0.001
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Cystic keratinizing epithelioma
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 0 mg/m^3^ | 17 | 0/50 (0%)
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 1.25 mg/m^3^ | 20 | 1/50 (2%)
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 2.5 mg/m^3^ | 16 | 0/50 (0%)
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 5 mg/m^3^ | 16 | 1/50 (2%)
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Multiple alveolar/bronchiolar carcinoma | | | Survival was significantly decreased in the mid-dose group. Strengths: A well-designed study in almost all factors such as long observation period, sufficient dose levels, adequate number of animals. Limitations: A significant decrease in survival of female rats and decreases in body weight in mid- and high-dose rats. Other comments: Historical controls were limited (100 rats). Significantly increased non-neoplastic lesions: Alveolar hyperplasia (pre-neoplastic) - all dose levels. Bronchiolar hyperplasia (pre-neoplastic) - all dose levels
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 0 mg/m^3^ | 35 | 0/50 (0%)
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 1.25 mg/m^3^ | 26 | 4/50 (8%)
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 2.5 mg/m^3^ | 24 | 3/50 (6%)
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 5 mg/m^3^ | 25 | 18/50 (36%)**
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Alveolar/bronchiolar carcinoma^a^
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 0 mg/m^3^ | 35 | 0/50 (0%)
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 1.25 mg/m^3^ | 26 | 9/50 (21%)***
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 2.5 mg/m^3^ | 24 | 17/50 (42%)***
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 5 mg/m^3^ | 25 | 30/50 (69%)***
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Trend-test p value: 0.001
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Multiple alveolar/bronchiolar adenoma
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 0 mg/m^3^ | 35 | 0/50 (0%)
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 1.25 mg/m^3^ | 26 | 1/50 (2%)
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 2.5 mg/m^3^ | 24 | 3/50 (6%)
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 5 mg/m^3^ | 25 | 4/50 (8%)
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Alveolar/bronchiolar adenoma^a^
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 0 mg/m^3^ | 35 | 2/50 (5%)
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 1.25 mg/m^3^ | 26 | 7/50 (16%)
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 2.5 mg/m^3^ | 24 | 9/50 (22%)*
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 5 mg/m^3^ | 25 | 13/50 (31%)**
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Trend-test p value: 0.002
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Alveolar/bronchiolar carcinoma or adenoma combined^a^
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 0 mg/m^3^ | 35 | 2/50 (4%)
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 1.25 mg/m^3^ | 26 | 15/50 (35%)***
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 2.5 mg/m^3^ | 24 | 20/50 (49%)***
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 5 mg/m^3^ | 25 | 38/50 (86%)***
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Trend-test p value: 0.001
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Squamous cell carcinoma
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 0 mg/m^3^ | 35 | 0/50 (0%)
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 1.25 mg/m^3^ | 26 | 0/50 (0%)
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 2.5 mg/m^3^ | 24 | 0/50 (0%)
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 5 mg/m^3^ | 25 | 1/50 (2%)
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Cystic keratinizing epithelioma^a^
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 0 mg/m^3^ | 35 | 0/50 (0%)
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 1.25 mg/m^3^ | 26 | 4/50 (10%)^i^
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 2.5 mg/m^3^ | 24 | 1/50 (3%)^i^
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 5 mg/m^3^ | 25 | 2/50 (5%)^i^
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Trend-test p value: 0.002
NTP (2014d) Mouse (B6C3F_1_/N) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Multiple alveolar/bronchiolar carcinoma | | | Survival significantly decreased at 2.5 and 5 mg/m^3^. Strengths: A well-designed study in almost all factors such as long observation period, sufficient dose levels, adequate number of animals. Limitations: A significant decrease in survival of male mice and decrease in body weight in high dose mice Significantly increased non-neoplastic lesions: Alveolar/bronchiolar epithelium hyperplasia (pre-neoplastic) - all dose levels Alveolar epithelium hyperplasia (pre-neoplastic) - all dose levels Bronchiolar epithelium hyperplasia (pre-neoplastic) - high dose
NTP (2014d) Mouse (B6C3F_1_/N) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 0 mg/m^3^ | 39 | 3/50 (6%)
NTP (2014d) Mouse (B6C3F_1_/N) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 1.25 mg/m^3^ | 31 | 18/49 (36%)**
NTP (2014d) Mouse (B6C3F_1_/N) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 2.5 mg/m^3^ | 29 | 24/50 (48%)**
NTP (2014d) Mouse (B6C3F_1_/N) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 5 mg/m^3^ | 25 | 36/50 (72%)**
NTP (2014d) Mouse (B6C3F_1_/N) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Trend-test p value: 0.001
NTP (2014d) Mouse (B6C3F_1_/N) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Alveolar/bronchiolar carcinoma^a^
NTP (2014d) Mouse (B6C3F_1_/N) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 0 mg/m^3^ | 39 | 11/50 (23%)
NTP (2014d) Mouse (B6C3F_1_/N) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 1.25 mg/m^3^ | 31 | 38/49 (79%)***
NTP (2014d) Mouse (B6C3F_1_/N) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 2.5 mg/m^3^ | 29 | 42/50 (88%)***
NTP (2014d) Mouse (B6C3F_1_/N) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 5 mg/m^3^ | 25 | 46/50 (94%)***
NTP (2014d) Mouse (B6C3F_1_/N) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Trend-test p value: 0.001
NTP (2014d) Mouse (B6C3F_1_/N) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Multiple alveolar/bronchiolar adenoma
NTP (2014d) Mouse (B6C3F_1_/N) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 0 mg/m^3^ | 39 | 0/50 (0%)
NTP (2014d) Mouse (B6C3F_1_/N) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 1.25 mg/m^3^ | 31 | 1/49 (2%)
NTP (2014d) Mouse (B6C3F_1_/N) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 2.5 mg/m^3^ | 29 | 1/50 (2%)
NTP (2014d) Mouse (B6C3F_1_/N) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 5 mg/m^3^ | 25 | 0/50 (0%)
NTP (2014d) Mouse (B6C3F_1_/N) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Alveolar/bronchiolar adenoma^a^
NTP (2014d) Mouse (B6C3F_1_/N) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 0 mg/m^3^ | 39 | 7/50 (15%)
NTP (2014d) Mouse (B6C3F_1_/N) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 1.25 mg/m^3^ | 31 | 11/49 (25%)
NTP (2014d) Mouse (B6C3F_1_/N) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 2.5 mg/m^3^ | 29 | 15/50 (36%)*
NTP (2014d) Mouse (B6C3F_1_/N) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 5 mg/m^3^ | 25 | 3/50 (7%)
NTP (2014d) Mouse (B6C3F_1_/N) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Alveolar/bronchiolar carcinoma or adenoma combined^a^
NTP (2014d) Mouse (B6C3F_1_/N) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 0 mg/m^3^ | 39 | 16/50 (33%)
NTP (2014d) Mouse (B6C3F_1_/N) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 1.25 mg/m^3^ | 31 | 41/49 (85%)***
NTP (2014d) Mouse (B6C3F_1_/N) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 2.5 mg/m^3^ | 29 | 43/50 (90%)***
NTP (2014d) Mouse (B6C3F_1_/N) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 5 mg/m^3^ | 25 | 47/50 (96%)***
NTP (2014d) Mouse (B6C3F_1_/N) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Trend-test p value: 0.001
NTP (2014d) Mouse (B6C3F_1_/N) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Multiple alveolar/bronchiolar carcinoma | | | Survival in exposed groups was similar to controls. Strengths: A well-designed study in all factors such as long observation period, sufficient dose levels, adequate number of animals. Limitations: Decrease in body weight in high Significantly increased non-neoplastic lesions: Alveolar/bronchiolar epithelium hyperplasia (pre-neoplastic) - all dose levels; Alveolar epithelium hyperplasia (pre-neoplastic) - all dose levels; Bronchiolar epithelium hyperplasia (pre-neoplastic)—mid- and high-dose levels
NTP (2014d) Mouse (B6C3F_1_/N) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 0 mg/m^3^ | 36 | 1/49 (10%)
NTP (2014d) Mouse (B6C3F_1_/N) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 1.25 mg/m^3^ | 36 | 7/50 (50%)*
NTP (2014d) Mouse (B6C3F_1_/N) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 2.5 mg/m^3^ | 27 | 20/50 (76%)**
NTP (2014d) Mouse (B6C3F_1_/N) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 5 mg/m^3^ | 26 | 24/50 (86%)**
NTP (2014d) Mouse (B6C3F_1_/N) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Trend-test p value: 0.001
NTP (2014d) Mouse (B6C3F_1_/N) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Alveolar/bronchiolar carcinoma^a^
NTP (2014d) Mouse (B6C3F_1_/N) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 0 mg/m^3^ | 36 | 5/49 (11%)
NTP (2014d) Mouse (B6C3F_1_/N) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 1.25 mg/m^3^ | 36 | 25/50 (54%)***
NTP (2014d) Mouse (B6C3F_1_/N) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 2.5 mg/m^3^ | 27 | 38/50 (79%)***
NTP (2014d) Mouse (B6C3F_1_/N) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 5 mg/m^3^ | 26 | 43/50 (88%)***
NTP (2014d) Mouse (B6C3F_1_/N) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Trend-test p value: 0.001
NTP (2014d) Mouse (B6C3F_1_/N) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Multiple alveolar/bronchiolar adenoma
NTP (2014d) Mouse (B6C3F_1_/N) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 0 mg/m^3^ | 36 | 0/49 (0%)
NTP (2014d) Mouse (B6C3F_1_/N) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 1.25 mg/m^3^ | 36 | 1/50 (2%)
NTP (2014d) Mouse (B6C3F_1_/N) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 2.5 mg/m^3^ | 27 | 0/50 (0%)
NTP (2014d) Mouse (B6C3F_1_/N) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 5 mg/m^3^ | 26 | 1/50 (2%)
NTP (2014d) Mouse (B6C3F_1_/N) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Alveolar/bronchiolar adenoma^a^
NTP (2014d) Mouse (B6C3F_1_/N) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 0 mg/m^3^ | 36 | 3/49 (7%)
NTP (2014d) Mouse (B6C3F_1_/N) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 1.25 mg/m^3^ | 36 | 9/50 (20%)
NTP (2014d) Mouse (B6C3F_1_/N) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 2.5 mg/m^3^ | 27 | 8/50 (19%)
NTP (2014d) Mouse (B6C3F_1_/N) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 5 mg/m^3^ | 26 | 10/50 (25%)*
NTP (2014d) Mouse (B6C3F_1_/N) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Trend-test p value: 0.037
NTP (2014d) Mouse (B6C3F_1_/N) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Alveolar/bronchiolar carcinoma or adenoma combined^a^
NTP (2014d) Mouse (B6C3F_1_/N) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 0 mg/m^3^ | 36 | 8/49 (18%)
NTP (2014d) Mouse (B6C3F_1_/N) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 1.25 mg/m^3^ | 36 | 30/50 (64%)***
NTP (2014d) Mouse (B6C3F_1_/N) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 2.5 mg/m^3^ | 27 | 41/50 (85%)***
NTP (2014d) Mouse (B6C3F_1_/N) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 5 mg/m^3^ | 26 | 45/50 (92%)***
NTP (2014d) Mouse (B6C3F_1_/N) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Trend-test p value: 0.001
NTP (1998) Rat (F344) Male (6 wk old) 2 yr | Cobalt sulfate 99% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | Alveolar/bronchiolar carcinoma^b^ | | | Survival in exposed groups was similar to controls. Strengths: A well-designed study in all factors Limitations: None. Significantly increased non-neoplastic lesions: Alveolar epithelium metaplasia - all dose levels; Alveolar epithelium hyperplasia (pre-neoplastic) - all dose levels
NTP (1998) Rat (F344) Male (6 wk old) 2 yr | Cobalt sulfate 99% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 0 mg/m^3^ | 17 | 0/50 (0%)
NTP (1998) Rat (F344) Male (6 wk old) 2 yr | Cobalt sulfate 99% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 0.3 mg/m^3^ | 15 | 0/50 (0%)
NTP (1998) Rat (F344) Male (6 wk old) 2 yr | Cobalt sulfate 99% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 1.0 mg/m^3^ | 21 | 3/48 (11%)
NTP (1998) Rat (F344) Male (6 wk old) 2 yr | Cobalt sulfate 99% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 3.0 mg/m^3^ | 15 | 1/50 (7%)
NTP (1998) Rat (F344) Male (6 wk old) 2 yr | Cobalt sulfate 99% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | Alveolar/bronchiolar adenoma^b^
NTP (1998) Rat (F344) Male (6 wk old) 2 yr | Cobalt sulfate 99% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 0 mg/m^3^ | 17 | 1/50 (2%)
NTP (1998) Rat (F344) Male (6 wk old) 2 yr | Cobalt sulfate 99% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 0.3 mg/m^3^ | 15 | 4/50 (18%)
NTP (1998) Rat (F344) Male (6 wk old) 2 yr | Cobalt sulfate 99% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 1.0 mg/m^3^ | 21 | 1/48 (2%)
NTP (1998) Rat (F344) Male (6 wk old) 2 yr | Cobalt sulfate 99% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 3.0 mg/m^3^ | 15 | 6/50 (28%)
NTP (1998) Rat (F344) Male (6 wk old) 2 yr | Cobalt sulfate 99% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | Alveolar/bronchiolar adenoma or carcinoma combined^b^
NTP (1998) Rat (F344) Male (6 wk old) 2 yr | Cobalt sulfate 99% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 0 mg/m^3^ | 17 | 1/50 (2%)
NTP (1998) Rat (F344) Male (6 wk old) 2 yr | Cobalt sulfate 99% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 0.3 mg/m^3^ | 15 | 4/50 (18%)
NTP (1998) Rat (F344) Male (6 wk old) 2 yr | Cobalt sulfate 99% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 1.0 mg/m^3^ | 21 | 4/48 (13%)
NTP (1998) Rat (F344) Male (6 wk old) 2 yr | Cobalt sulfate 99% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 3.0 mg/m^3^ | 15 | 7/50 (34%)*
NTP (1998) Rat (F344) Male (6 wk old) 2 yr | Cobalt sulfate 99% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | Trend-test p value: 0.032
NTP (1998) Rat (F344) Female (6 wk old) 2 yr | Cobalt sulfate (99% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | Alveolar/bronchiolar carcinoma^b^ | | | Survival in exposed groups was similar to controls. Strengths: A well-designed study in all factors such as long observation period, sufficient dose levels, adequate number of animals. Limitations: None. Significantly increased non-neoplastic lesions: Alveolar epithelium metaplasia - all dose levels; Alveolar epithelium hyperplasia (pre-neoplastic) - high dose; Alveolar epithelium hyperplasia, atypical (pre-neoplastic) - high dose
NTP (1998) Rat (F344) Female (6 wk old) 2 yr | Cobalt sulfate (99% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 0 mg/m^3^ | 28 | 0/50 (0%)
NTP (1998) Rat (F344) Female (6 wk old) 2 yr | Cobalt sulfate (99% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 0.3 mg/m^3^ | 25 | 2/49 (8%)
NTP (1998) Rat (F344) Female (6 wk old) 2 yr | Cobalt sulfate (99% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 1.0 mg/m^3^ | 26 | 6/50 (20%)*
NTP (1998) Rat (F344) Female (6 wk old) 2 yr | Cobalt sulfate (99% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 3.0 mg/m^3^ | 30 | 6/50 (18%)*
NTP (1998) Rat (F344) Female (6 wk old) 2 yr | Cobalt sulfate (99% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | Trend-test p value: 0.023
NTP (1998) Rat (F344) Female (6 wk old) 2 yr | Cobalt sulfate (99% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | Alveolar/bronchiolar adenoma^b^
NTP (1998) Rat (F344) Female (6 wk old) 2 yr | Cobalt sulfate (99% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 0 mg/m^3^ | 28 | 0/50 (0%)
NTP (1998) Rat (F344) Female (6 wk old) 2 yr | Cobalt sulfate (99% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 0.3 mg/m^3^ | 25 | 1/49 (3%)
NTP (1998) Rat (F344) Female (6 wk old) 2 yr | Cobalt sulfate (99% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 1.0 mg/m^3^ | 26 | 10/50 (36%)***
NTP (1998) Rat (F344) Female (6 wk old) 2 yr | Cobalt sulfate (99% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 3.0 mg/m^3^ | 30 | 9/50 (30%)***
NTP (1998) Rat (F344) Female (6 wk old) 2 yr | Cobalt sulfate (99% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | Trend-test p value: 0.001
NTP (1998) Rat (F344) Female (6 wk old) 2 yr | Cobalt sulfate (99% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | Alveolar/bronchiolar adenoma or carcinoma combined^b^
NTP (1998) Rat (F344) Female (6 wk old) 2 yr | Cobalt sulfate (99% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 0 mg/m^3^ | 28 | 0/50 (0%)
NTP (1998) Rat (F344) Female (6 wk old) 2 yr | Cobalt sulfate (99% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 0.3 mg/m^3^ | 25 | 3/49 (11%)^c^
NTP (1998) Rat (F344) Female (6 wk old) 2 yr | Cobalt sulfate (99% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 1.0 mg/m^3^ | 26 | 15/50 (51%)***^c^
NTP (1998) Rat (F344) Female (6 wk old) 2 yr | Cobalt sulfate (99% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 3.0 mg/m^3^ | 30 | 15/50 (46%)***^c^
NTP (1998) Rat (F344) Female (6 wk old) 2 yr | Cobalt sulfate (99% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | Trend-test p value: 0.001
NTP (1998) Rat (F344) Female (6 wk old) 2 yr | Cobalt sulfate (99% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | Squamous cell carcinoma
NTP (1998) Rat (F344) Female (6 wk old) 2 yr | Cobalt sulfate (99% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 0 mg/m^3^ | 28 | 0/50 (0%)
NTP (1998) Rat (F344) Female (6 wk old) 2 yr | Cobalt sulfate (99% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 0.3 mg/m^3^ | 25 | 0/49 (0%)
NTP (1998) Rat (F344) Female (6 wk old) 2 yr | Cobalt sulfate (99% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 1.0 mg/m^3^ | 26 | 1/50 (2%)
NTP (1998) Rat (F344) Female (6 wk old) 2 yr | Cobalt sulfate (99% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 3.0 mg/m^3^ | 30 | 1/50 (2%)
NTP (1998) Rat (F344) Female (6 wk old) 2 yr | Cobalt sulfate (99% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | Alveolar/bronchiolar adenoma, carcinoma, or squamous cell carcinoma combined^b^
NTP (1998) Rat (F344) Female (6 wk old) 2 yr | Cobalt sulfate (99% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 0 mg/m^3^ | 28 | 0/50 (0%)
NTP (1998) Rat (F344) Female (6 wk old) 2 yr | Cobalt sulfate (99% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 0.3 mg/m^3^ | 25 | 3/49 (11%)
NTP (1998) Rat (F344) Female (6 wk old) 2 yr | Cobalt sulfate (99% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 1.0 mg/m^3^ | 26 | 16/50 (54%)***
NTP (1998) Rat (F344) Female (6 wk old) 2 yr | Cobalt sulfate (99% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 3.0 mg/m^3^ | 30 | 16/50 (49%)***
NTP (1998) Rat (F344) Female (6 wk old) 2 yr | Cobalt sulfate (99% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | Trend-test p value: 0.001
NTP (1998) Mice (B6C3F_1_) Male (6 wk old) 2 yr | Cobalt sulfate 99% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | Alveolar/bronchiolar carcinoma^b^ | | | Survival in exposed groups was similar to controls. Strengths: A well-designed study in all factors such as long observation period, sufficient dose levels, adequate number of animals. Limitations: None. No significant increase in non-neoplastic lesions.
NTP (1998) Mice (B6C3F_1_) Male (6 wk old) 2 yr | Cobalt sulfate 99% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 0 mg/m^3^ | 22 | 4/50 (13%)
NTP (1998) Mice (B6C3F_1_) Male (6 wk old) 2 yr | Cobalt sulfate 99% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 0.3 mg/m^3^ | 31 | 5/50 (16%)
NTP (1998) Mice (B6C3F_1_) Male (6 wk old) 2 yr | Cobalt sulfate 99% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 1.0 mg/m^3^ | 24 | 7/50 (25%)
NTP (1998) Mice (B6C3F_1_) Male (6 wk old) 2 yr | Cobalt sulfate 99% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 3.0 mg/m^3^ | 20 | 11/50 (44%)*^d^
NTP (1998) Mice (B6C3F_1_) Male (6 wk old) 2 yr | Cobalt sulfate 99% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | Trend-test p value: 0.006
NTP (1998) Mice (B6C3F_1_) Male (6 wk old) 2 yr | Cobalt sulfate 99% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | Alveolar/bronchiolar adenoma^b^
NTP (1998) Mice (B6C3F_1_) Male (6 wk old) 2 yr | Cobalt sulfate 99% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 0 mg/m^3^ | 22 | 9/50 (30%)
NTP (1998) Mice (B6C3F_1_) Male (6 wk old) 2 yr | Cobalt sulfate 99% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 0.3 mg/m^3^ | 31 | 12/50 (31%)
NTP (1998) Mice (B6C3F_1_) Male (6 wk old) 2 yr | Cobalt sulfate 99% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 1.0 mg/m^3^ | 24 | 13/50 (41%)
NTP (1998) Mice (B6C3F_1_) Male (6 wk old) 2 yr | Cobalt sulfate 99% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 3.0 mg/m^3^ | 20 | 18/50 (55%)*^e^
NTP (1998) Mice (B6C3F_1_) Male (6 wk old) 2 yr | Cobalt sulfate 99% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | Trend-test p value: 0.018
NTP (1998) Mice (B6C3F_1_) Male (6 wk old) 2 yr | Cobalt sulfate 99% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | Alveolar/bronchiolar carcinoma or adenoma combined^b^
NTP (1998) Mice (B6C3F_1_) Male (6 wk old) 2 yr | Cobalt sulfate 99% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 0 mg/m^3^ | 22 | 11/50 (36%)
NTP (1998) Mice (B6C3F_1_) Male (6 wk old) 2 yr | Cobalt sulfate 99% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 0.3 mg/m^3^ | 31 | 14/50 (37%)
NTP (1998) Mice (B6C3F_1_) Male (6 wk old) 2 yr | Cobalt sulfate 99% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 1.0 mg/m^3^ | 24 | 19/50 (57%)
NTP (1998) Mice (B6C3F_1_) Male (6 wk old) 2 yr | Cobalt sulfate 99% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 3.0 mg/m^3^ | 20 | 28/50 (79%)***^f^
NTP (1998) Mice (B6C3F_1_) Male (6 wk old) 2 yr | Cobalt sulfate 99% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | Trend-test p value: 0.001
NTP (1998) Mice (B6C3F_1_) Female (6 wk old) 2 yr | Cobalt sulfate 99% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | Alveolar/bronchiolar carcinoma^b^ | | | Survival in exposed groups was similar to controls. Strengths: A well-designed study in all factors and survival was similar to controls. Limitations: None. No significant increase in non-neoplastic lesions.
NTP (1998) Mice (B6C3F_1_) Female (6 wk old) 2 yr | Cobalt sulfate 99% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 0 mg/m^3^ | 34 | 1/50 (3%)
NTP (1998) Mice (B6C3F_1_) Female (6 wk old) 2 yr | Cobalt sulfate 99% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 0.3 mg/m^3^ | 37 | 1/50 (3%)
NTP (1998) Mice (B6C3F_1_) Female (6 wk old) 2 yr | Cobalt sulfate 99% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 1.0 mg/m^3^ | 32 | 4/50 (9%)
NTP (1998) Mice (B6C3F_1_) Female (6 wk old) 2 yr | Cobalt sulfate 99% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 3.0 mg/m^3^ | 28 | 9/50 (25%)**^g^
NTP (1998) Mice (B6C3F_1_) Female (6 wk old) 2 yr | Cobalt sulfate 99% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | Trend-test p value: 0.001
NTP (1998) Mice (B6C3F_1_) Female (6 wk old) 2 yr | Cobalt sulfate 99% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | Alveolar/bronchiolar adenoma^b^
NTP (1998) Mice (B6C3F_1_) Female (6 wk old) 2 yr | Cobalt sulfate 99% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 0 mg/m^3^ | 34 | 3/50 (9%)
NTP (1998) Mice (B6C3F_1_) Female (6 wk old) 2 yr | Cobalt sulfate 99% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 0.3 mg/m^3^ | 37 | 6/50 (15%)
NTP (1998) Mice (B6C3F_1_) Female (6 wk old) 2 yr | Cobalt sulfate 99% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 1.0 mg/m^3^ | 32 | 9/50 (25%)
NTP (1998) Mice (B6C3F_1_) Female (6 wk old) 2 yr | Cobalt sulfate 99% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 3.0 mg/m^3^ | 28 | 10/50 (33%)*^h^
NTP (1998) Mice (B6C3F_1_) Female (6 wk old) 2 yr | Cobalt sulfate 99% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | Trend-test p value: 0.024
NTP (1998) Mice (B6C3F_1_) Female (6 wk old) 2 yr | Cobalt sulfate 99% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | Alveolar/bronchiolar carcinoma or adenoma combined^b^
NTP (1998) Mice (B6C3F_1_) Female (6 wk old) 2 yr | Cobalt sulfate 99% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 0 mg/m^3^ | 34 | 4/50 (12%)
NTP (1998) Mice (B6C3F_1_) Female (6 wk old) 2 yr | Cobalt sulfate 99% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 0.3 mg/m^3^ | 37 | 7/50 (18%)
NTP (1998) Mice (B6C3F_1_) Female (6 wk old) 2 yr | Cobalt sulfate 99% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 1.0 mg/m^3^ | 32 | 13/50 (33%)*^i^
NTP (1998) Mice (B6C3F_1_) Female (6 wk old) 2 yr | Cobalt sulfate 99% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 3.0 mg/m^3^ | 28 | 18/50 (50%)***^i^
NTP (1998) Mice (B6C3F_1_) Female (6 wk old) 2 yr | Cobalt sulfate 99% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | Trend-test p value: 0.001
Steinhoff and Mohr (1991) Rat (Sprague-Dawley) Male (10 wk old) life span | Cobalt(II) oxide “Chemically pure.” 80% of particles were 5–40 μm) | Intratracheal instillation (dry particulate) 1 dose/2 wk × 18 doses, then 1 dose/4 weeks × 11 doses (up to 30th dose), then 1 dose/2 weeks × 9 doses (total 39 doses) | Bronchioalveolar carcinoma | | | Survival in exposed groups was similar as controls. Strengths: Two dose levels tested in a high number of both sexes of rats for two years, with observations for the lifespan without any significant difference in survival compared to untreated controls. Limitations: Only the high-dose group received full necropsies. Details of the chemical and animal husbandry were not reported. Significantly increased non-neoplastic lesions: Bronchioalveolar proliferation - both dose levels.
Steinhoff and Mohr (1991) Rat (Sprague-Dawley) Male (10 wk old) life span | Cobalt(II) oxide “Chemically pure.” 80% of particles were 5–40 μm) | Intratracheal instillation (dry particulate) 1 dose/2 wk × 18 doses, then 1 dose/4 weeks × 11 doses (up to 30th dose), then 1 dose/2 weeks × 9 doses (total 39 doses) | 0 mg/kg bw | NR | 0/50 (0%)
Steinhoff and Mohr (1991) Rat (Sprague-Dawley) Male (10 wk old) life span | Cobalt(II) oxide “Chemically pure.” 80% of particles were 5–40 μm) | Intratracheal instillation (dry particulate) 1 dose/2 wk × 18 doses, then 1 dose/4 weeks × 11 doses (up to 30th dose), then 1 dose/2 weeks × 9 doses (total 39 doses) | 2 mg/kg bw | NR | 0/50 (0%)
Steinhoff and Mohr (1991) Rat (Sprague-Dawley) Male (10 wk old) life span | Cobalt(II) oxide “Chemically pure.” 80% of particles were 5–40 μm) | Intratracheal instillation (dry particulate) 1 dose/2 wk × 18 doses, then 1 dose/4 weeks × 11 doses (up to 30th dose), then 1 dose/2 weeks × 9 doses (total 39 doses) | 10 mg/kg bw | NR | 3/50 (6%)j
Steinhoff and Mohr (1991) Rat (Sprague-Dawley) Male (10 wk old) life span | Cobalt(II) oxide “Chemically pure.” 80% of particles were 5–40 μm) | Intratracheal instillation (dry particulate) 1 dose/2 wk × 18 doses, then 1 dose/4 weeks × 11 doses (up to 30th dose), then 1 dose/2 weeks × 9 doses (total 39 doses) | Bronchioalveolar adenoma
Steinhoff and Mohr (1991) Rat (Sprague-Dawley) Male (10 wk old) life span | Cobalt(II) oxide “Chemically pure.” 80% of particles were 5–40 μm) | Intratracheal instillation (dry particulate) 1 dose/2 wk × 18 doses, then 1 dose/4 weeks × 11 doses (up to 30th dose), then 1 dose/2 weeks × 9 doses (total 39 doses) | 0 mg/kg bw | NR | 0/50 (0%)
Steinhoff and Mohr (1991) Rat (Sprague-Dawley) Male (10 wk old) life span | Cobalt(II) oxide “Chemically pure.” 80% of particles were 5–40 μm) | Intratracheal instillation (dry particulate) 1 dose/2 wk × 18 doses, then 1 dose/4 weeks × 11 doses (up to 30th dose), then 1 dose/2 weeks × 9 doses (total 39 doses) | 2 mg/kg bw | NR | 0/50 (0%)
Steinhoff and Mohr (1991) Rat (Sprague-Dawley) Male (10 wk old) life span | Cobalt(II) oxide “Chemically pure.” 80% of particles were 5–40 μm) | Intratracheal instillation (dry particulate) 1 dose/2 wk × 18 doses, then 1 dose/4 weeks × 11 doses (up to 30th dose), then 1 dose/2 weeks × 9 doses (total 39 doses) | 10 mg/kg bw | NR | 2/50 (4%)
Steinhoff and Mohr (1991) Rat (Sprague-Dawley) Male (10 wk old) life span | Cobalt(II) oxide “Chemically pure.” 80% of particles were 5–40 μm) | Intratracheal instillation (dry particulate) 1 dose/2 wk × 18 doses, then 1 dose/4 weeks × 11 doses (up to 30th dose), then 1 dose/2 weeks × 9 doses (total 39 doses) | Bronchioalveolar adenomas or bronchioalveolar carcinomas combined
Steinhoff and Mohr (1991) Rat (Sprague-Dawley) Male (10 wk old) life span | Cobalt(II) oxide “Chemically pure.” 80% of particles were 5–40 μm) | Intratracheal instillation (dry particulate) 1 dose/2 wk × 18 doses, then 1 dose/4 weeks × 11 doses (up to 30th dose), then 1 dose/2 weeks × 9 doses (total 39 doses) | 0 mg/kg bw | NR | 0/50 (0%)
Steinhoff and Mohr (1991) Rat (Sprague-Dawley) Male (10 wk old) life span | Cobalt(II) oxide “Chemically pure.” 80% of particles were 5–40 μm) | Intratracheal instillation (dry particulate) 1 dose/2 wk × 18 doses, then 1 dose/4 weeks × 11 doses (up to 30th dose), then 1 dose/2 weeks × 9 doses (total 39 doses) | 2 mg/kg bw | NR | 0/50 (0%)
Steinhoff and Mohr (1991) Rat (Sprague-Dawley) Male (10 wk old) life span | Cobalt(II) oxide “Chemically pure.” 80% of particles were 5–40 μm) | Intratracheal instillation (dry particulate) 1 dose/2 wk × 18 doses, then 1 dose/4 weeks × 11 doses (up to 30th dose), then 1 dose/2 weeks × 9 doses (total 39 doses) | 10 mg/kg bw | NR | 5/50 (10%)*
Steinhoff and Mohr (1991) Rat (Sprague-Dawley) Male (10 wk old) life span | Cobalt(II) oxide “Chemically pure.” 80% of particles were 5–40 μm) | Intratracheal instillation (dry particulate) 1 dose/2 wk × 18 doses, then 1 dose/4 weeks × 11 doses (up to 30th dose), then 1 dose/2 weeks × 9 doses (total 39 doses) | Benign squamous epithelial tumor
Steinhoff and Mohr (1991) Rat (Sprague-Dawley) Male (10 wk old) life span | Cobalt(II) oxide “Chemically pure.” 80% of particles were 5–40 μm) | Intratracheal instillation (dry particulate) 1 dose/2 wk × 18 doses, then 1 dose/4 weeks × 11 doses (up to 30th dose), then 1 dose/2 weeks × 9 doses (total 39 doses) | 0 mg/kg bw | NR | 0/50 (0%)
Steinhoff and Mohr (1991) Rat (Sprague-Dawley) Male (10 wk old) life span | Cobalt(II) oxide “Chemically pure.” 80% of particles were 5–40 μm) | Intratracheal instillation (dry particulate) 1 dose/2 wk × 18 doses, then 1 dose/4 weeks × 11 doses (up to 30th dose), then 1 dose/2 weeks × 9 doses (total 39 doses) | 2 mg/kg bw | NR | 1/50 (2%)
Steinhoff and Mohr (1991) Rat (Sprague-Dawley) Male (10 wk old) life span | Cobalt(II) oxide “Chemically pure.” 80% of particles were 5–40 μm) | Intratracheal instillation (dry particulate) 1 dose/2 wk × 18 doses, then 1 dose/4 weeks × 11 doses (up to 30th dose), then 1 dose/2 weeks × 9 doses (total 39 doses) | 10 mg/kg bw | NR | 0/50 (0%)
Steinhoff and Mohr (1991) Rat (Sprague-Dawley) Female (10 wk old) life span | Cobalt(II) oxide “Chemically pure” 80% of particles were 5–40 μm) | Intratracheal instillation (dry particulate) 1 dose/2 wk × 18 doses, then 1 dose/4 weeks × 11 doses (up to 30th dose), then 1 dose/2 weeks × 9 doses (total 39 doses) | Bronchioalveolar carcinoma | | | Survival in exposed groups was similar to controls. Strengths: Two dose levels tested in a high number of both sexes of rats for two years, with observations for the lifespan without any significant difference in survival compared to untreated controls. Limitations: Only the high-dose group received full necropsies. Details of the chemical and animal husbandry were not reported. Significantly increased non-neoplastic lesions: Bronchioalveolar proliferation - both dose levels.
Steinhoff and Mohr (1991) Rat (Sprague-Dawley) Female (10 wk old) life span | Cobalt(II) oxide “Chemically pure” 80% of particles were 5–40 μm) | Intratracheal instillation (dry particulate) 1 dose/2 wk × 18 doses, then 1 dose/4 weeks × 11 doses (up to 30th dose), then 1 dose/2 weeks × 9 doses (total 39 doses) | 0 mg/kg bw | NR | 0/50 (0%)
Steinhoff and Mohr (1991) Rat (Sprague-Dawley) Female (10 wk old) life span | Cobalt(II) oxide “Chemically pure” 80% of particles were 5–40 μm) | Intratracheal instillation (dry particulate) 1 dose/2 wk × 18 doses, then 1 dose/4 weeks × 11 doses (up to 30th dose), then 1 dose/2 weeks × 9 doses (total 39 doses) | 2 mg/kg bw | NR | 0/50 (0%)
Steinhoff and Mohr (1991) Rat (Sprague-Dawley) Female (10 wk old) life span | Cobalt(II) oxide “Chemically pure” 80% of particles were 5–40 μm) | Intratracheal instillation (dry particulate) 1 dose/2 wk × 18 doses, then 1 dose/4 weeks × 11 doses (up to 30th dose), then 1 dose/2 weeks × 9 doses (total 39 doses) | 10 mg/kg bw | NR | 1/50 (2%)
Steinhoff and Mohr (1991) Rat (Sprague-Dawley) Female (10 wk old) life span | Cobalt(II) oxide “Chemically pure” 80% of particles were 5–40 μm) | Intratracheal instillation (dry particulate) 1 dose/2 wk × 18 doses, then 1 dose/4 weeks × 11 doses (up to 30th dose), then 1 dose/2 weeks × 9 doses (total 39 doses) | Bronchioalveolar adenoma
Steinhoff and Mohr (1991) Rat (Sprague-Dawley) Female (10 wk old) life span | Cobalt(II) oxide “Chemically pure” 80% of particles were 5–40 μm) | Intratracheal instillation (dry particulate) 1 dose/2 wk × 18 doses, then 1 dose/4 weeks × 11 doses (up to 30th dose), then 1 dose/2 weeks × 9 doses (total 39 doses) | 0 mg/kg bw | NR | 0/50 (0%)
Steinhoff and Mohr (1991) Rat (Sprague-Dawley) Female (10 wk old) life span | Cobalt(II) oxide “Chemically pure” 80% of particles were 5–40 μm) | Intratracheal instillation (dry particulate) 1 dose/2 wk × 18 doses, then 1 dose/4 weeks × 11 doses (up to 30th dose), then 1 dose/2 weeks × 9 doses (total 39 doses) | 2 mg/kg bw | NR | 1/50 (2%)
Steinhoff and Mohr (1991) Rat (Sprague-Dawley) Female (10 wk old) life span | Cobalt(II) oxide “Chemically pure” 80% of particles were 5–40 μm) | Intratracheal instillation (dry particulate) 1 dose/2 wk × 18 doses, then 1 dose/4 weeks × 11 doses (up to 30th dose), then 1 dose/2 weeks × 9 doses (total 39 doses) | 10 mg/kg bw | NR | 0/50 (0%)
Steinhoff and Mohr (1991) Rat (Sprague-Dawley) Female (10 wk old) life span | Cobalt(II) oxide “Chemically pure” 80% of particles were 5–40 μm) | Intratracheal instillation (dry particulate) 1 dose/2 wk × 18 doses, then 1 dose/4 weeks × 11 doses (up to 30th dose), then 1 dose/2 weeks × 9 doses (total 39 doses) | Bronchioalveolar adenoma or bronchioalveolar carcinoma combined
Steinhoff and Mohr (1991) Rat (Sprague-Dawley) Female (10 wk old) life span | Cobalt(II) oxide “Chemically pure” 80% of particles were 5–40 μm) | Intratracheal instillation (dry particulate) 1 dose/2 wk × 18 doses, then 1 dose/4 weeks × 11 doses (up to 30th dose), then 1 dose/2 weeks × 9 doses (total 39 doses) | 0 mg/kg bw | NR | 0/50 (0%)
Steinhoff and Mohr (1991) Rat (Sprague-Dawley) Female (10 wk old) life span | Cobalt(II) oxide “Chemically pure” 80% of particles were 5–40 μm) | Intratracheal instillation (dry particulate) 1 dose/2 wk × 18 doses, then 1 dose/4 weeks × 11 doses (up to 30th dose), then 1 dose/2 weeks × 9 doses (total 39 doses) | 2 mg/kg bw | NR | 1/50 (2%)
Steinhoff and Mohr (1991) Rat (Sprague-Dawley) Female (10 wk old) life span | Cobalt(II) oxide “Chemically pure” 80% of particles were 5–40 μm) | Intratracheal instillation (dry particulate) 1 dose/2 wk × 18 doses, then 1 dose/4 weeks × 11 doses (up to 30th dose), then 1 dose/2 weeks × 9 doses (total 39 doses) | 10 mg/kg bw | NR | 1/50 (2%)

* = p value ≤ 0.05; ** = p value ≤ 0.01; *** = p value ≤ 0.001. NR = Not reported, wk = week, yr = year.

^+^ = Number of animals necropsied for NTP (2014d) and NTP (1998) (each group started with 50 animals per sex in the NTP studies) and is the number of animals at the beginning of the study for all other studies.

^a^ Adjusted percent incidence based on Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^b^ Adjusted percent incidence based on Kaplan-Meier estimated incidence at the end of the study after adjustment for intercurrent mortality.

^c^ Increased over historical control levels with a mean of 7/650 and range of 0% to 4%.

^d^ Increased over historical control levels with a mean of 75/947 and range of 0% to 16%.

^e^ Increased over historical control levels with a mean of 141/947 and range of 6% to 36%.

^f^ Increased over historical control levels with a mean of 205/947 and range of 10% to 42%.

^g^ Increased over historical control levels with a mean of 38/939 and range of 0% to 12%.

^h^ Increased over historical control levels with a mean of 61/939 and range of 0% to 14%.

^i^ Increased over historical control levels with a mean of 97/939 and range of 0% to 16%.

^j^ Includes adenocarcinoma (2) and bronchioalveolar adenocarcinoma (1).

Table 5-4 Injection Site Neoplasms and Non-neoplastic Lesions in Experimental Animals Exposed to Cobalt Compounds

Reference & Year, Animal, Study Duration | Substance & Purity | Dosing Regimen | Dose Levels | # Animals at Sacrifice | Tumor Incidence (n/N^+^) (%) | Comments
Hansen et al. (2006) Rat (Sprague-Dawley) Male (NR) 12 mo | Cobalt metal [bulk and nano]- Bulk metal particles: 6.5 mm diameter by 1 mm in height; surface area to mass ratio of 4.73; nanoparticles: 50–200 nm in size (average 120 nm); surface area to mass ratio of 50,000; PVC (bulk and nano)- bulk PVC, without additives: 10 mm in diameter by 1 mm in height; surface area to mass ratio of 4.2; PVC nanoparticles: 60–170 nm in size (average 130 nm); surface area to mass ratio of 50,000.) | Nano (dry particles): IM implant (left side of vertebra) Single dose Bulk (solid metal): SC implant (right side of vertebra) Single dose | Fibroblastic proliferation 6 months | | | 4 animals (PVC control and treated) sacrificed at 6 months and the remaining 6 animals sacrificed at either 8 (treated) or 12 months (PVC controls). Treated animals sacrificed at 8 months due to mortality. Strengths: Tested multiple materials in addition to cobalt and thus able to provide information on whether effects were due to physical state. Limitations: Inert polyvinyl chloride particles were used as a negative control. Only a small number of males were tested at a single dose level. Short duration and unable to fully evaluate effects from cobalt bulk particles.
Hansen et al. (2006) Rat (Sprague-Dawley) Male (NR) 12 mo | | Nano (dry particles): IM implant (left side of vertebra) Single dose Bulk (solid metal): SC implant (right side of vertebra) Single dose | 0 cm^2^ | 4 | 0
Hansen et al. (2006) Rat (Sprague-Dawley) Male (NR) 12 mo | | Nano (dry particles): IM implant (left side of vertebra) Single dose Bulk (solid metal): SC implant (right side of vertebra) Single dose | Nano 2 cm^2^ | 4 | 2
Hansen et al. (2006) Rat (Sprague-Dawley) Male (NR) 12 mo | | Nano (dry particles): IM implant (left side of vertebra) Single dose Bulk (solid metal): SC implant (right side of vertebra) Single dose | Bulk 2 cm^2^ | 4 | 0
Hansen et al. (2006) Rat (Sprague-Dawley) Male (NR) 12 mo | | Nano (dry particles): IM implant (left side of vertebra) Single dose Bulk (solid metal): SC implant (right side of vertebra) Single dose | Sarcoma 6 months
Hansen et al. (2006) Rat (Sprague-Dawley) Male (NR) 12 mo | | Nano (dry particles): IM implant (left side of vertebra) Single dose Bulk (solid metal): SC implant (right side of vertebra) Single dose | 0 cm^2^ | 4 | 0
Hansen et al. (2006) Rat (Sprague-Dawley) Male (NR) 12 mo | | Nano (dry particles): IM implant (left side of vertebra) Single dose Bulk (solid metal): SC implant (right side of vertebra) Single dose | Nano 2 cm^2^ | 4 | 1
Hansen et al. (2006) Rat (Sprague-Dawley) Male (NR) 12 mo | | Nano (dry particles): IM implant (left side of vertebra) Single dose Bulk (solid metal): SC implant (right side of vertebra) Single dose | Bulk 2 cm^2^ | 4 | 0
Hansen et al. (2006) Rat (Sprague-Dawley) Male (NR) 12 mo | | Nano (dry particles): IM implant (left side of vertebra) Single dose Bulk (solid metal): SC implant (right side of vertebra) Single dose | Fibroblastic proliferation 8 months
Hansen et al. (2006) Rat (Sprague-Dawley) Male (NR) 12 mo | | Nano (dry particles): IM implant (left side of vertebra) Single dose Bulk (solid metal): SC implant (right side of vertebra) Single dose | 0 cm^2^ (12 mo) | 6 | 0/6 (0%)
Hansen et al. (2006) Rat (Sprague-Dawley) Male (NR) 12 mo | | Nano (dry particles): IM implant (left side of vertebra) Single dose Bulk (solid metal): SC implant (right side of vertebra) Single dose | Nano 2 cm^2^ | 6 | 1/6 (16.7%)
Hansen et al. (2006) Rat (Sprague-Dawley) Male (NR) 12 mo | | Nano (dry particles): IM implant (left side of vertebra) Single dose Bulk (solid metal): SC implant (right side of vertebra) Single dose | Bulk 2 cm^2^ | 6 | 1/6 (16.7%)
Hansen et al. (2006) Rat (Sprague-Dawley) Male (NR) 12 mo | | Nano (dry particles): IM implant (left side of vertebra) Single dose Bulk (solid metal): SC implant (right side of vertebra) Single dose | Sarcoma 8 months
Hansen et al. (2006) Rat (Sprague-Dawley) Male (NR) 12 mo | | Nano (dry particles): IM implant (left side of vertebra) Single dose Bulk (solid metal): SC implant (right side of vertebra) Single dose | 0 cm^2^ (12 mo) | 6 | 0/6 (0%)
Hansen et al. (2006) Rat (Sprague-Dawley) Male (NR) 12 mo | | Nano (dry particles): IM implant (left side of vertebra) Single dose Bulk (solid metal): SC implant (right side of vertebra) Single dose | Nano 2 cm^2^ | 6 | 5/6 (83.3%)[**]
Hansen et al. (2006) Rat (Sprague-Dawley) Male (NR) 12 mo | | Nano (dry particles): IM implant (left side of vertebra) Single dose Bulk (solid metal): SC implant (right side of vertebra) Single dose | Bulk 2 cm^2^ | 6 | 0/6 (0%)
Heath (1956) Rat (Hooded) Male (2–3 mo old) life span | Cobalt metal “Spectroscopically pure” Particle size: 3.5 × 3.5 μm to 17 × 12 μm) | IM inj. (in fowl serum) Single dose | Rhabdomyofibrosarcoma or sarcoma combined | | | Survival: No data was given on the survival of untreated controls. 2/10 treated males without tumors died before final sacrificed. Strengths: Observation duration was sufficient and both sexes were tested. Limitations: Incomplete reporting of many elements. Limited sensitivity due to only one dose level and few rats tested. Full necropsies were not reported.
Heath (1956) Rat (Hooded) Male (2–3 mo old) life span | Cobalt metal “Spectroscopically pure” Particle size: 3.5 × 3.5 μm to 17 × 12 μm) | IM inj. (in fowl serum) Single dose | 0 mg/rat | NR | 0/10 (0%)
Heath (1956) Rat (Hooded) Male (2–3 mo old) life span | Cobalt metal “Spectroscopically pure” Particle size: 3.5 × 3.5 μm to 17 × 12 μm) | IM inj. (in fowl serum) Single dose | 28 mg/rat | 8 | 4/10 (40%)
Heath (1956) Rat (Hooded) Female (2–3 mo old) life span | Cobalt metal “Spectroscopically pure” Particle size: 3.5 × 3.5 μm to 17 × 12 μm) | Series I and Series II i.m. inj. (in fowl serum) Single dose | Sarcoma (Rhabdomyofibrosarcoma or fibrosarcoma) | | | Survival: No data were reported on the survival of untreated controls. For treated animals, 4/10 rats (Series I) and 0/10 (Series II) without tumors died before final sacrificed. Strengths: Observation duration was sufficient and both sexes were tested. Limitations: Incomplete reporting of many elements. Limited sensitivity due to only one dose level and few rats tested. Full necropsies were not reported. Other comments: Series I used a concurrent control, but Series II used the same controls, which was non-concurrent. 6/7 sarcoma in Series I and 2/5 in Series II were rhabdomyo-fibrosarcoma
Heath (1956) Rat (Hooded) Female (2–3 mo old) life span | Cobalt metal “Spectroscopically pure” Particle size: 3.5 × 3.5 μm to 17 × 12 μm) | Series I and Series II i.m. inj. (in fowl serum) Single dose | 0 mg/rat | NR | 0/10 (0%)
Heath (1956) Rat (Hooded) Female (2–3 mo old) life span | Cobalt metal “Spectroscopically pure” Particle size: 3.5 × 3.5 μm to 17 × 12 μm) | Series I and Series II i.m. inj. (in fowl serum) Single dose | 28 mg/rat Series I | 6 | 5/10 (50%)
Heath (1956) Rat (Hooded) Female (2–3 mo old) life span | Cobalt metal “Spectroscopically pure” Particle size: 3.5 × 3.5 μm to 17 × 12 μm) | Series I and Series II i.m. inj. (in fowl serum) Single dose | 28 mg/rat Series II | 10 | 7/10 (70%)
Heath and Daniel (1962) Rat (Hooded) Female (2–3 mo old) 28 months | Cobalt metal Purity not reported, Particle size: 3.5 × 3.5 μm to 17 × 12 μm) | Intrathoracic inj. (in serum) Single injection | Mixed sarcoma intrathoracic region | | | Survival was only reported for exposed rats, which was 12/20 on day 3 and 11/20 after 11 months. Strengths: Observation duration was sufficient Limitations: Historical controls from Heath 1956 used because there was no concurrent control. Few animals were used, and full necropsies were not done, only skin tumors were histologically examined. Incomplete reporting of many elements. Other comments: 3 of 4 tumors originated in part from cardiac muscle, which are very rare.
Heath and Daniel (1962) Rat (Hooded) Female (2–3 mo old) 28 months | Cobalt metal Purity not reported, Particle size: 3.5 × 3.5 μm to 17 × 12 μm) | Intrathoracic inj. (in serum) Single injection | 0 mg/dose^a^ | NR | 0/10 (0%)
Heath and Daniel (1962) Rat (Hooded) Female (2–3 mo old) 28 months | Cobalt metal Purity not reported, Particle size: 3.5 × 3.5 μm to 17 × 12 μm) | Intrathoracic inj. (in serum) Single injection | 28 mg/dose | 11 | 4/12 (33%)
Jasmin and Riopelle (1976) Rat (Sprague-Dawley) Female (120–140 g) 12 months | Cobalt metal NR | Intrarenal placement (in glycerin) Single dose | Kidney neoplasm NOS | | | Survival was not reported. Strengths: Moderate number of animals. Limitations: Only a single dose level, which was lower than other studies, was tested in only females. Incomplete reporting for many elements. Full necropsies were not performed, though the abdominal and thoracic cavities were examined.
Jasmin and Riopelle (1976) Rat (Sprague-Dawley) Female (120–140 g) 12 months | Cobalt metal NR | Intrarenal placement (in glycerin) Single dose | 0 mg/rat | NR | 0/16 (0%)
Jasmin and Riopelle (1976) Rat (Sprague-Dawley) Female (120–140 g) 12 months | Cobalt metal NR | Intrarenal placement (in glycerin) Single dose | 10 mg/rat | NR | 0/18 (0%)
Shabaan et al. (1977) Rat (Wistar) Male (4 wk old) 8 and 12 mo | Cobalt chloride NR | SC inj. (in saline) 1 dose/day × 5 days, then 9 days off, then 1 dose/day × 5 days (total 19 days) | Injection site and non-injection fibrosarcoma | | | Treatment-related decrease in survival; 16/20 survived at 8 months and 11/20 survived at 12 months. Limitations: Exposure resulted in persisent hyperlipaemia and high mortality. Animals dying before the end of observation period were not exmained for tumors. The tumors at injection sites and non-injection sites weren’t clearly reported Other comments: No concurrent untreated controls used at 8 months, 12-month controls used as comparison group. Statistical testing (Fisher’s Exact Test) reported by IARC.
Shabaan et al. (1977) Rat (Wistar) Male (4 wk old) 8 and 12 mo | Cobalt chloride NR | SC inj. (in saline) 1 dose/day × 5 days, then 9 days off, then 1 dose/day × 5 days (total 19 days) | 0 mg/kg bw 12 mo | 19 | 0/19 (0%)
Shabaan et al. (1977) Rat (Wistar) Male (4 wk old) 8 and 12 mo | Cobalt chloride NR | SC inj. (in saline) 1 dose/day × 5 days, then 9 days off, then 1 dose/day × 5 days (total 19 days) | 40 mg/kg bw 8 mo | 16 | 6/16 (30%)[**]
Shabaan et al. (1977) Rat (Wistar) Male (4 wk old) 8 and 12 mo | Cobalt chloride NR | SC inj. (in saline) 1 dose/day × 5 days, then 9 days off, then 1 dose/day × 5 days (total 19 days) | 40 mg/kg bw 12 mo | 11 | 8/11 (40%)[***]
Steinhoff and Mohr (1991) Rat (Sprague-Dawley) Male and Female (10 wk old) life span | Cobalt(II) oxide “Chemically pure,” 80% of particles were 5–40 μm) | i.p. inj. (in saline) 1 dose/2 mo × 6 mo | Sarcoma | | | Survival was not reported. Strengths: Both sexes of rats were tested with a long duration of observation. Limitations: Incomplete reporting. Limited sensitivity because of few animals per group, only one dose level was tested, and exposure was for less than one year. Limited histological examination Other comments: Results were reported as combined for males and females.
Steinhoff and Mohr (1991) Rat (Sprague-Dawley) Male and Female (10 wk old) life span | Cobalt(II) oxide “Chemically pure,” 80% of particles were 5–40 μm) | i.p. inj. (in saline) 1 dose/2 mo × 6 mo | 0 mg/kg | NR | 1/20 (5%)
Steinhoff and Mohr (1991) Rat (Sprague-Dawley) Male and Female (10 wk old) life span | Cobalt(II) oxide “Chemically pure,” 80% of particles were 5–40 μm) | i.p. inj. (in saline) 1 dose/2 mo × 6 mo | 200 mg/kg | NR | 3/20 (15%)[*]
Steinhoff and Mohr (1991) Rat (Sprague-Dawley) Male and Female (10 wk old) life span | Cobalt(II) oxide “Chemically pure,” 80% of particles were 5–40 μm) | i.p. inj. (in saline) 1 dose/2 mo × 6 mo | Mesothelioma
Steinhoff and Mohr (1991) Rat (Sprague-Dawley) Male and Female (10 wk old) life span | Cobalt(II) oxide “Chemically pure,” 80% of particles were 5–40 μm) | i.p. inj. (in saline) 1 dose/2 mo × 6 mo | 0 mg/kg | NR | 0/20 (0%)
Steinhoff and Mohr (1991) Rat (Sprague-Dawley) Male and Female (10 wk old) life span | Cobalt(II) oxide “Chemically pure,” 80% of particles were 5–40 μm) | i.p. inj. (in saline) 1 dose/2 mo × 6 mo | 200 mg/kg | NR | 1/20 (5%)
Steinhoff and Mohr (1991) Rat (Sprague-Dawley) Male and Female (10 wk old) life span | Cobalt(II) oxide “Chemically pure,” 80% of particles were 5–40 μm) | i.p. inj. (in saline) 1 dose/2 mo × 6 mo | Histiocytoma
Steinhoff and Mohr (1991) Rat (Sprague-Dawley) Male and Female (10 wk old) life span | Cobalt(II) oxide “Chemically pure,” 80% of particles were 5–40 μm) | i.p. inj. (in saline) 1 dose/2 mo × 6 mo | 0 mg/kg | NR | 1/20 (5%)
Steinhoff and Mohr (1991) Rat (Sprague-Dawley) Male and Female (10 wk old) life span | Cobalt(II) oxide “Chemically pure,” 80% of particles were 5–40 μm) | i.p. inj. (in saline) 1 dose/2 mo × 6 mo | 200 mg/kg | NR | 10/20 (50%)[**]
Steinhoff and Mohr (1991) Rat (Sprague-Dawley) Male (10 wk old) life span | Cobalt oxide (“Chemically pure,” 80% of particles were 5–40 μm) | s.c. inj. (in saline) 1 inj/day, 5 day/week × 730 days | Histiocytoma or sarcoma combined | | | Survival was not reported. Strengths: Duration of exposure and observation were sufficient. One dose level was tested, at two intensity levels and two untreated control groups used. Limitations: Limited sensitivity due to few animals per group and only males tested. Limited histological examination. Incomplete reporting of many elements.
Steinhoff and Mohr (1991) Rat (Sprague-Dawley) Male (10 wk old) life span | Cobalt oxide (“Chemically pure,” 80% of particles were 5–40 μm) | s.c. inj. (in saline) 1 inj/day, 5 day/week × 730 days | 0 mg/kg/wk | NR | 0/10 (0%)
Steinhoff and Mohr (1991) Rat (Sprague-Dawley) Male (10 wk old) life span | Cobalt oxide (“Chemically pure,” 80% of particles were 5–40 μm) | s.c. inj. (in saline) 1 inj/day, 5 day/week × 730 days | 0 mg/kg/wk | NR | 0/10 (0%)
Steinhoff and Mohr (1991) Rat (Sprague-Dawley) Male (10 wk old) life span | Cobalt oxide (“Chemically pure,” 80% of particles were 5–40 μm) | s.c. inj. (in saline) 1 inj/day, 5 day/week × 730 days | 2 mg/kg × 5/wk | NR | 5/10 (50%)[*]
Steinhoff and Mohr (1991) Rat (Sprague-Dawley) Male (10 wk old) life span | Cobalt oxide (“Chemically pure,” 80% of particles were 5–40 μm) | s.c. inj. (in saline) 1 inj/day, 5 day/week × 730 days | 10 mg/kg/wk | NR | 4/10 (40%)[*]
Gilman and Ruckerbauer (1962) Rat (Wistar) Male and female (2–3 mo old) 489 days | Cobalt oxide purity not reported, particle size was <5 μm | i.m. inj. (in aqueous suspension of penicillin G procaine) Single dose | Sarcoma | | | Survival was similar to control at 90 days. Strengths: The duration of observation was sufficient and both sexes were tested. Limitations: Limited sensitivity because only a single dose was given at one dose level and few animals per group were tested. Incomplete reporting for many elements. Animal bedding was periodically dusted with rotenone powder. Other comments: Results were reported as combined for males and females.
Gilman and Ruckerbauer (1962) Rat (Wistar) Male and female (2–3 mo old) 489 days | Cobalt oxide purity not reported, particle size was <5 μm | i.m. inj. (in aqueous suspension of penicillin G procaine) Single dose | 0 mg/rat | 10 | 0/10 (0%)
Gilman and Ruckerbauer (1962) Rat (Wistar) Male and female (2–3 mo old) 489 days | Cobalt oxide purity not reported, particle size was <5 μm | i.m. inj. (in aqueous suspension of penicillin G procaine) Single dose | 30 mg/rat | 10 | 5/10 (50%)[*]
Gilman and Ruckerbauer (1962) Mouse (Swiss) Female (2–3 mo old) 751 days | Cobalt oxide purity not reported, particle size was <5 μm | i.m. inj. (in aqueous suspension of penicillin G procaine) Single dose | Sarcoma | | | Survival was similar to control at 90 days. Strengths: The duration of observation and the numbers of animals per group were sufficient. Limitations: Limited sensitivity due to only a single dose was given at one dose level, without a rationale, to females only. Half of the mice were survivors from a preliminary study who received unwashed cobalt, which was known to contain other toxic chemicals. Bedding was periodically dusted with rotenone powder. Incomplete reporting for many elements.
Gilman and Ruckerbauer (1962) Mouse (Swiss) Female (2–3 mo old) 751 days | Cobalt oxide purity not reported, particle size was <5 μm | i.m. inj. (in aqueous suspension of penicillin G procaine) Single dose | 0 mg/mouse | 48 | 0/51 (0%)
Gilman and Ruckerbauer (1962) Mouse (Swiss) Female (2–3 mo old) 751 days | Cobalt oxide purity not reported, particle size was <5 μm | i.m. inj. (in aqueous suspension of penicillin G procaine) Single dose | 20 mg/mouse | 46 | 0/50 (0%)
Jasmin and Riopelle (1976) Rat (Sprague-Dawley) Female (120–140 g) 12 months | Cobalt sulfide NR | Intrarenal placement (in glycerin) Single dose | Kidney neoplasm NOS | | | Survival was not reported. Strengths: Moderate number of rats per groups. Limitations: Limited sensitivity due to only a single dose level, which was lower than other studies and only females tested. Incomplete reporting. Full necropsies were not performed, though the abdominal and thoracic cavities were examined.
Jasmin and Riopelle (1976) Rat (Sprague-Dawley) Female (120–140 g) 12 months | Cobalt sulfide NR | Intrarenal placement (in glycerin) Single dose | 0 mg/rat | NR | 0/16 (0%)
Jasmin and Riopelle (1976) Rat (Sprague-Dawley) Female (120–140 g) 12 months | Cobalt sulfide NR | Intrarenal placement (in glycerin) Single dose | 10 mg/rat | NR | 0/20 (0%)

* = p value ≤ 0.05; ** = p value ≤ 0.01; *** = p value ≤ 0.001.

NR = Not reported, inj. = injection, i.p. = intraperitoneal, i.m. = intramuscular, s.c. = subcutaneous, wk = week, mo = month.

^+^ = Number of animals at the beginning of the study, except for Hansen et al. (2006) and Heath and Daniel (1962), which used the number of animals that were examined at the time of sacrifice, 10 animals were originally assigned to each group (Hansen et al. 2006) or the number of animals that survived beyond day 4, 10 control and 20 exposed animals were originally assigned (Heath and Daniel 1962).

[ ] = Statistical significance calculated by NTP using Fisher’s Exact Test.

^a^ Historical control group from earlier study by the same author.

Table 5-5 Other and Distal Site Neoplasms and Relevant Non-neoplastic Lesions in Experimental Animals Exposed to Cobalt Compounds

Reference & Year, Animal, Study Duration | Substance & Purity | Dosing Regimen | Dose Levels | # Animals at Sacrifice | Tumor Incidence (n/N^+^) (%) | Comments
Adrenal gland
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Bilateral malignant pheochromocytoma | | | Survival was similar to controls. Strengths: A well-designed study in all factors such as long observation period, sufficient dose levels, adequate number of animals. Limitations: Decreases in body weight in mid and high dose rats. Other comments: Historical controls were limited (100 rats). No significantly increased non-neoplastic lesions.
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 0 mg/m^3^ | 17 | 0/50 (0%)
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 1.25 mg/m^3^ | 20 | 0/50 (0%)
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 2.5 mg/m^3^ | 16 | 0/50 (0%)
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 5 mg/m^3^ | 16 | 7/50 (14%)**
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Malignant pheochromocytoma^a^
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 0 mg/m^3^ | 17 | 2/50 (5%)
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 1.25 mg/m^3^ | 20 | 2/50 (5%)
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 2.5 mg/m^3^ | 16 | 9/50 (21%)*
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 5 mg/m^3^ | 16 | 16/50 (39%)***
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Trend-test p value: 0.001
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Benign pheochromocytoma^a^
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 0 mg/m^3^ | 17 | 15/50 (36%)
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 1.25 mg/m^3^ | 20 | 23/50 (54%)
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 2.5 mg/m^3^ | 16 | 37/50 (81%)***
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 5 mg/m^3^ | 16 | 34/50 (76%)***
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Trend-test p value: 0.001
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Malignant or benign combined pheochromocytoma^a^
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 0 mg/m^3^ | 17 | 17/50 (40%)
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 1.25 mg/m^3^ | 20 | 23/50 (54%)
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 2.5 mg/m^3^ | 16 | 38/50 (83%)***
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 5 mg/m^3^ | 16 | 41/50 (91%)***
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal 98% pure mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Trend-test p value: 0.001
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Bilateral malignant pheochromocytoma | | | Survival was significantly decreased in the mid-dose group. Strengths: A well-designed study in almost all factors such as long observation period, sufficient dose levels, adequate number of animals. Limitations: A significant decrease in survival of female rats. Decreases in body weight in mid- and high-dose rats. Other comments: Historical controls were limited, as Fischer 344/NTac rats (100 rats). Significantly increased non-neoplastic lesions: Hyperplasia - low and medium
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 0 mg/m^3^ | 35 | 0/50 (0%)
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 1.25 mg/m^3^ | 26 | 1/50 (2%)
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 2.5 mg/m^3^ | 24 | 1/49 (2%)
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 5 mg/m^3^ | 25 | 4/50 (8%)*
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Malignant pheochromocytoma^a^
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 0 mg/m^3^ | 35 | 0/50 (0%)
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 1.25 mg/m^3^ | 26 | 2/50 (5%)
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 2.5 mg/m^3^ | 24 | 3/49 (8%)
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 5 mg/m^3^ | 25 | 11/50 (27%)***
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Trend-test p value: 0.001
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Bilateral benign pheochromocytoma
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 0 mg/m^3^ | 35 | 2/50 (4%)
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 1.25 mg/m^3^ | 26 | 4/50 (8%)
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 2.5 mg/m^3^ | 24 | 8/49 (16%)*
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 5 mg/m^3^ | 25 | 19/50 (38%)**
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Benign pheochromocytoma^a^
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 0 mg/m^3^ | 35 | 6/50 (14%)
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 1.25 mg/m^3^ | 26 | 12/50 (27%)
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 2.5 mg/m^3^ | 24 | 22/49 (52%)***
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 5 mg/m^3^ | 25 | 36/50 (81%)***
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Trend-test p value: 0.001
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Malignant or benign combined pheochromocytoma^a^
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 0 mg/m^3^ | 35 | 6/50 (14%)
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 1.25 mg/m^3^ | 26 | 13/50 (29%)
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 2.5 mg/m^3^ | 24 | 23/49 (55%)***
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 5 mg/m^3^ | 25 | 40/50 (89%)***
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal 98% pure, mass median aerodynamic diameter 1–3 μm | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Trend-test p value: 0.001
NTP (1998) Rat (F344) Male (6 wk old) 2 yr | Cobalt sulfate 99% pure) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | Benign pheochromocytoma^b^ | | | Survival was similar to controls. Strengths: A well-designed study in all factors and survival was similar to controls such as long observation period, sufficient dose levels, adequate number of animals. Limitations: None. No significantly increased non-neoplastic lesions.
NTP (1998) Rat (F344) Male (6 wk old) 2 yr | Cobalt sulfate 99% pure) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 0 mg/m^3^ | 17 | 14/50 (51%)
NTP (1998) Rat (F344) Male (6 wk old) 2 yr | Cobalt sulfate 99% pure) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 0.3 mg/m^3^ | 15 | 19/50 (70%)
NTP (1998) Rat (F344) Male (6 wk old) 2 yr | Cobalt sulfate 99% pure) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 1.0 mg/m^3^ | 21 | 23/48 (72%)
NTP (1998) Rat (F344) Male (6 wk old) 2 yr | Cobalt sulfate 99% pure) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 3.0 mg/m^3^ | 15 | 20/50 (71%)
NTP (1998) Rat (F344) Male (6 wk old) 2 yr | Cobalt sulfate 99% pure) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | Malignant, benign, or complex pheochromocytoma combined^b^
NTP (1998) Rat (F344) Male (6 wk old) 2 yr | Cobalt sulfate 99% pure) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 0 mg/m^3^ | 17 | 15/50 (52%)
NTP (1998) Rat (F344) Male (6 wk old) 2 yr | Cobalt sulfate 99% pure) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 0.3 mg/m^3^ | 15 | 19/50 (70%)
NTP (1998) Rat (F344) Male (6 wk old) 2 yr | Cobalt sulfate 99% pure) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 1.0 mg/m^3^ | 21 | 25/48 (74%)*^c^
NTP (1998) Rat (F344) Male (6 wk old) 2 yr | Cobalt sulfate 99% pure) | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 3.0 mg/m^3^ | 15 | 20/50 (71%)
NTP (1998) Rat (F344) Female (6 wk old) 2 yr | Cobalt sulfate 99% pure | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | Benign pheochromocytoma^b^ | | | Survival was similar to controls. Strengths: A well-designed study in all factors such as such as long observation period, sufficient dose levels, adequate number of animals. Limitations: None Significantly increased non-neoplastic lesions: Adrenal gland: hyperplasia - high dose.
NTP (1998) Rat (F344) Female (6 wk old) 2 yr | Cobalt sulfate 99% pure | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 0 mg/m^3^ | 28 | 2/48 (5%)
NTP (1998) Rat (F344) Female (6 wk old) 2 yr | Cobalt sulfate 99% pure | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 0.3 mg/m^3^ | 25 | 1/49 (3%)
NTP (1998) Rat (F344) Female (6 wk old) 2 yr | Cobalt sulfate 99% pure | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 1.0 mg/m^3^ | 26 | 3/50 (9%)
NTP (1998) Rat (F344) Female (6 wk old) 2 yr | Cobalt sulfate 99% pure | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 3.0 mg/m^3^ | 30 | 8/48 (26%)*
NTP (1998) Rat (F344) Female (6 wk old) 2 yr | Cobalt sulfate 99% pure | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | Trend-test p value: 0.004
NTP (1998) Rat (F344) Female (6 wk old) 2 yr | Cobalt sulfate 99% pure | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | Malignant, benign, or complex combined^b^
NTP (1998) Rat (F344) Female (6 wk old) 2 yr | Cobalt sulfate 99% pure | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 0 mg/m^3^ | 28 | 2/48 (4%)
NTP (1998) Rat (F344) Female (6 wk old) 2 yr | Cobalt sulfate 99% pure | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 0.3 mg/m^3^ | 25 | 1/49 (2%)
NTP (1998) Rat (F344) Female (6 wk old) 2 yr | Cobalt sulfate 99% pure | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 1.0 mg/m^3^ | 26 | 4/50 (8%)
NTP (1998) Rat (F344) Female (6 wk old) 2 yr | Cobalt sulfate 99% pure | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | 3.0 mg/m^3^ | 30 | 10/48 (21%)*^d^
NTP (1998) Rat (F344) Female (6 wk old) 2 yr | Cobalt sulfate 99% pure | Inhalation (dry particulate) 6 hr/day, 5 days/wk × 105 wk | Trend-test p value: 0.001
Wehner et al. (1977) Hamster (Syrian Golden, random bred ENG:ELA) Male (2 mo old) Lifespan | Cobalt(II) oxide Purity not reported Median diameter of particles 0.14 μm, Median mass diameter 0.45 μm Geometric standard deviation 1.9 μm | Inhalation (dry particulate) 7 hr/day, 5 days/wk × lifespan | Adenoma (cortex) | | | Survival in exposed group is similar to control Strengths: Duration of exposure and observation were sufficient. Limitations: Incomplete reporting. Low sensitivity because of relatively poor survival of both exposed and controls, only a single dose level was tested with no justification for choosing that level. Other comments: The study looked at cobalt’s effect on cigarette smoke, but a cobalt oxide only group was tested. Cobalt-exposed hamsters developed pneumoconiosis.
Wehner et al. (1977) Hamster (Syrian Golden, random bred ENG:ELA) Male (2 mo old) Lifespan | Cobalt(II) oxide Purity not reported Median diameter of particles 0.14 μm, Median mass diameter 0.45 μm Geometric standard deviation 1.9 μm | Inhalation (dry particulate) 7 hr/day, 5 days/wk × lifespan | 0 μg/L | NR | 0/51 (0%)
Wehner et al. (1977) Hamster (Syrian Golden, random bred ENG:ELA) Male (2 mo old) Lifespan | Cobalt(II) oxide Purity not reported Median diameter of particles 0.14 μm, Median mass diameter 0.45 μm Geometric standard deviation 1.9 μm | Inhalation (dry particulate) 7 hr/day, 5 days/wk × lifespan | 10.1 μg/L | NR | 1/50 (2%)
Pancreas
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Carcinoma^a^ | | | Survival was similar to controls. Strengths: A well-designed study in all factors such as long observation period, sufficient dose levels, adequate number of animals. Limitations: Decreases in body weight in mid- and high-dose rats. Other comments: Historical controls were limited (100 rats). No significantly increased non-neoplastic lesions.
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 0 mg/m^3^ | 17 | 2/50 (5%)
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 1.25 mg/m^3^ | 20 | 1/50 (3%)
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 2.5 mg/m^3^ | 16 | 5/48 (13%)^e^
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 5 mg/m^3^ | 16 | 6/49 (15%)^e^
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Trend-test p value: 0.021
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Adenoma^a^
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 0 mg/m^3^ | 17 | 0/50 (0%)
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 1.25 mg/m^3^ | 20 | 1/50 (3%)
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 2.5 mg/m^3^ | 16 | 6/48 (15%)*
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 5 mg/m^3^ | 16 | 3/49 (8%)
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Carcinoma or adenoma combined^a^
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 0 mg/m^3^ | 17 | 2/50 (5%)
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 1.25 mg/m^3^ | 20 | 2/50 (5%)
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 2.5 mg/m^3^ | 16 | 10/48 (25%)*^e^
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 5 mg/m^3^ | 16 | 9/49 (23%)*^e^
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Trend-test p value: 0.002
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Carcinoma^a^ | | | Survival was significantly decreased in the mid-dose group. Strengths: A well-designed study in almost all factors such as long observation period, sufficient dose levels, adequate number of animals. Limitations: A significant decrease in survival of female rats. Decreases in body weight in mid- and high-dose rats. Other comments: Historical controls were limited (100 rats). No significantly increased non-neoplastic lesions
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 0 mg/m^3^ | 35 | 1/50 (2%)
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 1.25 mg/m^3^ | 26 | 0/50 (0%)
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 2.5 mg/m^3^ | 24 | 0/50 (0%)
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 5 mg/m^3^ | 25 | 3/50 (7%)^f^
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Adenoma
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 0 mg/m^3^ | 35 | 0/50 (0%)
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 1.25 mg/m^3^ | 26 | 0/50 (0%)
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 2.5 mg/m^3^ | 24 | 0/50 (0%)
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 5 mg/m^3^ | 25 | 1/50 (2%)
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Carcinoma or adenoma combined^a^
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 0 mg/m^3^ | 35 | 1/50 (2%)
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 1.25 mg/m^3^ | 26 | 0/50 (0%)
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 2.5 mg/m^3^ | 24 | 0/50 (0%)
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 5 mg/m^3^ | 25 | 3/50 (7%)^f^
Hematopoietic system
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Mononuclear cell leukemia^a^ | | | Survival was similar to controls. Strengths: A well-designed study in all factors such as long observation period, sufficient dose levels, adequate number of animals. Limitations: None. Other comments: Historical controls were limited (100 rats). No significantly increased non-neoplastic lesions.
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 0 mg/m^3^ | 17 | 21/50 (49%)
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 1.25 mg/m^3^ | 20 | 25/50 (58%)
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 2.5 mg/m^3^ | 16 | 22/50 (50%)
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 5 mg/m^3^ | 16 | 22/50 (48%)
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Mononuclear cell leukemia^a^ | | | Survival was significantly decreased in the mid-dose group. Strengths: A well-designed study in almost all factors such as long observation period, sufficient dose levels, adequate number of animals. Limitations: A significant decrease in survival of female rats. Decreases in body weight in mid- and high-dose rats. Other comments: Historical controls were limited (100 rats). No significantly increased non-neoplastic lesions
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 0 mg/m^3^ | 35 | 16/50 (36%)
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 1.25 mg/m^3^ | 26 | 29/50 (62%)**^g^
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 2.5 mg/m^3^ | 24 | 28/50 (61%)*^g^
NTP (2014d) Rat (F344/NTac) Female (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 5 mg/m^3^ | 25 | 27/50 (59%)*^g^
Kidney
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Tubule adenoma^a^ | | | Survival was similar to controls. Strengths: A well-designed study in all factors. Limitations: Decreases in body weight in mid- and high-dose rats. Other comments: Historical controls were limited (100 rats.) No significantly increased non-neoplastic lesions
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 0 mg/m^3^ | 17 | 0/50 (0%)
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 1.25 mg/m^3^ | 20 | 1/50 (3%)^h^
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 2.5 mg/m^3^ | 16 | 0/50 (0%)
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 5 mg/m^3^ | 16 | 3/50 (8%)^h^
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Tubule carcinoma or adenoma^a^
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 0 mg/m^3^ | 17 | 0/50 (0%)
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 1.25 mg/m^3^ | 20 | 1/50 (3%)^h^
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 2.5 mg/m^3^ | 16 | 0/50 (0%)
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 5 mg/m^3^ | 16 | 4/50 (10%)^h^
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Trend-test p value: 0.018
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Tubule carcinoma or adenoma^ai^
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 0 mg/m^3^ | 17 | 3/50 (8%)
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 1.25 mg/m^3^ | 20 | 1/50 (3%)
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 2.5 mg/m^3^ | 16 | 1/50 (2%)
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | 5 mg/m^3^ | 16 | 7/50 (17%)
NTP (2014d) Rat (F344/NTac) Male (5–6 wk old) 105 wk | Cobalt metal (98% pure, mass median aerodynamic diameter 1–3 μm) | Inhalation (dry particulate) 6 hr/day, 5 day/wk × 105 wk | Trend-test p value: 0.023

* p value < 0.05; **p value < 0.01; ***p value < 0.01.

^+^ = Number of animals necropsied for NTP (2014d) and NTP (1998) (each group started with 50 animals per sex in the NTP studies) and is the number of animals at the beginning of the study for all other studies.

NR = Not reported, M = male, F = female, hr = hour, wk = week, mo = month, yr = year.

^a^ Adjusted percent incidence based on Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^b^ Adjusted percent incidence based on Kaplen-Meier estimated incidence at the end of the study after adjustment for intercurrent mortality.

^c^ Increased over historical control levels with a mean of 176/623 and range of 8% to 50%.

^d^ Increased over historical control levels with a mean of 39/608 and range of 2% to 14%.

^e^ Increased over historical control levels with a mean of 2/100 and range of 0% to 4%.

^f^ Increased over historical control levels with a mean of 1/100 and range of 0% to 2%.

^g^ Increased over historical control levels with a mean of 35/100 and range of 32% to 38%.

^h^ Increased over historical control levels with a mean of 1/100 and range of 0% to 2%.

^i^ Analyzed by standard and extended evaluation. In a standard evaluation a single section of each kidney is examined histologically, while in an extended evaluation, three to four additional sections, taken at 1 mm intervals are examined histologically.

#### Lung

Different types of cobalt compounds—cobalt metal (NTP 2014d), a soluble cobalt salt, cobalt sulfate heptahydrate (NTP 1998), and a poorly soluble cobalt compound, cobalt(II) oxide (Steinhoff and Mohr 1991)—caused lung neoplasms after exposure by inhalation or intratracheal instillation. Study results for six respiratory exposure studies are reported in Table 5-3 including two studies in mice, three studies in rats, and one study in hamsters. Four of these studies were high-quality, well-designed, and well-conducted studies (NTP 1998; 2014d) and all had either high (NTP 1998; 2014d) or moderate (Steinhoff and Mohr 1991; Wehner et al. 1977) utility for evaluating potential cancer hazards.

Four studies found strong evidence that cobalt (both cobalt metal and cobalt sulfate) causes lung tumors in both mice and rats (NTP 1998; 2014d). Significant dose-related increases were seen for alveolar/bronchiolar carcinoma and for alveolar/bronchiolar adenoma or carcinoma combined in all dose groups (low, 1.25 mg/m^3^; medium, 2.5 mg/m^3^; high, 5 mg/m^3^) in male and female mice and rats exposed to cobalt metal by inhalation (NTP 2014d). The incidences of alveolar/bronchiolar adenoma were also significantly increased in rats and mice, although not always in all dose groups. The incidences of carcinoma were very high; when adjusted for intercurrent mortality, incidences in the high-dose groups were 81% for male rats, 69% for female rats, 94% for male mice, and 88% for female mice. In addition, dose-related significant increases in multiplicity (animals with more than one lung tumor) of carcinoma were also found for all dose groups in male and female mice and male rats and in the high-dose (5 mg/m^3^) groups for female rats (NTP 2014d). Female rats also had, in all dose groups, non-significant increases in cystic keratinizing epithelioma, which is a benign squamous-cell neoplasm that can progress to squamous-cell carcinoma. Cystic keratinizing epithelioma (CKE) is considered to be exposure-related in females because it is very rare, and a single squamous-cell carcinoma was also observed in the high-dose group. In males, a single CKE was found in each of the low- and high-exposure groups and may have been exposure-related. Lesions of alveolar or bronchiolar epithelial hyperplasia, which can progress to neoplasms, was also significantly increased in both sexes of rats and mice in all dose levels tested, except for bronchiolar epithelium hyperplasia in mice, which were significantly increased in mid- and high-dose groups in females and high-dose group in males.

In the NTP (1998) inhalation studies of cobalt sulfate heptahydrate, significant dose-related increases were observed for alveolar/bronchiolar carcinoma, and alveolar/bronchiolar adenoma in male and female mice (high dose, 3.0 mg/m^3^) and female rats (high and mid dose, 1.0 mg/m^3^) and for alveolar/bronchiolar carcinoma or adenoma combined for male rats (high dose) (NTP 1998). A single squamous-cell carcinoma was also found in the mid- and high-dose groups of female rats. Non-neoplastic lesions of alveolar or bronchiolar epithelial hyperplasia (considered pre-neoplastic) and metaplasia were also significantly increased in both sexes of rats, but not in mice.

The fifth study reported significant increases in lung neoplasms (alveolar/bronchiolar adenoma, benign squamous epithelial neoplasm, or alveolar/bronchiolar carcinoma combined) in male rats administered cobalt(II) oxide by intratracheal instillation (Steinhoff and Mohr 1991). Non-significant increases in lung neoplasms (alveolar/bronchiolar carcinoma and alveolar/bronchiolar adenoma) were seen in females. There were significant increases in alveolar/bronchiolar proliferation (types of lesions not described) in both sexes combined. Histological examinations were performed on all high-dose group animals; in the low-dose group and untreated control group, only those organs with gross lesions suspected of having tumors and all respiratory tracts were examined, which could underestimate the incidence by not detecting microscopic neoplasms.

In the last study, lung tumors were not observed in hamsters exposed to cobalt(II) oxide by inhalation, although exposure did cause pneumoconiosis, which was evidenced by a variety of lesions including, e.g., interstitial pneumonitis, diffuse granulomatous pneumonia, fibrosis of alveolar septa, and bronchial and bronchiolar epithelial (basal cell) hyperplasia (Wehner et al. 1977). There was relatively poor survival among the cobalt-treated animals and the corresponding dust sham-treated controls, which may have limited the sensitivity to detect an effect. In addition, hamsters have been described as a less sensitive model for detecting lung tumors than rats or mice (McInnes et al. 2013; Steinhoff and Mohr 1991). (Findings not reported in Table 5-3 because no tumors were observed.)

#### Injection Sites (Subcutaneous, Intramuscular, Intraperitoneal, Intrapleural, and Intrarenal)

Exposure to several different cobalt forms (cobalt metal, cobalt chloride, and cobalt(II) oxide) by injection increased injection-site tumors in several studies in rats (Gilman and Ruckerbauer 1962; Hansen et al. 2006; Heath 1956; Heath and Daniel 1962; Shabaan et al. 1977; Steinhoff and Mohr 1991). However, no injection tumors were observed in other studies in rats (Hansen et al. 2006; Jasmin and Riopelle 1976) or in the only study in mice (Gilman and Ruckerbauer 1962). Differences in dose levels, sex, and inadequate statistical power could explain these different findings. These studies were considered to have moderate (Hansen et al. 2006; Steinhoff and Mohr 1991) or low utility (Gilman and Ruckerbauer 1962; Heath 1956; Heath and Daniel 1962; Jasmin and Riopelle 1976; Shabaan et al. 1977). However, many concerns for potential biases were related to sensitivity such as limited dosing regimens and statistical power and thus would not necessarily decrease confidence in positive findings. Many studies also had limited reporting, which in part may be typical of older studies (published in the 1950s to 1970s). The relevance of injection studies for evaluating carcinogenicity in humans is discussed in the synthesis (Section 5.3).

Injection of cobalt metal (nanoparticles or microparticles) caused significant increases in the incidences of various types of sarcoma in several studies. Hansen et al. (2006) directly compared potential carcinogenic effects of cobalt metal nanoparticles and larger size cobalt metal particles in rats. However, both sizes of particles were placed into the same animals; cobalt nanoparticles were administered intramuscularly, and bulk cobalt metal was administered subcutaneously. The study also used a similar design to test other materials (nickel, titanium dioxide, and silicon dioxide). Cobalt-treated animals were sacrificed at 6 and 8 months (due to mortality from tumors) and compared to controls, which were administered polyvinyl chloride (PVC) and sacrificed at 6 and 12 months. Local sarcomas developed around the site of the nanoparticles in one of four rats at the 6-month sacrifice and in five of six rats at the 8-month sacrifice. No tumors were observed around the injection site of the bulk cobalt metal at either sacrifice time, although a single lesion of local fibroblastic proliferation occurred in one of six rats sacrificed at 8 months. The short duration period of 8 months limited the ability to see if the fibroblastic proliferation caused by microparticles would progress into neoplasms. The study also had limited statistical power because of small numbers of animals in the exposed and control groups. With respect to the other materials, tumors were observed in animals after implantation (nanoparticles) or subcutaneous injection (bulk) with nickel but not with injections of titanium dioxide or silicon dioxide. The ratio of surface area to volume between the nickel/cobalt and other compounds was not significantly different, which suggests that the neoplasms were not mediated by physical events and thus supports that the carcinogenic effect is due to cobalt.

A series of studies in hooded rats (Heath 1956; Heath and Daniel 1962) that injected cobalt metal by different exposure routes rats reported sarcomas—rhabdomyofibrosarcoma (including in the heart, intercostal muscle), rhabdomyosarcoma, fibrosarcoma, or other sarcoma—at the site of injection, but not in the controls. The earlier study (Heath 1956) injected cobalt into male and female rats intramuscularly in the thigh and the later study injected cobalt into the intrathoracic region (Heath and Daniel 1962). The controls from the 1956 study were used for the 1962 study. Rhabdomyofibrosarcoma, especially cardiac rhabdomyofibrosarcoma, are very rare tumors. Evidence that the sarcomas were caused by a local carcinogenic effect—beyond the fact that they only developed at injection sites—was seen by their tissue of origin. The 1962 study was limited by poor survival at the beginning of the study (eight rats died within three days) caused by the injections. Sarcomas originating from muscle tissue were only found in studies that injected cobalt metal by intramuscular injection (rhabdomyofibrosarcoma or rhabdomyosarcoma) or intrapleural injection (cardiac or intercostal muscle rhabdomyosarcoma). Relatively high incidences in sarcomas were observed in both studies although the studies had limited sensitivity because only a few animals were tested at only one dose.

In contrast, no neoplasms were reported in a study in which cobalt metal was injected directly into the kidney of female rats, (Jasmin and Riopelle 1976). Compared to the other injection-site studies that used a single dose, Jasmin and Riopelle used a lower dose (10 mg/rat) than those used in the studies that induced neoplasms (>20 mg/rat) (Gilman and Ruckerbauer 1962; Heath 1956; Heath and Daniel 1962), suggesting that the dose might have been too low; in addition the study duration was only 12 months. The purpose of this study was to evaluate kidney carcinogenicity.

Cobalt chloride was tested in only one study by subcutaneous injection in male rats (Shabaan et al. 1977) in two similar experiments, one that ended after 8 months and one that lasted for 12 months. Only the 12-month study included an untreated control, but it seems reasonable to use that control for the 8-month study, especially since no neoplasms developed in the controls at 12 months. In the 12-month experiment, fibrosarcomas were found in 8/11 survivors at both the subcutaneous injection sites (4) and at sites distant from the injection site (4). In the 8-month experiment, 6 of the 16 animals who were alive at the end of the observation period had tumors (Shabaan et al. 1977). (Animals who died before 8 or 12 months were not examined for tumors.) Due to poor reporting, it was not possible to differentiate between tumors that occurred at injection sites versus non-injection sites. The cobalt-exposed animals developed persistent hyperlipaemia, and mortality was high for the treated animals.

Cobalt(II) oxide was injected (i.p., s.c., i.m.) into rats in three studies (Gilman and Ruckerbauer 1962; Steinhoff and Mohr 1991) and into mice (i.m.) in one study (Gilman and Ruckerbauer 1962). All rat studies reported significant increases in local neoplasms, either sarcoma, histiocytoma, or both combined. Although few rats were used in the studies, more than 50% of the rats developed injection-site tumors. No treatment-related increase in neoplasms was found in the one study in mice. The number of animals was adequate in this study; however, only one dose was used (lower than the rat study) and there was little information on dose selection. There were some concerns about potential for confounding from the animal husbandry conditions and limited information on chemical purity in the studies in rats and mice by Gilman and Ruckerbauer (1962). However, no tumors were observed in mice, the controls, or rats and mice injected with thorium dioxide, thus arguing against any potential confounding.

Only one study tested cobalt sulfide, which was injected intrarenally into female rats (Jasmin and Riopelle 1976). No neoplasms were reported in this study; however, the doses used in this study may have been low since they were similar to the doses used in the study with cobalt metal that was also negative.

#### Other Neoplasms Including Those at Distal Sites

Several lines of evidence support systemic exposure of rats and mice to cobalt. Cobalt concentrations and burdens increased with increasing exposure concentrations in all studies in all tissues examined; however, tissue burdens normalized by exposure concentration showed increased levels only in the liver [(NTP 2014d); see Section 5.1.3]. In addition, neoplasms were observed at several organ sites (pancreas, hematopoietic system, and kidney distal to the route of administration.

##### Adrenal Gland

Neoplasms of the adrenal gland were reported in two inhalation studies that tested cobalt metal and cobalt sulfate (see Table 5-5) (NTP 1998; 2014d; Wehner et al. 1977). In the four NTP studies, cobalt metal and cobalt sulfate heptahydrate were each tested in both mice and rats, but adrenal gland neoplasms developed only in rats. One study reported a single adrenal gland neoplasm in hamsters exposed to cobalt(II) oxide (Wehner et al. 1977). There is a high background of adrenal tumors in the male rats in the two NTP studies. Adrenal gland neoplasms can develop because of damage to lungs that causes obstructive sequelae by causing systemic hypoxemia, leading to chronic stimulation of catecholamine release by the adrenal medulla and subsequent neoplastic development (NTP 2014d). Since inhalation of cobalt caused lesions in the lung that could cause obstruction (chronic inflammation), it is possible that the adrenal glands are not directly caused by systemic exposure to cobalt but could be a secondary response to lung damage. However, there is not enough evidence to differentiate between a direct or indirect cause of adrenal gland neoplasms from cobalt exposure.

The strongest evidence for a treatment-related effect comes from the rat studies with cobalt metal. Inhalation exposure to cobalt metal significantly increased bilateral malignant pheochromocytoma in the high-dose group (5 mg/m^3^) and all malignant pheochromocytoma, malignant or benign pheochromocytoma combined, and benign pheochromocytoma in both the mid- (2.5 mg/m^3^) and high-dose groups in male rats. In females, there was a significantly increased incidence of bilateral malignant pheochromocytoma as well as malignant pheochromocytoma overall at the high dose and malignant or benign pheochromocytoma combined, and bilateral benign pheochromocytoma as well as benign pheochromocytoma in both the mid- and high-dose groups (NTP 2014d). Hyperplasia of the adrenal gland was also significantly increased in females at mid and high doses and was significantly decreased in males in the mid- and high-dose groups.

Cobalt sulfate heptahydrate caused significant increases in malignant, benign, or complex adrenal neoplasms combined in both sexes, which were higher than historical controls (NTP 1998). However, increases were only significant in the high-dose (3 mg/m^3^) group in females and the mid-dose (1 mg/m^3^) group in males. Females had a significant trend of increasing tumor incidence with increasing dose for benign pheochromocytoma and all tumor types combined. Hyperplasia was significantly increased in females and the high-dose but was significantly decreased in the low-dose (0.3 mg/m^3^) males.

Wehner et al. (1977) reported finding a single adrenal gland adenoma in the cortex of hamsters after inhalation of cobalt(II) oxide. Wehner et al. (1977) only tested one dose level, 10 mg/m^3^, which was higher than those used in mice or rats in the two NTP studies. The significant increases in rats, but not mice or hamsters, could indicate a species difference in sensitivity to developing adrenal gland tumors from cobalt exposure, especially considering hamsters received a higher dose level than the rats.

##### Distal Sites: Pancreatic Islet Cell, Hematopoietic System, and Kidney

Inhalation exposure to cobalt metal also caused other tumors at sites distant from the route of administration: pancreas in male rats and mononuclear-cell leukemia in female rats in the NTP inhalation bioassay of cobalt metal (Behl et al. 2015; NTP 2014d). A non-significant increase in the incidence of kidney tumors was observed in male rats. It is not clear whether the kidney tumors were treatment related. Tumors were not observed in the pancreas, kidney, or hematopoietic system of rats exposed to cobalt sulfate or mice exposed to either form of cobalt. Findings are presented in Table 5-5 and briefly summarized below.

Male rats exposed to cobalt metal were found to have a significant increase in the incidences of pancreatic islet-cell carcinoma or adenoma combined in both the mid- and high-dose groups and a significant positive dose-related trend was observed. A significant increase in the incidence of pancreatic adenoma was also observed in the mid-dose group in males. The non-significant increases in the incidence of pancreatic islet-cell carcinoma observed in female rats exceeded the historical controls for all routes of administration and thus might have been related to exposure. However, historical controls were limited as they were based on a dataset of only 100 Fischer 344/NTac rats from two NTP carcinogenicity studies. Significant increases in the incidence of mononuclear-cell leukemia were seen in females in all dose groups, which exceeded the limited historical controls for all exposure routes. In addition, time to first tumor was shorter in cobalt-exposed animals (117 to 590 days) compared to the concurrent control (663 days) albeit there was no pattern of decreasing duration with increasing dose and because of the limited historical control database, it is not known how much time to first tumor in untreated animals varies across studies. The incidence of mononuclear-cell leukemia was similar in male rats compared to the untreated controls.

The incidence of kidney neoplasms (adenoma or carcinoma combined) was higher (although not significantly so) in the low- and high-dose male rats compared to the concurrent controls and a significant trend was observed. The incidence exceeded the historical controls for all routes of administration, but the historical controls are limited as mentioned above. Four of the five neoplasms were adenomas. In analyses of standard and extended evaluations, a significant trend was observed; two of the seven neoplasms in the high-dose group were carcinomas. Kidney neoplasms are relatively rare, so non-significant increases may be related to cobalt exposure (NTP 2014d). No treatment-related non-neoplastic lesions were observed. Two studies injected cobalt sulfide or cobalt metal directly into the kidneys of female rats in one publication (Jasmin and Riopelle 1976). No kidney tumors or any other tumors were reported as being significantly increased. Only a single dose was given at one dose level and the dose was lower than that used in other injection studies.

## 5.2 Co-carcinogenicity Studies

### 5.2.1 Overview of the Studies

Nine co-carcinogen studies were identified that tested soluble compounds, including four studies using cobalt chloride (Finogenova 1973; Kasirsky et al. 1965; O’Hara et al. 1971; Zeller 1975) and three studies using sodium cobaltinitrite (O’Hara et al. 1971; Orzechowski et al. 1964; Thompson et al. 1965); and a poorly soluble compound, cobalt(II) oxide, in two studies (Steinhoff and Mohr 1991; Wehner et al. 1977) (see Table 5-6). Most co-carcinogen studies were conducted in mice, though two studies were conducted in rats (Steinhoff and Mohr 1991; Zeller 1975) and one study conducted in hamsters (Wehner et al. 1977). Almost all of the co-carcinogen studies used dermal exposure to methylcholanthrene as the known carcinogen, with Zeller using subcutaneous injections of diethylnitrosamine, Steinhoff and Mohr using intratracheal instillation of benzo[a]pyrene, and Wehner using inhalation exposure to cigarette smoke. Methylcholanthrene induced skin tumors, while diethylnitrosamine induced liver and nasal tumors, benzo[a]pyrene induced lung tumors, and cigarette smoke increased incidences of total malignant or total benign neoplasms. Cobalt compounds were administered by intraperitoneal injection in all but four studies, which used subcutaneous injection (Zeller 1975), drinking water (Thompson et al. 1965), inhalation (Wehner et al. 1977), and intratracheal instillation (Steinhoff and Mohr 1991) as routes of exposure.

Table 5-6 Overview of Co-carcinogenicity Studies in Experimental Animals Reviewed

Strain (Sex) | Substance | Route | Co-carcinogen & Route | Exposure Period/Study Duration | Reference
Rat Wistar (M&F) | Cobalt chloride | SC inj. | diethylnitrosamine SC inj. | 43 wk/lifespan | Zeller (1975)
Mouse CBAxC57B_1_ (F) | Cobalt chloride | IP inj. | methylcholanthrene dermal | 8 wk/8 wk | Finogenova (1973)
Mouse CF-1 (M&F) | Cobalt chloride | IP inj. | methylcholanthrene dermal | 5 wk/17 wk | O’Hara et al. (1971)
Mouse CF-1 (M&F) | Cobalt chloride | IP inj. | methylcholanthrene dermal | 10 wk/10 wk | Kasirsky et al. (1965)
Mouse CF-1 (M&F) | Sodium cobaltinitrite | IP inj. | methylcholanthrene dermal | 5 wk/17 wk | O’Hara et al. (1971)
Mouse CF-1 (M&F) | Sodium cobaltinitrite | Drinking water | methylcholanthrene dermal | 11 wk/11 wk | Thompson et al. (1965)
Mouse CF-1 (M&F) | Sodium cobaltinitrite | IP inj. | methylcholanthrene dermal | 72 days/75 days | Orzechowski et al. (1964)
Rat Sprague-Dawley (F) | Cobalt(II) oxide | Intratracheal instill. | benzo[a]pyrene intratracheal instill. | 47 wk/lifespan | Steinhoff and Mohr (1991)
Hamster Syrian Golden (M) | Cobalt(II) oxide | Inhalation | cigarette smoke inhalation | Lifespan/lifespan | Wehner et al. (1977)

M = male, F = female, instill. = instillation, inj. = injection, IP = intraperitoneal, IM = intramuscular, SC = subcutaneous, wk = week, yr = year.

### 5.2.2 Overview of the Assessment of Study Quality and Utility

Each of these primary studies was systematically evaluated for its ability to inform the cancer hazard similar to that described for the carcinogenicity studies in Section 5.1.2. O’Hara et al. (1971) conducted two co-carcinogenicity studies (one using cobalt chloride and the other using sodium cobaltinitrite) that were considered inadequate for evaluation of the carcinogenicity of cobalt, because the authors did not test the influence of cobalt on tumor formation, as cobalt was not administered until after neoplasms were already detectable. No critical concerns were identified in the remaining studies although they were considered to be of low quality. Finogenova (1973) did not report neoplasm incidences but did report neoplasm onset and latency. The other studies had poor reporting of duration, survival, and results, as they were not reported for each gender, but had combined data for both sexes. The study quality assessment is discussed in Appendix D. All co-carcinogenicity studies were categorically restricted to being ranked no higher than “low” for the utility to inform the carcinogenicity evaluation. This restriction was applied to account for the indirect measure of carcinogenicity that co-carcinogenicity studies provide.

### 5.2.3 Assessment of Findings from Co-carcinogenicity Studies

Co-carcinogenicity studies are also divided by site of neoplasm development into skin, lung, liver, nasal neoplasms, and neoplasms of unspecified location. Only one co-carcinogen study demonstrated an increased incidence of lung neoplasms from cobalt (cobalt(II) oxide), while three studies showed no effect from cobalt (cobalt chloride and cobalt(II) oxide) and three studies reported a decrease in neoplastic incidence with the additional exposure to cobalt compounds (cobalt chloride and sodium cobaltinitrite).

#### Skin

Four co-carcinogenicity studies of cobalt and methylcholanthrene were reviewed (Finogenova 1973; Kasirsky et al. 1965; O’Hara et al. 1971; Orzechowski et al. 1964; Thompson et al. 1965). In all of the studies, methylcholanthrene was applied dermally to mice and either sodium cobaltinitrite or cobalt chloride was administered in drinking water or by i.p injection. All studies reported skin squamous-cell carcinoma (Finogenova was translated from Russian and was reported as skin cancer NOS). Skin tumor incidences were reduced by co-administration of cobalt in three of the four studies (Kasirsky et al. 1965; Orzechowski et al. 1964; Thompson et al. 1965). In the fourth study, no differences were seen in the onset or latency of neoplasm development for either skin “cancer NOS” or papilloma from the addition of cobalt chloride (Finogenova 1973). The authors didn’t report any tumor incidences.

#### Lung

Two co-carcinogenicity studies used either inhalation or intratracheal instillation as the route of exposure for both the cobalt compound and the known carcinogen (Steinhoff and Mohr 1991; Wehner et al. 1977). Steinhoff and Mohr (1991) administered benzo[a]pyrene and cobalt(II) oxide to female rats by intratracheal instillation. The addition of cobalt(II) oxide increased the incidence of squamous-cell carcinoma of the lung (Steinhoff and Mohr 1991). An adenocarcinoma was also reported in the group exposed to both compounds, but not in the group exposed to just benzo[a]pyrene. However, the incidence of adenocarcinoma was not significantly increased by cobalt(II) oxide. Wehner exposed male hamsters to cigarette smoke and cobalt(II) oxide by inhalation (Wehner et al. 1977). No significant change in tumor incidence from the addition of cobalt(II) oxide was reported, but the locations of the neoplasms were not clearly reported.

#### Liver and Nose

Only one co-carcinogen study reported neoplasms of the liver and nose (Zeller 1975). In this study, the known carcinogen, diethylnitrosamine, was subcutaneously injected together with cobalt chloride into male and female rats. Diethylnitrosamine induced neoplasms of the nose (esthesioneuroepithelioma, poorly differentiated carcinoma NOS, and squamous-cell carcinoma) and liver (hepatoma NOS, hepatocellular carcinoma, and cholangioma), but the addition of cobalt chloride had no effect on the incidences.

#### Locations of Unspecified Neoplastic or Non-neoplastic Lesions

Only one co-carcinogen study reported neoplasms that were not specified as to their location or even their histological type (Wehner et al. 1977). Significant decreases in the incidences of neoplasms in cigarette smoke-exposed groups were seen with the addition of cobalt oxide. Groups that were exposed to cobalt and cigarette smoke also had significantly lower body weights than those exposed to just cigarette smoke, which might account for the lower neoplasm incidence. This co-carcinogen study included a cobalt(II) oxide alone group, which did not show a significant increase in neoplasm incidence above that of untreated controls.

## 5.3 Synthesis of the Findings across Studies

Strengths of the available dataset include testing of cobalt compounds with different properties such as particle versus salt and poorly soluble vs. readily soluble compounds. For some compounds, several studies were available including robust studies with high utility for evaluating carcinogenicity; importantly these include inhalation studies on both a water-soluble (cobalt sulfate) and poorly soluble species (cobalt metal). For other cobalt compounds, there were few studies, some of which were of more limited utility. The overall results for the carcinogenicity studies are summarized by cobalt compound in Table 5-7.

Table 5-7 Overall Results of Carcinogenicity Studies in Experimental Animals Sorted by Cobalt Compound

Substance | Strain (Sex) | Route | Exposure Period/Study Duration | | Results | Reference
Cobalt metal
Cobalt metal | Rat F344/NTac (M&F) | Inhalation | 2 yr/2 yr | | Lung Alveolar/bronchiolar adenoma and carcinoma, M&F Squamous-cell tumors (primarily cystic keratinizing epithelioma), F; [Equivocal] M Mononuclear-cell leukemia, F Adrenal gland Benign and malignant pheochromocytoma, M&F Pancreas Islet-cell adenoma or carcinoma, M; [Equivocal: carcinoma] F Kidney Adenoma or carcinoma combined, [Equivocal] M | NTP (2014d)
Cobalt metal | Mouse B6C3F_1_/N (M&F) | Inhalation | 2 yr/2 yr | Lung Alveolar/bronchiolar adenoma and carcinoma, M&F | | | | NTP (2014d)
Cobalt metal [Nano]^a^ | Rat Sprague-Dawley (M) | i.m. inj. | Single dose/1 yr | Injection site Sarcoma, M | | | | Hansen et al. (2006)
Cobalt metal [Bulk]^a^ | Rat Sprague-Dawley (M) | s.c. inj. | Single dose/1 yr | No increased incidence in tumors Fibroblastic proliferation (non-neoplasia) | | | | Hansen et al. (2006)
Cobalt metal | Rat Sprague-Dawley (F) | Intrarenal inj. | Single dose/1 yr | No increased incidence in tumors | | | | Jasmin and Riopelle (1976)
Cobalt metal | Rat Hooded (F) | Intrathoracic | Single dose/2.3 yr | Injection-site sarcoma [including rhabdomyosarcoma of cardiac and intercostal muscle, mixed | | | | Heath and Daniel (1962)
Cobalt metal | Rat Hooded (M&F) | i.m. inj. | Single dose/lifespan | Injection-site sarcoma [rhabdomyofibrosarcoma, M&F; sarcoma M; fibrosarcoma F | | | Heath (1956)
Soluble cobalt compounds
Cobalt sulfate heptahydrate | Rat F344/N (M&F) | Inhalation | 2 yr/2 yr | Lung Alveolar/bronchiolar adenoma and carcinoma, M&F Adrenal Benign or malignant pheochromocytoma, F | | | | NTP (1998)
Cobalt sulfate heptahydrate | Mouse B6C3F_1_ (M&F) | Inhalation | 2 yr/2 yr | Lung Alveolar/bronchiolar adenoma and carcinoma, M&F | | | | NTP (1998)
Cobalt chloride | Rat Wistar (M) | s.c. inj. | 8–12 mo/8–12 mo | Injection site Fibrosarcoma, M Non-injection site Fibrosarcoma. M | | | | Shabaan et al. (1977)
Poorly soluble cobalt compounds
Cobalt oxide | Rat Sprague-Dawley (M&F) | Intratracheal instill. | 1.5 yr/lifespan | Lung Alveolar/bronchiolar carcinoma, benign squamous epithelial neoplasm, or alveolar/bronchiolar adenoma combined M | | | | Steinhoff and Mohr (1991)
Cobalt oxide | Rat Sprague-Dawley (M&F) | i.p. inj. | 6 mo/lifespan | Injection site Histiocytoma and sarcoma, M&F | | | | Steinhoff and Mohr (1991)
Cobalt oxide | Rat Sprague-Dawley (M) | s.c. inj. | 730 day/ lifespan | Injection site Histiocytoma and sarcoma, M | | | | Steinhoff and Mohr (1991)
Cobalt oxide | Rat Wistar (M&F) | i.m. inj. | Single dose/1.3 yr | Injection site Sarcoma, M&F | | | | Gilman and Ruckerbauer (1962)
Cobalt oxide | Mouse Swiss (F) | i.m. inj. | Single dose/2 yr | No increased incidence in tumors | | | | Gilman and Ruckerbauer (1962)
Cobalt oxide | Hamster Syrian Golden (M) | Inhalation | Lifespan/ lifespan | No increased incidence in tumors | | | | Wehner et al. (1977)
Cobalt sulfide | Rat Sprague-Dawley (F) | Intrarenal inj. | Single dose/1 yr | No increased incidence in tumors | | | | Jasmin and Riopelle (1976)

F = female; inj. = injection; instill. = instillation; i.m. = intramuscular; i.p. = intraperitoneal; M = male; mo = month; s.c. = subcutaneous; wk = week; yr = year.

^a^ Cobalt bulk and nanoparticle tested in the same animal in the Hansen et al. (2006) study.

In general, the injection studies were less robust than the inhalation studies. Occupational exposure to cobalt compounds usually occurs by inhalation and not by injection. However, the injection route may be relevant to human exposure, in that cobalt is used in many types of surgical implant materials. The interpretation of the carcinogenicity of the injection studies is limited because many different types of particles or metals, including substances that are considered to be relatively inert, have induced tumors in rats (IARC 2006). Nevertheless, Hansen et al. (2006) found that implantation of some substances (e.g., titanium dioxide and silicon dioxide) did not induce neoplasms and these materials had the same physical characteristics (i.e., surface to volume ratio) as those material that did (cobalt and nickel) tumors, which suggests that the tumors were due to carcinogenic properties of cobalt and not just to a reaction to any physical implant. Further, neoplasms developed at the injection sites when exposed to a soluble cobalt compound, cobalt chloride, indicating a cobalt-specific, rather than a particle-specific effect (Shabaan et al. 1977). Overall, the injection studies are considered to provide supporting evidence for the carcinogenicity of cobalt.

Most of the neoplasms induced by cobalt compounds occur at the site of administration. Lung tumors are only seen in inhalation or intratracheal instillation studies and tissue sarcoma developed in the local tissue at the sites of injection. Both the lung tumors from inhalation and tissue sarcomas from injections were caused by different cobalt forms including cobalt metal, a poorly soluble compound (cobalt(II) oxide) and two water-soluble compounds (cobalt sulfate for lung tumors and cobalt chloride for injection tumors). In addition, cobalt metal induced several types of tumors distal from the site of administration that were not caused by the other cobalt species (with the possible exception of adrenal tumors from cobalt sulfate), although most of the cobalt compounds were not adequately tested in models to evaluate these sites.

The most widely studied form of cobalt was cobalt metal. Lung tumors were observed in rats and mice in both sexes after inhalation exposure (NTP 1998; 2014d), and injection-site sarcomas (primarily rhabdomyofibrosarcoma, fibrosarcoma or sarcoma) were observed in male and female rats in several studies injecting cobalt metal by different methods (i.m. or intrathoracic) (Heath 1956; Heath and Daniel 1962). In addition, inhalation exposure to cobalt metal also increased the incidences of adrenal gland tumors and tumors at distal sites—mononuclear-cell leukemia and pancreas, and possibly kidney tumors (NTP 2014d). Cobalt metal nanoparticles, when administered by i.m. injection, caused sarcoma in male rats; however, no inhalation studies were identified (Hansen et al. 2006).

Similarly, a poorly soluble cobalt compound (cobalt(II) oxide) caused both lung neoplasms (after intratracheal instillation) in male rats and sarcoma and histiocytoma in several studies of male and/or female rats after injection by various methods (s.c., i.m., i.p.) (Gilman and Ruckerbauer 1962; Steinhoff and Mohr 1991). Inhalation exposure to cobalt(II) oxide did not increase the incidences of lung tumors in Syrian golden hamsters, but the hamster is a less sensitive model for evaluating lung carcinogenicity (McInnes et al. 2013; Steinhoff and Mohr 1991) than the rat or mouse. No tumors were observed in the only study of another poorly soluble cobalt compound, cobalt sulfide, after intrarenal injection, but there were concerns about the dose level in that study (Jasmin and Riopelle 1976).

Finally, consistent findings are also found for soluble cobalt salts. Inhalation exposure to cobalt sulfate heptahydrate caused lung tumors in rats and mice and adrenal tumors in female rats. Adrenal gland tumors were also induced by exposure to cobalt sulfate (NTP 1998). Although no injection studies were identified that tested cobalt sulfate heptahydrate, a subcutaneous study of cobalt chloride provided suggestive evidence that cobalt causes fibrosarcoma at the site of administration and possibly at sites distant from the sites of administration; however, the confidence in the evidence is reduced somewhat because of possible inadequate reporting or procedures (Shabaan et al. 1977).

Co-carcinogenicity studies overall provided little if any support for the co-carcinogenicity of cobalt compounds. One study reported that cobalt enhanced carcinogenicity, but the remaining co-carcinogenicity studies reported either no effect or a decrease in carcinogenicity with co-exposure to cobalt.