# 4 Human Cancer Studies

## Introduction

The objective of the cancer hazard evaluation of cobalt and cobalt compounds that release cobalt ions in vivo (hereinafter referred to as cobalt) is to reach a level of evidence conclusion (sufficient, limited, or inadequate) for the carcinogenicity of cobalt from studies in humans by applying the RoC listing criteria to the body of evidence.

In general, most of the human studies do not provide information on the type(s) of cobalt compounds to which the subjects were exposed.

The steps in the cancer hazard evaluation, including the location of the discussion of these steps in the document, are listed below.

1. 1. Selection of the relevant literature included in the cancer evaluation (Section 4.1 and Cobalt Protocol (NTP 2014b)).
2. 2. Description of the study methods and characteristics (Table C-1 through Table C-9) and evaluation of study quality and other elements related to the utility of the studies to inform the cancer hazard evaluation: Section 4.2 (cohort studies of lung cancer), Section 4.3 (case-control studies of esophageal, and other aerodigestive cancers (i.e., oral cavity, laryngeal, and pharyngeal cancers), and Table C-10 through Table C-12.
3. 3. Cancer assessment: Lung (Section 4.2.3), esophagus (Section 4.3.3), and other cancers (Section 4.4).
4. 4. Level of evidence conclusion for carcinogenicity (sufficient, limited, or inadequate) of cobalt from human studies (Section 4.5).

The cancer hazard evaluation of cobalt primarily focuses on cancers of the lung, the esophagus, and other aerodigestive cancers (i.e., oral cavity, laryngeal, and pharyngeal cancers) since these are the only tissue sites evaluated in multiple studies. (For rationale, see Protocol: Methods for Preparing the Draft Report on Carcinogens Monograph on Cobalt [“Cobalt Protocol”; NTP (2014b)] and Table 4-1). Because the occupational cohort studies primarily reported on lung cancer and the case-control studies reported on esophageal cancers and other aerodigestive cancers, this section is organized by study design (following the selection of literature): cohort studies and lung cancer are discussed in Section 4.2, case-control studies and esophageal cancer in Section 4.3, and aerodigestive and other cancers (reported in both case-control and cohort studies) in Section 4.4.

Table 4-1 Cohort and Nested Case-control Studies of Exposure to Cobalt

Reference | Population | Design and Outcome (Cancer Sites) | Exposure: Cobalt Compounds, Assessment, Metrics
Tüchsen et al. (1996) | Danish porcelain painters 1943–1992 N = 1,394 female workers 874 exposed 520 unexposed | Cancer incidence cohort study (SIR); Danish cancer registry ICD-7: Lung (162.0, 162.1) and 16 other tissue/organ sites | Cobalt-aluminate spinel; cobalt silicate Company records Exposed: Ever employed in two plate underglazing factories Unexposed: workers employed in a cobalt-free department in one factory
Mur et al. (1987) Moulin et al. (1993) (follow-up) | French electrochemical workers Mur et al. (1987) 1950–1980 N = 1,143 males Moulin et al. (1993) 1950–1988 N = 1,148 Number of cobalt production workers NR | Historical mortality cohort study (SMR) and nested case-control analysis (OR) Mur et al. (1987) ICD-8: All causes; trachea, bronchus, and lung (162); buccal cavity/pharynx/larynx (140–149, 161) Moulin et al. (1993) ICD-8: All causes; bronchus, lung (162); brain (191) | Production of cobalt, cobalt salts, and oxides. Company records classified workers exclusively employed in one of four work groups including cobalt production workshop Mur et al. (1987) Cohort analysis: Only or never employed in cobalt production Nested case-control analysis: Ever/never employed in cobalt production Moulin et al. (1993) Mortality SMR analysis Only vs. never employed in cobalt production
Moulin et al. (1998) (multi-plant) Wild et al. (2000) (sub-study of largest plant) | French hard-metal workers Moulin et al. (1998) 1945–1991 N = 7,459 men and women; 68 cases and 180 controls Wild et al. (2000) 1950–1992 N = 2,860 men and women Number of workers employed in cobalt production only NR | Nested case-control analysis (OR) and historical mortality cohort study (SMR) Moulin et al. (1998) ICD-8: Lung (162) Wild et al. (2000) ICD-8: Lung (162) | Production of magnets, stainless steel, and cobalt powders “Other” cobalt exposure may have included metallic and ionized cobalt Semi-quantitative JEM Moulin et al. (1998) Duration, intensity, and cumulative exposure Wild et al. (2000) Ever exposed
Moulin et al. (2000b) | French stainless and alloyed steel worker cohort 1968–1991 N = 4,897; 54 cases and 160 controls | Nested case-control analysis (OR) within a historical mortality cohort study ICD-8: Lung (162) | Steel production and casting of stainless steel, nickel, ferro-chromium, and other ferroalloys in which iron, chromium, nickel, and cobalt compounds are used Powder manufacture of metallic powders Semi-quantitative JEM Duration, intensity, and cumulative exposure
Grimsrud et al. (2005) (methods described in Grimsrud et al. 2002; Grimsrud et al. 2003) | Nickel refinery worker cohort 1952–1995 N = 5,389; 213 cases and 524 controls | Nested case-control analysis (OR) within an incidence cohort study; Norwegian Cancer Registry ICD NR: Lung | Cobalt present in raw materials and intermediates in refinery and produced electrolytically in an electrowinning process Breathing zone personal samples for cobalt and nickel JEM Quantitative cumulative exposure

## 4.1 Selection of the Relevant Literature

Details of the procedures (such as the databases and literature search terms and screening methods) used to identify and select the primary studies and supporting literature for the human cancer evaluation are detailed in Appendix A and the cobalt protocol.

Primary epidemiologic studies were considered for the cancer evaluation if the study was (1) peer reviewed; (2) provided risk estimates (or sufficient information to calculate risk estimates) for cobalt and human cancer, and (3) provided exposure-specific analyses for cobalt at an individual level, or based on the authors’ report, cobalt exposure was probable or predominant in the population, job, or occupation under study.

Because cobalt can be released from hip and other joint implants, a preliminary literature search was also conducted to identify case reports and cohort studies of joint replacements or prosthetic devices. The case reports included at least 15 cases of malignant fibrous histiocytoma (12 cases reviewed by Hughes et al. 1987; Lucas et al. 2001; Min et al. 2008; Visuri et al. 2006), at least 5 cases of osteosarcoma (4 reviewed by Swann 1984; Visuri et al. 2006), at least 6 cases of other types of sarcoma (4 reviewed by Tayton 1980; van der List et al. 1988; Visuri et al. 2006), and at least 3 cases of non-Hodgkin or B-cell lymphoma (Cheuk et al. 2005; Dodion et al. 1983; McDonald 1981) occurring at the site of implantation of joint prosthetic devices (e.g., hip, knee, screws) containing cobalt alloys (primary cobalt-chromium). Case-reports of these types of cancer were also found among non-cobalt containing implants (reviewed by Visuri et al. 2006). The cohort studies (at least 16) were primarily record linkage studies conducted in Nordic countries, the United Kingdom, Austria and the United States, the majority of which did not provide information on the type of implants and most likely included patients with cobalt- and non-cobalt-containing implants. Two cohort studies (Visuri et al. 2010; Visuri et al. 1996) and patient series study (Visuri et al. 1996) reported on cancer risk among patients with McKee-Farrar implants, which contain a cobalt-chromium-molybdenum alloy. Overall, these studies were considered to be uninformative for evaluating effects due to cobalt because of study design (case reports have no comparison group), lack of specificity to cobalt (implants that are not made of cobalt or other metals present in cobalt-containing implants) and inadequate information on the extent of exposure to cobalt, and thus were excluded from the cancer assessment.

Studies of radioactive cobalt were also excluded, because of potential confounding from radioactivity. In general, cohort or case-control studies of populations with jobs, workplaces, or environmental exposures in which cobalt exposure may have occurred (e.g., studies of hard-metal workers) were excluded if a specific risk estimate for potential cobalt exposure alone was not reported.

Biomarker studies of cobalt and cancer were included if they were conducted within defined populations and provided risk estimates for cobalt levels and cancer. A series of clinical studies that compared cobalt and other metal levels in target tissues (such as tumors of different stages or normal tissue) or surrogates (e.g., hair, nails, blood) from cancer patients with a referent group (e.g., healthy humans, patients with cancer, other diseases) were identified and are summarized in Table B-2 (hair) and Table B-3 (tissues). For most studies, the source of the exposure was unknown, and it could not be distinguished whether metal levels could be a cause of cancer or whether the cancer process itself affected accumulation of cobalt in the tissue. Because these studies did not provide information to calculate an effect estimate, and most did not have defined methods for selecting the subjects, they are not included in the cancer hazard evaluation.

Environmental studies of cobalt and cancer were included if they were conducted within defined populations and provided risk estimates for cobalt levels and cancer. A total of four studies was identified, two of which investigated the relationship between cobalt in air to breast (Coyle et al. 2006) and lung (Coyle et al. 2005) cancer. The other two studies investigated the relationship between soil levels of cobalt and cancer (Kibblewhite et al. 1984; McKinley et al. 2013). None of the studies moved forward into the cancer hazard evaluation because they did not provide a risk estimate (or sufficient information to calculate one) or exposure-specific analyses at the individual level.

## 4.2 Cohort Studies and Nested Case-control Studies Reporting on Lung Cancer

This section provides an overview of the cohort and nested case-control studies (Section 4.2.1), an overview of the adequacy of the studies to inform the cancer hazard evaluation (Section 4.2.2) and an assessment of the evidence from the studies on the association between cobalt exposure and lung cancer risk (Section 4.2.3).

### 4.2.1 Overview of the Methodologies and Study Characteristics

For each of the reviewed cohort studies, detailed data on study design, methods, and findings were systematically extracted from relevant publications, as described in the study protocol, and into Table 4-1, Table C-1 through Table C-7, and Table 4-2.

Table 4-2 Bias and Quality Summary for Cohort and Nested Case-control Studies

Citation | Bias | | | | | | | | Quality^a^ | Utility^b^
Citation | Selection | | Exposure | Outcome | Confounding Methods | Adequacy of Analysis | Selective Reporting | | Sensitivity | Integration
Porcelain painters Tüchsen et al. (1996) | ++ | ++ | | +++ | ++ | ++ | | +++ | + | ++
Electrochemical workers Moulin et al. (1993) (with Mur et al. 1987) | ++ | ++ | | ++ | + | +++ | | +++ | + | +
Hard-metal workers Moulin et al. (1998) | ++ | ++/+++ | | +++ | + | +++ | | +++ | ++ | ++
Wild et al. (2000) | ++ | ++/+++ | | +++ | + | ++ | | +++ | ++ | ++
Stainless and alloyed steel workers Moulin et al. (2000b) | +++ | ++ | | +++ | + | +++ | | +++ | ++ | ++
Nickel refinery workers Grimsrud et al. (2005) | +++ | +++ | | +++ | ++ | +++ | | +++ | +++ | +++

^a^ Levels of concern for bias and for study quality rating. Equal column width for types of bias does not imply they have equal weight (see appendix for description of terms): Scoring system: +++ = low/minimal concern or high quality; ++ = some concern or medium quality; + = major concern or low quality; 0 = critical concern.

^b^ Utility of the study to inform the hazard evaluation (see Appendix C for description of terms) scoring system: ++++ = high utility; +++ = moderate utility; ++ = moderate/low utility; + = low utility; 0 = inadequate utility.

The available epidemiological studies that satisfy the criteria for consideration in the cancer evaluation consist of a series of occupational cohort or nested case-control studies conducted in five independent populations. These include a cohort of female Danish porcelain painters; a cohort of French electrochemical workers; and French cohorts of hard-metal workers, and stainless and alloyed steel workers; and Norwegian nickel refinery workers.

Tüchsen et al. (1996) reported on cancer incidence at multiple tissue sites among 1,394 female porcelain painters employed in underglazing departments of two porcelain plate factories in Denmark where cobalt-aluminate spinel and/or cobalt silicate was used, compared with top glaze decorators in a department in one of the factories without cobalt exposure.

Studies on the French electrochemical workers producing cobalt were reported in two publications. The first publication was on a historical mortality cohort and nested case-control study of lung cancer among 1,143 cobalt production workers in a French electrochemical plant (Mur et al. 1987). This study included workers who had been employed for at least one year between 1950 and 1980. At this plant, cobalt was produced from a cobalt chloride solution by etching roasted ore, neutralization, filtration, and electrolysis. The manufacturing process also included production of cobalt salts and oxides. The second publication was a re-analysis of the cohort (N = 1,148), incorporating revised case-ascertainment and an extended period of follow-up (Moulin et al. 1993). The electrochemical worker cohort analyses reported findings for trachea/bronchus/lung cancer, buccal cavity/pharynx, and larynx cancers (Mur et al. 1987); and bronchus/lung, buccal-cavity/pharynx, larynx, esophagus, and brain cancers (Moulin et al. 1993). Although both studied the same population, the original cohort is discussed because it contains additional information (e.g., a nested case-control analysis) not included in the update.

Two publications reported on overlapping populations of hard-metal workers. The first was a historical mortality cohort and nested case-control study of lung cancer among 7,459 workers at 10 hard-metal producing factories in France (Moulin et al. 1998) where activities also included powder metallurgy processes. The second was a sub-study of lung cancer among 2,860 workers in the largest hard-metal producing factory in France (the factory was included in the Moulin et al. (1998) study, with an additional year of follow-up included) which also produced magnets and stainless steel with cobalt, and cobalt powders by calcination and reduction of cobalt hydroxide (Wild et al. 2000). This study also provided complete job histories.

A historical cohort and nested case-control study of stainless and alloyed steel workers and lung cancer conducted in one factory in France (N = 4,897), which produced and cast stainless and alloyed steel from cobalt, was also identified. Lastly, an incident nested case-control study of 213 cases of lung cancer among Norwegian nickel refinery workers was conducted to evaluate whether exposure to cobalt (and other metals) could explain the elevated risk of lung cancer in nickel workers.

In the two studies of electrochemical workers (Moulin et al. 1993; Mur et al. 1987), exposure was assessed based on company records, which grouped workers into general service, maintenance, and sodium production or cobalt production areas. Analysis was conducted for “ever employment” in the cobalt production workshop, or for exclusive employment in this area. Similarly, in the porcelain factories, exposure was based on company records, which grouped workers into those who worked in departments with and without cobalt exposure (Tüchsen et al. 1996). Exposure to cobalt in the hard-metal factories, and the stainless and alloyed steel factory was classified using a semi-quantitative job-exposure matrix (JEM) developed by experts; the nickel refinery workers were classified using this JEM which incorporated quantitative personal measurements from the breathing zone.

All of the cohort and nested case-control studies reported on lung cancer alone, or lung cancer and aerodigestive cancers, with only one of these reporting specifically about aerodigestive cancers (i.e., buccal cavity/pharynx, and larynx cancers) (Mur et al. 1987) in relation to cobalt exposure. Only one study reported on multiple sites in relation to cobalt (i.e., cervix, ovary, breast, and skin) (Tüchsen et al. 1996); thus, lung cancer is the only site with an adequate database to contribute to the cobalt and cancer assessment.

The description of study methods and characteristics of each study is included in Table C-1 through Table C-7.

### 4.2.2 Study Quality and Utility Evaluation

This section provides an overview of the adequacy of the cohort and nested case-control studies to inform the cancer hazard evaluation (see Appendix C for details on the assessment). This assessment considers factors related to study quality (potential for selection and attrition bias, information bias regarding exposure and outcome, and concern for inadequate analytical methods, selected reporting, and inadequate methods or information to evaluate confounding) and study sensitivity (e.g., such as adequate numbers of individuals exposed to substantial levels of cobalt). The ratings for each of these factors are provided in Table 4-2 and a detailed description of the rationale for the rating is provided in Appendix C.

No critical concerns for the potential for any of the biases (domains) were identified in the available studies; thus, each may have some utility for evaluating potential cancer hazards. All of the reported cohorts are relatively small or moderate sized and are, consequently, underpowered due to few exposed cases or deaths. With one exception (Grimsrud et al. 2005), the cohort or nested case-control studies included only very few cases exposed to cobalt alone, limiting their statistical power to evaluate a modest risk of lung cancer (if it exists) from cobalt. In addition, the level of exposure to cobalt alone in the cohort and nested studies was not defined with enough detail (excepting Grimsrud et al. 2005) to explore exposure-response relationships. Table 4-2 depicts the overall assessment of the ability to inform the cancer evaluation based on the overall utility of the studies, including potential for biases and study sensitivity.

The study of nickel refinery workers (Grimsrud et al. 2005) was considered to have the highest quality because it had adequate numbers of exposed cases, evaluated cancer incidence, incorporated quantitative assessments of exposure to cobalt, and had sufficient information on potential confounders and co-exposures to incorporate these factors into analyses. However, exposure to cobalt was highly correlated with nickel, which compromises the ability of the statistical models to disentangle effects from the two exposures.

The remaining studies were also considered to have low/moderate ability to inform the cancer hazard evaluation primarily because of more limited (semi-quantitative or qualitative) exposure assessments, potential bias, and/or lower sensitivity. The major concern in the studies of hard-metal workers (Moulin et al. 1998; Wild et al. 2000) and stainless-steel workers was potential confounding from potential co-exposure to other lung carcinogens; this was also the case, but to a lesser extent, for the electrochemical workers cohort. In the porcelain worker study (Tüchsen et al. 1996), subcohorts of workers employed prior to 1981 when biomonitoring began and exposure levels began to fall, would have contributed information about high exposures; however, only estimates for the entire cohort were reported, potentially diluting the effect. No relationship with duration of employment was found, but this was not reported by calendar period. In the electrochemical workers cohort, concerns arose about the changing source of outcome information from the first analysis (Mur et al. 1987) to the updated analysis (Moulin et al. 1993). The change from use of medical records to death certificates, in combination with a restriction to account for loss to follow-up in the foreign-born workers, reduced the estimate of the risk in the follow-up study. In general, potential bias from these studies was in the direction of the null, and they had limited sensitivity to detect an effect due to their small size or inadequate information regarding level of exposure.

### 4.2.3 Cancer Assessment: Lung

The goal of the cancer assessment is to evaluate the evidence for the carcinogenicity of cobalt for lung cancer. The conclusions regarding the assessment of study utility are brought forward, and these are considered together with the evidence from the individual studies. Next, the evidence is integrated across studies to reach a level of evidence conclusion to determine whether there is credible evidence of an association between cobalt and lung cancer, and whether such an observed association could be explained by chance, bias, or confounding.

Several of the considerations developed by Hill (Hill 1965) are relevant to the evaluation of the level of evidence for this assessment, including the magnitude (strength) and consistency of any observed associations across studies, evidence of an exposure-response gradient, and temporality of exposure. The NTP listing recommendation is provided in Section 4.5.

#### Background Information

Lung cancer is the third most common cancer in the United States, making up 13.5% of all new cancers. The age-adjusted annual lung cancer rates (including trachea and bronchus) (per 100,000 males or females) in the United States from 2007 to 2011 (NCI 2015c) were approximately 72.2 (male) and 51.1 (female) for incidence; and 61.6 (male) and 38.5 (female) for mortality, with a 5-year survival rate of 16.8%. These data suggest that mortality and incidence data are approximately comparable for informing the cancer assessment. Rates for new lung and bronchus cancer cases have decreased on average 1.5% each year over the last 10 years; and death rates have decreased on average 1.8% each year from 2002 to 2011. Incidence trends and rates in European countries where all of the cohort studies were conducted are broadly similar (Ferlay et al. 2013). For example, in the European Union, lung cancer incidence per 100,000 males is 66.3, and mortality is 56.4.

Latencies for solid tumors such as lung cancer are generally estimated to exceed approximately 20 years but may vary considerably. Incidence rates of lung cancer generally increase after 50 years of age, and this cancer is most frequently diagnosed among people aged 65 to 74; the median age at diagnosis is 70. None of the studies of cobalt and lung cancer included in this review have indicated the sub-type(s) of lung cancer included in their analyses.

The single most important non-occupational risk factor for the development of lung cancer is smoking. Other risk factors of concern include exposure to arsenic, asbestos, cadmium, silica, chromates, nickel compounds, and polycyclic aromatic hydrocarbons, all of which are found in cobalt manufacturing processes.

#### Evidence from Individual Studies

Based on the study quality evaluation, all six cohort and/or nested case-control studies reporting on lung cancer and cobalt exposure were considered to have some utility for inclusion in the cancer assessment. The findings from the individual studies are discussed below and presented in Table 4-3. The available cohort and nested case-control studies of cobalt and lung cancer include a cohort of Danish female porcelain painters, a cohort of French electrochemical workers, a French multi-centric cohort of hard-metal factory workers, a related cohort of workers from the largest factory in the multi-centric French hard-metal factory cohort, a cohort of French stainless and alloyed steel workers, and a cohort of Norwegian nickel-refinery workers.

Table 4-3 Evidence from Cohort and Case-control Studies on Lung Cancer and Exposure to Cobalt

Reference, Study Design, Location, and Year | Population Description & Exposure Assessment Method | Exposure Category or Level | Exposed Cases/ Deaths | Risk Estimate (95% CI) | Co-variates Controlled | Comments, Strengths, and Weaknesses
Tüchsen et al. (1996) Cohort Copenhagen, Denmark Factory 1: 1943–1992; Factory 2: 1962–1992 | Danish porcelain painters. 1,394 total; 874 cobalt-exposed workers, 520 unexposed workers. Exposure assessment method: company records | Lung (162 and 162.1) | | | | Employment in factories/departments with or without cobalt. Confounding: No control for smoking; however, smoking data on subset of workers suggests that smoking was not associated with exposure. Strengths: Population exposed primarily to cobalt compounds alone; only female population with data on cobalt. Limitations: Small number of exposed cases. Differential selection out of the cohort could have occurred as the authors mentioned that records of ill persons may have been removed potentially resulting in an underestimate of the true incidence of cancer.
Tüchsen et al. (1996) Cohort Copenhagen, Denmark Factory 1: 1943–1992; Factory 2: 1962–1992 | Danish porcelain painters. 1,394 total; 874 cobalt-exposed workers, 520 unexposed workers. Exposure assessment method: company records | All exposed | 8 | SIR 2.35 (1.09–4.45) | Age, calendar year
Tüchsen et al. (1996) Cohort Copenhagen, Denmark Factory 1: 1943–1992; Factory 2: 1962–1992 | Danish porcelain painters. 1,394 total; 874 cobalt-exposed workers, 520 unexposed workers. Exposure assessment method: company records | Factory 1 exposed to cobalt silicate from 1972 | 3 | 1.6 (0.41–4.37) | Age, calendar year
Tüchsen et al. (1996) Cohort Copenhagen, Denmark Factory 1: 1943–1992; Factory 2: 1962–1992 | Danish porcelain painters. 1,394 total; 874 cobalt-exposed workers, 520 unexposed workers. Exposure assessment method: company records | Factory 2 exposed to cobalt-aluminate spinel dye thru 1988 | 5 | 3.25 (1.19–7.2) | Age, calendar year
Tüchsen et al. (1996) Cohort Copenhagen, Denmark Factory 1: 1943–1992; Factory 2: 1962–1992 | Danish porcelain painters. 1,394 total; 874 cobalt-exposed workers, 520 unexposed workers. Exposure assessment method: company records | Referents | 7 | 1.99 (0.87–3.94) | Age, calendar year
Mur et al. (1987) Cohort France 1950–1980 | Electrochemical workers N = 1,143; number of cobalt production workers NR ~ 25% of current staff at time of publication Exposure assessment method: company records | Lung (162) | | | | Exposure duration: 60% worked greater than 10 years; 75% hired before 1975. Confounding: Likely inadequate control for smoking; however, likely co-exposure to nickel and arsenic with no control for co-exposures. Strengths: Cobalt production workers exposed primarily to cobalt compounds. Limitations: Small number of exposed cases; high loss to follow-up (20%); potential for selection bias due to left truncation
Mur et al. (1987) Cohort France 1950–1980 | Electrochemical workers N = 1,143; number of cobalt production workers NR ~ 25% of current staff at time of publication Exposure assessment method: company records | Only employed in cobalt production | 4 | SMR 4.66 (1.46–10.64) | Age, year of death
Mur et al. (1987) Nested case-control France 1950–1980 | Electrochemical plant workers Cases: 9; controls: 18 Exposure assessment method: company records | Lung (162) | | | | Confounding: Cases (deaths from lung cancer) were matched to controls (deaths from cause other than cancer) for year of birth, age at death, and smoking habits; smoking data on only 30% of the cohort; co-exposures to nickel and arsenic were not controlled. Strengths: Nested design reduces concern of potential confounding from lifestyle factors Limitations: Small numbers with limited information on exposures (only ever/never employment in cobalt production department); also, 46% of the cohort was hired prior to the start of follow-up which could induce a downward bias in the effect estimate due to over-prevalence of healthier workers (left truncation).
Mur et al. (1987) Nested case-control France 1950–1980 | Electrochemical plant workers Cases: 9; controls: 18 Exposure assessment method: company records | Ever worked in cobalt production | 4 | OR [4.0 (0.66–24.4)] | None
Moulin et al. (1993) Cohort France Extended follow-up of the Mur et al. (1987) study through 1988 | Electrochemical workers Cohort 1: N = 1,148; Cohort II: N = 870; number of cobalt workers NR Exposure assessment method: company records | Lung (162) | | | | Confounding: No reported control for period effects, duration, or time since first exposure; no consideration of smoking; potential co-exposures to nickel and arsenic from its presence in cobalt ore not controlled. Strengths: Cobalt production workers exposed primarily to cobalt compounds. Limitations: Small number of exposed cases in overall or sub-cohort; low power to detect an effect; concern about outcome misclassification; potential for selection bias due to left truncation
Moulin et al. (1993) Cohort France Extended follow-up of the Mur et al. (1987) study through 1988 | Electrochemical workers Cohort 1: N = 1,148; Cohort II: N = 870; number of cobalt workers NR Exposure assessment method: company records | Exclusive employment in cobalt production, Cohort I | 3 | OR 0.85 (0.18–2.5) | Age
Moulin et al. (1993) Cohort France Extended follow-up of the Mur et al. (1987) study through 1988 | Electrochemical workers Cohort 1: N = 1,148; Cohort II: N = 870; number of cobalt workers NR Exposure assessment method: company records | Exclusive employment in cobalt production, Cohort II | 3 | 1.16 (0.24–3.4) | Age
Moulin et al. (1993) Cohort France Extended follow-up of the Mur et al. (1987) study through 1988 | Electrochemical workers Cohort 1: N = 1,148; Cohort II: N = 870; number of cobalt workers NR Exposure assessment method: company records | Ever worked in Cobalt production, Cohort I | 4 | 0.88 (0.24–2.25) | Age
Moulin et al. (1993) Cohort France Extended follow-up of the Mur et al. (1987) study through 1988 | Electrochemical workers Cohort 1: N = 1,148; Cohort II: N = 870; number of cobalt workers NR Exposure assessment method: company records | Ever worked in cobalt production, Cohort II | 4 | 1.18 (0.32–3.03) | Age
Moulin et al. (1998) Nested case-control France 1968–1991 | Workers in all 10 hard-metal factories in France Cases: 61; controls: 180 Exposure assessment method: JEM | Lung (162) | | | | No information on actual exposure level or average exposure duration for the cohort. Confounding: Potential concern for exposure to other lung carcinogens, which were not controlled in the cobalt alone analyses. Strengths: Exposure-response analyses with multiple exposure metrics; JEM validated for atmospheric concentrations of cobalt; incident cohort reducing the potential for left truncation; internal analysis reducing the impact of the reported HWE; and lagged analysis. Limitations: Potential confounding by co-exposures classified only as “ever/never” in the JEM.
Moulin et al. (1998) Nested case-control France 1968–1991 | Workers in all 10 hard-metal factories in France Cases: 61; controls: 180 Exposure assessment method: JEM | Exposure level 2 to 9 | 15 | OR 2.21 (0.99–4.9) | Age
Moulin et al. (1998) Nested case-control France 1968–1991 | Workers in all 10 hard-metal factories in France Cases: 61; controls: 180 Exposure assessment method: JEM | Exposure intensity trend | 15 | 2.05 (0.94–4.45) | Age
Moulin et al. (1998) Nested case-control France 1968–1991 | Workers in all 10 hard-metal factories in France Cases: 61; controls: 180 Exposure assessment method: JEM | Exposure duration | 15 | 2.2 (0.99–4.87) | Age
Moulin et al. (1998) Nested case-control France 1968–1991 | Workers in all 10 hard-metal factories in France Cases: 61; controls: 180 Exposure assessment method: JEM | Unweighted cumulative exposure | 15 | 1.83 (0.86–3.91) | Age
Moulin et al. (1998) Nested case-control France 1968–1991 | Workers in all 10 hard-metal factories in France Cases: 61; controls: 180 Exposure assessment method: JEM | Frequency weighted cumulative exposure trend | 15 | 2.03 (0.94–4.39) | Age
Wild et al. (2000) Cohort France 1968–1992 | Hard-metal workers - Largest plant in France 2,216 men and 644 women Exposure assessment method: JEM | Lung (162) | | | | No information on actual exposure level or average exposure duration for the cohort Confounding: Potential exposure to lung carcinogens which were not controlled in cobalt-only analyses. Strengths: Incident cohort; lagged analysis. Limitations: External analysis only presented; no exposure metrics except for ever/never provided.
Wild et al. (2000) Cohort France 1968–1992 | Hard-metal workers - Largest plant in France 2,216 men and 644 women Exposure assessment method: JEM | Cobalt except in hard metals | 15 | SMR 1.95 (1.09–3.22) | Age, sex
Moulin et al. (2000b) Nested case-control France 1968–1992 | Stainless and alloyed steel workers Cases: 54 (17 cobalt exposed); controls: 162 (67 cobalt exposed) Exposure assessment method: JEM | Lung (162) | | | | No information on actual exposure level or average exposure duration for the cohort Confounding: Potential confounding from exposure to chromium and/or nickel, and iron; controlled for smoking Strengths: Semi-quantitative JEM; exposure metrics including duration and cumulative dose, frequency weighted and unweighted provided; HWE mitigated by use of internal analyses. Limitations: Known carcinogens had non-significant ORs <1.0, indicating that the study had low sensitivity to detect an effect.
Moulin et al. (2000b) Nested case-control France 1968–1992 | Stainless and alloyed steel workers Cases: 54 (17 cobalt exposed); controls: 162 (67 cobalt exposed) Exposure assessment method: JEM | Exposed, Crude | 17 | OR 0.64 (0.33–1.25) | –
Moulin et al. (2000b) Nested case-control France 1968–1992 | Stainless and alloyed steel workers Cases: 54 (17 cobalt exposed); controls: 162 (67 cobalt exposed) Exposure assessment method: JEM | Exposed, known smoking status, Crude | 12 | 0.62 (0.26–1.46) | –
Moulin et al. (2000b) Nested case-control France 1968–1992 | Stainless and alloyed steel workers Cases: 54 (17 cobalt exposed); controls: 162 (67 cobalt exposed) Exposure assessment method: JEM | Exposed, known smoking status, smoking adjusted | 12 | 0.43 (0.16–1.14) | –
Moulin et al. (2000b) Nested case-control France 1968–1992 | Stainless and alloyed steel workers Cases: 54 (17 cobalt exposed); controls: 162 (67 cobalt exposed) Exposure assessment method: JEM | Exposed, known smoking status, PAH, silica, and smoking adjusted | 12 | 0.44 (0.17–1.16) | –
Grimsrud et al. (2005) Nested case-control Norway 1910–1995 | Nickel refinery workers Cases: 213; controls: 525 Exposure assessment method: JEM | Lung | | | | Exposure levels (μg/m^3^): high (144–3,100); medium (29.7–142); low (0.31–29.5). Confounding: No multivariate estimates for the categorical variable (low, high, medium exposures) were possible due to collinearity with nickel. Continuous rise in OR controlled for smoking and co-exposures. Strengths: Quantitative cobalt levels reported based on measurements from the breathing zone; incident cases; internal analyses; relatively large number of cases compared to other cobalt studies. Limitations: Collinearity with nickel.
Grimsrud et al. (2005) Nested case-control Norway 1910–1995 | Nickel refinery workers Cases: 213; controls: 525 Exposure assessment method: JEM | Rise in OR per mg/m^3^ × years, smoking adjusted | NR | OR 1.3 (0.9–1.8) | Smoking
Grimsrud et al. (2005) Nested case-control Norway 1910–1995 | Nickel refinery workers Cases: 213; controls: 525 Exposure assessment method: JEM | Low (0.31–29.5 μg/m^3^ × years | 49 | 1.5 (0.6–3.8) | Smoking
Grimsrud et al. (2005) Nested case-control Norway 1910–1995 | Nickel refinery workers Cases: 213; controls: 525 Exposure assessment method: JEM | Med (29.7–142 μg/m^3^ × years | 73 | 2.4 (1–5.6) | Smoking
Grimsrud et al. (2005) Nested case-control Norway 1910–1995 | Nickel refinery workers Cases: 213; controls: 525 Exposure assessment method: JEM | High (144–3,100 μg/m^3^ × years | 82 | 2.9 (1.2–6.8) | Smoking
Grimsrud et al. (2005) Nested case-control Norway 1910–1995 | Nickel refinery workers Cases: 213; controls: 525 Exposure assessment method: JEM | Lung
Grimsrud et al. (2005) Nested case-control Norway 1910–1995 | Nickel refinery workers Cases: 213; controls: 525 Exposure assessment method: JEM | Rise in OR per mg/m^3^ × years, smoking and co-exposure adjusted | NR | 0.7 (0.3–1.4) | Smoking, nickel, sulfuric acid mists, asbestos, arsenic
Grimsrud et al. (2005) Nested case-control Norway 1910–1995 | Nickel refinery workers Cases: 213; controls: 525 Exposure assessment method: JEM | Lung
Grimsrud et al. (2005) Nested case-control Norway 1910–1995 | Nickel refinery workers Cases: 213; controls: 525 Exposure assessment method: JEM | Cobalt electrolysis workshop, 0.03–2.2 yr | 23 | 1.6 (0.8–3) | Smoking, and employment in other workshops
Grimsrud et al. (2005) Nested case-control Norway 1910–1995 | Nickel refinery workers Cases: 213; controls: 525 Exposure assessment method: JEM | Cobalt electrolysis workshop, 2.3–11.8 yr | 44 | 2.8 (1.5–5) | Smoking, and employment in other workshops
Grimsrud et al. (2005) Nested case-control Norway 1910–1995 | Nickel refinery workers Cases: 213; controls: 525 Exposure assessment method: JEM | Cobalt electrolysis workshop 12–48 yr | 62 | 5.1 (2.9–9.1) | Smoking, and employment in other workshops

HWE = Healthy worker effect; HWSE = Healthy worker survival effect; JEM = job-exposure matrix/ NR = Exposure levels or duration not reported; OR = odds ratio; PAHs = polycyclic aromatic hydrocarbons.

#### Porcelain Painters

Tüchsen et al. (1996) reported a significantly increased risk of lung cancer in all exposed female workers compared with the Danish female population (SIR = 2.35, 95% CI = 1.01 to 4.62, based on 8 exposed cases). Factory-specific SIRs for lung cancer were also reported, indicating that Factory 1, where cobalt aluminate-spinel was replaced by cobalt silicate in 1972, had a non-significantly elevated SIR of 1.6 based on 3 exposed cases (no CI provided); and that Factory 2, where workers continued to be exposed to cobalt aluminate-spinel until 1989, had a significantly elevated SIR of 3.25 based on 5 exposed cases. In addition, the authors reported an elevated SIR of lung cancer in the referent group (SIR = 1.99, 95% CI = 0.80 to 4.11, 7 cases), similar in magnitude to that found in the exposed group.

This study had low sensitivity to detect an effect because of (1) small numbers of exposed cases in this relatively small cohort and (2) potentially combining workers with high and low exposures together, which could dilute any effect and bias the results towards the null. In addition, no lagged analyses were reported. A concern about differential selection also exists in this study. The authors suggested that removal of records of ill persons was known to take place in Danish manufacturing. The possibility of differential selection out of the cohort could have resulted in an underestimation of the true incidence of lung cancer in this study.

An elevated lung cancer SIR, similar in magnitude to that reported in the exposed group, was also observed in the referents; a comparison of the exposed departments with the reference department gave a relative risk ratio of 1.2 (95% CI = 0.4 to 3.8). The referents were reported to be top glaze decorators employed in a department without cobalt exposure. Data from a previous publication in this factory (Raffn et al. 1988) indicated an overlap of cobalt levels in referents and exposed individuals, suggesting that the referents in the Tüchsen et al. (1996) paper were not completely “unexposed.” Limited information regarding smoking and its potential relationship with cobalt exposure was provided from two surveys of subsamples of workers (Prescott et al. 1992; Raffn et al. 1988). Based on a calculation of the weighted average of exposed and unexposed respondents from both studies taken over the total sample size of the two studies and disregarding the specific cobalt compound to which workers were exposed, the smoking rate is calculated to be 52% for exposed and 38% for referent women. The rate of smoking among exposed women is close to that of skilled Danish women taken in 1982 (47%) and 1987 (55%); and the rate of smoking in the referent group is similar to, but lower than, the rate in the general population of Danish women (43% and 42% in these two years). This suggests that there may be a non-smoking cause for the increased rate of lung cancer in the referent population, which might be due either to misclassification of cobalt exposure, or to another unmeasured confounder. It is also possible that cobalt-exposed workers are also exposed to the same unmeasured confounder, although data from the substudy indicates that levels of silica, nickel, and dust were very low based on air monitoring done in 1981 (Raffn et al. 1988). The porcelain painters cohort provides inconclusive evidence for a carcinogenic effect of cobalt and lung cancer because of the finding of similarly elevated levels of lung cancer among the referents.

The Tüchsen et al. (1996) study stands out from others in that it consists entirely of women. Christensen et al. (1993) conducted a cross-over study of oral administration of soluble and insoluble cobalt compounds and found that there are clear differences in biological levels by gender, with significantly higher urinary cobalt (higher uptake) levels and urinary excretion of cobalt in females compared with males.

#### Electrochemical Workers

Two publications reported on the same cohort of cobalt production workers in a French electrochemical plant (Moulin et al. 1993; Mur et al. 1987). Findings from both publications are reported because the methodologies employed in each differ in important ways that shed light on their interpretation; that is, the later paper (Moulin et al. 1993) is not simply an update of the earlier paper. The first paper reported a statistically significantly increased SMR for lung cancer among the workers employed in cobalt production only (SMR = 4.66, 95% CI = 1.46 to 10.64, based on 4 observed deaths) (Mur et al. 1987). There was large loss to follow-up and clear evidence of a healthy worker effect in the overall cohort (all-cause mortality SMR = 0.77 [95% CI = 0.67 to 0.88]), but not among cobalt production workers. However, in an internal matched analysis (matching variables were year of birth, age at death, and smoking habits), the percent of cases and controls matched on year of birth, age at death and smoking habits ever employed at cobalt production was provided, without estimated odds ratio or confidence interval. An unadjusted calculation computed by NTP = OR of 4.0 (95% CI = 0.7 to 24.4), indicating internal consistency with the reported SMR for those working only in cobalt production.

However, in an extension of the follow-up of the same cohort (Moulin et al. 1993) the SMR for lung cancer among French-born workers exclusively employed in cobalt production was 1.16, (95% CI = 0.24 to 3.40), based on 3 observed deaths. (Confidence in the SMR for the entire cohort is lower because of high loss to follow-up and strong healthy worker effect due to 24% foreign-born workers). In addition, Moulin et al. (1993) reported a discrepancy in the number of observed cases exclusively employed in cobalt production in the two analyses (e.g., Mur et al. (1987) [N = 4]; Moulin et al. (1993) [N = 3]) due to differences in the methods used to ascertain cause of death. The Mur et al. (1987) study used physicians’ medical records, whereas Moulin et al. (1993) used death certificates for the years when they were available and, in the process, one exposed case was re-classified as non-diseased; furthermore, during the extended follow-up, no additional lung cancer cases were observed.

A further limitation of this study is its very weak consideration of risk factors for lung cancer, particularly smoking status, and possible co-exposures in the cobalt production process to nickel and arsenic. Mur et al. (1987) initially reported that smoking histories were available for 30% of workers, and the authors reported matching cases and controls on smoking status; however, no explanation was given regarding the methods of matching given the small percentage of workers with information on smoking status. Moulin et al. (1993) did not address smoking in the analysis but reported no excess of mortality from circulatory and respiratory diseases, suggesting that smoking is unlikely to be higher in this cohort than in the local French referent population.

Selection bias is somewhat of a concern in this cohort, as 46% of members were hired prior to the start of follow-up, which suggests that the cohort had a high proportion of healthy prevalent workers, which can bias the risk estimate downward (left truncation) (Applebaum et al. 2011).

The evidence from these electrochemical studies is inconclusive, based on the low sensitivity of the Moulin et al. (1993) study to detect an effect, the lack of exposure metrics in both studies, potential selection bias from left-truncation, and the inability to control for confounding. The changed outcome classification across the two analyses does not inspire confidence in the methods used in either study. The Mur et al. (1987) analysis was consistent across the internal and external analyses, reducing concerns about confounding from the HWE, however, selection bias due to left-truncation remains a concern.

#### French Hard-metal Worker Cohorts

The populations included in the two studies of cobalt exposure and lung cancer among hard-metal workers overlap, and both studies report either statistically significant elevated risks or borderline statistically significant risks of lung cancer among those exposed to cobalt without tungsten carbide. Moulin et al. (1998) first reported results from the multi-center study of 10 hard-metal factories in France. In the internal nested case-control analysis (Moulin et al. 1998), based on 15 exposed cases, a borderline statistically significant increased risk of lung cancer was associated with exposure to “cobalt alone or simultaneously with agents other than tungsten carbide” (levels 2 to 9) compared with little or no exposure (levels 0 or 1) (OR = 2.21, 95% CI = 0.99 to 4.90). Regarding the presence of an exposure-response relationship, Moulin et al. (1998) reported two-fold elevated trend tests (although not reaching statistical significance) based on 15 cases across levels of exposure (OR = 2.05, 95% CI = 0.94 to 4.45), levels of duration (2.20, 95% CI = 0.99 to 4.87), cumulative weighted (1.83, 95% CI = 0.86 to 3.91), and cumulative un-weighted doses (2.03, 95% CI = 0.94 to 4.39). Numbers of cases and category-specific OR estimates for levels or categories of duration or cumulative dose were not provided. Wild et al. (2000) added years of follow-up to the cohort from the largest factory included in the multi-center study and found a statistically significant elevated SMR of lung cancer among those exposed to “cobalt except in hard metals” based on the JEM (SMR = 1.95, 95% CI = 1.09 to 3.22). Wild et al. (2000), however, did not provide information on exposure-response relationships; and neither study provided an examination of latency.

Moulin et al. (1998) and Wild et al. (2000) both measured and addressed co-exposures to 9 workplace lung carcinogens and smoking in analyses for cobalt-tungsten carbide. In both studies, the JEM was used to assess exposure to other workplace carcinogens. Ever vs. never smoking was obtained through interviews with cohort members, and their colleagues and relatives in the Moulin et al. (1998) study and from occupational health department records in the Wild et al. (2000) study. However, in both studies, it is unclear whether the analyses of cobalt alone included models for adjusting for co-exposures to other carcinogens or smoking. In the Wild et al. (2000) study, exposure to any IARC carcinogen without considering exposure to cobalt-tungsten carbide was related to lung cancer (SMR = 2.05, 95% CI = 1.34 to 3.0).

Potential confounding from exposure to smoking is less of a concern in this study than potential confounding from exposure to other carcinogens. There is no evidence from data presented to indicate that exposure to cobalt alone and smoking was related. In addition, the low mortality from smoking-related disease suggests a limited potential for confounding, as smoking is unlikely to be more prevalent among the workers than in the overall population. In the French cohort, mortality from chronic bronchitis and emphysema was low (SMR = 0.4, 95% CI = 0.05 to 1.44) and there was no consistent mortality pattern for other smoking-related cancers (e.g., larynx, bladder, buccal cavity/pharynx, and esophagus). In addition, as internal analyses are usually assumed to be less affected by confounding from lifestyle factors (e.g., smoking) than SMRs, the OR estimate from the multivariate model reported by Moulin et al. (1998) in the internal analysis is likely to be the better estimate for cobalt and lung cancer from this cohort. Due to the lack of information about control of carcinogenic co-exposures, confidence in the finding is reduced.

#### Stainless and Alloyed Steel Cohort

No association between cobalt exposure and lung cancer was found in this study (Moulin et al. 2000b). In internal analyses of cobalt exposure based on the JEM in the stainless and alloyed steel plant, Moulin et al. (2000b) reported a crude OR of 0.64 (95% CI = 0.33 to 1.25), and an OR adjusted for PAHs and silica of 0.58 (95% CI = 0.29 to 1.17) based on 17 exposed cases and 67 controls in 10-year lagged analyses. Similar findings were found among those with known smoking habits (e.g., 12 cases and 36 controls). Moulin et al. (2000b) also reported significant decreasing trends in duration, and frequency un-weighted and weighted cumulative dose for workers with known smoking habits. (The overall cohort SMR for smoking and lung cancer was 5.37 [95% CI = 1.74 to 12.53] for those working less than 10 years). ORs adjusted for smoking were all less than 1.0 (Moulin et al. 2000b). It is likely that non-differential exposure misclassification was introduced into the exposure assessment because some job periods of cases or controls went back many decades, yet exposure was assessed based on memories of processes and exposures of current workers or reports in the literature, as historical exposure measurements were lacking. Models were reported controlling for PAHs and silica, none of which made any material difference; however, in the correlation matrix, neither of these was related to cobalt exposure. Exposure to nickel and/or chromium was related to cobalt exposure, although these exposures were not included in the cobalt model. However, these exposures were also not associated with lung cancer risk in these analyses.

In this study, chromium and/or nickel and asbestos, all lung carcinogens classified by RoC and IARC, were found to be unrelated to lung cancer, decreasing the confidence in this study and in the findings for cobalt. Only exposure to PAHs and silica were statistically significantly related to lung cancer along with increasing trends not confounded by smoking.

Misclassification of exposure in this study, its inability to control for the appropriate confounders correlated with cobalt, and the negative findings for lung cancer and other known lung carcinogens (e.g., nickel, chromium, asbestos) suggest little confidence in the evidence put forth in this study.

#### Norwegian Nickel Refinery Workers

The Grimsrud et al. (2005) cancer incidence study of nickel and lung cancer in a Norwegian nickel refinery was conducted to determine if cobalt or other potential carcinogens could explain the elevated risks of lung cancer in nickel workers. The authors reported that the cobalt variable could not be retained in the full model in its categorical form due to collinearity (all individuals exposed to nickel were also exposed to cobalt, although the correlation between cobalt and nickel was reported as r = 0.63); however, the positive exposure-response effect noted for the continuous cobalt variable adjusted only for smoking changed sign when smoking and co-exposures (nickel, arsenic, asbestos, and sulfuric acid mists) were controlled. The smoking-adjusted rise in OR per mg/m^3^ × year was 1.3 (95% CI = 0.9 to 1.8), which was reduced to 0.7 (95% CI = 0.3 to 1.4) after adjustment for occupational co-exposures. The categorical ORs adjusted only for smoking were low exposure (0.31 to 29.5 μg/m^3^) based on 49 cases, OR = 1.5 (95% CI = 0.6 to 3.8); medium exposure (29.7 to 142 μg/m^3^) based on 73 cases, OR = 2.4 (95% CI = 1.0 to 5.6); and high exposure (144 to 3,100 μg/m^3^) based on 82 cases, OR = 2.9 (95% CI = 1.2 to 6.8). No value for trend was reported for the smoking-adjusted variable. However, the fully adjusted model for this cobalt variable (including smoking as well as all co-exposures) could not be calculated due to collinearity.

The authors reported that cobalt levels typically amount to 4% to 15% of the total nickel levels, except in the cobalt electrolysis process where cobalt levels are triple the amount of nickel levels. This process is included in hydrometallurgical production, for which results are reported by duration of work. Strong gradients were found by duration of work in the hydrometallurgical production department with a 5-fold increase in the OR for 12 or more years (OR = 5.1, 95% CI = 2.9 to 9.1) based on 62 exposed cases, with the linear trend (per 10 years) (OR = 1.7, 95% CI = 1.4 to 2.1). However, no analyses were provided to help separate effects of exposure to cobalt and nickel.

Although the design of this study was of high quality, due to the collinearity with exposure to nickel, this study cannot separate out the effects of cobalt and nickel on lung cancer and thus the findings from the study are unclear.

#### Integration of Evidence across Studies

While almost all the cohort studies reported approximately a doubling of the risk of lung cancer mortality or incidence from exposure to various cobalt compounds, it is unclear that the excess lung cancer was due to exposure specifically to cobalt, because (1) it was not possible to rule out confounding by carcinogenic co-exposures, or (2) other complications prevented a clear interpretation of a cobalt effect (see Figure 4-1).

Figure 4-1

Forest Plot Showing Lung Cancer Risk Ratios (SIR, SMR, or OR as Noted) and 95% CI for Epidemiological Cohort Studies of Cobalt Exposure

The Danish porcelain painters study showed similarly elevated risks of lung cancer in both the exposed and unexposed workers and could not control directly for smoking. Findings from the French electrochemical workers cohort were based on two papers analyzing the same cohort using different methods to ascertain cancer and publishing conflicting results—the first indicated a significantly elevated risk of lung cancer based on four exposed cases, and the second showed virtually no differences in risk of lung cancer among the exposed and unexposed workers based on three exposed cases in a subset of workers born in France. In two French studies of hard-metal workers, measures of cobalt exposures were likely mixed with other carcinogens and the methods did not clearly indicate whether these were controlled in the analyses. Although an exposure-response relationship between cobalt exposure and lung cancer was observed in the Norwegian nickel refinery workers study, risk estimates could not be calculated in models controlling for other co-exposures because nickel and cobalt were highly correlated. However, in this study a significant trend was reported with increasing duration of employment in workshops where cobalt concentrations tripled those of nickel, with control for employment in other workshops and smoking. Confounding by smoking was considered in each of the studies to varying degrees, and smoking either did not reduce the risk estimates materially when it was controlled or was unlikely to materially reduce the risk estimates in studies where there was only auxiliary information.

## 4.3 Case-control Studies

This section provides an overview of the case-control studies (Section 4.3.1), an overview of the adequacy of the studies to inform the cancer hazard evaluation (Section 4.3.2) and an assessment of the evidence from the studies on the association between cobalt exposure and esophageal cancer risk (Section 4.3.3).

### 4.3.1 Overview of the Methodologies and Study Characteristics

The available epidemiological studies that satisfy the criteria for inclusion in the review consist of two population-based case-control studies of metals in biological tissues of cancer cases (lung, esophageal, oral cavity, and laryngeal cancers) and controls published in the literature between 1986 and 2012 (Table 4-4). Both of these studies (O’Rorke et al. 2012; Rogers et al. 1993) were initiated from an interest in the role of metals in the etiology of cancer, and specifically metals derived from nutritional sources. Detailed data on study design, methods, and findings were systematically extracted from relevant publications, as described in the study protocol, into Table 4-5, Table C-8, Table C-9, and Table 4-6.

Table 4-4 Case-control Biomarker Studies of Exposure to Cobalt

Reference | Design and Population | Outcome | Exposure: Cobalt Compounds, Assessment, Metrics
Rogers et al. (1993) | Population-based case-control biomarker study Western WA state USA 1983–1987 501 cases (153 laryngeal, 73 esophageal, 359 oral cavity cancers)/434 controls | ICD-O Larynx (140.0–141.9) Esophagus (143.0–146.9) Oral cavity (148.0–150.9; 161.0–161.9) | Source and type of compounds unknown Cobalt levels in toenails measured Tertiles (ppm)
Rogers et al. (1993) | Population-based case-control biomarker study Ireland FINBAR* study 2002–2004 | ICD not reported Esophagus Barrett’s esophagus (metastatic precursor to esophageal cancer) | Source and type of compounds unknown Cobalt levels in toenails measured Tertiles (log transformed - cut points μg/g)

* FINBAR = Factors Influencing the Barrett’s Adenocarcinoma Relationship.

Table 4-5 Bias and Quality Summary for Case-control Studies

Citation | Bias^a^ | | | | | | Quality^a^ | Utility^b^
Citation | Selection | Exposure | Outcome | Confounding Methods | Adequacy of Analysis | Selective Reporting | Sensitivity | Integration
Rogers et al. (1993) | +++ | + | +++ | +++ | +++ | +++ | + | +
O’Rorke et al. (2012) | ++ | + | +++ | +++ | +++ | +++ | + | +

^a^ Levels of concern for bias and for study quality rating. Equal column width for types of bias does not imply they have equal weight (see appendix for description of terms): +++ = low/minimal concern or high quality; ++ = some concern or medium quality; + = major concern or low quality; 0 = critical concern.

^b^ Utility of the study to inform the hazard evaluation (See appendix for description of terms): ++++ = high utility; +++ = moderate utility; ++ = moderate/low utility; + = low utility; 0 = inadequate utility.

Table 4-6 Evidence from Studies of Aerodigestive Cancers and Exposure to Cobalt

Reference, Study Design, Location, and Year | Population Description & Exposure Assessment Method | Exposure Category or Level | Exposed Cases/ Deaths | Risk Estimate (95% CI) | Co-variates Controlled | Comments, Strengths, and Weaknesses
Rogers et al. (1993) Case-control Western WA state, USA 9/1/83–2/28/87 | Population based study of aerodigestive cancers, USA Cases: N = 507; N = 153 laryngeal, N = 73 esophageal, N = 359 oral cavity cancers; Controls: N = 434 Exposure assessment method: personal monitoring | Esophagus (143.0–146.9) | | | | Exposure levels: Tertiles of cobalt in toenails; highest level = 0.17 ppm Confounding: Cases and controls were matched on key likely confounders. No information provided about correlation of cobalt with other measured trace metal levels, and nutrients not correlated with cobalt were kept in the model because they resulted in ORs closer to the null. ORs for esophageal cancer were significantly elevated for iron and calcium Strengths: Population-based study; histologically confirmed cancers; cases and controls from same source population. Limitations: Not all samples reflect pre-diagnostic window of exposure. No USDA data available on cobalt levels in food as measured by a food frequency questionnaire. Single sample collected even though cobalt in toenails shown to have low reproducibility; window of exposure a concern with long latency cancer.
Rogers et al. (1993) Case-control Western WA state, USA 9/1/83–2/28/87 | | <0.05 | 92 | OR = 1.0 | Age, sex, smoking (pack-years), alcohol (drink-years), beta-carotene (mg/day), energy intake (kcal/day), ascorbic acid (mg/day)
Rogers et al. (1993) Case-control Western WA state, USA 9/1/83–2/28/87 | | 0.05–0.17 | 127 | 2.4 (0.8–7.2) | Age, sex, smoking (pack-years), alcohol (drink-years), beta-carotene (mg/day), energy intake (kcal/day), ascorbic acid (mg/day)
Rogers et al. (1993) Case-control Western WA state, USA 9/1/83–2/28/87 | | >0.17 | 66 | 9 (2.7–30) | Age, sex, smoking (pack-years), alcohol (drink-years), beta-carotene (mg/day), energy intake (kcal/day), ascorbic acid (mg/day)
Rogers et al. (1993) Case-control Western WA state, USA 9/1/83–2/28/87 | | Larynx (140.0–141.9)
Rogers et al. (1993) Case-control Western WA state, USA 9/1/83–2/28/87 | | <0.05 | 114 | OR = 1.0 | Age, sex, smoking (pack-years), energy intake (kcal/day), beta-carotene (mg/day), ascorbic acid (mg/day), alcohol (drink-years)
Rogers et al. (1993) Case-control Western WA state, USA 9/1/83–2/28/87 | | 0.05–0.17 | 168 | 2 (1–3.8) | Age, sex, smoking (pack-years), energy intake (kcal/day), beta-carotene (mg/day), ascorbic acid (mg/day), alcohol (drink-years)
Rogers et al. (1993) Case-control Western WA state, USA 9/1/83–2/28/87 | | >0.17 | 62 | 1 (0.4–2.6) | Age, sex, smoking (pack-years), energy intake (kcal/day), beta-carotene (mg/day), ascorbic acid (mg/day), alcohol (drink-years)
Rogers et al. (1993) Case-control Western WA state, USA 9/1/83–2/28/87 | | Oral cavity cancer (148.0–150.9; 161.0–161.9)
Rogers et al. (1993) Case-control Western WA state, USA 9/1/83–2/28/87 | | <0.05 | 135 | OR = 1.0 | Age, sex, smoking (pack-years), alcohol (drink-years), energy intake (kcal/day), ascorbic acid (mg/day), beta-carotene (mg/day)
Rogers et al. (1993) Case-control Western WA state, USA 9/1/83–2/28/87 | | 0.05–0.17 | 190 | 1.5 (0.9–2.6) | Age, sex, smoking (pack-years), alcohol (drink-years), energy intake (kcal/day), ascorbic acid (mg/day), beta-carotene (mg/day)
Rogers et al. (1993) Case-control Western WA state, USA 9/1/83–2/28/87 | | >0.17 | 92 | 1.9 (1–3.6) | Age, sex, smoking (pack-years), alcohol (drink-years), energy intake (kcal/day), ascorbic acid (mg/day), beta-carotene (mg/day)
O’Rorke et al. (2012) Case-control All Ireland (Republic and Northern) 3/2002–12/2004 | All Ireland population-based study of esophageal cancer and Barrett's esophagus Cases: N = 137 for esophageal cancer, N = 182 for Barrett’s esophagus; Controls: N = 221 Exposure assessment method: personal monitoring | Esophageal cancer | | | | Exposure levels: Average (μg/g) ± SD: cases = 0.02 ± 0.06; controls = 0.02 ± 0.04. Range: cases = 0.002–0.60; controls = 0.002–0.47 Confounding: No correlation of cobalt levels with selenium, chromium, zinc, mercury, and cerium reported, nor were other metals included in models. Strengths: Population based; histologically confirmed cancer. Limitations: Differences in sources of cases and controls in N. Ireland and Rep. of Ireland may introduce some selection bias; low participation rate in controls, especially in Rep. of Ireland. Not all samples reflect pre-diagnostic window of exposure. Single sample collected even though cobalt in toenails shown to have low reproducibility; window of exposure a concern with long latency cancer.
O’Rorke et al. (2012) Case-control All Ireland (Republic and Northern) 3/2002–12/2004 | | < −5.4824 | 34 | OR = 1.0 | Age, sex, GI reflux, education, H. pylori infection, location, smoking
O’Rorke et al. (2012) Case-control All Ireland (Republic and Northern) 3/2002–12/2004 | | ≥ −5.4824 | 39 | 1.06 (0.57–1.98) | Age, sex, GI reflux, education, H. pylori infection, location, smoking
O’Rorke et al. (2012) Case-control All Ireland (Republic and Northern) 3/2002–12/2004 | | ≥ −4.4705 | 52 | 1.54 (0.84–2.85) | Age, sex, GI reflux, education, H. pylori infection, location, smoking
O’Rorke et al. (2012) Case-control All Ireland (Republic and Northern) 3/2002–12/2004 | | Trend-test p value: 0.16
O’Rorke et al. (2012) Case-control All Ireland (Republic and Northern) 3/2002–12/2004 | | Esophageal cancer
O’Rorke et al. (2012) Case-control All Ireland (Republic and Northern) 3/2002–12/2004 | | < −5.4824 | 34 | OR = 1.0 | Age, sex
O’Rorke et al. (2012) Case-control All Ireland (Republic and Northern) 3/2002–12/2004 | | ≥ −5.4824 | 39 | 1.13 (0.64–1.99) | Age, sex
O’Rorke et al. (2012) Case-control All Ireland (Republic and Northern) 3/2002–12/2004 | | ≥ −4.4705 | 52 | 1.54 (0.9–2.68) | Age, sex
O’Rorke et al. (2012) Case-control All Ireland (Republic and Northern) 3/2002–12/2004 | | Trend-test p value: 0.11
O’Rorke et al. (2012) Case-control All Ireland (Republic and Northern) 3/2002–12/2004 | | Barrett's Esophagus
O’Rorke et al. (2012) Case-control All Ireland (Republic and Northern) 3/2002–12/2004 | | < −5.4824 | 55 | OR = 1.0 | Age, sex, GI reflux, H. pylori infection, smoking habits, energy intake, location
O’Rorke et al. (2012) Case-control All Ireland (Republic and Northern) 3/2002–12/2004 | | ≥ −5.4824 | 54 | 1.08 (0.55–2.1) | Age, sex, GI reflux, H. pylori infection, smoking habits, energy intake, location
O’Rorke et al. (2012) Case-control All Ireland (Republic and Northern) 3/2002–12/2004 | | ≥ −4.4705 | 64 | 1.97 (1.01–3.85) | Age, sex, GI reflux, H. pylori infection, smoking habits, energy intake, location
O’Rorke et al. (2012) Case-control All Ireland (Republic and Northern) 3/2002–12/2004 | | Trend-test p value: 0.05
O’Rorke et al. (2012) Case-control All Ireland (Republic and Northern) 3/2002–12/2004 | | Barrett's Esophagus
O’Rorke et al. (2012) Case-control All Ireland (Republic and Northern) 3/2002–12/2004 | | <5.4824 | 55 | OR = 1.0 | Age, sex
O’Rorke et al. (2012) Case-control All Ireland (Republic and Northern) 3/2002–12/2004 | | ≥5.4824 | 54 | 0.97 (0.59–1.59) | Age, sex
O’Rorke et al. (2012) Case-control All Ireland (Republic and Northern) 3/2002–12/2004 | | ≥4.4705 | 64 | 1.18 (0.72–1.93) | Age, sex
O’Rorke et al. (2012) Case-control All Ireland (Republic and Northern) 3/2002–12/2004 | | Trend-test p value: 0.5
Mur et al. (1987) Cohort France 1950–1980 | Electrochemical workers N = 1,143; number of cobalt production workers NR ~ 25% of current staff at time of publication Exposure assessment method: company records | Buccal cavity, pharynx, larynx (140–149, 161) | | | | Exposure duration: 60% worked greater than 10 years; 75% hired before 1975. Confounding: Likely inadequate control for smoking; however, likely co-exposure to nickel and arsenic with no control for co-exposures. Strengths: Cobalt production workers exposed primarily to cobalt compounds. Limitations: Small number of exposed cases; high loss to follow-up (20%); potential for selection bias due to left truncation
Mur et al. (1987) Cohort France 1950–1980 | Electrochemical workers N = 1,143; number of cobalt production workers NR ~ 25% of current staff at time of publication Exposure assessment method: company records | Employed only in cobalt Production | 2 | SMR 3.36 (0.29–10.3) | Age, year of death

GI = gastrointestinal; HWE = healthy worker effect; HWSE = healthy worker survival effect; OR = odds ratio.

### 4.3.2 Study Quality and Utility Evaluation

This section provides an overview of the adequacy of the cohort and nested case-control studies to inform the cancer hazard evaluation (see Appendix C for details on the assessment). This assessment considers factors related to study quality (potential for selection and attrition bias, information bias regarding exposure and outcome, and concern for inadequate analytical methods, selected reporting, and inadequate methods or information to evaluate confounding) and study sensitivity (e.g., such as adequate numbers of individuals exposed to substantial levels of cobalt). The ratings for each of these factors are provided in Table 4-5 and a detailed description of the rationale for the rating is provided in Appendix C.

Both of the case-control studies of cobalt in toenails have either low/minimal or some concern for most biases except for exposure assessment and sensitivity. Their overall low utility to inform the cancer hazard evaluation, however, is due to the potentially irrelevant window of exposure. Toenail clippings likely reflect an integrated exposure that occurred 12 to 18 months prior to clipping, and toenail samples were collected after cancer diagnosis in these studies. Many factors (including disease) can affect nail growth and metal deposition. The available studies (that evaluated cobalt levels and cancer stage [lung or laryngeal] are conflicting, thus it unclear whether the cancer process can affect cobalt levels in toenails Benderli Cihan et al. 2011; Klatka et al. 2011; Kuo et al. 2006). However, although exposure was assessed after the disease process began, in most cases it represents at least some pre-diagnosis exposure, but not pre-cancer exposure as the latency period of both esophageal cancer and Barrett’s esophagus is of long duration (Butt and Kandel 2014). Rogers et al. (1993) conducted stratified analyses on tumor stage and time of diagnosis, which indicated no differences in cobalt levels, suggesting that reverse causality may not be a concern.

### 4.3.3 Cancer Assessment: Esophageal Cancer

#### 1.1.1.2 Background Information

Esophageal cancer is a relatively rare cancer, ranking as the eighteenth most common cancer in the United States, making up 1.1% of all new cancers. The age-adjusted annual rates of esophageal cancer (per 100,000 males or females) in the United States from 2007 to 2011 (NCI 2015b) were approximately 7.7 (male) and 1.8 (female) for incidence; and 7.5 (male) and 1.6 (female) for mortality, with a 5-year survival rate of 17.5%. Like lung cancer, these data suggest that mortality and incidence data are approximately comparable for informing the cancer assessment. Incidence trends and rates in European countries where all of the cohort studies were conducted are broadly similar (Ferlay et al. 2013); and in the European Union the annual incidence of esophageal cancer is 8.4 and the annual mortality rate is 7.0 (Cancer Research U.K. 2014). Evaluations of esophageal cancer risk factors have reported that sufficient evidence exists for x-and gamma-radiation, alcoholic beverages, betel quid, tobacco smoking, and smokeless tobacco; limited evidence exists for dry-cleaning, mate drinking, pickled vegetables, rubber production industry, tetrachloroethylene exposures, red and processed meats, and high temperature drinks. The sub-types of esophageal cancer, esophageal adenocarcinoma and, however, have distinct risk factors and trends. Esophageal adenocarcinoma, with risk factors being white race, increasing age, body fatness, and male gender, is the predominant histological type among men, while for women, esophageal squamous-cell cancer is more common, and rates are still increasing in several European countries. Unlike esophageal squamous-cell carcinoma, alcohol is not a risk factor for either Barrett’s esophagus or for esophageal adenocarcinoma (Anderson et al. 2009; Freedman et al. 2011; Kubo et al. 2009); however, smoking is a risk factor for both subtypes and Barrett’s esophagus (Cook et al. 2010).

Barrett’s esophagus is a condition of intestinal metaplasia in which tissue that is similar to the lining of the intestine replaces the tissue lining the esophagus. The prevalence of Barrett’s esophagus is estimated to be between 1.6% and 6.8% (Gilbert et al. 2011), although a more precise estimate is not possible as many patients are asymptomatic, and its natural history has been difficult to assess. Barrett’s esophagus has an extended latency period prior to progressing to cancer (Butt and Kandel 2014). A recent meta-analysis of studies reports incidence rates for the development of esophageal cancer in nondysplastic Barrett’s esophagus of 0.33% per year and 0.19% for short-segment Barrett’s esophagus (Desai et al. 2012). About 5% of patients with esophageal adenocarcinoma have a pre-cancer diagnosis of Barrett’s esophagus (Corley et al. 2002); but its presence conveys a 30- to 40-fold increased risk of esophageal carcinoma (Sharma 2004). As incidence of esophageal adenocarcinoma has increased more than six-fold in the last decade, investigations of the risk factors for Barrett’s esophagus have been of interest (Jemal et al. 2013). Barrett’s esophagus incidence increases with age; the prevalence among non-Hispanic whites is 6.1% compared to 1.7% among Hispanics and 1.6% among blacks; and the male/female ratio is about 2:1 (Abrams et al. 2008), similar to esophageal cancer.

#### 1.1.1.3 Evidence from Individual Studies

Both of the case-control studies (O’Rorke et al. 2012; Rogers et al. 1993) compared cobalt in toenails of cases of esophageal cancer and population-based controls. O’Rorke et al. (2012) limited their analysis to esophageal adenocarcinoma, while no histologic information was provided by Rogers et al. (1993), thus it is likely that the Rogers et al. (1993) study included both subtypes in unknown proportions. Findings are presented in Table 4-6.

#### 1.1.1.4 Western Washington State Study of Aerodigestive Cancers

Rogers et al. (1993) reported elevated odds ratio for esophageal cancer for those with the highest levels (≥0.17 ppm) of cobalt concentration in toenails compared to those with the lowest level (<0.05 ppm) of cobalt (OR = 9.0, 95% CI = 2.7 to 30.0). The OR was elevated but not significant for those with medium levels (0.05 to 0.17 ppm) of cobalt concentration compared to those with low levels (OR = 2.4, 95% CI = 0.8 to 7.2). The exposure-response test for trend was significant (p < 0.001). It is not possible to comment on the distribution of levels of cobalt in the cases compared to the controls, as cases and controls are combined across exposure levels.

Confounding from known risk factors for esophageal cancer can reasonably be ruled out, however, other metals measured and associated with esophageal cancer in this analysis, were not controlled for in the cobalt models, nor were additional data presented to show any relationship between cobalt levels and other metal levels. In this study, the risk of esophageal cancer was also associated with elevated levels of calcium and iron. Smoking and alcohol use were controlled in the multivariate models along with age and gender, energy intake, beta-carotene, and ascorbic acid; however, while cases were less educated than controls, this variable was not included in the model. Neither beta-carotene nor ascorbic acid confounded the relationships between cobalt and esophageal cancer, but the authors included these two nutrients in the logistic model as it reduced the ORs slightly, raising the concern that the model estimates might have been over-controlled, biasing them slightly towards the null. Co-exposures from other metals were not reported or considered in the analysis of cobalt, and no correlations among the metals were reported.

The source of the cobalt exposure is unknown. When cobalt in nail tissue was expressed as a continuous variable, there were no associations between nail concentration of cobalt and dietary intake of foods high in cobalt (e.g., meat) suggesting that diet does not explain the elevated levels of cobalt in cases. Although occupational histories using questionnaires were collected in this study, no exposure assessment or analyses were done specifically for exposure to cobalt.

Although the Rogers et al. (1993) study provides some evidence of an association, the analysis of a single sample of toenail clippings collected near the time of diagnosis, with no accompanying data on potential sources of cobalt from the environment or occupational exposure, limits the utility of the study. Based on data on reproducibility of measurements of metals in toenails, cobalt has low to intermediate within-person reliability, suggesting that a single sample is less than ideal. Measurements of nail cobalt reflect an integration of exposures that occurred 12 to 18 months prior to clipping, raising the question about whether cobalt levels sampled in toenails close to, and in many cases after cancer diagnosis, reflect the relevant period of exposure for long latency cancer. No differences in cobalt levels were found between those with early- or late-stage cancer nor between those who provided samples within 7 months or beyond 7 months of diagnosis, which helps reduce concerns regarding reverse causality.

#### 1.1.1.5 FINBAR Study – Ireland

O’Rorke et al. (2012) reported a non-significant elevated risk of esophageal adenocarcinoma among those with the highest cobalt levels (OR = 1.54, 95% CI = 0.84 to 2.85). In addition, they reported a significantly increased risk of Barrett’s esophagus among participants with higher toenail concentrations of cobalt (≥ −4.4705, log transformed values equivalent to ≥0.011 μg/g) (OR = 1.97, 95% CI = 1.01 to 3.85), with a significant (p = 0.05) linear test for trend. Both of the estimates were adjusted for age, sex, smoking, location (Northern Ireland or Republic of Ireland), energy intake, gastro-esophageal reflux, and H. pylori infection. O’Rorke et al. (2012) reported no information regarding the correlation between dietary intake of cobalt and nail concentration. In this study, a 2-fold risk of Barrett’s esophagus was also associated with higher toenail concentrations of zinc.

The major limitation of this study, similar to the Rogers et al. (1993) study, however, is the exposure assessment method, which is an analysis of a single sample of toenail clippings collected near the time of diagnosis, with no accompanying data on potential sources of cobalt from the environment or occupational exposure. Given the long latency period for both Barrett’s esophagus and esophageal cancer, there is concern that a measurement reflecting integrated exposures 12 to 18 months in the past is relevant. Similar to the Rogers et al. (1993) study, co-exposures from other metals were not reported or considered in the analysis of cobalt, and no correlations among the metals were reported.

#### 1.1.1.6 Integration of the Evidence across Studies

While these two well-conducted, population-based, case-control studies in Ireland and in Western Washington state reported relatively consistent findings, had adequate numbers of participants, used sound methodologies, and demonstrated exposure-response relationships, the key issue of temporality remains unaddressed. The dependence of these studies upon a single sample of toenails collected at the time of diagnosis meant that neither had complete or even adequate data on cobalt during the relevant windows of exposure throughout the natural history of the two conditions to definitely establish temporality.

## 4.4 Cancer Assessment: Other Types of Cancers

### 4.4.1 Other Aerodigestive Cancers – Oral Cavity, Pharyngeal, and Laryngeal Cancers

The available data to evaluate cobalt in relation to other aerodigestive cancers, specifically cancers of the oral cavity, pharynx, and larynx, consist of the electrochemical workers cohort study (Mur et al. 1987), and one population-based case-control biomarker study (Rogers et al. 1993). The first publication from the electrochemical workers cohort (Mur et al. 1987) provided an SMR for buccal cavity, pharyngeal, and laryngeal cancers for those working in cobalt production. Rogers et al. (1993) provided OR estimates of cobalt in toenails among incident laryngeal cancers and oral cavity cancers and controls and included exposure-response data as well. These are rare cancers (incidence 11.0 per 100,000 men and women for oral cavity cancer; and 3.3 per 100,000 men and women for laryngeal cancers) (NCI 2015a); and unlike lung and esophageal cancers, 5-year survival rates are much higher for oral cavity/pharyngeal and laryngeal cancers (62.7% and 60.0%, respectively), suggesting that mortality statistics are less useful for informing the cobalt and cancer assessment. Potential risk factors for these cancers include smoking and other tobacco use, alcohol (tobacco and alcohol together are worse than either alone), asbestos, and nickel.

The risk of death from buccal cavity, pharyngeal, and laryngeal cancer among electrochemical workers was SMR = 3.36 (95% CI = 0.29 to 10.29), based on 2 observed deaths (Mur et al. 1987).

Rogers et al. (1993) reported a borderline significantly elevated odds ratio for oral cavity cancer for the highest level (≥0.17 ppm) of cobalt concentration in toenails compared to the lowest level (<0.05 ppm) of cobalt (OR = 1.9, 95% CI = 1.0 to 3.6). The OR was elevated but not significant for those with medium levels (0.05 to 0.17 ppm) of cobalt concentration compared to those with low levels (OR = 1.5, 95% CI = 0.9 to 2.6). The exposure-response test for trend was not significant (p value not reported). The finding was present in both in situ/localized tumors and individuals with regional/distant tumors. In this study, diet was not found to be an explanation for the higher risks, and tobacco and alcohol levels were controlled in the analyses.

A borderline significantly elevated odds ratio for laryngeal cancer was reported for medium toenail levels (0.05 to 0.17 ppm) compared to the lowest level (<0.05 ppm) of cobalt (OR = 2.0, 95% CI = 1.0 to 3.8). However, the OR for the highest level of cobalt was 1.0 (95% CI = 0.4 to 2.6), with no indication of a trend in exposure response.

As with esophageal cancer, it is not possible to assess the actual exposure levels among cases and controls as they are combined at each concentration level. Because nails were collected after diagnosis, to address potential reverse causation, cases were stratified by stage at diagnosis (in situ/localized versus regional/distant) and by time from diagnosis to interview (<7 months vs. ≥7 months). No statistically significant differences in the odds ratios by time from diagnosis to interview or stage of disease were observed, which argues against reverse causation.

With respect to these aerodigestive cancers, information is inadequate to evaluate the association with exposure to cobalt based on findings from these two studies, one of which was underpowered (Mur et al. 1987) and one of which had critical concerns regarding exposure misclassification due to the use of a single sample of toenails collected at the time of diagnosis, which might not have been the relevant window of exposure (Rogers et al. 1993).

### 4.4.2 Other Types of Cancers

The available data to evaluate cobalt in relation to other types of cancers is inadequate as it was primarily limited to one cohort study reporting on multiple cancers (Tüchsen et al. 1996) and two studies reporting on brain cancer (Moulin et al. 1993; Tüchsen et al. 1996) (data not shown). Neither of the two studies had adequate numbers of exposed cases (2 cases or fewer) to evaluate brain cancer risk from exposure to cobalt. Among porcelain painters exposed to cobalt dyes, the authors reported that cervical cancer was elevated (SIR = 2.31, lower confidence limit >1.0) based on 12 exposed cases (Tüchsen et al. 1996). For other cancer sites with at least four cases, elevated SIRs (not statistically significant) were also observed for ovary and other skin, and the SIR was close to 1.0 for breast cancer.

## 4.5 NTP Listing Recommendation

The data available from studies in humans are inadequate to evaluate the relationship between human cancer and exposure to cobalt. While almost all the cohort studies reported approximately a doubling of the risk of lung cancer mortality or incidence from exposure to various cobalt compounds, it is unclear that the excess lung cancer was due to exposure specifically to cobalt, because (1) it was not possible to rule out confounding by carcinogenic co-exposures; or (2) other complications prevented a clear interpretation of a cobalt effect.

The relevant data for evaluation of exposure specifically to cobalt are from studies of five major cohorts of workers exposed to cobalt in Denmark (Tüchsen et al. 1996), France (Moulin et al. 2000b; Moulin et al. 1993; Moulin et al. 1998; Mur et al. 1987; Wild et al. 2000), Norway (Grimsrud et al. 2005), and two population based case-control studies of aerodigestive cancers: one in Ireland (O’Rorke et al. 2012) and the other in Washington State, United States (Rogers et al. 1993). The Danish study showed similarly elevated risks of lung cancer in both the exposed and unexposed workers and could not control directly for smoking. Findings from the French electrochemical workers cohort were based on two papers using different methods to ascertain cancer, which produced conflicting results—the first indicated a significantly elevated risk of lung cancer based on 4 exposed cases, and the second showed virtually no differences in risk of lung cancer among the exposed and unexposed workers based on 3 exposed cases in a subset of workers born in France. In two French studies of hard-metal workers, measures of cobalt exposures were likely mixed with other carcinogens and the methods did not clearly indicate whether these were controlled in the analyses. The Norwegian study attempted to control for other co-exposures and smoking, but nickel and cobalt were highly correlated and an estimate for the full model could not be produced. However, a significant trend was reported with increasing duration of employment in workshops where cobalt concentrations three times those of nickel was reported in this study, which controlled for employment in other workshops and smoking.

In addition to lung cancer, esophageal cancer was of interest. Increased risks of esophageal cancer were found in the two population-based case-control studies; however, cobalt exposure was assessed based on one sample of toenails collected at or after cancer diagnosis. Thus, it is unclear whether these cobalt levels reflect exposure to cobalt during the relevant time window necessary for the induction of cancer. The data were inadequate to evaluate cancer at other tissue sites.