# 3 Disposition and Toxicokinetics

Disposition and toxicokinetics refer to how a chemical can enter and leave the body, what happens to it once it is in the body, and the rates of these processes. Section 3.1 discusses the disposition of cobalt and cobalt compounds in humans and experimental animals, and toxicokinetic data are presented in Section 3.2. Disposition and toxicokinetic data are important because they describe various factors that affect the toxicity of a chemical. These factors include routes and rates of absorption, distribution, and retention; routes of elimination; and gender and/or species differences in these factors. The mechanistic implications of these data are discussed in Section 7.

## 3.1 Disposition

Disposition includes absorption, deposition, distribution, metabolism, retention, and excretion. The disposition of cobalt is affected by several factors including the chemical form, solubility, dose, particle size, route of exposure, nutritional status, and age of the species exposed. The primary exposure, distribution, and excretion pathways of cobalt are illustrated in Figure 3-1. Data derived from studies in humans are discussed in Section 3.1.1 while studies in experimental animals are discussed in Section 3.1.2.

Figure 3-1

Cobalt Disposition

Source: Adapted from Keegan et al. (2008).

### 3.1.1 Humans

Dietary intake of cobalt has been reported as the largest source of exposure for the general population; an average daily intake of cobalt in Canada was reported as 11 μg/day (ATSDR 2004) (see Section 2.7). Most of the cobalt in the diet is inorganic with a very small fraction from vitamin B_12_ (Lison 2015). The normal range of cobalt concentrations (nonoccupational exposure) in the blood and urine are about 0.1 to 0.5 μg/L and <2 μg/L, respectively (IARC 2006; Paustenbach et al. 2013) (see Section 2). About 90% to 95% of cobalt in blood is bound to serum albumin while the concentration of free cobalt is about 5% to 12% of the total cobalt concentration (Paustenbach et al. 2013; Simonsen et al. 2012). Letourneau et al. (1972) showed that a dose of vitamin B_12_ had no impact on retention of inorganic cobalt in humans. The total body burden of cobalt in humans is estimated as 1.1 to 1.5 mg with about 85% present in the vitamin B_12_ organometallic complex (Paustenbach et al. 2013; WHO 2006).

#### Absorption

Cobalt absorption from the gastrointestinal (GI) tract is highly variable, with reported values ranging from <5% to 97% (Holstein et al. 2015; IARC 2006; NTP 2014d; Paustenbach et al. 2013; Smith et al. 1972; WHO 2006). Unice et al. (2012) suggested a central tendency value of 25% for GI absorption of soluble inorganic cobalt while Unice et al. (2014) assumed GI absorption of 20% to 45% for aqueous forms and 10% to 25% for solid forms. Cobalt concentrations in whole blood increased 9 to 36 times above normal background concentrations in volunteers who ingested a liquid dietary supplement that contained cobalt chloride for up to 16 days (Tvermoes et al. 2013). Soluble cobalt compounds are better absorbed than insoluble forms (Christensen and Poulsen 1994; Christensen et al. 1993). For example, men and women volunteers who ingested tablets containing soluble cobalt chloride (CoCl_2_) had approximately 10-fold higher concentrations of cobalt in blood and 50- to 90-fold higher concentrations in urine than when they ingested tablets containing insoluble cobalt oxide (Co_3_O_4_) (Christensen et al. 1993). Controlled studies in human volunteers also indicate that GI uptake is higher in women than in men with adjusted mean whole blood concentrations about two-fold higher in women (Christensen et al. 1993; Finley et al. 2013). The higher cobalt uptake in women may be due to a higher incidence of iron deficiency since cobalt absorption efficiency is higher in individuals with iron deficiency (31% to 71% compared to 18% to 44% in control subjects) (Sorbie et al. 1971; Valberg et al. 1969). Meltzer et al. (2010) reported that cobalt whole blood concentrations were significantly elevated in women with low serum ferritin concentrations compared to women with higher serum ferritin concentrations and in women with mild to moderate anemia compared to women with only slightly reduced hemoglobin. Low iron status was a prerequisite for high blood concentrations of cobalt; however, not everyone with low iron status had increased blood levels of cobalt. These data suggest that cobalt and iron may share a common gastrointestinal uptake mechanism that may be upregulated with anemia or iron deficiency (Paustenbach et al. 2013). Other nutritional factors may affect cobalt absorption due to the formation of complexes with certain organic anions (e.g., amino acids) present in foods.

Studies describing absorption of cobalt from the respiratory tract in humans are limited. Cobalt levels in blood and urine of workers generally increase in proportion to inhalation exposure levels to airborne cobalt dust and fumes, especially when workers were exposed to soluble cobalt-containing particles (IARC 2006; NTP 2014d). The pattern of urinary excretion of cobalt in workers exposed to less soluble cobalt oxide particles indicated a lower absorption rate and longer retention time in the lungs. Deposition in the respiratory tract primarily depends on particle size and breathing pattern (ATSDR 2004; WHO 2006). In general, particles larger than 2 μm tend to deposit in the upper respiratory tract due to higher airstream velocities and inertial impaction. These particles are readily cleared through mucociliary action and swallowed. Smaller particles escape inertial impaction and deposit in the bronchiolar or alveolar regions via sedimentation and diffusion. Particles deposited in the respiratory tract may dissolve and be absorbed into the blood or undergo phagocytosis or endocytosis by macrophages. In addition, some nanoparticles can translocate rapidly from the lungs to the mediastinal lymph nodes and bloodstream (Luyts et al. 2013). Recent in vitro studies with human lung cells show that water-insoluble cobalt oxide particles (CoO or Co_3_O_4_) are readily taken up through endocytosis and are partially solubilized at the low pH within lysosomes while soluble cobalt salts utilize cellular transporters such as calcium channels or the divalent metal ion transporter to enter cells (Ortega et al. 2014; Papis et al. 2009; Sabbioni et al. 2014b; Smith et al. 2014). Controlled aerosol studies using human volunteers show that about half of the initial lung burden of inhaled cobalt oxide (Co_3_O_4_) particles may remain in the respiratory tract after six months (Bailey et al. 1989; Foster et al. 1989).

Dermal absorption of cobalt was demonstrated in two studies that measured increased cobalt concentrations in the urine of volunteers who immersed their hands in hard metal dust containing 5% to 15% cobalt for 90 minutes (Scansetti et al. 1994) or in a used coolant solution containing 1,600 mg/L cobalt for one hour (Linnainmaa and Kiilunen 1997). Cobalt also accumulated in the fingernails of three cobalt-sensitive patients after immersing a finger in a cobalt salt solution for 10 minutes/day for 2 weeks (Nielsen et al. 2000). In vitro percutaneous absorption studies were conducted with cobalt powder dispersed in synthetic sweat and applied to human skin mounted on Franz diffusion cells (Larese Filon et al. 2009; Larese Filon et al. 2007; Larese Filon et al. 2004). The mean permeation flux was 0.0123 μg/cm^2^/hr, the lag time was 1.55 hr, and the permeation coefficient was 0.00037 cm/hr. Median cobalt concentrations in the receiving phase indicated that significantly more (~400 fold) cobalt penetrated damaged skin compared with intact skin (Larese Filon et al. 2009). Cobalt was detected in its ionic form in both the donor and the receiving phase. Significant amounts of cobalt also remained within the skin. These experiments showed that skin absorption was closely related to the capacity of synthetic sweat to oxidize metallic cobalt powder to soluble cobalt ions. No significant dermal absorption occurred when cobalt was dispersed in a saline solution (Larese Filon et al. 2004).

#### Distribution and Excretion

Numerous studies have shown that cobalt is found in blood, urine, hair, nails, and most other tissues. (See (1) Figure 2-1, Figure 2-2 or Table B-2 and Table B-3 for studies of cobalt levels in blood, urine, hair, and nails in specific exposed groups and the general population and (2) Table B-4 for cobalt levels reported in surrogate (hair and nails) or target tissues from cancer patients and referent groups, e.g., patients with other non-cancer diseases or healthy controls reported in several clinical studies.) In humans, inorganic cobalt is distributed to liver, kidney, heart, and spleen with lower concentrations found in bone, hair, lymph, brain, and pancreas (Paustenbach et al. 2013; WHO 2006). Cobalt chloride administered intravenously (i.v.) or orally to human volunteers was distributed primarily to the liver (Jansen et al. 1996; Smith et al. 1972). Whole body radioisotope scans (measured at various times up to 1,000 days) following i.v. administration of inorganic cobalt indicated that 10% to 30% (mean 20%) was found in the liver (Smith et al. 1972). Cobalt levels in plasma declined rapidly in this study due to rapid distribution to tissues and renal excretion; however, about 9% to 16% of the administered dose was retained with a half-life of about 800 days. Measurements of cobalt retention for up to 1,018 days indicated that about one fifth of the total body content was present in the liver. Cobalt can also transfer to human milk and across the placenta (Rudge et al. 2009; Wappelhorst et al. 2002). Most of the cobalt in plasma is bound to leukocytes or plasma proteins with a maximum free fraction of 12%. Free cobalt is also taken up by red blood cells via a membrane transport pathway shared with calcium (Simonsen et al. 2011; Simonsen et al. 2012). Uptake of cobalt by red blood cells is practically irreversible because the ions bind to hemoglobin and are not extruded by the calcium pump. Thus, it has been speculated that cobalt partitions primarily into tissues with high calcium turnover and accumulates in tissues with slow turnover of cells although cobalt can be detected in most tissues. Although elevated concentrations of cobalt have been reported in the liver and kidney (oral or parental exposure) or lung (inhalation of insoluble particles), cobalt levels in the body do not appear to increase in any specific organ with age (IARC 2006; Lison 2015; Paustenbach et al. 2013).

Renal excretion of absorbed cobalt is rapid over the first days following exposure but is followed by a second, slower phase that lasts several weeks (IARC 2006; Simonsen et al. 2012). However, a small proportion (~10%) is retained in the tissues with a biological half-life of 2 to 15 years. Controlled experimental studies in humans indicate that 3% to 99% of an orally administered dose of cobalt is excreted in the feces and primarily represents unabsorbed cobalt (WHO 2006). Fecal elimination decreases as cobalt solubility increases. Following i.v. administration of cobalt chloride to 6 volunteers, fecal elimination accounted for about 2% to 12% of the administered dose while about 28% to 56% was eliminated in the urine after 8 days (Smith et al. 1972). Valberg et al. (1969) reported similar results in subjects administered cobalt by intramuscular injections and followed for 10 days (~6% excreted in feces and 58% in urine). Solubility and particle size affect elimination following inhalation exposure (WHO 2006). Clearance of cobalt particles from the lungs has been reported to follow three-phase kinetics (see Section 3.2.1). Large particles are rapidly cleared from the upper airways via the mucociliary pathway, swallowed, and eliminated in the feces. Urinary excretion of inhaled cobalt particles increases with time. Foster et al. (1989) reported that following inhalation of cobalt oxide (Co_3_O_4_) particles, about 17% was cleared mechanically to the gastrointestinal tract and eliminated in the feces within the first week. After 6 months, about 33% of the initial lung burden was eliminated in the urine and about 28% was eliminated in the feces.

### 3.1.2 Experimental Animals

The disposition of cobalt has been investigated in mice, rats, hamsters, guinea pigs, rabbits, dogs, miniature swine, and baboons and show some similarities with human studies. These data are briefly reviewed below. As in humans, cobalt as part of vitamin B_12_ is an essential micronutrient in experimental animals. However, cobalt deficiency has been described in ruminants (e.g., sheep, goats, and cattle) raised in areas with very low cobalt (Yamada 2013). Cobalt supplements were beneficial in these cases because cobalamin can be synthesized by gut bacteria and absorbed.

#### Absorption

Cobalt absorption in experimental animals is highly variable and depends on the chemical form of the compound, age of the animal, species, and nutritional status (Ayala-Fierro et al. 1999; NTP 2014d; WHO 2006). In rats, cobalt chloride was absorbed more efficiently from the gastrointestinal tract than insoluble cobalt oxide (Co_3_O_4_) (13% to 34% compared to 1% to 3%) (NTP 2014d). Gastrointestinal absorption of soluble cobalt compounds was lower in cows (1% to 2%) and guinea pigs (4% to 5%) compared with rats. Cobalt absorption was 3% to 15% greater in young rats and guinea pigs than in adults (Naylor and Harrison 1995). As observed in humans, cobalt absorption was increased in iron-deficient rats (Thomson et al. 1971).

Inhalation studies of cobalt metal, cobalt oxides, or soluble cobalt salts in experimental animals show that dissolved cobalt is absorbed rapidly from the lungs while a small percentage is absorbed over several months (IARC 1991; 2006; Kyono et al. 1992; Leggett 2008; NTP 1998; 2014d). Cobalt particles are mechanically cleared by mucociliary action and swallowed or phagocytized by macrophages. The fraction of the remaining lung content of cobalt oxide (Co_3_O_4_) translocated to blood per day (i.e., dissolution of particles and absorption into the blood) varied according to particle size, particle surface area, species, and time (Andre et al. 1989; Bailey et al. 1989; Collier et al. 1989; Kreyling et al. 1991a; Patrick et al. 1989). Initially, translocation of the smaller particles (0.8 μm) ranged from about 0.4%/day in baboons to about 1.4%/day in HMT (inbred strain) rats. Initial translocation rates for the larger particles (1.7 μm) were lower in all species and ranged from about 0.2%/day in baboons to 0.6%/day in HMT rats (Bailey et al. 1989). Translocation rates for higher density Co_3_O_4_ particles were about a factor of 3 slower than for less dense particles (Bailey et al. 1989; Kreyling et al. 1991a). Translocation rates reported by Bailey et al. (1989) showed a variety of different forms with time, particularly for the smaller particles; this is discussed further in the following section (Figure 3-2). Translocation of cobalt from the lung to the blood also was significantly faster in younger rats compared with older rats (Collier et al. 1991).

Figure 3-2

Rate of Translocation of Cobalt from Lung to Blood Following Inhalation of Cobalt Oxide Particles

Source: Bailey et al. (1989). Used with permission.

Dermal absorption of cobalt (applied as cobalt chloride) has been investigated in mice, guinea pigs, and hamsters (Inaba and Suzuki-Yasumoto 1979; Kusama et al. 1986; Lacy et al. 1996). Dermal absorption of cobalt applied to intact or acid-burned skin of mice was about 0.1% after one hour but increased to 25% to 50% when applied to skin damaged by incision, abrasion, or punctures (Kusama et al. 1986). In a similar study in guinea pigs, absorption of cobalt through intact skin was less than 1% while absorption through abraded skin was about 80% 3 hours after exposure (Inaba and Suzuki-Yasumoto 1979). Lacy et al. (1996) did not report the amount of cobalt absorbed through the intact skin of hamsters but reported that small amounts of cobalt were detected in urine 24 to 48 hours after application and that much of the metal was retained in the skin after 48 hours. These authors also reported that uptake of cobalt by keratinocytes exposed in vitro was about 5% of the dose.

#### Distribution and Excretion

Absorbed cobalt is distributed rapidly to all tissues in experimental animals and is similar to that in humans (NTP 2014d; WHO 2006). Edel et al. (1994) reported that tissue distribution depended on dose, route of administration (oral versus parenteral), and time. Following oral administration of cobalt compounds, the highest tissue concentrations generally occur in the liver and kidney with lower amounts in the heart, spleen, muscle, bone, brain, pancreas, lung, and gonads (Ayala-Fierro et al. 1999; Bourg et al. 1985; Clyne et al. 1988; Gregus and Klaassen 1986; Hollins and McCullough 1971; Thomas et al. 1976). Following single-dose parenteral administration, some studies reported that concentrations were initially highest in the liver and kidney but declined rapidly (Hollins and McCullough 1971; Thomas et al. 1976). However, Edel et al. (1994) reported higher concentrations in the lung, large intestine, kidney, liver, and spleen 24 hours after a single i.v. injection of cobalt chloride. One hundred days after a single i.p. injection, tissue distribution was affected by dose with higher concentrations in the spleen, pancreas, and bone following the lower dose but mainly in bone following higher doses with some accumulation in the heart.

Distribution of cobalt following inhalation exposure is similar to that observed for other routes with the exception of greater retention in the lung for both soluble and insoluble cobalt (Bailey et al. 1989; Bucher et al. 1990; Collier et al. 1991; Kerfoot et al. 1975; Kreyling et al. 1986; Kyono et al. 1992; NTP 2014d; Patrick et al. 1989; Patrick et al. 1994; Wehner and Craig 1972). Long-term retention of insoluble cobalt particles and soluble cobalt salts deposited in the lung shows wide interspecies variation and represents a potential continuing source of cobalt ion release (Bailey et al. 1989; Kreyling et al. 1991a; Patrick et al. 1994). In addition, some particles can translocate to the pulmonary interstitium where they are cleared from the lungs through the lymphatic system (Pauluhn 2009). Nanoparticles also may penetrate the alveolar membrane and distribute to extrapulmonary tissues via the circulation (Mo et al. 2008). The average size of the long-term retention component in humans is greater than in experimental animals (Bailey et al. 1989; Leggett 2008). Retention of insoluble cobalt oxide (Co_3_O_4_) particles (0.8 μm and 1.7 μm) after 90 and 180 days are shown in Table 3-1. These data show that lung retention is generally greater for larger particles than smaller particles and suggests temporal interspecies differences in the rate of particle dissolution and absorption. However, the percentage of total body cobalt content found in the lungs 30 and 180 days after exposure generally exceeded 90% in all species for both particle sizes. In spite of considerable clearance from the lung, very little accumulated in other tissues.

Table 3-1 Interspecies Comparison of Lung Retention of Cobalt Oxide (Co_3_O_4_)

Species/Strain | Lung Retention (%)^a^
Species/Strain | 90 Days | | 180 Days
Species/Strain | 0.8 μm | 1.7 μm | 0.8 μm | 1.7 μm
Human | 64 | 75 | 45 | 56
Baboon | 55 | 55 | 26 | 37
Dog, beagle | 27 | 45 | 5.5 | 12
Guinea pig | 49 | 46 | 8.3 | 15
Rat, HMT (1985) | 5.2 | 20 | 1.3 | 8.0
Rat, HMT (1986) | 5.3 | 18 | 1.2 | 7.2
Rat, F-344 | 14 | 25 | 4.7 | 9.2
Rat, Sprague-Dawley | 8 | 39 | 1.0 | 15
Hamster, Syrian golden | 21 | 35 | 3.4 | 12
Mouse, CBA/H | 15 | ND | 2.8 | ND

Source: Bailey et al. (1989).

ND = no data.

^a^ Calculated as the fraction of lung content (measured as activity of ^57^Co) at 90 and 180 days relative to the lung activity at three days after inhalation. The amount retained after three days was thought to be representative of the amount deposited in long-term lung retention sites because, by this time, the rapid phase of mucociliary clearance should be complete.

Kreyling et al. (1991a) conducted a lung clearance study in baboons, dogs, and HMT rats using Co_3_O_4_ particles (0.9 μm diameter) that were chemically similar to those used by Bailey et al. (1989) but had a higher density (i.e., less porous) and a smaller specific surface area. In each species tested, the denser 0.9 μm particles had higher lung retention after 90 and 180 days than the more porous 0.8 μm particles.

Bailey et al. (1989) and Kreyling et al. (1991a) also applied a simple dissolution model to predict the diverse shapes of the time-dependent rate of cobalt translocation to blood from Co_3_O_4_ particles deposited in the lungs. This model was based on the assumption that the dissolution rate is proportional to the specific surface area of the particle (surface area per unit mass). Since the specific surface area increases as the particles dissolve, a high initial dissolution rate results in a rapid increase in specific surface area and, in turn, causes an increase in the dissolution rate with time. Thus, translocation will peak when another slow clearance mechanism is superimposed on particle dissolution. A small fraction of the dissolved cobalt will not immediately translocate to the blood but will be retained in the lungs and slowly released. The translocation rate was defined in terms of two parameters: (1) the initial fractional absorption rate and (2) the fraction of dissolved cobalt that is retained long-term in tissues (predicted as 1% to 10%). Although there were some discrepancies between the curves predicted by the model and the observed translocation rates (see Figure 3-2), overall, the model accounted remarkably well for the different forms of translocation rates by varying the fractional dissolution rate and the long-term retention fraction and suggested marked species differences in these parameters. The rate-determining step for translocation was intracellular particle dissolution.

In an attempt to better understand the basis for the interspecies differences in the rate of Co_3_O_4_ absorption, species differences in lung retention and translocation (absorption) of soluble cobalt chloride also was investigated (Patrick et al. 1994). The mean fraction of cobalt retained in the lungs in the various test species administered cobalt chloride or cobalt nitrate (dog only) (expressed as percent of initial body content) ranged from about 0.13% (hamster) to 1.2% (dog, estimated value) after 100 days while the fraction retained in the whole body ranged from 0.35% (hamster) to 3.2% (dog). Lung retention by species declined in the following order: dog > HMT rat > guinea pig > baboon > F344 rat > hamster. These long-term retention values were lower than the predicted values of 1% to 10% used in the model (see previous paragraph). The mean fraction of cobalt retained in the lungs after 100 days in the various test species (expressed as percent of cobalt remaining in the body after 100 days) ranged from 11.8% (baboon) to 60% (HMT rat) with no significant accumulation in other organs with the exception of the trachea. However, relative concentrations in the trachea showed no significant interspecies differences. During the first week, 90% or more of the administered dose was cleared from the lung and was similar to the pattern observed for i.v.-injected Co(NO_3_)_2_ in the same species (Bailey et al. 1989; Patrick et al. 1994). These data suggest that interspecies differences in the time-dependent absorption rates (i.e., translocation of dissolved cobalt from the lung to the blood) for inhaled Co_3_O_4_ particles were not explained by differences in the fraction of dissolved cobalt retained long-term in lung tissue. Kreyling et al. (1991b) also found little interspecies variation in pH within alveolar macrophages; therefore, interspecies differences in translocation rates were not explained by differences in phagolysosomal pH. Alternative explanations for these interspecies differences could include a second long-term phase of lung retention as particles or as particle fragments (Patrick et al. 1994).

A recent inhalation study with rats and mice exposed to cobalt metal showed that cobalt concentrations increased with increasing exposure in all tissues examined; however, tissue burdens normalized to exposure levels did not increase with increasing exposure, with the exception of the liver (NTP 2014d). Cobalt tissue concentrations (μg Co/g tissue) in male and female rats showed the following order: lung > liver > kidney > femur > heart > serum > blood (NTP 2014d). Tissue cobalt burdens (μg Co/tissue) showed a similar order with the exceptions that liver accumulated more cobalt than the lung, and the heart accumulated more cobalt than the femur. At three weeks post-exposure in female rats, cobalt concentrations were markedly reduced in blood, serum, and lung (no data were available for other tissues). Tissue distribution in mice was similar to that observed in rats but concentrations in the femur and heart were similar to concentrations in blood and serum. These data from rodents exposed to cobalt by inhalation indicated that tissues tended to accumulate cobalt at concentrations greater than levels found in the blood and serum and that cobalt was distributed to extra-pulmonary tissues.

Cobalt excretion occurs rapidly with the majority of the administered dose eliminated within hours to a few days after exposure ceases (Gregus and Klaassen 1986; Paustenbach et al. 2013). Cobalt is excreted in the urine, feces, and bile with similar excretion patterns reported for all species studied (ATSDR 2004; NTP 2014d; WHO 2006). Most of the i.v.-injected dose of cobalt chloride (~73% to 75%) was eliminated in the urine while smaller amounts were excreted in the bile (2% to 5%) and feces (10% to 15%) (Ayala-Fierro et al. 1999; Gregus and Klaassen 1986). Soluble cobalt compounds are cleared from the lungs at a faster rate than less soluble compounds. The rate of urinary excretion correlates with the rate of translocation of cobalt from the lungs to the blood while fecal excretion rates correlate with the rate of mechanical clearance of cobalt particles from the lung (ATSDR 2004; WHO 2006). Following oral exposure, cobalt is primarily excreted in the feces but the rate decreases as cobalt particle solubility increases (WHO 2006). However, species and sex differences in cobalt excretion rates have been reported. Cobalt urinary excretion rates (μg/16 hr) in male rats were about two-fold higher than in females exposed to various concentrations of cobalt sulfate for 13 weeks (Bucher et al. 1990). In another study, mean urinary excretion rates of cobalt (administered as CoCl_2_ solution to the lungs or inhaled as an aerosol) ranged from 0.002% of the initial body content per day in HMT rats to 0.026% per day in dogs (Patrick et al. 1994). Mean daily fecal excretion rates ranged from 0.0009% (dog) to 0.004% (HMT rat).

## 3.2 Toxicokinetics

Various toxicokinetic parameters of inorganic cobalt have been measured, and several pharmacokinetic models have been developed that describe cobalt disposition in the body (ATSDR 2004; Leggett 2008; Paustenbach et al. 2013; Unice et al. 2014; Unice et al. 2012). This section provides a brief review of toxicokinetic data in humans (Section 3.2.1) and laboratory animals (Section 3.2.2).

### 3.2.1 Humans

The kinetics of inhaled cobalt are determined by mechanical (mucociliary) clearance and by translocation to blood and the lymphatic system (Figure 3-1) (ATSDR 2004). Foster et al. (1989) calculated average translocation and mechanical clearance rates of inhaled cobalt oxide (Co_3_O_4_) particles in four human volunteers. The ratio of translocation to mechanical clearance was about 5:1 for particle sizes of 0.8 and 1.7 μm. Inhalation studies in workers and volunteers exposed to cobalt have shown that the elimination of poorly soluble cobalt metal or cobalt oxides (CoO or Co_3_O_4_) from the lungs is multiphasic with reported half-lives for the phases of 2 to 44 hours, 10 to 78 days, and years (Apostoli et al. 1994; Beleznay and Osvay 1994; Mosconi et al. 1994b; NTP 2014d; Newton and Rundo 1971; WHO 2006). The elimination pattern was independent of the degree of exposure. About 17% of the initial lung burden was eliminated within the first week while about 40% was retained at 6 months after exposure (Foster et al. 1989; WHO 2006). These elimination phases likely involve mucociliary clearance of cobalt particles from the tracheobronchial region, macrophage-mediated clearance of cobalt particles from the lungs, and long-term retention and clearance from the lung. The slower clearance with time likely reflects cobalt that is bound to cellular components in the lung (ATSDR 2004; Foster et al. 1989; Kreyling et al. 1986; WHO 2006). Studies in human volunteers administered cobalt chloride by i.v. injection also showed a multiphasic elimination pattern (Holstein et al. 2015; Jansen et al. 1996; Letourneau et al. 1972; Smith et al. 1972). These studies showed that 36% to 44% of the administered dose is cleared with a biological half-life of 6 to 12 hours, 45% to 56% is cleared with a biological half-life of 2 days to 60 days, and 9% to 11% is cleared with a biological half-life of 600 to 800 days (Paustenbach et al. 2013). Jansen et al. (1996) reported an apparent volume of distribution at steady state of 48 L that likely reflected inl accumulation in the liver (~50% of the administered dose).

Leggett (2008) developed a biokinetic model for inorganic cobalt that depicts recycling of cobalt between blood and four systemic tissues (liver, kidneys, skeleton, and other soft tissues) and transfer from blood to excretion pathways. The model assumes first-order kinetics, and parameter values are expressed as transfer coefficients (fractional transfers per day) that were largely derived from controlled human studies. Unice et al. (2014; 2012) further refined this model by incorporating different gastrointestinal absorption rates, adding compartments to account for albumin-bound cobalt in intravascular and extravascular fluid, and accounting for additional parameters such as total blood volume, red blood cell age, and urinary excretion rates. The model was a reasonably good predictor of cobalt blood and urine concentrations measured in male and female volunteers who ingested a cobalt supplement for 16 days to 3 months (Tvermoes et al. 2013; Tvermoes et al. 2014; Unice et al. 2014).

### 3.2.2 Experimental Animals

Lung clearance kinetics of cobalt particles include both mechanical transport and translocation (Bailey et al. 1989; Kreyling et al. 1991a). Lung clearance of inhaled cobalt metal particles in rats and mice showed a well-defined two-phase elimination profile following 3-month or 2-year studies (NTP 2014d). The majority (>95% in rats and >82% in mice) of the deposited cobalt was cleared rapidly (half-life of 1 to 5 days) while the remainder was cleared more slowly (half-lives of ~20 to >400 days) depending on the concentration and study duration. Lung steady-state burdens were reached after approximately 6 months and were similar in rats and mice. Lung cobalt burdens were well below the levels that would cause lung overload. Other studies showed that interspecies differences in clearance patterns associated with mechanical transport and translocation were not correlated. Initial mechanical clearance rates were typically 10- to 20-fold greater in rodents than in other species, decreased monotonically with time, and were similar for different particle sizes. In contrast, interspecies differences in translocation rates varied by 3- to 10-fold, remained constant or increased and then decreased with time, and were affected by particle size (see Figure 3-2). Thus, in HMT rats, both rates were initially high, while in baboons and humans both rates were low. Mice, hamsters, and F344 rats had high rates of mechanical clearance but low to moderate rates of translocation while dogs had slow mechanical transport but rapid translocation.

Thomas et al. (1976) reported that the whole-body half-life of ^60^CoCl_2_ administered by i.v. injection was longer in the mouse (495 days) than in the rat (309 days), monkey (183 days), or dog (180 days), but all were lower than values reported in humans (see Section 3.2.1). Other studies in rats and dogs showed multiphasic first-order elimination kinetics following oral, inhalation, or i.v. exposure (Table 3-2). These data indicate that soluble cobalt compounds are cleared faster than cobalt metal in rats and that the cobalt oxide particle clearance in dogs during the intermediate phase was proportional to particle size. Elimination of cobalt from the blood in the recent NTP (2014d) study also indicated rapid and slow clearance phases; however, it was not possible to fit the blood data to a two-compartment model due to the lack of early sampling times. However, cobalt elimination half-lives estimated from blood concentrations on the last day of exposure (2-week studies) and 3 weeks post-exposure were 9.2 to 11.1 days in female rats and 4.1 to 7.3 days in female mice.

Table 3-2 Elimination Half-lives for Cobalt Administered to Experimental Animals

Reference | Species: Exposure Route | Compound(s) | Elimination T½
Reference | Species: Exposure Route | Compound(s) | Phase 1 | Phase 2 | Phase 3
Ayala-Fierro et al. (1999) | Male F344 rats: i.v. | CoCl_2_ | 1.3 hr | 4.3 hr | 19 hr
Ayala-Fierro et al. (1999) | Male F344 rats: oral | CoCl_2_ | 0.9 hr^a^ | 4.6 hr | 22.9 hr
Menzel et al. (1989) | Male SD rats: inhalation | CoCl_2_ | 1.8 hr | 3.7–8.7 hr^b^ | –
Kyono et al. (1992) | Male SD rats: inhalation | Co metal | 52.8 hr^c^ 52.8 hr^d^ | 156 hr^c^ 172.8 hr^d^ | –
Kreyling et al. (1986) | Male beagles: inhalation (endotracheal tube) | Co_3_O_4_ Co_3_O_4_ + CoO Co(NO_3_)_2_ | 0.5 d 1–4 d 0.8 d | 6–80 d^e^ 20–86 d^e^ 27 d | 300–380 d 340–440 d 400 d

– = No data.

^a^ Absorption half-life.

^b^ Calculated from elimination rate constants of 0.188 h^-1^ (single exposure) and 0.08 h^-1^ (repeat exposure).

^c^ Lung.

^d^ Blood.

^e^ Half-lives were proportional to particle size.

## 3.3 Synthesis

Cobalt is absorbed from the GI tract, lungs, and skin and rapidly distributed throughout the body. Absorption from the gastrointestinal tract is highly variable and is affected by the chemical form, dose, age, formation of complexes with organic ions, and nutritional status. Soluble compounds are absorbed to a greater extent than poorly soluble forms. Current biokinetic models assume GI absorption of 20% to 45% for aqueous forms and 10% to 25% for solid forms. Studies in experimental animals indicate higher absorption in young rats and guinea pigs than in adults while studies in human volunteers indicate higher GI absorption in women than in men and may reflect iron status. Cobalt absorption from the GI tract is higher in iron deficient humans and experimental animals and suggests that cobalt and iron share a common uptake mechanism. Cobalt levels in blood and urine of workers generally increase in proportion to airborne concentrations. Although absorbed cobalt is distributed systemically, it does not accumulate in any specific organ with age. Translocation rates of cobalt from the lung to the blood show considerable interspecies variation with time and particle size with humans and baboons generally having lower rates than dogs or rodents, and the whole-body half-life of cobalt was longer in humans than in mouse, rat, monkey, or dog.

Cobalt excretion occurs rapidly with the majority of the administered dose eliminated within hours to a few days after exposure ceases. Cobalt is excreted in the urine, feces, and bile with similar excretion patterns reported for all species studied. Elimination in the feces primarily represents unabsorbed cobalt while absorbed cobalt is eliminated in the urine. Toxicokinetic studies indicate multiphasic elimination following inhalation of cobalt particles or i.v. injection of cobalt chloride and generally show shorter elimination half-lives in experimental animals compared to humans. Elimination half-lives reported for poorly soluble cobalt metal or cobalt oxide particles from human lung ranged from 2 to 44 hours, 10 to 78 days, and years. These elimination phases likely represent an initial rapid elimination from the tracheobronchial region via mucociliary clearance, macrophage-mediated clearance, and long-term retention and clearance. A similar pattern was reported in human volunteers given an i.v. injection of cobalt chloride with about 40% cleared with a half-life of 6 to 12 hours, 50% cleared with a half-life of 2 to 60 days, and 10% cleared with a half-life of 600 to 800 days.