# 1 Chemical Identification and Properties

The candidate substance reviewed in this monograph is the class, “Cobalt and cobalt compounds that release cobalt ions in vivo.”

Cobalt (Co) is a naturally occurring transition element with magnetic properties. It is the 33^rd^ most abundant element and makes up approximately 0.0025% of the weight of Earth’s crust. Cobalt is a component of more than 70 naturally occurring minerals including arsenides, sulfides, and oxides. The only stable and naturally occurring cobalt isotope is ^59^Co. Metallic cobalt, Co(0), exists in two allotropic forms, hexagonal and cubic, which are stable at room temperature (ATSDR 2004; IARC 1991; WHO 2006). Cobalt predominantly occurs in two oxidation states, +2 (Co(II)) and +3 (Co(III)).

Cobalt compounds can be organic or inorganic as well as water soluble or insoluble. Water-soluble cobalt compounds dissolve in the fluids outside cells for cellular uptake, while particles of poorly soluble cobalt compounds can be taken up intact by cells and release ions within the cell (see Table 1-1). Of note, vitamin B_12_, which is an essential cobalt-containing nutrient, does not meet the criteria for this review because it does not release cobalt ions in acidic gastric or lysosomal fluids and passes through the body intact while bound to specific carrier proteins (Neale 1990).

Table 1-1 Physical and Chemical Properties for Cobalt Metal and Representative Cobalt Compounds^a,b^

Name (+2 Valence Unless Otherwise Indicated) | CAS No. | Formula | Molecular Weight | Physical Form | Density or Specific Gravity | Solubility (Grams per 100 cc Cold Water) | Particle Size, μm (Surface Area, m^2^/g) | Bioaccessiblity^c^
Metal
Cobalt | 7440-48-4 | Co | 58.9 | Grey hexagonal or cubic metal | 8.92 | 0.00029 | 7.2 (1.20) | 100/100
Cobalt nanoparticles | 7440-48-4 | Co | 58.9 | – | – | – | – | –
Soluble cobalt compounds
Sulfate heptahydrate | 10026-24-1 | CoSO_4_•7H_2_O | 281.1 | Red pink, monoclinic | 1.95 | 60.4 | 942.0 (3.49) | 100/100
Chloride | 7646-79-9 | CoCl_2_ | 129.9 | Blue hexagonal leaflets | 3.36 | 45 | 458.0 (0.78) | 100/100
Acetate (org.) | 71-48-7 | Co(C_2_H_2_O_2_)_2_ | 249.1 | Red-violet, monoclinic | 1.70 | 34.8 | – | 98/80
Nitrate | 10141-05-6 | CoN_2_O_6_ | 182.9 | Red powder or crystals | 2.49 | 67.0 | – | 96/100
Poorly soluble compounds
(II) Oxide (II, III) Oxide | 1307-96-6 1308-06-1 | CoO Co_3_O_4_ | 74.9 240.8 | Green-brown cubic Black, cubic | 6.45 6.07 | 0.00049 0.00016 | 0.692 (4.79) – | 100/92.4 2/2 (50%^d^)
2-ethyl-hexanoate (org.) | 136-52-7 | Co(C_8_H_15_O_2_)_2_ | 173.7 | Blue liquid (12% Co) | 1.01 | 0.630 | 0.73 (ND) | 100/100
Carbonate (org.) | 513-79-1 | CoCO_3_ | 118.9 | Red, trigonal | 4.13 | 0.00114 | 1.834 (103.05) | 100/100
Naphthenate (org.) | 61789-51-3 | Co(C_11_H_7_O_2_)_2_ | 401.3 | Purple liquid (6% Co) | 0.97 | 0.0293 | 0.70 (ND) | 100/100
Hydroxide | 21041-93-0 | Co(OH)_2_ | 93.0 | Rose-red, rhomb | 3.60 | 0.00032 | – | 95/98
Sulfide | 1317-42-6 | CoS | 91.0 | Reddish octahedral | 5.45 | 0.00038 | – | 1/1
Oxalate (org.) | 814-89-1 | CoC_2_O_4_ | 147.0 | White or reddish | 3.02 | 0.00322 | – | 37/55
Propionate (org.) | 1560-69-6 | Co(C_3_H_5_O_2_)_2_ | 205.1 | Reddish solid | – | 7.49 | – | 91/94
Stearate (org.) | 1002-88-6 | Co(C_18_H_35_O_2_)_2_ | 625.9 | Grey solid | – | 0.00705 | – | 14/16

Sources: SciFinder (2015); PubChem (2015); ChemIDplus (2015); Cobalt Development Institute (CDI) (2006); National Library of Medicine (HSDB) (2004; 2012); Stopford et al. (2003). Personal communication, CDI, July 21, 2015, and October 19, 2015.

org. = organic compound; all others are inorganic.

^a^ Cobalt compounds selected for inclusion in the table include those with toxicological data or of commercial importance. All compounds contain Co(II) except where noted. Forms in italics have been tested for carcinogenicity, genetic toxicity, or have mechanistic data; org. = organic compound; all others are inorganic.

^b^ Bioaccessibility usually assessed as % solubility in gastric/lysosomal fluids.

^c^ () = Bioaccessibility assessed by release of cobalt ions into RPMI 1640 culture medium in the presence of canine alveolar macrophages after 2 weeks of culture (Kreyling et al. 1990).

The available database on cobalt and cobalt compounds varies by cobalt form; however, there are carcinogenicity, genotoxicity, and toxicity studies on cobalt metal and of some water-soluble and poorly water-soluble compounds. Of note are the two NTP bioassay studies, one with a very soluble cobalt compound, cobalt sulfate (NTP 1998), and one with cobalt metal (NTP 2014d). Together, the carcinogenicity, genotoxicity, and other mechanistic information on these representative forms of cobalt inform the discussion in this document on cobalt and cobalt compounds that release cobalt ions in vivo.

## 1.1 Properties of Cobalt Metal and Cobalt Compounds, Both Soluble and Poorly Soluble

Table 1-1 presents physical and chemical properties (molecular weight, crystalline form, density or specific gravity, water solubility, and bioaccessibility) for cobalt and cobalt compounds for which animal or genotoxicity testing data are available or that are in commercial use greater than 100,000 pounds per year in the United States (per EPA Chemical Data Reporting rule). Additional cobalt compounds that do not meet either of these criteria are described in Table B-1. The physical and chemical properties are divided into three groups, including metals, soluble cobalt compounds, and poorly soluble cobalt compounds, to provide a framework for relating chemicals for which potential biological effects are unknown to chemicals for which biological effect data are available.

## 1.2 Water Solubility and Bioaccessibility

Evaluation of toxicological and carcinogenic effects of cobalt compounds depends largely on the release of cobalt ions that can either be transported to and taken up at target sites or released within cells from particles (see Section 6, Mechanistic and Other Relevant Effects).

### 1.2.1 Water Solubility

Cobalt sulfate, chloride, and nitrate tend to be soluble in water, while oxides (including the mixed oxide, Co_3_O_4_), hydroxides, and sulfides tend to be poorly soluble or insoluble (Lison 2015). Organic cobalt compounds can be either soluble (e.g., cobalt(II) acetate) or insoluble (e.g., cobalt carbonate, cobalt(II) oxalate, cobalt propionate, cobalt stearate, cobalt naphthenate, cobalt 2-ethyl-hexanoate) (CDI 2006) (see Table 1-1). The water solubility of cobalt compounds is largely pH dependent, and cobalt is generally more mobile in acidic solutions than in alkaline solutions.

Co(0) metal nano- (reported particle size range = 20 nm to 500 nm) and microparticles (reported particle size range = 1.9 μm to 2.7 μm) dissolve in cell-free culture medium in a concentration- and time-dependent manner while cobalt(II, III) oxide particles (reported average particle size = 372 nm) are practically insoluble in water or culture medium (Ortega et al. 2014; Ponti et al. 2009; Sabbioni et al. 2014b). Smaller particles dissolve faster than larger particles (Kyono et al. 1992; Lison 2015).

### 1.2.2 Bioaccessibility

Solubilization of some water-insoluble compounds may be enhanced in biological fluids at low pH and in the presence of binding proteins (IARC 2006) (see below). Because in vivo bioavailability testing can be cost prohibitive and time consuming, solubility of compounds in artificial fluids (i.e., bioaccessibility) using synthetic equivalents of gastric and intestinal fluids (for ingestion exposure); alveolar, interstitial, and lysosomal fluids (for inhalation exposure); perspiration fluids (for dermal exposure); and synovial fluid (for metal joint prostheses), identified from exposure scenarios including manufacturing and use of alloy materials (Brock and Stopford 2003; Hillwalker and Anderson 2014; Stopford et al. 2003, personal communication from CDI to Dr. Ruth Lunn) can often be used as a surrogate for bioavailability. Cobalt metal, and several water-soluble compounds (e.g., cobalt sulfate heptahydrate, chloride, cobalt acetate) and poorly soluble compounds (e.g., cobalt(II) oxide, bis(2-ethyl-hexanoate), carbonate, naphthenate) were found to be soluble in biological fluids, suggesting that they release cobalt ions (see the right-hand column of Table 1-1 and Table B-1).

Some compounds that appear to be insoluble in these tests might actually be soluble in biological fluids in vivo. This is due to the inability of a simple model with an artificial biological fluid and a cobalt compound not providing for the potential equilibrium between cellular compartments such as the lysosomes with the cytoplasm and ultimately the extracellular fluid. Thus, additional assays that are more physiologically relevant because of the presence of lung cells are potentially more informative. For example, although very low values (≤2%) for bioavailability have been reported for the sulfide and mixed (II, III) oxide and intermediate values (14% to 55%) for stearate and oxalate under the test conditions reported in Table 1-1, other test conditions in the presence of lung cells have indicated that Co_3_O_4_ (cobalt (II, III) oxide) releases cobalt ions. Kreyling et al. (1990) reported that cobalt ions dissolved from Co_3_O_4_ particles of different sizes were ultimately released into the culture medium (RPMI 1640) in the presence of canine alveolar macrophages with up to 50% solubilized from 0.3 μm particles after 2 weeks of culture (larger particles released 2% to 5% under the same conditions). The differences in findings between this study and the 2% solubility in gastric or lysosomal fluid may be due to the interaction of cobalt particles within cells as the soluble fraction of an initial particle mass of Co_3_O_4_ increased with time when the particles were taken up by alveolar macrophages in culture compared with the solubility in culture medium alone. Moreover, Ortega et al. (2014), found that intracellular concentrations of solubilized cobalt ions were similar for Co_3_O_4_ and cobalt chloride in human lung cells, suggesting that Co_3_O_4_ would release cobalt ions in vivo (see Section 6.1 for details). A similar result was reported for CoO nanoparticles, which increased intracellular cobalt ion concentration in human lung fibroblasts in culture in a concentration-dependent manner (Smith et al. 2014).

The intra- and inter-laboratory variability of bioaccessibility testing results for metals and metal compounds including cobalt powder and cobalt oxide in synthetic gastric, perspiration, lysosomal, and interstitial fluids was reported by Henderson et al. (2014), and the authors concluded that results demonstrated overall satisfactory within-laboratory variability. Relative standard deviation (RSD) values and associated threshold levels were used to assess sample-to-sample result variability (i.e., repeatability) and lab-to-lab result variability (i.e., reproducibility). Acceptable variability for this analysis was defined as RSD for repeatability <10% (per Wragg et al. 2011) and RSD for reproducibility <20% (per Ashley et al. 2012; and Wragg et al. 2011). Henderson et al. (2014) further noted that absolute bioaccessibility results in some biological fluids might vary between different laboratories.

Cobalt(II) ions released into solution can form complexes with organic or inorganic anions with equilibrium conditions determined by activity of electrons (Eh), activity of hydrogen ions (pH), and anion presence (Smith and Carson 1981). In general, lower pH generates higher free Co(II) concentrations in solution, and higher pH gives rise to cobalt-carbonate complex formation (WHO 2006). The in vivo concentration of free Co(II) ions is relatively low because these cations are complexed in the presence of physiological concentrations of phosphates and also bind nonspecifically to proteins such as albumin (Lison 2015).

## 1.3 Variability of Valence

As noted above, cobalt exists primarily as Co(II) and Co(III), and Co(II) is much more stable in aqueous solution (Nilsson et al. 1985; Paustenbach et al. 2013). Electron-donor ligands (e.g., NH_3_) can stabilize Co(III) in aqueous solution (IARC 1991). In acid solution, Co(II) is the stable form in the absence of electron-donor ligands, and Co(III) ions are so unstable that they quickly reduce to Co(II), oxidizing water and liberating oxygen. In contrast, air or hydrogen peroxide can oxidize Co(II) to the Co(III) complex, which is more stable in alkaline solutions containing ammonium hydroxide or cyanide. This interconversion between Co(II) and Co(III) is important in the use of cobalt compounds as catalysts and paint driers (IARC 1991; Paustenbach et al. 2013).

Cobalt is present in its stable +2 valence state in the environment and in most commercially available cobalt compounds, with the exception of the mixed oxide (Co(II, III) or Co_3_O_4_) (IARC 1991; Paustenbach et al. 2013). Some simple salts of cobalt in its +3 valence state (e.g., Co_2_O_3_) have been used commercially. Cobalt compounds of commercial and toxicological interest include cobalt metal, alloys, and composite materials; oxides (e.g., cobalt oxide and tetraoxide); and salts (e.g., cobalt(II) chloride, sulfide, and sulfate) (Lison 2015). Important salts of carboxylic acids include formate, acetate, citrate, naphthenate, linoleate, oleate, oxalate, resinate, stearate, succinate, sulfamate, and 2-ethylhexanoate. (See Table 1-1 and Table B-1.)

Cobalt can also exist in −1, +1, and +4 oxidation states (Nilsson et al. 1985). Cobalt is in its −1 state in cobalt carbonyls such as [Co(CO)_4_]H and in cobalt-nitrosyls, in its +1 state in some cobalt-cyanide complexes, and in its +4 state in compounds with cobalt bonded to fluoride or oxygen.

## 1.4 Summary

Cobalt metal particles have been found to be 100% bioaccessible (i.e., dissolving to release cobalt ions) in both artificial gastric and lysosomal fluids. The soluble compounds, cobalt(II) sulfate heptahydrate and cobalt(II) chloride, and the poorly soluble compounds, cobalt(II) oxide, cobalt bis(2-ethyl hexanoate), cobalt carbonate, and cobalt naphthenate, also were completely (or almost completely) soluble in the two acidic fluids. The metals and poorly soluble compounds tended to be less bioaccessible in neutral biological fluids, which is consistent with the pH dependence for releasing cobalt ions in solution. Although very low values (≤2%) for bioavailability in artificial gastric and lysosomal fluids have been reported for the sulfide and mixed (II, III) oxide and intermediate values (14% to 55%) for stearate and oxalate under the same test conditions, more informative tests (e.g., using more physiologically relevant conditions) in the presence of lung cells have shown higher bioavailability values for cobalt(II, III) oxide (i.e., Co_3_O_4_) in culture media in the presence of alveolar macrophages. Other studies have reported uptake of Co_3_O_4_ by lung cells, which suggests that compound would release ions in vivo.