# Peer Review

Peer review of the Draft RoC Monograph on Cobalt and Certain Cobalt Compounds^1^ was conducted by an ad hoc expert panel at a public meeting held July 22, 2015, in the Rodbell Auditorium at the National Institute of Environmental Health Sciences, David P. Rall Building, Research Triangle Park, NC (see https://ntp.niehs.nih.gov/go/38854 for materials, minutes, and panel recommendations from meeting). The selection of panel members and conduct of the peer review were performed in accordance with the Federal Advisory Committee Act and Federal policies and regulations. The panel members served as independent scientists, not as representatives of any institution, company, or governmental agency.

The charge to the Peer-Review Panel was as follows:

- Comment on the draft cancer evaluation component for cobalt and certain cobalt compounds, specifically, whether it was technically correct and clearly stated, whether the NTP had objectively presented and assessed the scientific evidence, and whether the scientific evidence was adequate for applying the RoC listing criteria.
- Comment on the draft profile for cobalt and certain cobalt compounds, specifically, whether the scientific justification presented in the profile supported the NTP’s preliminary policy decision on the RoC listing status of the substance (available in the 14th edition of the Report on Carcinogens).

The Panel was asked to vote on the following questions:

- Whether the scientific information presented from human cancer studies supported the NTP’s preliminary level of evidence conclusion of cobalt and cobalt compounds that release cobalt ions in vivo.^1^
- Whether the scientific information presented from studies in experimental animals supported the NTP’s preliminary level of conclusion of cobalt and cobalt compounds that release cobalt ions in vivo.^1^
- Whether NTP’s preliminary policy decision for ‘cobalt and cobalt compounds that release cobalt ions in vivo’^1^ in the RoC.

The RoC Monograph on Cobalt and Cobalt Compounds That Release Cobalt Ions In vivo has been revised based on NTP’s review of the Panel’s peer-review comments. The Peer-Review Panel Report, which captures the Panel recommendations for listing status of cobalt and cobalt compounds that release cobalt ions in vivo in the RoC and their scientific comments, and the NTP Response to the Peer-Review Report are available on the Peer-Review Meeting webpage for cobalt and certain cobalt compounds (https://ntp.niehs.nih.gov/go/38854).

^1^During the meeting the Panel recommended using the definition of “certain cobalt compounds,” i.e., “cobalt compounds that release cobalt ions in vivo” in the listing rather than the word “certain.”

## Peer Reviewers

- Melissa A. McDiarmid, M.D., DABT (Chair)
  Professor, Medicine and Epidemiology & Public Health
  Director, Division of Occupational and Environmental Medicine
  University of Maryland School of Medicine
  Baltimore, Maryland, USA
- Robert F. Herrick, Sc.D.
  Senior Lecturer on Industrial Hygiene
  Department of Environmental Health
  Harvard School of Public Health
  Boston, Massachusetts, USA
- C. William Jameson, Ph.D.
  Consultant
  CWJ Consulting, LLC
  Cape Coral, Florida, USA
- Clark Lantz, Ph.D.
  Professor
  Cellular and Molecular Medicine
  The University of Arizona
  Tucson, Arizona, USA
- John LaPres, Ph.D.
  Associate Professor
  Department of Biochemistry and Molecular Biology
  Michigan State University
  East Lansing, Michigan, USA
- Marie-Elise Parent, Ph.D.
  Professor, Epidemiology and Biostatistics Unit
  INRS-Institut Armand-Frappier
  Université du Québec
  Laval, Quebec, Canada
- Michael V. Pino, D.V.M., Ph.D., DACVP
  Consultant, Veterinary Toxicological Pathology and Preclinical Drug Development
  Albuquerque, New Mexico, USA
- Lisa De Roo, Ph.D.
  Department of Global Public Health and Primary Care
  University of Bergen
  Bergen, Norway
- John Pierce Wise, Sr., Ph.D.
  Professor and University Scholar
  Department of Pharmacology and Toxicology
  School of Medicine
  University of Louisville
  Louisville, Kentucky, USA
- Anatoly Zhitkovich, Ph.D.
  Professor, Medical Science
  Department of Pathology and Laboratory Medicine
  Brown University
  Providence, Rhode Island, USA