# References

Abbracchio MP, Heck JD, Costa M. 1982. The phagocytosis and transforming activity of crystalline metal sulfide particles are related to their negative surface charge. Carcinogenesis. 3(2):175–180. 10.1093/carcin/3.2.175 7067046
Abrams JA, Fields S, Lightdale CJ, Neugut AI. 2008. Racial and ethnic disparities in the prevalence of Barrett’s esophagus among patients who undergo upper endoscopy. Clin Gastroenterol Hepatol. 6(1):30–34. 10.1016/j.cgh.2007.10.006 18063419
Adachi S, Takemoto K, Ohshima S, Shimizu Y, Takahama M. 1991. Metal concentrations in lung tissue of subjects suffering from lung cancer. Int Arch Occup Environ Health. 63(3):193–197. 10.1007/BF00381568 1917070
Adami G, Smarrelli D, Martinelli B, Acquavita A, Reisenhofer E. 2003. Cobalt blood levels after total hip replacement (THR): A new follow-up study in Trieste (Italy). Ann Chim. 93(1-2):1–10. 12650568
Adámik M, Bažantová P, Navrátilová L, Polášková A, Pečinka P, Holaňová L, Tichý V, Brázdová M. 2015. Impact of cadmium, cobalt and nickel on sequence-specific DNA binding of p63 and p73 in vitro and in cells. Biochem Biophys Res Commun. 456(1):29–34. 10.1016/j.bbrc.2014.11.027 25446071
Afridi HI, Kazi TG, Kazi NG, Jamali MK, Arain MB, Sirajuddin, Kandhro GA, Shah AQ, Baig JA. 2009. Evaluation of arsenic, cobalt, copper and manganese in biological samples of steel mill workers by electrothermal atomic absorption spectrometry. Toxicol Ind Health. 25(1):59–69. 10.1177/0748233709103036 19318505
Agency for Toxic Substances Disease Registry (ATSDR). 2004. Toxicological profile for cobalt. Atlanta, GA: Agency for Toxic Substances and Disease Registry. https://www.atsdr.cdc.gov/ToxProfiles/TP.asp?id=373&tid=64.
Alarifi S, Ali D, Al Omar SY, Ahamed M, Siddiqui MA, Al-Khedhairy AA. 2013. Oxidative stress contributes to cobalt oxide nanoparticles-induced cytotoxicity and DNA damage in human hepatocarcinoma cells. Int J Nanomedicine. 8:189–199. 23326189
Alessio L, Dell’Orto A. 1988. Biological monitoring of cobalt. In: T.W C, Friberg L, Nordberg GF, Sager PR, editors. Biological Monitoring of Toxic Metals. New York, NY: Springer US. p. 407-417. 10.1007/978-1-4613-0961-1_17
Alexander CS. 1969. Cobalt and the heart. Ann Intern Med. 70(2):411–413. 10.7326/0003-4819-70-2-411 5764511
Alexandersson R. 1988. Blood and urinary concentrations as estimators of cobalt exposure. Arch Environ Health. 43(4):299–303. 10.1080/00039896.1988.10545953 3415357
Alexandersson R, Swensson A. 1979. Studies on the pulmonary reaction of workers exposed to cobalt in the tungsten carbide industry. Arh Hig Rada Toksikol. 30 Suppl:355–361.533380
Alimonti A, Bocca B, Lamazza A, Forte G, Rahimi S, Mattei D, Fiori E, Iacomino M, Schillaci A, De Masi E, et al. 2008. A study on metals content in patients with colorectal polyps. J Toxicol Environ Health A. 71(5):342–347. 10.1080/15287390701839133 18214808
Alipázaga MV, Moreno RG, Linares E, Medeiros MH, Coichev N. 2008. DNA damage by sulfite autoxidation catalyzed by cobalt complexes. Dalton Trans. (41):5636–5644. 10.1039/b805222k 18854902
Allen MJ, Myer BJ, Millett PJ, Rushton N. 1997. The effects of particulate cobalt, chromium and cobalt-chromium alloy on human osteoblast-like cells in vitro. J Bone Joint Surg Br. 79-B(3):475–482. 10.1302/0301-620X.79B3.0790475 9180332
Almaguer D. 1987. Health hazard evaluation report. American cyanamid. Michigan City, IN: National Institute for Occupational Safety and Health. HETA 86-251-1842.
Amacher DE, Paillet SC. 1980. Induction of trifluorothymidine-resistant mutants by metal ions in L5178Y/TK+/- cells. Mutat Res. 78(3):279–288. 10.1016/0165-1218(80)90110-X 7432364
Anard D, Kirsch-Volders M, Elhajouji A, Belpaeme K, Lison D. 1997. In vitro genotoxic effects of hard metal particles assessed by alkaline single cell gel and elution assays. Carcinogenesis. 18(1):177–184. 10.1093/carcin/18.1.177 9054604
Andersen I, Høgetveit AC. 1984. Analysis of cobalt in plasma by electrothermal atomic absorption spectrometry. Z Anal Chem. 318:41–44. 10.1007/BF00532837
Andersen O. 1983. Effects of coal combustion products and metal compounds on sister chromatid exchange (SCE) in a macrophagelike cell line. Environ Health Perspect. 47:239–253. 10.1289/ehp.8347239 6337826
Anderson LA, Cantwell MM, Watson RG, Johnston BT, Murphy SJ, Ferguson HR, McGuigan J, Comber H, Reynolds JV, Murray LJ. 2009. The association between alcohol and reflux esophagitis, Barrett’s esophagus, and esophageal adenocarcinoma. Gastroenterology. 136(3):799–805. 10.1053/j.gastro.2008.12.005 19162028
Andre S, Metivier H, Masse R. 1989. An interspecies comparison of the lung clearance of inhaled monodisperse cobalt oxide particles - Part III: Lung clearance of inhaled cobalt oxide particles in baboons. J Aerosol Sci. 20(2):205–217. 10.1016/0021-8502(89)90044-X
Angelé-Martínez C, Goodman C, Brumaghim J. 2014. Metal-mediated DNA damage and cell death: Mechanisms, detection methods, and cellular consequences. Metallomics. 6(8):1358–1381. 10.1039/C4MT00057A 24788233
Angerer J. 1989. Cobalt. In: Henschler D, Lehnert G, editors. Weinheim: VCH-Varlag; p. 1–13. [Biological Occupational Tolerance Value, Occupational Medical-toxicological Basis].
Angerer J, Heinrich R, Szadkowski D, Lehnert G. 1985. Occupational exposure to cobalt powder and salts - Biological monitoring and health effects. In: Proceedings of an International Conference on Heavy Metals in the Environment, Athens, September 1985. Luxembourg: Commisson of the European Community. p. 11-13.
Annangi B, Bach J, Vales G, Rubio L, Marcos R, Hernández A. 2014. Long-term exposures to low doses of cobalt nanoparticles induce cell transformation enhanced by oxidative damage. Nanotoxicology. Early Online.
Apol AG. 1976. Health hazard evaluation determination: Rycraft, Inc., Corvallis, Oregon. Cincinnati, OH: National Institute for Occupational Health and Safety. HETA 76-38-326.
Apostoli P, Porru S, Alessio L. 1994. Urinary cobalt excretion in short time occupational exposure to cobalt powders. Sci Total Environ. 150(1-3):129–132. 10.1016/0048-9697(94)90139-2 7939585
Applebaum KM, Malloy EJ, Eisen EA. 2011. Left truncation, susceptibility, and bias in occupational cohort studies. Epidemiology. 22(4):599–606. 10.1097/EDE.0b013e31821d0879 21543985
Arai F, Yamamura Y, Yoshida M, Kishimoto T. 1994. Blood and urinary levels of metals (Pb, Cr, Cd, Mn, Sb, Co and Cu) in cloisonne workers. Ind Health. 32(2):67–78. 10.2486/indhealth.32.67 7806447
Araya J, Maruyama M, Inoue A, Fujita T, Kawahara J, Sassa K, Hayashi R, Kawagishi Y, Yamashita N, Sugiyama E, et al. 2002. Inhibition of proteasome activity is involved in cobalt-induced apoptosis of human alveolar macrophages. Am J Physiol Lung Cell Mol Physiol. 283(4):L849–L858. 10.1152/ajplung.00422.2001 12225962
Ardyanto TD, Osaki M, Nagahama Y, Yamaga K, Maeta N, Tamura T, Ito H. 2008. Down-regulation of cobalt-induced HIF-1alpha expression correlates with cell proliferation and apoptosis in human gastric carcinoma cells. Oncol Rep. 19(2):339–343. 18202779
Arlauskas A, Baker RS, Bonin AM, Tandon RK, Crisp PT, Ellis J. 1985. Mutagenicity of metal ions in bacteria. Environ Res. 36(2):379–388. 10.1016/0013-9351(85)90032-5 3884331
Arslan M, Demir H, Arslan H, Gokalp AS, Demir C. 2011. Trace elements, heavy metals and other biochemical parameters in malignant glioma patients. Asian Pac J Cancer Prev. 12(2):447–451. 21545211
Asante KA, Agusa T, Biney CA, Agyekum WA, Bello M, Otsuka M, Itai T, Takahashi S, Tanabe S. 2012. Multi-trace element levels and arsenic speciation in urine of e-waste recycling workers from Agbogbloshie, Accra in Ghana. Sci Total Environ. 424:63–73. 10.1016/j.scitotenv.2012.02.072 22446112
Ashley K, Shulman SA, Brisson MJ, Howe AM. 2012. Interlaboratory evaluation of trace element determination in workplace air filter samples by inductively coupled plasma mass spectrometry. J Environ Monit. 14(2):360–367. 10.1039/C1EM10695C 22038017
Asmuss M, Mullenders LH, Eker A, Hartwig A. 2000. Differential effects of toxic metal compounds on the activities of Fpg and XPA, two zinc finger proteins involved in DNA repair. Carcinogenesis. 21(11):2097–2104. 10.1093/carcin/21.11.2097 11062174
Auffan M, Rose J, Wiesner MR, Bottero JY. 2009. Chemical stability of metallic nanoparticles: A parameter controlling their potential cellular toxicity in vitro. Environ Pollut. 157(4):1127–1133. 10.1016/j.envpol.2008.10.002 19013699
Ayala-Fierro F, Firriolo JM, Carter DE. 1999. Disposition, toxicity, and intestinal absorption of cobaltous chloride in male Fischer 344 rats. J Toxicol Environ Health A. 56(8):571–591. 10.1080/009841099157908 10321386
Azuma K, Kawahara A, Hattori S, Taira T, Tsurutani J, Watari K, Shibata T, Murakami Y, Takamori S, Ono M, et al. 2012. NDRG1/Cap43/Drg-1 may predict tumor angiogenesis and poor outcome in patients with lung cancer. J Thorac Oncol. 7(5):779–789. 10.1097/JTO.0b013e31824c92b4 22481237
Bailey MR, Kreyling WG, Andre S, Batchelor A, Collier CG, Drosselmeyer E, Ferron GA, Foster P, Haider B, Hodgson A, et al. 1989. An interspecies comparison of the lung clearance of inhaled monodisperse cobalt oxide particles - Part I: Objectives and summary of results. J Aerosol Sci. 20(2):169–188. 10.1016/0021-8502(89)90042-6
Bal W, Sokołowska M, Kurowska E, Faller P. 2013. Binding of transition metal ions to albumin: Sites, affinities and rates. Biochim Biophys Acta. 1830(12):5444–5455. 23811338
Baldwin EL, Byl JA, Osheroff N. 2004. Cobalt enhances DNA cleavage mediated by human topoisomerase II alpha in vitro and in cultured cells. Biochemistry. 43(3):728–735. 10.1021/bi035472f 14730977
Barrera G. 2012. Oxidative stress and lipid peroxidation products in cancer progression and therapy. ISRN Oncol. 2012:137289. 10.5402/2012/137289 23119185
Battaglia V, Compagnone A, Bandino A, Bragadin M, Rossi CA, Zanetti F, Colombatto S, Grillo MA, Toninello A. 2009. Cobalt induces oxidative stress in isolated liver mitochondria responsible for permeability transition and intrinsic apoptosis in hepatocyte primary cultures. Int J Biochem Cell Biol. 41(3):586–594. 10.1016/j.biocel.2008.07.012 18708157
Bax M. 1981. Lead and impaired abilities. Dev Med Child Neurol. 23:565–566. 10.1111/j.1469-8749.1981.tb02037.x
Beaucham CC, Kawamoto MM, Brueck SE. 2014. Evaluation of exposure to metals at an electronics scrap recycling facility. Cincinnati, OH: National Institute for Occupational Safety and Health. HETA 2013-0130-3226.
Befani C, Mylonis I, Gkotinakou IM, Georgoulias P, Hu CJ, Simos G, Liakos P. 2013. Cobalt stimulates HIF-1-dependent but inhibits HIF-2-dependent gene expression in liver cancer cells. Int J Biochem Cell Biol. 45(11):2359–2368. 10.1016/j.biocel.2013.07.025 23958427
Behl M, Stout MD, Herbert RA, Dill JA, Baker GL, Hayden BK, Roycroft JR, Bucher JR, Hooth MJ. 2015. Comparative toxicity and carcinogenicity of soluble and insoluble cobalt compounds. Toxicology. 333:195–205. 10.1016/j.tox.2015.04.008 25896363
Beleznay E, Osvay M. 1994. Long-term clearance of accidentally inhaled 60Co aerosols in humans. Health Phys. 66(4):392–399. 10.1097/00004032-199404000-00003 8138404
Ben-Skowronek I, Kozaczuk S. 2015. Von Hippel-Lindau Syndrome. Horm Res Paediatr. 84(3):145–152. 10.1159/000431323 26279462
Bencko V, Wagner V, Wagnerova M, Zavazal V. 1986. Human exposure to nickel and cobalt: Biological monitoring and immunobiochemical response. Environ Res. 40(2):399–410. 10.1016/S0013-9351(86)80115-3 3732211
Benderli Cihan Y, Öztürk Yildirim S. 2011. A discriminant analysis of trace elements in scalp hair of healthy controls and stage-IIIB non-small cell lung cancer (NSCLC) patients. Biol Trace Elem Res. 144(1-3):272–294. 10.1007/s12011-011-9086-x 21618005
Benderli Cihan Y, Sözen S, Öztürk Yildirim S. 2011. Trace elements and heavy metals in hair of stage III breast cancer patients. Biol Trace Elem Res. 144(1-3):360–379. 10.1007/s12011-011-9104-z 21660533
Benigni R, Bossa C, Tcheremenskaia O, Battistelli CL, Giuliani A. 2015. The Syrian hamster embryo cells transformation assay identifies efficiently nongenotoxic carcinogens, and can contribute to alternative, integrated testing. Mutat Res Genet Toxicol Environ Mutagen. Forthcoming. 10.1016/j.mrgentox.2015.02.001 25813724
Bergomi M, Vinceti M, Nacci G, Pietrini V, Bratter P, Alber D, Ferrari A, Vescovi L, Guidetti D, Sola P, et al. 2002. Environmental exposure to trace elements and risk of amyotrophic lateral sclerosis: A population-based case-control study. Environ Res. 89(2):116–123. 10.1006/enrs.2002.4361 12123644
Bernstein J, Derman P. 2014. Dramatic increase in total knee replacement utilization rates cannot be fully explained by a disproportionate increase among younger patients. Orthopedics. 37(7):e656–e659. 10.3928/01477447-20140626-58 25020250
Beyersmann D, Hartwig A. 1992. The genetic toxicology of cobalt. Toxicol Appl Pharmacol. 115(1):137–145. 10.1016/0041-008X(92)90377-5 1631889
Beyersmann D, Hartwig A. 2008. Carcinogenic metal compounds: Recent insight into molecular and cellular mechanisms. Arch Toxicol. 82(8):493–512. 10.1007/s00204-008-0313-y 18496671
Bibi M, Hashmi MZ, Malik RN. 2016. The level and distribution of heavy metals and changes in oxidative stress indices in humans from Lahore district, Pakistan. Hum Exp Toxicol. 35(1):78–90. 10.1177/0960327115578063 25791319
Bourg WJ, Nation JR, Clark DE. 1985. The effects of chronic cobalt exposure on passive-avoidance performance in the adult rat. Bull Psychon Soc. 23(6):527–530. 10.3758/BF03329874
Bracken CP, Whitelaw ML, Peet DJ. 2003. The hypoxia-inducible factors: Key transcriptional regulators of hypoxic responses. Cell Mol Life Sci. 60(7):1376–1393. 10.1007/s00018-003-2370-y 12943226
Bradberry SM, Wilkinson JM, Ferner RE. 2014. Systemic toxicity related to metal hip prostheses. Clin Toxicol (Phila). 52(8):837–847. 10.3109/15563650.2014.944977 25132471
Bresson C, Darolles C, Carmona A, Gautier C, Sage N, Roudeau S, Ortega R, Ansoborlo E, Malard V. 2013. Cobalt chloride speciation, mechanisms of cytotoxicity on human pulmonary cells, and synergistic toxicity with zinc. Metallomics. 5(2):133–143. 10.1039/c3mt20196a 23505636
Broberg K, Engstrom K, Shegufta A. 2015. Gene-environment interactions for metals. In: Nordberg GF, Fowler BA, Nordberg M, editors. Handbook on the Toxicology of Metals. 4th ed. Waltham, MA: Elsevier; p. 239–264. 10.1016/B978-0-444-59453-2.00012-3
Brock T, Stopford W. 2003. Bioaccessibility of metals in human health risk assessment: Evaluating risk from exposure to cobalt compounds. J Environ Monit. 5(4):71N–76N. 12948221
Bryant C, Rondinelli R, Singal M. 1987. Health hazard evaluation report: GTE/Valenite Corporation, Westminster, South Carolina. Cincinnati, OH: National Institute for Occupational Health and Safety. HETA 85-064-1844.
Bucher JR, Elwell MR, Thompson MB, Chou BJ, Renne R, Ragan HA. 1990. Inhalation toxicity studies of cobalt sulfate in F344/N rats and B6C3F1 mice. Fundam Appl Toxicol. 15(2):357–372. 10.1016/0272-0590(90)90061-N 2227161
Burr G, Habes D, Driscoll R, Krake A. 2005. Health hazard evaluation report: Freudenberg-NOK high quality plastics division, Findlay, Ohio. Cincinnati, OH: National Institute for Occupational Health and Safety. HETA 2003-0351-2972.
Burr G, Singal M, Hartle R, Rondinelli R. 1988. Health hazard evaluation report: General Electric Company, Evendale, Ohio. Cincinnati, OH: National Institute for Occupational Health and Safety. HETA 85-423-1904.
Burr G, Sinks T. 1988. Health hazard evaluation report: General Electric Carboloy Systems, Detroit, Michigan. Cincinnati, OH: National Institute for Occupational Health and Safety. HETA 85-295-1907.
Butt J, Kandel G. 2014. Barrett esophagus: When to endoscope. Clin Endosc. 47(1):40–46. 10.5946/ce.2014.47.1.40 24570882
Cadex Eletronics Inc. 2015. BU-205: Types of lithium ion. https://batteryuniversity.com/learn/article/types_of_lithium_ion. [Accessed: October 14, 2015]
Caicedo M, Jacobs JJ, Reddy A, Hallab NJ. 2007. Analysis of metal ion-induced DNA damage, apoptosis, and necrosis in human (Jurkat) T-cells demonstrates Ni2+ and V3+ are more toxic than other metals: Al3+, Be2+, Co2+, Cr3+, Cu2+, Fe3+, Mo5+, Nb5+, Zr2+. J Biomed Mater Res Part A.905-913.
Campbell CA, Peet M, Ward NI. 1988. Vanadium and other trace elements in patients taking lithium. Biol Psychiatry. 24(7):775–781. 10.1016/0006-3223(88)90253-3 3228565
Cancer Research U.K. 2014. Oesophageal cancer risk factors. London, UK: Cancer Research U.K. http://www.cancerresearchuk.org/cancer-info/cancerstats/types/oesophagus/riskfactors/oesophageal-cancer-risk-factors#Overview. [Accessed: March 30, 2015]
Carneiro MF, Grotto D, Batista BL, Rhoden CR, Barbosa F Jr. 2011. Background values for essential and toxic elements in children’s nails and correlation with hair levels. Biol Trace Elem Res. 144(1-3):339–350. 10.1007/s12011-011-9102-1 21671087
Casto BC, Meyers J, DiPaolo JA. 1979. Enhancement of viral transformation for evaluation of the carcinogenic or mutagenic potential of inorganic metal salts. Cancer Res. 39(1):193–198. 570089
Cavallo D, Ciervo A, Fresegna AM, Maiello R, Tassone P, Buresti G, Casciardi S, Iavicoli S, Ursini CL. 2015. Investigation on cobalt-oxide nanoparticles cyto-genotoxicity and inflammatory response in two types of respiratory cells. J Appl Toxicol. 10.1002/jat.3133 25772588
Centers for Disease Control and Prevention (CDC). 2013. Biomonitoring summary: Cobalt. Atlanta, GA: Centers for Disease Control and Prevention. https://www.cdc.gov/biomonitoring/Cobalt_BiomonitoringSummary.html. [January 31, 2015]
Centers for Disease Control and Prevention (CDC). 2015. Fourth national report on human exposure to environmental chemicals, updated tables, February 2015. Atlanta, GA: Centers for Disease Control and Prevention.
Centers for Disease Control and Prevention (CDC), National Center for Health Statistics (NCHS). 2011. National Health and Nutrition Examination Survey Questionnaire (or Examination Protocol, or Laboratory Protocol). Hyattsville, MD: U.S. Department of Health and Human Services, Centers for Disease Control and Prevention, [2011-2012]. https://wwwn.cdc.gov/nchs/nhanes/continuousnhanes/default.aspx?BeginYear=2011.
Chadwick JK, Wilson HK, White MA. 1997. An investigation of occupational metal exposure in thermal spraying processes. Sci Total Environ. 199(1-2):115–124. 10.1016/S0048-9697(97)05487-9 9200854
Chandel NS, Maltepe E, Goldwasser E, Mathieu CE, Simon MC, Schumacker PT. 1998. Mitochondrial reactive oxygen species trigger hypoxia-induced transcription. Proc Natl Acad Sci USA. 95(20):11715–11720. 10.1073/pnas.95.20.11715 9751731
Chattopadhyay S, Dash SK, Tripathy S, Das B, Mandal D, Pramanik P, Roy S. 2015. Toxicity of cobalt oxide nanoparticles to normal cells; an in vitro and in vivo study. Chem Biol Interact. 226:58–71. 10.1016/j.cbi.2014.11.016 25437709
ChemIDplus. 2015. ChemIDplus lite. National Library of Medicine. http://chem.sis.nlm.nih.gov/chemidplus/chemidlite.jsp and search by CAS number. [Accessed: March 24, 2015]
Chen L, Ramsey J, Brueck S. 2008. Evaluation of exposures at a pottery shop. Health hazard evaluation report: FUNKe Fired Arts (formerly known as Annie’s Mud Pie Shop), Cincinnati, Ohio. Cincinnati, OH: National Institute for Occupational Health and Safety. HETA 2007-0127-3068.
Cheng Y, Chen G, Hong L, Zhou L, Hu M, Li B, Huang J, Xia L, Li C. 2013. How does hypoxia inducible factor-1alpha participate in enhancing the glycolysis activity in cervical cancer? Ann Diagn Pathol. 17(3):305–311. 10.1016/j.anndiagpath.2012.12.002 23375385
Cheuk W, Chan AC, Chan JK, Lau GT, Chan VN, Yiu HH. 2005. Metallic implant-associated lymphoma: A distinct subgroup of large B-cell lymphoma related to pyothorax-associated lymphoma? Am J Surg Pathol. 29(6):832–836. 10.1097/01.pas.0000157747.10967.f4 15897752
Cheyns K, Banza Lubaba Nkulu C, Ngombe LK, Asosa JN, Haufroid V, De Putter T, Nawrot T, Kimpanga CM, Numbi OL, Ilunga BK, et al. 2014. Pathways of human exposure to cobalt in Katanga, a mining area of the D.R. Congo. Sci Total Environ. 490:313–321. 10.1016/j.scitotenv.2014.05.014 24858229
Christensen JM. 1995. Human exposure to toxic metals: Factors influencing interpretation of biomonitoring results. Sci Total Environ. 166:89–135. 10.1016/0048-9697(95)04478-J 7754357
Christensen JM, Mikkelsen S. 1986. Cobalt concentration in whole blood and urine from pottery plate painters exposed to cobalt paint. Proceedings of an International Conference, Heavy Metals in the Environment, Athens, September 1985. Luxembourg: Commission of the European Communities. p. 86-88.
Christensen JM, Poulsen OM. 1994. A 1982-1992 surveillance programme on Danish pottery painters. Biological levels and health effects following exposure to soluble or insoluble cobalt compounds in cobalt blue dyes. Sci Total Environ. 150(1-3):95–104. 10.1016/0048-9697(94)90134-1 7939615
Christensen JM, Poulsen OM, Thomsen M. 1993. A short-term cross-over study on oral administration of soluble and insoluble cobalt compounds: Sex differences in biological levels. Int Arch Occup Environ Health. 65(4):233–240. 10.1007/BF00381196 8144233
Clyne N, Lins LE, Pehrsson SK, Lundberg A, Werner J. 1988. Distribution of cobalt in myocardium, skeletal muscle and serum in exposed and unexposed rats. Trace Elem Med. 5(2):52–54.
Cobalt Development Institute. 2006. Cobalt facts. Surrey, UK: Cobalt Development Institute. http://thecdi.com/cobaltfacts.php. [Accessed: February 12, 2015]
Collecchi P, Esposito M, Brera S, Mora E, Mazzucotelli A, Oddone M. 1986. The distribution of arsenic and cobalt in patients with laryngeal carcinoma. J Appl Toxicol. 6(4):287–289. 10.1002/jat.2550060410 3760455
Collier CG, Bailey MR, Hodgson A. 1989. An interspecies comparison of the lung clearance of inhaled monodisperse cobalt oxide particles - Part V: Lung clearance of inhaled cobalt oxide particles in hamster, rats and guinea pigs. J Aerosol Sci. 20(2):233–247. 10.1016/0021-8502(89)90046-3
Collier CG, Hodgson A, Gray A, Moody JC, Ball A. 1991. The lung clearance kinetics of 57Co3O4 in rats of various ages. J Aerosol Sci. 22(4):537–549. 10.1016/0021-8502(91)90009-7
Colognato R, Bonelli A, Ponti J, Farina M, Bergamaschi E, Sabbioni E, Migliore L. 2008. Comparative genotoxicity of cobalt nanoparticles and ions on human peripheral leukocytes in vitro. Mutagenesis. 23(5):377–382. 10.1093/mutage/gen024 18504271
Cook MB, Kamangar F, Whiteman DC, Freedman ND, Gammon MD, Bernstein L, Brown LM, Risch HA, Ye W, Sharp L, et al. 2010. Cigarette smoking and adenocarcinomas of the esophagus and esophagogastric junction: A pooled analysis from the international BEACON consortium. J Natl Cancer Inst. 102(17):1344–1353. 10.1093/jnci/djq289 20716718
Coombs M. 1996. Biological monitoring of cobalt oxide workers. Int Arch Occup Environ Health. 68(6):511–512. 10.1007/BF00377878 8891794
Corley DA, Levin TR, Habel LA, Weiss NS, Buffler PA. 2002. Surveillance and survival in Barrett’s adenocarcinomas: A population-based study. Gastroenterology. 122(3):633–640. 10.1053/gast.2002.31879 11874995
Cornelis R, Heinzow B, Herber RFM, Molin Christensen J, Paulsen OM, Sabbioni E, Templeton DM, Thomassen Y, Vahter M, Vesterberg O. 1995. Sample collection guidelines for trace elements in blood and urine. Pure Appl Chem. 67(8-9):1575–1608. 10.1351/pac199567081575
Costa M, Heck JD, Robison SH. 1982. Selective phagocytosis of crystalline metal sulfide particles and DNA strand breaks as a mechanism for the induction of cellular transformation. Cancer Res. 42(7):2757–2763. 7083166
Coyle YM, Hynan LS, Euhus DM, Minhajuddin AT. 2005. An ecological study of the association of environmental chemicals on breast cancer incidence in Texas. Breast Cancer Res Treat. 92(2):107–114. 10.1007/s10549-004-8268-z 15986119
Coyle YM, Minahjuddin AT, Hynan LS, Minna JD. 2006. An ecological study of the association of metal air pollutants with lung cancer incidence in Texas. J Thorac Oncol. 1(7):654–661. 17409932
Daniels WJ, Arnold SJ, Orris P. 1986. Health hazard evaluation report: Ladish Company, Cudahy, Wisconsin. Cincinnati, OH: National Institute for Occupational Health and Safety. HETA 84-102-1653.
Davidson T, Ke Q, Costa M. 2015. Selected molecular mechanisms of metal toxicity and carcinogenicity. In: Nordberg GF, Fowler BA, Nordberg M, editors. Handbook on the Toxicology of Metals. 4th ed. Waltham, MA: Elsevier; p. 173–196. 10.1016/B978-0-444-59453-2.00009-3
Davies AP, Sood A, Lewis AC, Newson R, Learmonth ID, Case CP. 2005. Metal-specific differences in levels of DNA damage caused by synovial fluid recovered at revision arthroplasty. J Bone Joint Surg Br. 87-B(10):1439–1444. 10.1302/0301-620X.87B10.16541 16189324
Davis JR. 2000. Nickel, cobalt, and their alloys. Materials Park, OH: ASM International; p. 345–406.
Dawber R, Baran R. 1987. Nail growth. Cutis. 39(2):99–103. 3829726
De Boeck M, Kirsch-Volders M, Lison D. 2003 a. Cobalt and antimony: Genotoxicity and carcinogenicity. Mutat Res. 533(1-2):135–152. 10.1016/j.mrfmmm.2003.07.012 14643417
De Boeck M, Lardau S, Buchet JP, Kirsch-Volders M, Lison D. 2000. Absence of significant genotoxicity in lymphocytes and urine from workers exposed to moderate levels of cobalt-containing dust: A cross-sectional study. Environ Mol Mutagen. 36(2):151–160. 10.1002/1098-2280(2000)36:2<151::AID-EM10>3.0.CO;2-V 11013414
De Boeck M, Lison D, Kirsch-Volders M. 1998. Evaluation of the in vitro direct and indirect genotoxic effects of cobalt compounds using the alkaline comet assay. Influence of interdonor and interexperimental variability. Carcinogenesis. 19(11):2021–2029. 10.1093/carcin/19.11.2021 9855019
De Boeck M, Lombaert N, De Backer S, Finsy R, Lison D, Kirsch-Volders M. 2003 b. In vitro genotoxic effects of different combinations of cobalt and metallic carbide particles. Mutagenesis. 18(2):177–186. 10.1093/mutage/18.2.177 12621074
De Olivera JV, Boufleur LA, Dos Santos CE, Dias JF, Squeff CH, Silva GR, Ianistcki M, Benvegnu VC, Da Silva J. 2012. Occupational genotoxicity among copper smelters. Toxicol Ind Health. 28(9):789–795. 10.1177/0748233711422735 22042770
De Palma G, Goldoni M, Catalani S, Carbognani P, Poli D, Mozzoni P, Acampa O, Internullo E, Rusca M, Apostoli P. 2008. Metallic elements in pulmonary biopsies from lung cancer and control subjects. Acta Biomed. 79 Suppl 1:43–51. 18924309
Decker JA. 1991. Health hazard evaluation report. Rockwell International. Newark, OH: National Institute for Occupational Safety and Health;, HETA 90-368-2137.
Deitchman S, Kelly J, Miller ADL. 1994. Health hazard evaluation report. Tinker Air Force Base. Oklahoma City, OK: National Institute for Occupational Safety and Health;, HETA 91-0259-2420.
Delahant AB. 1955. An experimental study of the effects of rare metals on animal lungs. AMA Arch Ind Health. 12(2):116–120. 14397854
Demir C, Demir H, Esen R, Sehitogullari A, Atmaca M, Alay M. 2011. Altered serum levels of elements in acute leukemia cases in Turkey. Asian Pac J Cancer Prev. 12(12):3471–3474. 22471499
Deng JF, Elliot L, Sinks T, Smith D. 1990. Health hazard evaluation report. Hitachi Magnetics Corporation. Edmore, MI: National Institute for Occupational Safety and Health;, HETA 88-192-1998.
Deng X, Tüysüz H. 2014. Cobalt-oxide-based materials as water oxidation catalyst: Recent progress and challenges. ACS Catal. 4:3701–3714. 10.1021/cs500713d
Desai TK, Krishnan K, Samala N, Singh J, Cluley J, Perla S, Howden CW. 2012. The incidence of oesophageal adenocarcinoma in non-dysplastic Barrett’s oesophagus: A meta-analysis. Gut. 61(7):970–976. 10.1136/gutjnl-2011-300730 21997553
Devlin JJ, Pomerleau AC, Brent J, Morgan BW, Deitchman S, Schwartz M. 2013. Clinical features, testing, and management of patients with suspected prosthetic hip-associated cobalt toxicity: A systematic review of cases. J Med Toxicol. 9(4):405–415. 10.1007/s13181-013-0320-0 24222555
Dick CA, Brown DM, Donaldson K, Stone V. 2003. The role of free radicals in the toxic and inflammatory effects of four different ultrafine particle types. Inhal Toxicol. 15(1):39–52. 10.1080/08958370304454 12476359
Dodion P, Putz P, Amiri-Lamraski MH, Efira A, de Martelaere E, Heimann R. 1982. Immunoblastic lymphoma at the site of an infected vitallium bone plate. Histopathology. 6:807–813. 10.1111/j.1365-2559.1982.tb02776.x 6897644
Donaldson JD, Beyersmann D. 2012. Cobalt and cobalt compounds. In: Ullmann's Encyclopedia of Industrial Chemistry. Weinheim: Wiley-VCH Verlag GmbH & Co. KGaA. p. 429-465.
Dongarrà G, Lombardo M, Tamburo E, Varrica D, Cibella F, Cuttitta G. 2011. Concentration and reference interval of trace elements in human hair from students living in Palermo, Sicily (Italy). Environ Toxicol Pharmacol. 32(1):27–34. 10.1016/j.etap.2011.03.003 21787726
Doran A, Law FC, Allen MJ, Rushton N. 1998. Neoplastic transformation of cells by soluble but not particulate forms of metals used in orthopaedic implants. Biomaterials. 19(7-9):751–759. 10.1016/S0142-9612(97)00209-3 9663750
Dunstan E, Sanghrajka AP, Tilley S, Unwin P, Blunn G, Cannon SR, Briggs TW. 2005. Metal ion levels after metal-on-metal proximal femoral replacements: A 30-year follow-up. J Bone Joint Surg Br. 87-B(5):628–631. 10.1302/0301-620X.87B5.15384 15855362
Durgam S, Aristeguieta C. 2010. Evaluation of potential exposures at an electrolytic manganese dioxide processing plant. Health hazard evaluation report: Erachem Comilog, Inc., New Johnsonville, TN. Cincinnati, OH: National Institute for Occupational Safety and Health. HETA 2007-0331-3100.
Edel J, Pozzi G, Sabbioni E, Pietra R, Devos S. 1994. Metabolic and toxicological studies on cobalt. Sci Total Environ. 150(1-3):233–244. 10.1016/0048-9697(94)90159-7 7939602
Edmonds L, McQuilkin S, Orris P, Daniels W. 1981. Health hazard evaluation report: Federal Mogul, Metal Removal Tooling Division, Chicago, Illinois. Cincinnati, OH: National Institute for Occupational Health and Safety. HETA 80-058-874.
Egilsson V, Evans IH, Wilkie D. 1979. Toxic and mutagenic effects of carcinogens on the mitochondria of Saccharomyces cerevisiae. Mol Gen Genet. 174(1):39–46. 10.1007/BF00433303 384160
Elenge MM, Aubry JC, Jacob L, De Brouwer C. 2011. Heavy metal in hair samples of 109 non-industrial (miners) population in Katanga. Sante. 21(1):41–46. 10.1684/san.2011.0229 21700541
Erturk FA, Ay H, Nardemir G, Agar G. 2013. Molecular determination of genotoxic effects of cobalt and nickel on maize (Zea mays L.) by RAPD and protein analyses. Toxicol Ind Health. 29(7):662–671. 10.1177/0748233712442709 22499271
European Chemicals Agency (ECHA). 2009. Practical guide 6: How to report read-across and categories. Helsinki, Finland: European Chemicals Agency. ECHA-10-B-11-EN.
European Commission Integrated Pollution Prevention and Control (IPPC). 2014. Best available techniques (BAT) reference document for the non-ferrous metal industries. Seville, Spain: European Commission, Integrated Pollution Prevention and Control. MR/GC/EIPPCB/NFM_Draft_3.
Evarts E. 2013. What happens to electric car batteries when the car is retired?: Consumer Reports. https://www.consumerreports.org/cro/news/2013/10/what-happens-to-electric-car-batteries-when-the-car-is-retired/index.htm# (https://www.consumerreports.org/cro/news/2013/10/what-happens-to-electric-car-batteries-when-the-car-is-retired/index.htm). [Accessed: October 14, 2015]
Fairhall LT, Keenan RG, Brinton HP. 1949. Cobalt and the dust environment of the cemented tungsten carbide industry. Public Health Rep. 64(15):485–490. 10.2307/4586920 18114620
Farah SB. 1983. The in vivo effect of cobalt chloride on chromosomes. Rev Bras Genet. 6:433–442.
Farquharson JP. 2015. Formation Metals Inc. - President's letter to shareholders. Formation Metals, Inc. http://www.formationmetals.com/s/CobaltNews.asp?ReportID=697830. [Accessed: March 6, 2015]
Ferdenzi P, Giaroli C, Mori P, Pedroni C, Piccinini R, Ricci R, Sala O, Veronesi C, Mineo F. 1994. Cobalt powdersintering industry (stone cutting diamond wheels): A study of environmental-biological monitoring, workplace improvement and health surveillance. Sci Total Environ. 150(1-3):245–248. 10.1016/0048-9697(94)90160-0 7939603
Ferlay J, Steliarova-Foucher E, Lortet-Tieulent J, Rosso S, Coebergh JW, Comber H, Forman D, Bray F. 2013. Cancer incidence and mortality patterns in Europe: Estimates for 40 countries in 2012. Eur J Cancer. 49(6):1374–1403. 10.1016/j.ejca.2012.12.027 23485231
Ferri F, Candela S, Bedogni L, Piccinini R, Sala O. 1994. Exposure to cobalt in the welding process with stellite. Sci Total Environ. 150(1-3):145–147. 10.1016/0048-9697(94)90142-2 7939588
Figgitt M, Newson R, Leslie IJ, Fisher J, Ingham E, Case CP. 2010. The genotoxicity of physiological concentrations of chromium (Cr(III) and Cr(VI)) and cobalt (Co(II)): An in vitro study. Mutat Res. 688(1-2):53–61. 10.1016/j.mrfmmm.2010.03.008 20227425
Finley BL, Unice KM, Kerger BD, Otani JM, Paustenbach DJ, Galbraith DA, Tvermoes BE. 2013. 31-day study of cobalt(II) chloride ingestion in humans: Pharmacokinetics and clinical effects. J Toxicol Environ Health A. 76(21):1210–1224. 10.1080/15287394.2013.848391 24283372
Finogenova MA. 1973. [The influence of cobalt on induced cutaneous carcinogenesis]. Biull Eksp Biol Med. 74(2):73–75. 4804627
Fleckman P. 1985. Anatomy and physiology of the nail. Dermatol Clin. 3(3):373–381. 10.1016/S0733-8635(18)30874-X 3830499
Fleckman P. 1997. Basic science of the nail unit. In: Scher RK, Daniel CR, editors. Nails: Therapy, Diagnosis, Surgery. Philadelphia, PA: Saunders; p. 99–103.
Formation Metals Inc. 2015. Cobalt - A better future. Vancouver, B.C. Canada: Formation Metals, Inc.
Forooghian F, Razavi R, Timms L. 2007. Hypoxia-inducible factor expression in human RPE cells. Br J Ophthalmol. 91(10):1406–1410. 10.1136/bjo.2007.123125 17567660
Foster PP, Pearman I, Ramsden D. 1989. An interspecies comparison of the lung clearance of inhaled monodisperse cobalt oxide particles - Part II: Lung clearance of inhaled cobalt oxide particles in man. J Aerosol Sci. 20(2):189–204. 10.1016/0021-8502(89)90043-8
Frank E. 2012. Metal-on-metal hip systems. U.S. Food and Drug Administration. https://www.fda.gov/downloads/AdvisoryCommittees/CommitteesMeetingMaterials/MedicalDevices/MedicalDevicesAdvisoryCommittee/OrthopaedicandRehabilitationDevicesPanel/UCM310217.pdf%20target=.
Freedman ND, Murray LJ, Kamangar F, Abnet CC, Cook MB, Nyren O, Ye W, Wu AH, Bernstein L, Brown LM, et al. 2011. Alcohol intake and risk of oesophageal adenocarcinoma: A pooled analysis from the BEACON Consortium. Gut. 60(8):1029–1037. 10.1136/gut.2010.233866 21406386
Fu OY, Hou MF, Yang SF, Huang SC, Lee WY. 2009. Cobalt chloride-induced hypoxia modulates the invasive potential and matrix metalloproteinases of primary and metastatic breast cancer cells. Anticancer Res. 29(8):3131–3138. 19661326
Fukunaga M, Kurachi Y, Mizuguchi Y. 1982. Action of some metal ions on yeast chromosomes. Chem Pharm Bull (Tokyo). 30(8):3017–3019. 10.1248/cpb.30.3017 6754115
Gaines L. 2014. The future of automotive lithium-ion battery recycling: Charting a sustainable course. Sustainable Mat Technol. 1-2:2–7. 10.1016/j.susmat.2014.10.001
Galán-Cobo A, Sánchez-Silva R, Serna A, Abreu-Rodríguez I, Muñoz-Cabello AM, Echevarría M. 2013. Cellular overexpression of Aquaporins slows down the natural HIF-2α degradation during prolonged hypoxia. Gene. 522(1):18–26. 10.1016/j.gene.2013.03.075 23545307
Galanis A, Karapetsas A, Sandaltzopoulos R. 2009. Metal-induced carcinogenesis, oxidative stress and hypoxia signalling. Mutat Res. 674(1-2):31–35. 10.1016/j.mrgentox.2008.10.008 19022395
Galanis A, Pappa A, Giannakakis A, Lanitis E, Dangaj D, Sandaltzopoulos R. 2008. Reactive oxygen species and HIF-1 signalling in cancer. Cancer Lett. 266(1):12–20. 10.1016/j.canlet.2008.02.028 18378391
Gao S, Zhou J, Zhao Y, Toselli P, Li W. 2013. Hypoxia-response element (HRE)-directed transcriptional regulation of the rat lysyl oxidase gene in response to cobalt and cadmium. Toxicol Sci. 132(2):379–389. 10.1093/toxsci/kfs327 23161664
Garland M, Morris JS, Rosner BA, Stampfer MJ, Spate VL, Baskett CJ, Willett WC, Hunter DJ. 1993. Toenail trace element levels as biomarkers: Reproducibility over a 6-year period. Cancer Epidemiol Biomarkers Prev. 2(5):493–497. 8220096
Garrick MD, Dolan KG, Horbinski C, Ghio AJ, Higgins D, Porubcin M, Moore EG, Hainsworth LN, Umbreit JN, Conrad ME, et al. 2003. DMT1: A mammalian transporter for multiple metals. Biometals. 16(1):41–54. 10.1023/A:1020702213099 12572663
Gerhardsson L, Brune D, Lundstrom NG, Nordberg G, Wester PO. 1993. Biological specimen bank for smelter workers. Sci Total Environ. 139-140:157–173. 10.1016/0048-9697(93)90016-Y 8272826
Gerhardsson L, Brune D, Nordberg IG, Wester PO. 1985. Protective effect of selenium on lung cancer in smelter workers. Br J Ind Med. 42(9):617–626. 10.1136/oem.42.9.617 4041390
Gerhardsson L, Nordberg GF. 1993. Lung cancer in smelter workers—interactions of metals as indicated by tissue levels. Scand J Work Environ Health. 19 Suppl 1:90–94. 8159982
Gerhardsson L, Wester PO, Nordberg GF, Brune D. 1984. Chromium, cobalt and lanthanum in lung, liver and kidney tissue from deceased smelter workers. Sci Total Environ. 37(2-3):233–246. 10.1016/0048-9697(84)90099-8 6484565
Gilbert EW, Luna RA, Harrison VL, Hunter JG. 2011. Barrett’s esophagus: A review of the literature. J Gastrointest Surg. 15(5):708–718. 10.1007/s11605-011-1485-y 21461873
Gilman JP. 1962. Metal carcinogenesis. II. A study on the carcinogenic activity of cobalt, copper, iron, and nickel compounds. Cancer Res. 22:158–162. 13898693
Gilman JP, Ruckerbauer GM. 1962. Metal carcinogenesis. I. Observations on the carcinogenicity of a refinery dust, cobalt oxide, and colloidal thorium dioxide. Cancer Res. 22:152–157. 13898692
González-Muñoz MJ, Sánchez-Muniz FJ, Ródenas S, Sevillano MI, Larrea Marín MT, Bastida S. 2010. Differences in metal and metalloid content in the hair of normo- and hypertensive postmenopausal women. Hypertens Res. 33(3):219–224. 10.1038/hr.2009.221 20057484
Gori C, Zucconi L. 1957. [L’azione citologica indotta da un gruppo di composti inorganici su Allium cepa]. Caryologia. 10:29–45. 10.1080/00087114.1957.10797611
Grant K, Goldizen FC, Sly PD, Brune MN, Neira M, van den Berg M, Norman RE. 2013. Health consequences of exposure to e-waste: A systematic review. Lancet Glob Health. 1(6):e350–e361. 10.1016/S2214-109X(13)70101-3 25104600
Green SE, Luczak MW, Morse JL, DeLoughery Z, Zhitkovich A. 2013. Uptake, p53 pathway activation, and cytotoxic responses for Co(II) and Ni(II) in human lung cells: Implications for carcinogenicity. Toxicol Sci. 136(2):467–477. 10.1093/toxsci/kft214 24068677
Gregus Z, Klaassen CD. 1986. Disposition of metals in rats: A comparative study of fecal, urinary, and biliary excretion and tissue distribution of eighteen metals. Toxicol Appl Pharmacol. 85(1):24–38. 10.1016/0041-008X(86)90384-4 3726885
Greim H, Hartwig A, Reuter U, Richter-Reichhelm HB, Thielmann HW. 2009. Chemically induced pheochromocytomas in rats: Mechanisms and relevance for human risk assessment. Crit Rev Toxicol. 39(8):695–718. 10.1080/10408440903190861 19743946
Grimsrud TK, Berge SR, Haldorsen T, Andersen A. 2002. Exposure to different forms of nickel and risk of lung cancer. Am J Epidemiol. 156(12):1123–1132. 10.1093/aje/kwf165 12480657
Grimsrud TK, Berge SR, Haldorsen T, Andersen A. 2005. Can lung cancer risk among nickel refinery workers be explained by occupational exposures other than nickel? Epidemiology. 16(2):146–154. 10.1097/01.ede.0000152902.48916.d7 15703528
Grimsrud TK, Berge SR, Martinsen JI, Andersen A. 2003. Lung cancer incidence among Norwegian nickel-refinery workers 1953-2000. J Environ Monit. 5(2):190–197. 10.1039/b211722n 12729252
Gunn SA, Gould TC, Anderson WA. 1967. Specific response of mesenchymal tissue to cancerigenesis by cadmium. Arch Pathol. 83(6):493–499. 6024727
Guskov A, Eshaghi S. 2012. The mechanisms of Mg2+ and Co2+ transport by the CorA family of divalent cation transporters. Curr Top Membr. 69:393–414. 10.1016/B978-0-12-394390-3.00014-8 23046658
Guyton KZ, Kyle AD, Aubrecht J, Cogliano VJ, Eastmond DA, Jackson M, Keshava N, Sandy MS, Sonawane B, Zhang L, et al. 2009. Improving prediction of chemical carcinogenicity by considering multiple mechanisms and applying toxicogenomic approaches. Mutat Res. 681(2-3):230–240. 10.1016/j.mrrev.2008.10.001 19010444
Hall RM. 2003. Health hazard evaluation report: Sunset strip furniture stripping, Huntington Beach, California. Cincinnati, OH: National Institute for Occupational Health and Safety. HETA 2001- 0537-2897.
Hamilton-Koch W, Snyder RD, Lavelle JM. 1986. Metal-induced DNA damage and repair in human diploid fibroblasts and Chinese hamster ovary cells. Chem Biol Interact. 59(1):17–28. 10.1016/S0009-2797(86)80052-7 3757145
Hammond EM, Giaccia AJ. 2005. The role of p53 in hypoxia-induced apoptosis. Biochem Biophys Res Commun. 331(3):718–725. 10.1016/j.bbrc.2005.03.154 15865928
Hanna PM, Kadiiska MB, Mason RP. 1992. Oxygen-derived free radical and active oxygen complex formation from cobalt(II) chelates in vitro. Chem Res Toxicol. 5(1):109–115. 10.1021/tx00025a019 1316186
Hansen T, Clermont G, Alves A, Eloy R, Brochhausen C, Boutrand JP, Gatti AM, Kirkpatrick CJ. 2006. Biological tolerance of different materials in bulk and nanoparticulate form in a rat model: Sarcoma development by nanoparticles. J R Soc Interface. 3(11):767–775. 10.1098/rsif.2006.0145 17015296
Hartung M. 1986. [Lung fibrosis in hard-metal grinding—Significance of cobalt activity]. Bonn: Köllen-Druck & Verlag.
Hartwig A. 1998. Carcinogenicity of metal compounds: Possible role of DNA repair inhibition. Toxicol Lett. 102-103:235–239. 10.1016/S0378-4274(98)00312-9 10022259
Hartwig A, Asmuss M, Ehleben I, Herzer U, Kostelac D, Pelzer A, Schwerdtle T, Burkle A. 2002. Interference by toxic metal ions with DNA repair processes and cell cycle control: Molecular mechanisms. Environ Health Perspect. 110 Suppl 5:797–799. 10.1289/ehp.02110s5797 12426134
Hartwig A, Kasten U, Boakye-Dankwa K, Schlepegrell R, Beyersmann D. 1990. Uptake and genotoxicity of micromolar concentrations of cobalt chloride in mammalian cells. Toxicol Environ Chem. 28:205–215. 10.1080/02772249009357604
Hartwig A, Snyder RD, Schlepegrell R, Beyersmann D. 1991. Modulation by Co(II) of UV-induced DNA repair, mutagenesis and sister-chromatid exchanges in mammalian cells. Mutat Res. 248(1):177–185. 10.1016/0027-5107(91)90099-A 2030707
Harty LC, Guinee DG, Travis WD, Bennett WP, Jett J, Colby TV, Tazelaar H, Trastek V, Pairolero P, Liotta LA, et al. 1996. p53 mutations and occupational exposures in a surgical series of lung cancers. Cancer Epidemiol Biomarkers Prev. 5(12):997–1003. 8959323
He K. 2011. Trace elements in nails as biomarkers in clinical research. Eur J Clin Invest. 41(1):98–102. 10.1111/j.1365-2362.2010.02373.x 20813017
Heath JC. 1956. The production of malignant tumours by cobalt in the rat. Br J Cancer. 10(4):668–673. 10.1038/bjc.1956.80 13426378
Heath JC, Daniel MR. 1962. The production of malignant tumours by cobalt in the rat: Intrathoracic tumours. Br J Cancer. 16(3):473–478. 10.1038/bjc.1962.53 21772463
Heath JC, Webb M. 1967. Content and intracellular distribution of the inducing metal in the primary rhabdomyosarcomata induced in the rat by cobalt, nickel and cadmium. Br J Cancer. 21(4):768–779. 10.1038/bjc.1967.90 6074698
Heath JC, Webb M, Caffrey M. 1969. The interaction of carcinogenic metals with tissues and body fluids. Cobalt and horse serum. Br J Cancer. 23(1):153–166. 10.1038/bjc.1969.23 5768431
Henderson RG, Verougstraete V, Anderson K, Arbildua JJ, Brock TO, Brouwers T, Cappellini D, Delbeke K, Herting G, Hixon G, et al. 2014. Inter-laboratory validation of bioaccessibility testing for metals. Regul Toxicol Pharmacol. 70(1):170–181. 10.1016/j.yrtph.2014.06.021 24979734
Hengstler JG, Bolm-Audorff U, Faldum A, Janssen K, Reifenrath M, Gotte W, Jung D, Mayer-Popken O, Fuchs J, Gebhard S, et al. 2003. Occupational exposure to heavy metals: DNA damage induction and DNA repair inhibition prove co-exposures to cadmium, cobalt and lead as more dangerous than hitherto expected. Carcinogenesis. 24(1):63–73. 10.1093/carcin/24.1.63 12538350
Hennig FF, Raithel HJ, Schaller KH, Dohler JR. 1992. Nickel-, chrom- and cobalt-concentrations in human tissue and body fluids of hip prosthesis patients. J Trace Elem Electrolytes Health Dis. 6(4):239–243. 1304233
Hervin RL, Reifschneider R. 1973. Health hazard evaluation determination: Steel Tool and Engineering Company, Taylor, Michigan. Cincinnati, OH: National Institute for Occupational Health and Safety. HETA 72-42-76.
Hill AB. 1965. The environment and disease: Association or causation? Proc R Soc Med. 58:295–300. 10.1177/003591576505800503 14283879
Hillwalker WE, Anderson KA. 2014. Bioaccessibility of metals in alloys: Evaluation of three surrogate biofluids. Environ Pollut. 185:52–58. 10.1016/j.envpol.2013.10.006 24212234
Hollins JG, McCullough RS. 1971. Radiation dosimetry of internal contamination by inorganic compounds of cobalt: An analysis of cobalt metabolism in rats. Health Phys. 21(2):233–246. 10.1097/00004032-197108000-00010 5094193
Holstein H, Ranebo Y, Raaf CL. 2015. Human metabolism of orally administered radioactive cobalt chloride. J Environ Radioact. 143:152–158. 10.1016/j.jenvrad.2015.02.006 25791772
Hong HH, Hoenerhoff MJ, Ton TV, Herbert RA, Kissling GE, Hooth MJ, Behl M, Witt KL, Smith-Roe SL, Sills RC, et al. 2015. Kras, egfr, and tp53 mutations in B6C3F1/N mouse and F344/NTAC rat alveolar/bronchiolar carcinomas resulting from chronic Inhalation exposure to cobalt metal. Toxicol Pathol. 43(6):872–882. 10.1177/0192623315581192 26059825
Hopps HC, Stanley AJ, Shideler AM. 1954. Polycythemia induced by cobalt. III. Histologic studies with evaluation of toxicity of cobaltous chloride. Am J Clin Pathol. 24(12):1374–1380. 10.1093/ajcp/24.12.1374 13228371
Horev-Azaria L, Kirkpatrick CJ, Korenstein R, Marche PN, Maimon O, Ponti J, Romano R, Rossi F, Golla-Schindler U, Sommer D, et al. 2011. Predictive toxicology of cobalt nanoparticles and ions: Comparative in vitro study of different cellular models using methods of knowledge discovery from data. Toxicol Sci. 122(2):489–501. 10.1093/toxsci/kfr124 21602188
Horie M, Fujita K, Kato H, Endoh S, Nishio K, Komaba LK, Nakamura A, Miyauchi A, Kinugasa S, Hagihara Y, et al. 2012. Association of the physical and chemical properties and the cytotoxicity of metal oxide nanoparticles: Metal ion release, adsorption ability and specific surface area. Metallomics. 4(4):350–360. 10.1039/c2mt20016c 22419205
Hughes AW, Sherlock DA, Hamblen DL, Reid R. 1987. Sarcoma at the site of a single hip screw. A case report. J Bone Joint Surg Br. 69-B(3):470–472. 10.1302/0301-620X.69B3.3034914 3034914
Hunter DJ, Morris JS, Chute CG, Kushner E, Colditz GA, Stampfer MJ, Speizer FE, Willett WC. 1990. Predictors of selenium concentration in human toenails. Am J Epidemiol. 132(1):114–122. 10.1093/oxfordjournals.aje.a115623 2356804
Ichikawa Y, Kusaka Y, Goto S. 1985. Biological monitoring of cobalt exposure, based on cobalt concentrations in blood and urine. Int Arch Occup Environ Health. 55(4):269–276. 10.1007/BF00377685 4008051
Inaba J, Suzuki-Yasumoto M. 1979. A kinetic study of radionuclide absorption through damaged and undamaged skin of the guinea pig. Health Phys. 37(4):592–595. 536221
Inoue T, Ohta Y, Sadaie Y, Kada T. 1981. Effect of cobaltous chloride on spontaneous mutation induction in a Bacillus subtilis mutator strain. Mutat Res. 91(1):41–45. 10.1016/0165-7992(81)90068-3 6782475
International Agency for Research on Cancer (IARC). 1991. Chlorinated Drinking-water; Chlorination By-products; Some Other Halogenated Compounds; Cobalt and Cobalt Compounds. Lyon, France: International Agency for Research on Cancer; Cobalt and cobalt compounds; p. 363–434.
International Agency for Research on Cancer (IARC). 2006. Cobalt in Hard Metals. Lyon, France: International Agency for Research on Cancer; Metallic cobalt particles (with or without tungsten carbide); p. 39–155.
Itsara LS, Kennedy SR, Fox EJ, Yu S, Hewitt JJ, Sanchez-Contreras M, Cardozo-Pelaez F, Pallanck LJ. 2014. Oxidative stress is not a major contributor to somatic mitochondrial DNA mutations. PLoS Genet. 10(2):e1003974. 10.1371/journal.pgen.1003974 24516391
Jansen HM, Knollema S, van der Duin LV, Willemsen AT, Wiersma A, Franssen EJ, Russel FG, Korf J, Paans AM. 1996. Pharmacokinetics and dosimetry of cobalt-55 and cobalt-57. J Nucl Med. 37(12):2082–2086. 8970539
Jantzen C, Jørgensen HL, Duus BR, Sporring SL, Lauritzen JB. 2013. Chromium and cobalt ion concentrations in blood and serum following various types of metal-on-metal hip arthroplasties: A literature review. Acta Orthop. 84(3):229–236. 10.3109/17453674.2013.792034 23594249
Jasmin G, Riopelle JL. 1976. Renal carcinomas and erythrocytosis in rats following intrarenal injection of nickel subsulfide. Lab Invest. 35(1):71–78. 940323
Jemal A, Simard EP, Xu J, Ma J, Anderson RN. 2013. Selected cancers with increasing mortality rates by educational attainment in 26 states in the United States, 1993-2007. Cancer Causes Control. 24(3):559–565. 10.1007/s10552-012-9993-y 22729932
Jiang H, Liu F, Yang H, Li Y. 2012. Effects of cobalt nanoparticles on human T cells in vitro. Biol Trace Elem Res. 146(1):23–29. 10.1007/s12011-011-9221-8 21968949
Jomova K, Valko M. 2011. Advances in metal-induced oxidative stress and human disease. Toxicology. 283(2-3):65–87. 10.1016/j.tox.2011.03.001 21414382
Julander A, Lundgren L, Skare L, Grander M, Palm B, Vahter M, Liden C. 2014. Formal recycling of e-waste leads to increased exposure to toxic metals: An occupational exposure study from Sweden. Environ Int. 73:243–251. 10.1016/j.envint.2014.07.006 25300751
Kada T, Kanematsu N. 1978. Reduction of N -methyl-N’-nitrosoguanidine-induced mutations by cobalt chloride in Escherichia coli. Proc Jpn Acad. 54:234–237. 10.2183/pjab.54.234
Kadiiska MB, Maples KR, Mason RP. 1989. A comparison of cobalt(II) and iron(II) hydroxyl and superoxide free radical formation. Arch Biochem Biophys. 275(1):98–111. 10.1016/0003-9861(89)90354-8 2554814
Kain J, Karlsson HL, Moller L. 2012. DNA damage induced by micro- and nanoparticles—interaction with FPG influences the detection of DNA oxidation in the comet assay. Mutagenesis. 27(4):491–500. 10.1093/mutage/ges010 22447192
Kanabrocki EL, Kanabrocki JA, Greco J, Kaplan E, Oester YT, Brar SS, Gustafson PS, Nelson DM, Moore CE. 1979. Instrumental analysis of trace elements in thumbnails of human subjects. Sci Total Environ. 13(2):131–140. 10.1016/0048-9697(79)90067-6 493958
Kanematsu N, Hara M, Kada T. 1980. Rec assay and mutagenicity studies on metal compounds. Mutat Res. 77(2):109–116. 10.1016/0165-1218(80)90127-5 6769036
Kang GS, Li Q, Chen H, Costa M. 2006. Effect of metal ions on HIF-1alpha and Fe homeostasis in human A549 cells. Mutat Res. 610(1-2):48–55. 10.1016/j.mrgentox.2006.06.012 16877034
Kanias GD, Kouri E, Arvaniti H, Karaiosifidi H, Kouneli S. 1994. Trace element content in breasts with fibrocystic disease. Biol Trace Elem Res. 43-45:363–370. 10.1007/BF02917337 7710850
Karovic O, Tonazzini I, Rebola N, Edstrom E, Lovdahl C, Fredholm BB, Dare E. 2007. Toxic effects of cobalt in primary cultures of mouse astrocytes. Similarities with hypoxia and role of HIF-1alpha. Biochem Pharmacol. 73(5):694–708. 10.1016/j.bcp.2006.11.008 17169330
Kasirsky G, Gautieri RF, Mann DE Jr. 1965. Effect of cobaltous chloride on the minimal carcinogenic dose of methylcholanthrene in albino mice. J Pharm Sci. 54:491–493. 10.1002/jps.2600540345 14301601
Kasperek K, Kiem J, Iyengar GV, Feinendegen LE. 1981. Concentration differences between serum and plasma of the elements cobalt, iron, mercury, rubidium, selenium and zinc determined by neutron activation analysis. Sci Total Environ. 17:133–143. 10.1016/0048-9697(81)90179-0 7233153
Kasprzak KS. 2002. Oxidative DNA and protein damage in metal-induced toxicity and carcinogenesis. Free Radic Biol Med. 32(10):958–967. 10.1016/S0891-5849(02)00809-2 12008111
Kasprzak KS, Zastawny TH, North SL, Riggs CW, Diwan BA, Rice JM, Dizdaroglu M. 1994. Oxidative DNA base damage in renal, hepatic, and pulmonary chromatin of rats after intraperitoneal injection of cobalt(II) acetate. Chem Res Toxicol. 7(3):329–335. 10.1021/tx00039a009 8075364
Kasten U, Mullenders LH, Hartwig A. 1997. Cobalt(II) inhibits the incision and the polymerization step of nucleotide excision repair in human fibroblasts. Mutat Res. 383(1):81–89. 10.1016/S0921-8777(96)00052-3 9042422
Kawamoto MM, Echt A, Reh CM. 1999. Health hazard evaluation report: Eagle-Picher Industries, Joplin, Missouri. Cincinnati, OH: National Institute for Occupational Health and Safety. HETA 96-0016-2777.
Kawanishi S, Inoue S, Yamamoto K. 1989. Hydroxyl radical and singlet oxygen production and DNA damage induced by carcinogenic metal compounds and hydrogen peroxide. Biol Trace Elem Res. 21:367–372. 10.1007/BF02917277 2484615
Kawanishi S, Inoue S, Yamamoto K. 1994. Active oxygen species in DNA damage induced by carcinogenic metal compounds. Environ Health Perspect. 102 Suppl 3:17–20. 7843093
Keegan GM, Learmonth ID, Case CP. 2008. A systematic comparison of the actual, potential, and theoretical health effects of cobalt and chromium exposures from industry and surgical implants. Crit Rev Toxicol. 38(8):645–674. 10.1080/10408440701845534 18720105
Kennedy SM, Chan-Yeung M, Marion S, Lea J, Teschke K. 1995. Maintenance of stellite and tungsten carbide saw tips: Respiratory health and exposure-response evaluations. Occup Environ Med. 52(3):185–191. 10.1136/oem.52.3.185 7735392
Kerckaert GA, LeBoeuf RA, Isfort RJ. 1996. Use of the Syrian hamster embryo cell transformation assay for determining the carcinogenic potential of heavy metal compounds. Fundam Appl Toxicol. 34(1):67–72. 10.1006/faat.1996.0176 8937893
Kerfoot EJ, Fredrick WG, Domeier E. 1975. Cobalt metal inhalation studies on miniature swine. Am Ind Hyg Assoc J. 36(1):17–25. 10.1080/0002889758507202 1111264
Kerndt PR, Rondinelli R, Burr G. 1986. Health hazard evaluation report: United Technologies Diesel Systems, Springfield, Massachusetts. Cincinnati, OH: National Institute for Occupational Health and Safety. HETA 85-254-1722.
Kharab P, Singh I. 1985. Genotoxic effects of potassium dichromate, sodium arsenite, cobalt chloride and lead nitrate in diploid yeast. Mutat Res. 155(3):117–120. 10.1016/0165-1218(85)90128-4 3883155
Kharab P, Singh I. 1987. Induction of respiratory deficiency in yeast by salts of chromium, arsenic, cobalt and lead. Indian J Exp Biol. 25(2):141–142. 3311978
Kibblewhite MG, Van Rensburg SJ, Laker MC, Rose EF. 1984. Evidence for an intimate geochemical factor in the etiology of esophageal cancer. Environ Res. 33(2):370–378. 10.1016/0013-9351(84)90035-5 6714188
Kiefer M, Trout D, Decker J, Salisbury S. 1994. Health hazard evaluation report. General Electric Aircraft Engines. Madisonville, KY: National Institute for Occupational Safety and Health;, HETA 94-0151-2475.
Kitahara J, Yamanaka K, Kato K, Lee YW, Klein CB, Costa M. 1996. Mutagenicity of cobalt and reactive oxygen producers. Mutat Res. 370(3-4):133–140. 10.1016/S0165-1218(96)00042-0 8917658
Klatka J, Remer M, Dobrowolski R, Pietruszewska W, Trojanowska A, Siwiec H, Charytanowicz M. 2011. The content of cadmium, cobalt and nickel in laryngeal carcinoma. Arch Med Sci. 7(3):517–522. 10.5114/aoms.2011.23422 22295038
Klaunig JE, Kamendulis LM, Hocevar BA. 2010. Oxidative stress and oxidative damage in carcinogenesis. Toxicol Pathol. 38(1):96–109. 10.1177/0192623309356453 20019356
Klein CB, Su L, Rossman TG, Snow ET. 1994. Transgenic gpt+ V79 cell lines differ in their mutagenic response to clastogens. Mutat Res. 304(2):217–228. 10.1016/0027-5107(94)90214-3 7506365
Knee Replacement Costs. 2015. Which type of implant is right for you? Word Press: KneeReplacementCosts.com. https://www.kneereplacementcosts.com/implant-types.html. [Accessed: April 4, 2016]
Koedrith P, Seo YR. 2011. Advances in carcinogenic metal toxicity and potential molecular markers. Int J Mol Sci. 12(12):9576–9595. 10.3390/ijms12129576 22272150
Kopera E, Schwerdtle T, Hartwig A, Bal W. 2004. Co(II) and Cd(II) substitute for Zn(II) in the zinc finger derived from the DNA repair protein XPA, demonstrating a variety of potential mechanisms of toxicity. Chem Res Toxicol. 17(11):1452–1458. 10.1021/tx049842s 15540943
Kotake-Nara E, Saida K. 2007. Characterization of CoCl2-induced reactive oxygen species (ROS): Inductions of neurite outgrowth and endothelin-2/vasoactive intestinal contractor in PC12 cells by CoCl2 are ROS dependent, but those by MnCl2 are not. Neurosci Lett. 422(3):223–227. 10.1016/j.neulet.2007.06.026 17629402
Kraus T, Schramel P, Schaller KH, Zöbelein P, Weber A, Angerer J. 2001. Exposure assessment in the hard metal manufacturing industry with special regard to tungsten and its compounds. Occup Environ Med. 58(10):631–634. 10.1136/oem.58.10.631 11555683
Kreyling WG, Andre S, Collier CG, Ferron GA, Metivier H, Schumann G. 1991 a. Interspecies comparison of lung clearance after inhalation of monodisperse, solid cobalt oxide aerosol particles. J Aerosol Sci. 22(4):509–535. 10.1016/0021-8502(91)90008-6
Kreyling WG, Ferron GA, Haider B. 1986. Metabolic fate of inhaled Co aerosols in beagle dogs. Health Phys. 51(6):773–795. 10.1097/00004032-198612000-00007 3781852
Kreyling WG, Godleski JJ, Kariya ST, Rose RM, Brain JD. 1990. In vitro dissolution of uniform cobalt oxide particles by human and canine alveolar macrophages. Am J Respir Cell Mol Biol. 2(5):413–422. 10.1165/ajrcmb/2.5.413 2340182
Kreyling WG, Nyberg K, Nolibe D, Collier CG, Camner P, Heilman P, Lirsac PN, Lundborg M, Matejkova E. 1991 b. Interspecies comparison of phagolysosomal pH in alveolar macrophages. Inhal Toxicol. 3:91–100. 10.3109/08958379109145276
Kubo A, Levin TR, Block G, Rumore GJ, Quesenberry CP Jr, Buffler P, Corley DA. 2009. Alcohol types and sociodemographic characteristics as risk factors for Barrett’s esophagus. Gastroenterology. 136(3):806–815. 10.1053/j.gastro.2008.11.042 19111726
Kuo CY, Wong RH, Lin JY, Lai JC, Lee H. 2006. Accumulation of chromium and nickel metals in lung tumors from lung cancer patients in Taiwan. J Toxicol Environ Health A. 69(14):1337–1344. 10.1080/15287390500360398 16760140
Kusaka Y. 1996. Toxicology of Metals. Boca Raton, FL: CRC Lewis Publishers; Cobalt and nickel induced hard metal asthma; p. 461–468.
Kusaka Y, Yokoyama K, Sera Y, Yamamoto S, Sone S, Kyono H, Shirakawa T, Goto S. 1986. Respiratory diseases in hard metal workers: An occupational hygiene study in a factory. Br J Ind Med. 43(7):474–485. 10.1136/oem.43.7.474 3718895
Kusama T, Itoh S, Yoshizawa Y. 1986. Absorption of radionuclides through wounded skin. Health Phys. 51(1):138–141. 3455406
Kwon YM, Xia Z, Glyn-Jones S, Beard D, Gill HS, Murray DW. 2009. Dose-dependent cytotoxicity of clinically relevant cobalt nanoparticles and ions on macrophages in vitro. Biomed Mater. 4(2):025018. 10.1088/1748-6041/4/2/025018 19349653
Kyono H, Kusaka Y, Homma K, Kubota H, Endo-Ichikawa Y. 1992. Reversible lung lesions in rats due to short-term exposure to ultrafine cobalt particles. Ind Health. 30(3-4):103–118. 10.2486/indhealth.30.103 1301410
Lacy SA, Merritt K, Brown SA, Puryear A. 1996. Distribution of nickel and cobalt following dermal and systemic administration with in vitro and in vivo studies. J Biomed Mater Res. 32(2):279–283. 10.1002/(SICI)1097-4636(199610)32:2<279::AID-JBM18>3.0.CO;2-E 8884506
Laker M. 1982. On determining trace element levels in man: The uses of blood and hair. Lancet. 320(8292):260–262. 10.1016/S0140-6736(82)90336-1 6124683
Lantin AC, Mallants A, Vermeulen J, Speybroeck N, Hoet P, Lison D. 2011. Absence of adverse effect on thyroid function and red blood cells in a population of workers exposed to cobalt compounds. Toxicol Lett. 201(1):42–46. 10.1016/j.toxlet.2010.12.003 21182909
Larese Filon F, D’Agostin F, Crosera M, Adami G, Bovenzi M, Maina G. 2009. In vitro absorption of metal powders through intact and damaged human skin. Toxicol In Vitro. 23(4):574–579. 10.1016/j.tiv.2009.01.015 19490843
Larese Filon F, Gianpietro A, Venier M, Maina G, Renzi N. 2007. In vitro percutaneous absorption of metal compounds. Toxicol Lett. 170(1):49–56. 10.1016/j.toxlet.2007.02.009 17382494
Larese Filon F, Maina G, Adami G, Venier M, Coceani N, Bussani R, Massiccio M, Barbieri P, Spinelli P. 2004. In vitro percutaneous absorption of cobalt. Int Arch Occup Environ Health. 77(2):85–89. 10.1007/s00420-003-0455-4 12819972
Lark RM, Ander EL, Cave MR, Knights KV, Glennon MM, Scanlon RP. 2014. Mapping trace element deficiency by cokriging from regional geochemical soil data: A case study on cobalt for grazing sheep in Ireland. Geoderma. 226-227:64–78. 10.1016/j.geoderma.2014.03.002
Lee KA, Burgoon LD, Lamb L, Dere E, Zacharewski TR, Hogenesch JB, Lapres JJ. 2006. Identification and characterization of genes susceptible to transcriptional cross-talk between the hypoxia and dioxin signaling cascades. Chem Res Toxicol. 19(10):1284–1293. 10.1021/tx060068d 17040097
Lee JC, Son YO, Pratheeshkumar P, Shi X. 2012. Oxidative stress and metal carcinogenesis. Free Radic Biol Med. 53(4):742–757. 10.1016/j.freeradbiomed.2012.06.002 22705365
Lee SG, Lee H, Rho HM. 2001. Transcriptional repression of the human p53 gene by cobalt chloride mimicking hypoxia. FEBS Lett. 507(3):259–263. 10.1016/S0014-5793(01)02989-1 11696352
Leggett RW. 2008. The biokinetics of inorganic cobalt in the human body. Sci Total Environ. 389(2-3):259–269. 10.1016/j.scitotenv.2007.08.054 17920105
Leitão AC, Soares RA, Cardoso JS, Guillobel HC, Caldas LR. 1993. Inhibition and induction of SOS responses in Escherichia coli by cobaltous chloride. Mutat Res. 286(2):173–180. 10.1016/0027-5107(93)90181-E 7681528
Leonard S, Gannett PM, Rojanasakul Y, Schwegler-Berry D, Castranova V, Vallyathan V, Shi X. 1998. Cobalt-mediated generation of reactive oxygen species and its possible mechanism. J Inorg Biochem. 70(3-4):239–244. 10.1016/S0162-0134(98)10022-3 9720310
Leonard SS, Harris GK, Shi X. 2004. Metal-induced oxidative stress and signal transduction. Free Radic Biol Med. 37(12):1921–1942. 10.1016/j.freeradbiomed.2004.09.010 15544913
Letourneau EG, Jack GC, McCullough RS, Hollins JG. 1972. The metabolism of cobalt by the normal human male: Whole body retention and radiation dosimetry. Health Phys. 22(5):451–459. 10.1097/00004032-197205000-00003 4623524
Lewis CP, Demedts M, Nemery B. 1991. Indices of oxidative stress in hamster lung following exposure to cobalt(II) ions: In vivo and in vitro studies. Am J Respir Cell Mol Biol. 5(2):163–169. 10.1165/ajrcmb/5.2.163 1892647
Lewis CP, Demedts M, Nemery B. 1992. The role of thiol oxidation in Cobalt(II)-induced toxicity in hamster lung. Biochem Pharmacol. 43(3):519–525. 10.1016/0006-2952(92)90573-2 1540210
Lewis SA, O’Haver TC, Harnly JM. 1985. Determination of metals at the microgram-per-liter level in blood serum by simultaneous multielement atomic absorption spectrometry with graphite furnace atomization. Anal Chem. 57(1):2–5. 10.1021/ac00279a005 3985336
Lhotka C, Szekeres T, Steffan I, Zhuber K, Zweymuller K. 2003. Four-year study of cobalt and chromium blood levels in patients managed with two different metal-on-metal total hip replacements. J Orthop Res. 21(2):189–195. 10.1016/S0736-0266(02)00152-3 12568948
Li Q, Ke Q, Costa M. 2009. Alterations of histone modifications by cobalt compounds. Carcinogenesis. 30(7):1243–1251. 10.1093/carcin/bgp088 19376846
Limbach LK, Wick P, Manser P, Grass RN, Bruinink A, Stark WJ. 2007. Exposure of engineered nanoparticles to human lung epithelial cells: Influence of chemical composition and catalytic activity on oxidative stress. Environ Sci Technol. 41(11):4158–4163. 10.1021/es062629t 17612205
Linna A, Oksa P, Palmroos P, Roto P, Laippala P, Uitti J. 2003. Respiratory health of cobalt production workers. Am J Ind Med. 44(2):124–132. 10.1002/ajim.10258 12874844
Linnainmaa M, Kiilunen M. 1997. Urinary cobalt as a measure of exposure in the wet sharpening of hard metal and stellite blades. Int Arch Occup Environ Health. 69(3):193–200. 10.1007/s004200050136 9049670
Lippi G, Franchini M, Guidi GC. 2005. Cobalt chloride administration in athletes: A new perspective in blood doping? Br J Sports Med. 39(11):872–873. 10.1136/bjsm.2005.019232 16244201
Lison D. 2015. Cobalt. In: Nordberg GF, Fowler BA, Nordberg M, editors. Handbook on the Toxicology of Metals. 4th ed. ed. Waltham, MA: Elsevier. p. 743-763.
Lison D, De Boeck M, Verougstraete V, Kirsch-Volders M. 2001. Update on the genotoxicity and carcinogenicity of cobalt compounds. Occup Environ Med. 58(10):619–625. 10.1136/oem.58.10.619 11555681
Liu FC, Qin J, Wu HS, Wu YL, Zhu YL. 2011. Co and Cr accumulation in hair after metal-on-metal hip resurfacing arthroplasty. ANZ J Surg. 81(6):436–439. 10.1111/j.1445-2197.2010.05576.x 22295346
Lloyd DR, Carmichael PL, Phillips DH. 1998. Comparison of the formation of 8-hydroxy-2′-deoxyguanosine and single- and double-strand breaks in DNA mediated by fenton reactions. Chem Res Toxicol. 11(5):420–427. 10.1021/tx970156l 9585472
Lucas DR, Miller PR, Mott MP, Kronick JL, Unni KK. 2001. Arthroplasty-associated malignant fibrous histiocytoma: Two case reports. Histopathology. 39(6):620–628. 10.1046/j.1365-2559.2001.01253.x 11903581
Luyts K, Napierska D, Nemery B, Hoet PH. 2013. How physico-chemical characteristics of nanoparticles cause their toxicity: Complex and unresolved interrelations. Environ Sci Process Impacts. 15(1):23–38. 10.1039/C2EM30237C 24592425
Magaye R, Zhao J, Bowman L, Ding M. 2012. Genotoxicity and carcinogenicity of cobalt-, nickel- and copper-based nanoparticles. Exp Ther Med. 4(4):551–561. 10.3892/etm.2012.656 23170105
Swann M. 1984. Malignant soft tissue tumour at the site of a total hip replacement. J Bone Joint Surg Br. 66-B(5):629. 10.1302/0301-620X.66B5.6094587 6094587
Mao Y, Liu KJ, Jiang JJ, Shi X. 1996. Generation of reactive oxygen species by Co(II) from H2O2 in the presence of chelators in relation to DNA damage and 2′-deoxyguanosine hydroxylation. J Toxicol Environ Health. 47(1):61–75. 10.1080/009841096161933 8568912
Marsh GM, Esmen NA. 2007. Highlights of the NIOSH health hazard evaluation: Copperhill Smelter Worker Study. Cincinnati, OH: National Institute for Occupational Health and Safety. HETA 2001-0088-3048.
Matés JM, Segura JA, Alonso FJ, Marquez J. 2010. Roles of dioxins and heavy metals in cancer and neurological diseases using ROS-mediated mechanisms. Free Radic Biol Med. 49(9):1328–1341. 10.1016/j.freeradbiomed.2010.07.028 20696237
Maxwell P, Salnikow K. 2004. HIF-1: An oxygen and metal responsive transcription factor. Cancer Biol Ther. 3(1):29–35. 10.4161/cbt.3.1.547 14726713
Mayo Clinic. 2015. Test ID: COS. Cobalt, serum. Mayo Medical Laboratories. https://www.mayomedicallaboratories.com/test-catalog/Clinical+and+Interpretive/80084. [Accessed: April 10, 2015]
McCleery RE, Blade LM, Burt SE. 2001. Health hazard evaluation report: Special Metals Corporation, Princeton Powder Division, Princeton, Kentucky. Cincinnati, OH: National Institute for Occupational Health and Safety. HETA 97–0141–2819.
McDonald I. 1981. Malignant lymphoma associated with internal fixation of a fractured tibia. Cancer. 48(4):1009–1011. 10.1002/1097-0142(19810815)48:4<1009::AID-CNCR2820480426>3.0.CO;2-W 7272925
McInnes EF, Ernst H, Germann PG. 2013. Spontaneous neoplastic lesions in control Syrian hamsters in 6-, 12-, and 24-month short-term and carcinogenicity studies. Toxicol Pathol. 41(1):86–97. 10.1177/0192623312448938 22707381
McKinley JM, Ofterdinger U, Young M, Barsby A, Gavin A. 2013. Investigating local relationships between trace elements in soils and cancer data. Spat Stat. 5:25–41. 10.1016/j.spasta.2013.05.001
McLean JR, McWilliams RS, Kaplan JG, Birnboim HC. 1982. Rapid detection of DNA strand breaks in human peripheral blood cells and animal organs following treatment with physical and chemical agents. In: Bora KC, Douglas GR, Nestmann ER, editors. Progress in Mutation Research. Amsterdam: Elsevier Biomedical Press; p. 137–141.
McManus KP. 1982. Health hazard evaluation report: N.P.C. Systems, Inc., Milford, New Hampshire. Cincinnati, OH: National Institute for Occupational Health and Safety. HETA 81-212-1169.
Medicines and Healthcare Products Regulatory Agency (MHRA). 2012. Medical device alert: All Metal-on-Metal (MoM) hip replacements. Medicines and Healthcare Products Regulatory Agency. Ref: MDA/2012/036. https://assets.digital.cabinet-office.gov.uk/media/5485abf6ed915d4c10000273/con155767.pdf.
Meecham HM, Humphrey P. 1991. Industrial exposure to cobalt causing optic atrophy and nerve deafness: A case report. J Neurol Neurosurg Psychiatry. 54(4):374–375. 10.1136/jnnp.54.4.374 2056332
Meltzer HM, Brantsaeter AL, Borch-Iohnsen B, Ellingsen DG, Alexander J, Thomassen Y, Stigum H, Ydersbond TA. 2010. Low iron stores are related to higher blood concentrations of manganese, cobalt and cadmium in non-smoking, Norwegian women in the HUNT 2 study. Environ Res. 110(5):497–504. 10.1016/j.envres.2010.03.006 20381026
Menzel DB, Wolpert RL, Francovitch RJ, Shoaf CR, Boger Iii JR, Tayyeb MI. 1989. Respiratory tract burdens of cobalt from inhalation of soluble aerosols: Simulation by a two-compartment model. Inhal Toxicol. 1:49–69. 10.3109/08958378909145225
Méplan C, Richard MJ, Hainaut P. 2000. Metalloregulation of the tumor suppressor protein p53: Zinc mediates the renaturation of p53 after exposure to metal chelators in vitro and in intact cells. Oncogene. 19(46):5227–5236. 10.1038/sj.onc.1203907 11077439
Mikkelsen S, Raffn E, Altman D, Groth S, Christensen JM. 1984. Copenhagen: Arbejdsmitjøfondet; [Health and cobalt].
Miller AC, Mog S, McKinney L, Luo L, Allen J, Xu J, Page N. 2001. Neoplastic transformation of human osteoblast cells to the tumorigenic phenotype by heavy metal-tungsten alloy particles: Induction of genotoxic effects. Carcinogenesis. 22(1):115–125. 10.1093/carcin/22.1.115 11159749
Min WK, Kim SY, Oh CW, Kim SJ, Park TI, Koo KH. 2008. Malignant fibrous histiocytoma arising in the area of total hip replacement. Joint Bone Spine. 75(3):319–321. 10.1016/j.jbspin.2007.05.007 17977772
Mining Technology Market Customer Insight. 2015. Idaho cobalt mine, United States of America. Mining Technology Market & Customer Insight. http://www.mining-technology.com/projects/idaho-cobalt-mine/. [Accessed: March 16, 2015]
Miyaki M, Akamatsu N, Ono T, Koyama H. 1979. Mutagenicity of metal cations in cultured cells from Chinese hamster. Mutat Res. 68(3):259–263. 10.1016/0165-1218(79)90157-5 514305
Mo Y, Zhu X, Hu X, Tollerud DJ, Zhang Q. 2008. Cytokine and NO release from peripheral blood neutrophils after exposure to metal nanoparticles: In vitro and ex vivo studies. Nanotoxicology. 2(2):79–87. 10.1080/17435390802112874
Mochizuki H, Kada T. 1982. Antimutagenic action of cobaltous chloride on Trp-P-1-induced mutations in Salmonella typhimurium TA98 and TA1538. Mutat Res. 95(2-3):145–157. 10.1016/0027-5107(82)90253-6 6750380
Moorhouse CP, Halliwell B, Grootveld M, Gutteridge JM. 1985. Cobalt(II) ion as a promoter of hydroxyl radical and possible ‘crypto-hydroxyl’ radical formation under physiological conditions. Differential effects of hydroxyl radical scavengers. Biochim Biophys Acta. 843(3):261–268. 10.1016/0304-4165(85)90147-3 2998477
Moreno ME, Acosta-Saavedra LC, Meza-Figueroa D, Vera E, Cebrian ME, Ostrosky-Wegman P, Calderon-Aranda ES. 2010. Biomonitoring of metal in children living in a mine tailings zone in Southern Mexico: A pilot study. Int J Hyg Environ Health. 213(4):252–258. 10.1016/j.ijheh.2010.03.005 20418157
Mosconi G, Bacis M, Leghissa P, Maccarana G, Arsuffi E, Imbrogno P, Airoldi L, Caironi M, Ravasio G, Parigi PC, et al. 1994 a. Occupational exposure to metallic cobalt in the Province of Bergamo. Results of a 1991 survey. Sci Total Environ. 150(1-3):121–128. 10.1016/0048-9697(94)90138-4 7939584
Mosconi G, Bacis M, Vitali MT, Leghissa P, Sabbioni E. 1994 b. Cobalt excretion in urine: Results of a study on workers producing diamond grinding tools and on a control group. Sci Total Environ. 150(1-3):133–139. 10.1016/0048-9697(94)90140-6 7939586
Moulin JJ, Clavel T, Buclez B, Laffitte-Rigaud G. 2000 a. A mortality study among workers in a French aluminium reduction plant. Int Arch Occup Environ Health. 73(5):323–330. 10.1007/s004200000124 10963416
Moulin JJ, Clavel T, Roy D, Dananché B, Marquis N, Févotte J, Fontana JM. 2000 b. Risk of lung cancer in workers producing stainless steel and metallic alloys. Int Arch Occup Environ Health. 73(3):171–180. 10.1007/s004200050024 10787132
Moulin JJ, Wild P, Mur JM, Fournier-Betz M, Mercier-Gallay M. 1993. A mortality study of cobalt production workers: An extension of the follow-up. Am J Ind Med. 23(2):281–288. 10.1002/ajim.4700230205 8427256
Moulin JJ, Wild P, Romazini S, Lasfargues G, Peltier A, Bozec C, Deguerry P, Pellet F, Perdrix A. 1998. Lung cancer risk in hard-metal workers. Am J Epidemiol. 148(3):241–248. 10.1093/oxfordjournals.aje.a009631 9690360
Mur JM, Moulin JJ, Charruyer-Seinerra MP, Lafitte J. 1987. A cohort mortality study among cobalt and sodium workers in an electrochemical plant. Am J Ind Med. 11(1):75–81. 10.1002/ajim.4700110108 3812499
National Cancer Institute (NCI). 2015a. SEER cancer stat fact sheets. Bethesda, MD: National Cancer Institute. https://seer.cancer.gov/statfacts/. [Accessed: March 30, 2015]
National Cancer Institute (NCI). 2015b. SEER cancer statistics factsheets: Espohageal cancer. Bethesda, MD: National Cancer Institute. https://seer.cancer.gov/statfacts/html/esoph.html. [Accessed: March 30, 2015]
National Cancer Institute (NCI). 2015c. SEER cancer statistics factsheets: Lung and bronchus cancer. Bethesda, MD: National Cancer Institute. https://seer.cancer.gov/statfacts/html/lungb.html. [Accessed: March 30, 2015]
National Institute for Occupational Health and Safety (NIOSH). 1972. Health hazard evaluation report: Crane Company, St. Louis, Missouri. Cincinnati, OH: National Institute for Occupational Health and Safety. HETA 71-11-2.
National Institute for Occupational Health and Safety (NIOSH). 1987. Health Hazard Evaluation Report: GTE/Valenite Corporation, Westminster, South Carolina. Cincinnati, OH: U.S. Department of Health and Human Services, National Institute for Occupational Health and Safety. HETA 85-064-1844.
National Institute for Occupational Health and Safety (NIOSH). 1990. National occupational hazard survey (1981-1983). National Institute for Occupational Safety and Health. https://www.cdc.gov/noes/noes4/73470sco.html , https://www.cdc.gov/noes/noes4/x8305sco.html.
National Institute for Occupational Health and Safety (NIOSH). 1994 a. Cobalt and compounds, as Co: Method 7027. In: NIOSH Manual of Analytical Methods. 4th ed. National Institute for Occupational Health and Safety. p. 3.
National Institute for Occupational Health and Safety (NIOSH). 1994 b. Elements in blood or tissue: Method 8005. In: NIOSH Manual of Analytical Methods. 4th ed. National Institute for Occupational Health and Safety. p. 6.
National Institute for Occupational Health and Safety (NIOSH). 2003. Elements on wipes: Method 9102. In: NIOSH Manual of Analytical Methods. 4th ed. National Institute for Occupational Health and Safety. p. 5.
National Institute of Standards Technology (NIST). 2005. Why are there no volume li-ion battery manufacturers in the United States: Chapter II - rationale for li-ion Case. National Institute of Standards and Technology. http://www.atp.nist.gov/eao/wp05-01/chapt2.htm. [Accessed: May 22, 2015]
National Library of Medicine (HPD). 2014. Household products database. Bethesda, MD: National Library of Medicine. http://householdproducts.nlm.nih.gov/advancedsearch.htm and select “Ingredient” and search CAS No. [Accessed: October 10, 2014]
National Library of Medicine (HSDB). 2004. Hazardous substances database. Cobalt bis(2-ethylhexanoate). National Library of Medicine. http://toxnet.nlm.nih.gov/cgi-bin/sis/htmlgen?HSDB and search on CAS number or compound name. [Accessed: November 12, 2015]
National Library of Medicine (HSDB). 2012. Hazardous substances database. Cobaltous chloride. National Library of Medicine. http://toxnet.nlm.nih.gov/cgi-bin/sis/htmlgen?HSDB and search on CAS number or compound name. [Accessed: November 12, 2015]
National Toxicology Program (NTP). 1998. Toxicology and carcinogenesis studies of cobalt sulfate heptahydrate (CAS No. 10026-24-1) in F344/N rats and B6C3F1/N mice (inhalation studies). Research Triangle Park, NC: National Toxicology Program. NIH Publication No. 98-3961.
National Toxicology Program (NTP). 2002. Report on carcinogens background document for cobalt sulfate. Research Triangle Park, NC: National Toxicology Program.
National Toxicology Program (NTP). 2009. Report on carcinogens background document for cobalt-tungsten carbide: Powders and hard metals. Research Triangle Park, NC: National Toxicology Program.
National Toxicology Program (NTP). 2014 a. Report on Carcinogens. 13th ed. Research Triangle Park, NC: National Toxicology Program; Cobalt-tungsten carbide: Powders and hard metals.
National Toxicology Program (NTP). 2014b. Cobalt and certain cobalt compounds protocol. Research Triangle Park, NC: National Toxicology Program. https://ntp.niehs.nih.gov/ntp/roc/protocols/cobalt_508.pdf.
National Toxicology Program (NTP). 2014 c. Report on Carcinogens. 13th ed. Research Triangle Park, NC: National Toxicology Program; Cobalt sulfate.
National Toxicology Program (NTP). 2014d. Toxicology studies of cobalt metal (CAS No. 7440-48-4) in F344/N rats and B6C3F1/N mice and toxicology and carcinogenesis studies of cobalt metal in F344/NTac rats and B6C3F1/N mice (inhalation studies). Research Triangle Park, NC: National Toxicology Program. NIH Publication No. 14-5932.
Naylor GP, Harrison JD. 1995. Gastrointestinal iron and cobalt absorption and iron status in young rats and guinea pigs. Hum Exp Toxicol. 14(12):949–954. 10.1177/096032719501401203 8962745
Neale G. 1990. B12 binding proteins. Gut. 31(1):59–63. 10.1136/gut.31.1.59 2180793
Nemery B, Casier P, Roosels D, Lahaye D, Demedts M. 1992. Survey of cobalt exposure and respiratory health in diamond polishers. Am Rev Respir Dis. 145(3):610–616. 10.1164/ajrccm/145.3.610 1312313
Newton D, Rundo J. 1971. The long-term retention of inhaled cobalt-60. Health Phys. 21(3):377–384. 10.1097/00004032-197109000-00003 5095637
Nielsen NH, Kristiansen J, Borg L, Christensen JM, Poulsen LK, Menne T. 2000. Repeated exposures to cobalt or chromate on the hands of patients with hand eczema and contact allergy to that metal. Contact Dermatitis. 43(4):212–215. 10.1034/j.1600-0536.2000.043004212.x 11011920
Nilsson K, Jensen BS, Carlsen L. 1985. The migration chemistry of cobalt. Eur Appl Res Rept - Nucl Sci Technol. 7(1):23-86.
Nishioka H. 1975. Mutagenic activities of metal compounds in bacteria. Mutat Res. 31(3):185–189. 10.1016/0165-1161(75)90088-6 805366
Novick N. 2013. Understanding implants in knee and hip replacement. Hospital for Special Surgery. https://www.hss.edu/conditions_understanding-implants-in-knee-and-hip-replacement.asp. [Accessed: April 4, 2016]
Nowak HF. 1966. Neoplasia in mouse skeletal muscles under the influence of polyester resin activator. Arch Immunol Ther Exp (Warsz). 14(6):774–778. 5957998
Nyga A, Hart A, Tetley TD. 2015. Importance of the HIF pathway in cobalt nanoparticle-induced cytotoxicity and inflammation in human macrophages. Nanotoxicology. 9(7):905–917. 10.3109/17435390.2014.991430 25676618
O’Hara GP, Mann DE Jr, Gautieri RF. 1971. Effect of cobalt chloride and sodium cobaltinitrite on the growth of established epithelial tumors induced by methylcholanthrene. J Pharm Sci. 60(3):473–474. 10.1002/jps.2600600332 5572134
O’Rorke MA, Cantwell MM, Abnet CC, Brockman AJ, Murray LJ, Group FS. 2012. Toenail trace element status and risk of Barrett’s oesophagus and oesophageal adenocarcinoma: Results from the FINBAR study. Int J Cancer. 131(8):1882–1891. 10.1002/ijc.27434 22262413
Ogawa HI, Ohyama Y, Ohsumi Y, Kakimoto K, Kato Y, Shirai Y, Nunoshiba T, Yamamoto K. 1999. Cobaltous chloride-induced mutagenesis in the supF tRNA gene of Escherichia coli. Mutagenesis. 14(2):249–253. 10.1093/mutage/14.2.249 10229930
Ogawa HI, Sakata K, Inouye T, Jyosui S, Niyitani Y, Kakimoto K, Morishita M, Tsuruta S, Kato Y. 1986. Combined mutagenicity of cobalt(II) salt and heteroaromatic compounds in Salmonella typhimurium. Mutat Res. 172(2):97–104. 10.1016/0165-1218(86)90068-6 3531840
Ogawa HI, Shibahara T, Iwata H, Okada T, Tsuruta S, Kakimoto K, Sakata K, Kato Y, Ryo H, Itoh T, et al. 1994. Genotoxic activities in vivo of cobaltous chloride and other metal chlorides as assayed in the Drosophila wing spot test. Mutat Res. 320(1-2):133–140. 10.1016/0165-1218(94)90065-5 7506380
Ohno I. 2010. Electroless despoition of alloys. In: Schlesinger M, Paunovic M, editors. Modern Electroplating. 5th ed. John Wiley & Sons; p. 499–506.
Organisation for Economic Co-operation Development (OECD). 2014. Environment directorate joint meeting of the chemicals committee and the working party on chemicals, pesticides and biotechnology. Guidance on grouping of chemicals, Second Edition. Paris, France: Organisation for Economic Co-operation and Development. OECD Environment, Health and Safety Publications Series on Testing and Assessment No. 194, ENV/JM/MONO(2014)4.
Ortega R, Bresson C, Darolles C, Gautier C, Roudeau S, Perrin L, Janin M, Floriani M, Aloin V, Carmona A, et al. 2014. Low-solubility particles and a Trojan-horse type mechanism of toxicity: The case of cobalt oxide on human lung cells. Part Fibre Toxicol. 11:14. 10.1186/1743-8977-11-14 24669904
Orzechowski RF, Gautieri RF, Mann DE Jr. 1964. Effect of sodium cobaltinitrite on the minimal carcinogenic dose-50 (Mcd-50) of methylcholanthrene in albino mice. J Pharm Sci. 53:388–391. 10.1002/jps.2600530409 14189931
Ostapczuk P, Valenta P, Stoeppler M, Nürnberg HW. 1983. Voltammetric determination of nickel and cobalt in body fluids and other biological materials. In: Brown SS, Savory J, editors. Chemical Toxicology and Clinical Chemistry of Metals. London: Academic Press; p. 61–64.
Pagano DA, Zeiger E. 1992. Conditions for detecting the mutagenicity of divalent metals in Salmonella typhimurium. Environ Mol Mutagen. 19(2):139–146. 10.1002/em.2850190208 1541255
Paleček E, Brazdova M, Cernocka H, Vlk D, Brazda V, Vojtesek B. 1999. Effect of transition metals on binding of p53 protein to supercoiled DNA and to consensus sequence in DNA fragments. Oncogene. 18(24):3617–3625. 10.1038/sj.onc.1202710 10380883
Palit S, Ghosh AK, Sharma A, Talukder G. 1991 a. Modification of the clastogenic effects of cobalt by calcium in bone marrow cells of mice in vivo. Cytologia (Tokyo). 56:373–377. 10.1508/cytologia.56.373 30260327
Palit S, Sharma A, Talukder G. 1991 b. Chromosomal aberrations induced by cobaltous chloride in mice in vivo. Biol Trace Elem Res. 29(2):139–145. 10.1007/BF03032691 1713470
Palit S, Sharma A, Talukder G. 1991 c. Cytotoxic effects of cobalt chloride on mouse bone marrow cells in vivo. Cytobios. 68(273):85–89. 1807927
Palit S, Sharma A, Talukder G. 1991 d. Protection by chlorophyllin against induction of chromosomal aberrations by cobalt in bone marrow cells of mice in vivo. Fitoterapia. 62(5):425–428.
Papis E, Rossi F, Raspanti M, Dalle-Donne I, Colombo G, Milzani A, Bernardini G, Gornati R. 2009. Engineered cobalt oxide nanoparticles readily enter cells. Toxicol Lett. 189(3):253–259. 10.1016/j.toxlet.2009.06.851 19539014
Pasha Q, Malik SA, Iqbal J, Shah MH. 2007. Characterization and distribution of the selected metals in the scalp hair of cancer patients in comparison with normal donors. Biol Trace Elem Res. 118(3):207–216. 10.1007/s12011-007-0035-7 17916923
Patel E, Lynch C, Ruff V, Reynolds M. 2012. Co-exposure to nickel and cobalt chloride enhances cytotoxicity and oxidative stress in human lung epithelial cells. Toxicol Appl Pharmacol. 258(3):367–375. 10.1016/j.taap.2011.11.019 22172632
Paton GR, Allison AC. 1972. Chromosome damage in human cell cultures induced by metal salts. Mutat Res. 16(3):332–336. 10.1016/0027-5107(72)90166-2 5078138
Patrick G, Batchelor AL, Stirling C. 1989. An interspecies comparison of the lung clearance of inhaled monodisperse cobalt oxide particles - Part VI: Lung clearance of inhaled cobalt oxide particles in SPF Fischer rats. J Aerosol Sci. 20(2):249–255. 10.1016/0021-8502(89)90047-5
Patrick G, Stirling C, Kreyling WG, Poncy JL, Duserre C, Collier CG, Godleski J, Brain JD. 1994. Interspecies comparison of the clearance of ionic cobalt from the lngs. Inhal Toxicol. 6:225–240. 10.3109/08958379408995233
Paul SAM, Simons JW, Mabjeesh NJ. 2004. HIF at the crossroads between ischemia and carcinogenesis. J Cell Physiol. 200(1):20–30. 10.1002/jcp.10479 15137054
Pauluhn J. 2009. Comparative pulmonary response to inhaled nanostructures: Considerations on test design and endpoints. Inhal Toxicol. 21 SUPPL. 1:40–54. 10.1080/08958370902962291 19558233
Paustenbach DJ, Tvermoes BE, Unice KM, Finley BL, Kerger BD. 2013. A review of the health hazards posed by cobalt. Crit Rev Toxicol. 43(4):316–362. 10.3109/10408444.2013.779633 23656559
Pearce N, Checkoway H, Kriebel D. 2007. Bias in occupational epidemiology studies. Occup Environ Med. 64(8):562. 10.1136/oem.2006.026690 17053019
Pellet F, Perdrix A, Vincent M, Mallion JM. 1984. [Biological levels of urinary cobalt]. Arch Mal Prof. 45:81–85.
Permenter MG, Dennis WE, Sutto TE, Jackson DA, Lewis JA, Stallings JD. 2013. Exposure to cobalt causes transcriptomic and proteomic changes in two rat liver derived cell lines. PLoS One. 8(12):e83751. 10.1371/journal.pone.0083751 24386269
Petering HG, Yeager DW, Witherup SO. 1973. Trace metal content of hair. II. Cadmium and lead of human hair in relation to age and sex. Arch Environ Health. 27(5):327–330. 10.1080/00039896.1973.10666389 4743409
Peters K, Unger RE, Gatti AM, Sabbioni E, Tsaryk R, Kirkpatrick CJ. 2007. Metallic nanoparticles exhibit paradoxical effects on oxidative stress and pro-inflammatory response in endothelial cells in vitro. Int J Immunopathol Pharmacol. 20(4):685–695. 10.1177/039463200702000404 18179741
Petit A, Mwale F, Tkaczyk C, Antoniou J, Zukor DJ, Huk OL. 2005. Induction of protein oxidation by cobalt and chromium ions in human U937 macrophages. Biomaterials. 26(21):4416–4422. 10.1016/j.biomaterials.2004.11.019 15701370
Polyzois I, Nikolopoulos D, Michos I, Patsouris E, Theocharis S. 2012. Local and systemic toxicity of nanoscale debris particles in total hip arthroplasty. J Appl Toxicol. 32(4):255–269. 10.1002/jat.2729 22328167
Ponti J, Sabbioni E, Munaro B, Broggi F, Marmorato P, Franchini F, Colognato R, Rossi F. 2009. Genotoxicity and morphological transformation induced by cobalt nanoparticles and cobalt chloride: An in vitro study in Balb/3T3 mouse fibroblasts. Mutagenesis. 24(5):439–445. 10.1093/mutage/gep027 19605413
Posma FD, Dijstelberger SK. 1985. Serum and urinary cobalt levels as indicators of cobalt exposure in hard metal workers. Proceedings of an International Conference, Heavy Metals in the Environment, Athens, September 1985. Luxembourg: Commission of the European Communities. p. 89-91.
Poulsen OM, Olsen E, Christensen JM, Vinzent P, Petersen OH. 1995. Geltape method for measurement of work related surface contamination with cobalt containing dust: Correlation between surface contamination and airborne exposure. Occup Environ Med. 52:827–833. 10.1136/oem.52.12.827 8563847
Pourahmad J, O’Brien PJ, Jokar F, Daraei B. 2003. Carcinogenic metal induced sites of reactive oxygen species formation in hepatocytes. Toxicol In Vitro. 17(5-6):803–810. 10.1016/S0887-2333(03)00123-1 14599481
Prazmo W, Balbin E, Baranowska H, Ejchart A, Putrament A. 1975. Manganese mutagenesis in yeast. II. Conditions of induction and characteristics of mitochondrial respiratory deficient Saccharomyces cerevisiae mutants induced with manganese and cobalt. Genet Res. 26(1):21–29. 10.1017/S0016672300015810 767216
Prescott E, Netterstrom B, Faber J, Hegedus L, Suadicani P, Christensen JM. 1992. Effect of occupational exposure to cobalt blue dyes on the thyroid volume and function of female plate painters. Scand J Work Environ Health. 18(2):101–104. 10.5271/sjweh.1605 1604269
PubChem. 2015. PubChem compound. National Center for Biotechnology Information. https://www.ncbi.nlm.nih.gov/pccompound and search by Compound Identification Number. [Accessed: March 24, 2015]
Pulido MD, Parrish AR. 2003. Metal-induced apoptosis: Mechanisms. Mutat Res. 533(1-2):227–241. 10.1016/j.mrfmmm.2003.07.015 14643423
Putrament A, Baranowska H, Ejchart A, Jachymczyk W. 1977. Manganese mutagenesis in yeast. VI. Mn2+ uptake, mitDNA replication and ER induction: Comparison with other divalent cations. Mol Gen Genet. 151(1):69–76. 10.1007/BF00446914 325369
Qayyum MA, Shah MH. 2014. Comparative assessment of selected metals in the scalp hair and nails of lung cancer patients and controls. Biol Trace Elem Res. 158(3):305–322. 10.1007/s12011-014-9942-6 24671620
Qiao H, Li L, Qu ZC, May JM. 2009. Cobalt-induced oxidant stress in cultured endothelial cells: Prevention by ascorbate in relation to HIF-1alpha. Biofactors. 35(3):306–313. 10.1002/biof.43 19396871
Qiao Y, Ma L. 2013. Quantification of metal ion induced DNA damage with single cell array based assay. Analyst (Lond). 138(19):5713–5718. 10.1039/c3an00967j 23892322
Raffn E, Mikkelsen S, Altman DG, Christensen JM, Groth S. 1988. Health effects due to occupational exposure to cobalt blue dye among plate painters in a porcelain factory in Denmark. Scand J Work Environ Health. 14(6):378–384. 10.5271/sjweh.1903 3264937
Rasgele PG, Kekecoglu M, Muranli FDG. 2013. Induction of micronuclei in mice bone marrow cells by cobalt and copper chlorides. Arch Environ Prot. 39(1):75–82. 10.2478/aep-2013-0007
Reddy SB, Charles MJ, Kumar MR, Reddy BS, Anjaneyulu C, Raju GJN, Sundareswar B, Vijayan V. 2002. Trace elemental analysis of adenoma and carcinoma thyroid by PIXE method. Nucl Instrum Methods Phys Res B. 196:333–339. 10.1016/S0168-583X(02)01292-2
Reinardy HC, Syrett JR, Jeffree RA, Henry TB, Jha AN. 2013. Cobalt-induced genotoxicity in male zebrafish (Danio rerio), with implications for reproduction and expression of DNA repair genes. Aquat Toxicol. 126:224–230. 10.1016/j.aquatox.2012.11.007 23246864
Resende de Souza Nazareth H. 1976. [Efeito do cloreto de cobalto em não-disjunção]. Cienc Cult. 28:1472–1475.
Retriev Technologies. 2015. Lithium ion. https://www.retrievtech.com/recycling/lithium-ion. [Accessed: October 14, 2015]
Richardson HW, Meshri DT. 2001. Kirk-Othmer Encyclopedia of Chemical Technology. Vol. 7. John Wiley & Sons, Inc. Cobalt compounds. p. 229–249.
Richter PA, Bishop EE, Wang J, Swahn MH. 2009. Tobacco smoke exposure and levels of urinary metals in the U.S. youth and adult population: The National Health and Nutrition Examination Survey (NHANES) 1999-2004. Int J Environ Res Public Health. 6(7):1930–1946. 10.3390/ijerph6071930 19742163
Robison SH, Cantoni O, Costa M. 1982. Strand breakage and decreased molecular weight of DNA induced by specific metal compounds. Carcinogenesis. 3(6):657–662. 10.1093/carcin/3.6.657 7116559
Rodriguez de la Flor M, Hernandez-Vaquero D, Fernandez-Carreira JM. 2013. Metal presence in hair after metal-on-metal resurfacing arthroplasty. J Orthop Res. 31(12):2025–2031. 10.1002/jor.22450 23893786
Rogers MA, Thomas DB, Davis S, Vaughan TL, Nevissi AE. 1993. A case-control study of element levels and cancer of the upper aerodigestive tract. Cancer Epidemiol Biomarkers Prev. 2(4):305–312. 8348053
Romero A, Ramos E, De Los Ríos C, Egea J, Del Pino J, Reiter RJ. 2014. A review of metal-catalyzed molecular damage: Protection by melatonin. J Pineal Res. 56(4):343–370. 10.1111/jpi.12132 24628077
Rosensteel RE, Meyer CR, Flesch JP. 1977. Health hazard evaluation determination: Reinell Boats, Inc., Poplar Bluff, Missouri. Cincinnati, OH: National Institute for Occupational Health and Safety. HETA 75-150-378.
Rossman TG, Molina M, Meyer LW. 1984. The genetic toxicology of metal compounds: I. Induction of lambda prophage in E coli WP2s(lambda). Environ Mutagen. 6(1):59–69. 10.1002/em.2860060108 6229401
Rudge CV, Röllin HB, Nogueira CM, Thomassen Y, Rudge MC, Odland JØ. 2009. The placenta as a barrier for toxic and essential elements in paired maternal and cord blood samples of South African delivering women. J Environ Monit. 11(7):1322–1330. 10.1039/b903805a 20449220
Rufe PF. 2010. Testimony for United States senate committee on energy and natural resources, September 30, 2010. Salmon, ID. U.S.: Formation Capital Corporation.
Sabbioni E, Fortaner S, Farina M, Del Torchio R, Olivato I, Petrarca C, Bernardini G, Mariani-Costantini R, Perconti S, Di Giampaolo L, et al. 2014 a. Cytotoxicity and morphological transforming potential of cobalt nanoparticles, microparticles and ions in Balb/3T3 mouse fibroblasts: An in vitro model. Nanotoxicology. 8(4):455–464. 10.3109/17435390.2013.796538 23586465
Sabbioni E, Fortaner S, Farina M, Del Torchio R, Petrarca C, Bernardini G, Mariani-Costantini R, Perconti S, Di Giampaolo L, Gornati R, et al. 2014 b. Interaction with culture medium components, cellular uptake and intracellular distribution of cobalt nanoparticles, microparticles and ions in Balb/3T3 mouse fibroblasts. Nanotoxicology. 8(1):88–99. 10.3109/17435390.2012.752051 23167736
Sabbioni E, Minoia C, Pietra R, Mosconi G, Forni A, Scansetti G. 1994 a. Metal determinations in biological specimens of diseased and non-diseased hard metal workers. Sci Total Environ. 150(1-3):41–54. 10.1016/0048-9697(94)90127-9 7939608
Sabbioni E, Mosconi G, Minoia C, Seghizzi P. 1994 b. The European congress on cobalt and hard metal disease. Conclusions, highlights and need of future studies. Sci Total Environ. 150(1-3):263–270. 10.1016/0048-9697(94)90164-3 7939607
Sahakian N, Stefaniak A, Day G, Kanwal R. 2009. Report on respiratory symptoms and disease among cemented tungsten carbide workers. Health hazard evaluation report: Metalworking Products, Huntsville, Gurley, and Grant, Alabama. Cincinnati, OH: National Institute for Occupational Safety and Health. HETA 2003-0257-3088.
Saini Y, Greenwood KK, Merrill C, Kim KY, Patial S, Parameswaran N, Harkema JR, LaPres JJ. 2010 a. Acute cobalt-induced lung injury and the role of hypoxia-inducible factor 1 alpha in modulating inflammation. Toxicol Sci. 116(2):673–681. 10.1093/toxsci/kfq155 20511350
Saini Y, Kim KY, Lewandowski R, Bramble LA, Harkema JR, Lapres JJ. 2010 b. Role of hypoxia-inducible factor 1{alpha} in modulating cobalt-induced lung inflammation. Am J Physiol Lung Cell Mol Physiol. 298(2):L139–L147. 10.1152/ajplung.00252.2009 19915160
Salisbury S, Seligman PJ. 1987. Health hazard evaluation report: Wheel Trueing Tool Company, Columbia, South Carolina. Cincinnati, OH: National Institute for Occupational Health and Safety. HETA 84-288-1847.
Salnikow K, Donald SP, Bruick RK, Zhitkovich A, Phang JM, Kasprzak KS. 2004. Depletion of intracellular ascorbate by the carcinogenic metals nickel and cobalt results in the induction of hypoxic stress. J Biol Chem. 279(39):40337–40344. 10.1074/jbc.M403057200 15271983
Salnikow K, Su W, Blagosklonny MV, Costa M. 2000. Carcinogenic metals induce hypoxia-inducible factor-stimulated transcription by reactive oxygen species-independent mechanism. Cancer Res. 60(13):3375–3378. 10910041
Sampson B, Hart A. 2012. Clinical usefulness of blood metal measurements to assess the failure of metal-on-metal hip implants. Ann Clin Biochem. 49(2):118–131. 10.1258/acb.2011.011141 22155921
Savarino L, Cadossi M, Chiarello E, Fotia C, Greco M, Baldini N, Giannini S. 2014. How do metal ion levels change over time in hip resurfacing patients? A cohort study. ScientificWorldJournal. 291925. 10.1155/2014/291925 25580456
Scansetti G, Botta GC, Spinelli P, Reviglione L, Ponzetti C. 1994. Absorption and excretion of cobalt in the hard metal industry. Sci Total Environ. 150(1-3):141–144. 10.1016/0048-9697(94)90141-4 7939587
Scansetti G, Lamon S, Talarico S, Botta GC, Spinelli P, Sulotto F, Fantoni F. 1985. Urinary cobalt as a measure of exposure in the hard metal industry. Int Arch Occup Environ Health. 57(1):19–26. 10.1007/BF00383542 4077278
Scansetti G, Maina G, Botta GC, Bambace P, Spinelli P. 1998. Exposure to cobalt and nickel in the hard-metal production industry. Int Arch Occup Environ Health. 71(1):60–63. 10.1007/s004200050251 9523251
Schaffer AW, Pilger A, Engelhardt C, Zweymueller K, Ruediger HW. 1999. Increased blood cobalt and chromium after total hip replacement. J Toxicol Clin Toxicol. 37(7):839–844. 10.1081/CLT-100102463 10630267
Scharf B, Clement CC, Zolla V, Perino G, Yan B, Elci SG, Purdue E, Goldring S, Macaluso F, Cobelli N, et al. 2014. Molecular analysis of chromium and cobalt-related toxicity. Sci Rep. 4:5729. 10.1038/srep05729 25034144
Schumacher-Wittkopf E, Angerer J. 1981. [A practical method for the determination of cobalt in urine (author's transl)]. Int Arch Occup Environ Health. 49(1):77–81. 10.1007/BF00380811 7298216
SciFinder. 2015. SciFinder. https://www.cas.org/products/scifinder. [Accessed: April 30, 2015]
Shabaan AA, Marks V, Lancaster MC, Dufeu GN. 1977. Fibrosarcomas induced by cobalt chloride (CoCl2) in rats. Lab Anim. 11(1):43–46. 10.1258/002367777780959157 839722
Shacklette HT, Boerngen JG. 1984. Element concentrations in soils and other surficial materials of the conterminous United States. Washington, D.C. US Geol Surv Prof Pap. 1270.
Sharma P. 2004. Review article: Prevalence of Barrett’s oesophagus and metaplasia at the gastro-oesophageal junction. Aliment Pharmacol Ther. 20 Suppl 5:48–54, discussion 61–42. 10.1111/j.1365-2036.2004.02138.x 15456464
Shedd KB. 1993. The materials fow of cobalt in the United States. United States Department of the Interior. IC 9350.
Shedd KB. 2014a. USGS 2012 minerals yearbook: Cobalt [advance release]. http://minerals.usgs.gov/minerals/pubs/commodity/cobalt/index.html#myb. [Accessed: February 12, 2015]
Shedd KB. 2014b. USGS, mineral commodity summaries, February 2014: Cobalt. https://minerals.usgs.gov/minerals/pubs/commodity/cobalt/. [Accessed: February 12, 2015]
Sheftel A, Stehling O, Lill R. 2010. Iron-sulfur proteins in health and disease. Trends Endocrinol Metab. 21(5):302–314. 10.1016/j.tem.2009.12.006 20060739
Shi X, Dalal NS, Kasprzak KS. 1993. Generation of free radicals from model lipid hydroperoxides and H2O2 by Co(II) in the presence of cysteinyl and histidyl chelators. Chem Res Toxicol. 6(3):277–283. 10.1021/tx00033a005 8318649
Shukla SJ, Huang R, Simmons SO, Tice RR, Witt KL, Vanleer D, Ramabhadran R, Austin CP, Xia M. 2012. Profiling environmental chemicals for activity in the antioxidant response element signaling pathway using a high throughput screening approach. Environ Health Perspect. 120(8):1150–1156. 10.1289/ehp.1104709 22551509
Sidaginamale RP, Joyce TJ, Lord JK, Jefferson R, Blain PG, Nargol AVF, Langton DJ. 2013. Blood metal ion testing is an effective screening tool to identify poorly performing metal-on-metal bearing surfaces. Bone Joint Res. 2:84–95. 10.1302/2046-3758.25.2000148 23836464
Sighinolfi GL, Artoni E, Gatti AM, Corsi L. 2014. Carcinogenic potential of metal nanoparticles in BALB/3T3 cell transformation assay. Environ Toxicol. 10.1002/tox.22063 25358123
Simcox NJ, Stebbins A, Guffey S, Atallah R, Hibbard R, Camp J. 2000. Hard metal exposures. Part 2: Prospective exposure assessment. Appl Occup Environ Hyg. 15(4):342–353. 10.1080/104732200301467 10750278
Simonsen LO, Brown AM, Harbak H, Kristensen BI, Bennekou P. 2011. Cobalt uptake and binding in human red blood cells. Blood Cells Mol Dis. 46(4):266–276. 10.1016/j.bcmd.2011.02.009 21420882
Simonsen LO, Harbak H, Bennekou P. 2012. Cobalt metabolism and toxicology—a brief update. Sci Total Environ. 432:210–215. 10.1016/j.scitotenv.2012.06.009 22732165
Singh I. 1983. Induction of reverse mutation and mitotic gene conversion by some metal compounds in Saccharomyces cerevisiae. Mutat Res. 117(1-2):149–152. 10.1016/0165-1218(83)90162-3 6339905
Slotnick MJ, Nriagu JO. 2006. Validity of human nails as a biomarker of arsenic and selenium exposure: A review. Environ Res. 102(1):125–139. 10.1016/j.envres.2005.12.001 16442520
Smith IC, Carson BL. 1981. Section C. Geochemistry and occurence. Section D. Environmental transport. In: Smith IC, Carson BL, editors. Trace Metals in the Environment. Ann Arbor, MI: Ann Arbor Science Publishers. p. 359-367.
Smith LJ, Holmes AL, Kandpal SK, Mason MD, Zheng T, Wise JP Sr. 2014. The cytotoxicity and genotoxicity of soluble and particulate cobalt in human lung fibroblast cells. Toxicol Appl Pharmacol. 278(3):259–265. 10.1016/j.taap.2014.05.002 24823294
Smith ML, Seo YR. 2002. p53 regulation of DNA excision repair pathways. Mutagenesis. 17(2):149–156. 10.1093/mutage/17.2.149 11880544
Smith T, Edmonds CJ, Barnaby CF. 1972. Absorption and retention of cobalt in man by whole-body counting. Health Phys. 22(4):359–367. 10.1097/00004032-197204000-00007 4625611
Snyder RD, Davis GF, Lachmann PJ. 1989. Inhibition by metals of X-ray and ultraviolet-induced DNA repair in human cells. Biol Trace Elem Res. 21:389–398. 10.1007/BF02917280 2484618
Sorbie J, Olatunbosun D, Corbett WE, Valberg LS. 1971. Cobalt excretion test for the assessment of body iron stores. Can Med Assoc J. 104(9):777–782. 5578125
Sprince NL, Chamberlin RI, Hales CA, Weber AL, Kazemi H. 1984. Respiratory disease in tungsten carbide production workers. Chest. 86(4):549–557. 10.1378/chest.86.4.549 6434250
Steinhoff D, Mohr U. 1991. On the question of a carcinogenic action of cobalt-containing compounds. Exp Pathol. 41(4):169–174. 10.1016/S0232-1513(11)80084-8 2070839
Stopford W, Turner J, Cappellini D, Brock T. 2003. Bioaccessibility testing of cobalt compounds. J Environ Monit. 5(4):675–680. 10.1039/b302257a 12948248
Suardi R, Belotti L, Ferrari MT, Leghissa P, Caironi M, Maggi L, Alborghetti F, Storto T, Silva T, Piazzolla S. 1994. Health survey of workers occupationally exposed to cobalt. Sci Total Environ. 150(1-3):197–200. 10.1016/0048-9697(94)90150-3 7939596
Sunderman FW Jr, Hopfer SM, Swift T, Rezuke WN, Ziebka L, Highman P, Edwards B, Folcik M, Gossling HR. 1989. Cobalt, chromium, and nickel concentrations in body fluids of patients with porous-coated knee or hip prostheses. J Orthop Res. 7(3):307–315. 10.1002/jor.1100070302 2649648
Suzuki T, Yamamoto R. 1982. Organic mercury levels in human hair with and without storage for eleven years. Bull Environ Contam Toxicol. 28(2):186–188. 10.1007/BF01608573 7066559
Suzuki Y, Shimizu H, Nagae Y, Fukumoto M, Okonogi H, Kadokura M. 1993. Micronucleus test and erythropoiesis: Effect of cobalt on the induction of micronuclei by mutagens. Environ Mol Mutagen. 22(2):101–106. 10.1002/em.2850220208 8359151
Swennen B, Buchet JP, Stánescu D, Lison D, Lauwerys R. 1993. Epidemiological survey of workers exposed to cobalt oxides, cobalt salts, and cobalt metal. Br J Ind Med. 50(9):835–842. 10.1136/oem.50.9.835 8398878
Talakin YN, Ivanova LA, Kostetskaya NI, Komissarov VN, Belyaeva IV. 1991. [Hygienic characteristics of working conditions and health state of workers engaged in the production of cobalt salts]. Gig Tr Prof Zbl. 1(10-11).
Tanaka T, Wiesener M, Bernhardt W, Eckardt KU, Warnecke C. 2009. The human HIF (hypoxia-inducible factor)-3alpha gene is a HIF-1 target gene and may modulate hypoxic gene induction. Biochem J. 424(1):143–151. 10.1042/BJ20090120 19694616
Tayton KJ. 1980. Ewing’s sarcoma at the site of a metal plate. Cancer. 45(2):413–415. 10.1002/1097-0142(19800115)45:2<413::AID-CNCR2820450238>3.0.CO;2-# 6985837
Tharr D, Singal M. 1987. Health hazard evaluation report: Eccles Saw and Tool Company, Cincinnati, Ohio. Cincinnati, OH: National Institute for Occupational Health and Safety. HETA 85-415-1806.
Thoburn T, Larsen LB. 1976. Health hazard evaluation determination: Marathon Battery Company, Waco, Texas. Cincinnati, OH: National Institute for Occupational Health and Safety. HETA 74-16-272.
Thomas RG, Furchner JE, London JE, Drake GA, Wilson JS, Richmond CR. 1976. Comparative metabolism of radionuclides in mammals—X. Retention of tracer-level cobalt in the mouse, rat, monkey and dog. Health Phys. 31(4):323–333. 10.1097/00004032-197610000-00003 825483
Thomassen Y, Nieboer E, Ellingsen D, Hetland S, Norseth T, Odland JØ, Romanova N, Chernova S, Tchachtchine VP. 1999. Characterisation of workers’ exposure in a Russian nickel refinery. J Environ Monit. 1(1):15–22. 10.1039/a807771a 11529072
Thompson RS, Gautieri RF, Mann DE Jr. 1965. Effect of chronic oral administration of sodium cobaltinitrite and sodium nitrite on the minimal carcinogenic dose50 of methylcholanthrene in albino mice. J Pharm Sci. 54(4):595–598. 10.1002/jps.2600540423 5842348
Thomson AB, Valberg LS, Sinclair DG. 1971. Competitive nature of the intestinal transport mechanism for cobalt and iron in the rat. J Clin Invest. 50(11):2384–2394. 10.1172/JCI106737 5096521
Thorn R, Wrey S.inventors. 1958. Reducing the tendency of beer towards gushing and increasing its foam stability. United States patent no. 2865755.
Tso WW, Fung WP. 1981. Mutagenicity of metallic cations. Toxicol Lett. 8(4-5):195–200. 10.1016/0378-4274(81)90100-4 7022752
Tüchsen F, Jensen MV, Villadsen E, Lynge E. 1996. Incidence of lung cancer among cobalt-exposed women. Scand J Work Environ Health. 22(6):444–450. 10.5271/sjweh.166 9000312
Tvermoes BE, Finley BL, Unice KM, Otani JM, Paustenbach DJ, Galbraith DA. 2013. Cobalt whole blood concentrations in healthy adult male volunteers following two-weeks of ingesting a cobalt supplement. Food Chem Toxicol. 53:432–439. 10.1016/j.fct.2012.11.033 23207477
Tvermoes BE, Unice KM, Paustenbach DJ, Finley BL, Otani JM, Galbraith DA. 2014. Effects and blood concentrations of cobalt after ingestion of 1 mg/d by human volunteers for 90 d. Am J Clin Nutr. 99(3):632–646. 10.3945/ajcn.113.071449 24500148
Underwood EJ. 1977. Trace Elements in Human and Animal Nutrition. 4th ed. New York: Academic Press; Cobalt; p. 132–158. 10.1016/B978-0-12-709065-8.50009-2
Unice KM, Kerger BD, Paustenbach DJ, Finley BL, Tvermoes BE. 2014. Refined biokinetic model for humans exposed to cobalt dietary supplements and other sources of systemic cobalt exposure. Chem Biol Interact. 216:53–74. 10.1016/j.cbi.2014.04.001 24726710
Unice KM, Monnot AD, Gaffney SH, Tvermoes BE, Thuett KA, Paustenbach DJ, Finley BL. 2012. Inorganic cobalt supplementation: Prediction of cobalt levels in whole blood and urine using a biokinetic model. Food Chem Toxicol. 50(7):2456–2461. 10.1016/j.fct.2012.04.009 22538081
United States International Trade Commission (USITC). 2014. USITC interactive tariff and trade dataweb. United States International Trade Commission. https://dataweb.usitc.gov/scripts/user_set.asp and search on HTS no. 2836999050, 2836991000, 2833291000, 2833299100, 8105200000, 8105209000, 8105203000, 8105206000, 2836991000, 2833291000, 8105209000, 8105203000, 8105900000, 2915293000, 2827396000, 2605000000, 2822000000, 8105300000. [October, 2014]
U.S. Environmental Protection Agency (USEPA). 2012. EPA chemical data reporting. U.S. Environmental Protection Agency. https://java.epa.gov/oppt_chemical_search/ and search by CAS number. [Accessed: March 24, 2015]
U.S. Environmental Protection Agency (USEPA). 2014a. TRI explorer chemical report. On-site disposal to class I underground injection wells, RCRA subtitle C landfills, and other landfills. U.S. Environmental Protection Agency. https://www.epa.gov/triexplorer. [Accessed: October 13, 2014]
U.S. Environmental Protection Agency (USEPA). 2014b. TRI explorer chemical report. TRI on-site and off-site reported disposed of or otherwise released (in pounds), trend report for facilities in all industries, for cobalt chemical, U.S. U.S. Environmental Protection Agency. https://www.epa.gov/triexplorer. [Accessed: October 14, 2014]
U.S. Environmental Protection Agency (USEPA). 2014c. TRI explorer chemical report. TRI on-site and off-site reported disposed of or otherwise released (in pounds), trend report for facilities in all industries, for cobalt compounds Chemical, U.S. U.S. Environmental Protection Agency. https://www.epa.gov/triexplorer. [Accessed: October 13, 2014]
U.S. Environmental Protection Agency (USEPA). 2014d. TRI EZ search in envirofacts. Toxic chemical releases to the environment (in pounds), for cobalt and cobalt compounds, U.S. U.S. Environmental Protection Agency. https://www.epa.gov/enviro/facts/tri/ez.html. [Accessed: October 29, 2014]
Vaca CE, Wilhelm J, Harms-Ringdahl M. 1988. Interaction of lipid peroxidation products with DNA. A review. Mutat Res. 195(2):137–149. 10.1016/0165-1110(88)90022-X 3277035
Valberg LS, Ludwig J, Olatunbosun D. 1969. Alteration in cobalt absorption in patients with disorders of iron metabolism. Gastroenterology. 56(2):241–251. 10.1016/S0016-5085(69)80123-X 5764593
Vales G, Demir E, Kaya B, Creus A, Marcos R. 2013. Genotoxicity of cobalt nanoparticles and ions in Drosophila. Nanotoxicology. 7(4):462–468. 10.3109/17435390.2012.689882 22548285
Valko M, Morris H, Cronin MT. 2005. Metals, toxicity and oxidative stress. Curr Med Chem. 12(10):1161–1208. 10.2174/0929867053764635 15892631
Valko M, Rhodes CJ, Moncol J, Izakovic M, Mazur M. 2006. Free radicals, metals and antioxidants in oxidative stress-induced cancer. Chem Biol Interact. 160(1):1–40. 10.1016/j.cbi.2005.12.009 16430879
van den Oever R, Roosels D, Douwen M, Vanderkeel J, Lahaye D. 1990. Exposure of diamond polishers to cobalt. Ann Occup Hyg. 34(6):609–614. 2291584
van der List JJ, van Horn JR, Slooff TJ, ten Cate LN. 1988. Malignant epithelioid hemangioendothelioma at the site of a hip prosthesis. Acta Orthop Scand. 59(3):328–330. 10.3109/17453678809149376 3381668
Van Goethem F, Lison D, Kirsch-Volders M. 1997. Comparative evaluation of the in vitro micronucleus test and the alkaline single cell gel electrophoresis assay for the detection of DNA damaging agents: Genotoxic effects of cobalt powder, tungsten carbide and cobalt-tungsten carbide. Mutat Res. 392(1-2):31–43. 10.1016/S0165-1218(97)00043-8 9269329
Vengellur A, Phillips JM, Hogenesch JB, LaPres JJ. 2005. Gene expression profiling of hypoxia signaling in human hepatocellular carcinoma cells. Physiol Genomics. 22(3):308–318. 10.1152/physiolgenomics.00045.2004 15942021
Versieck J, Hoste J, Barbier F, Steyaert H, De Rudder J, Michels H. 1978. Determination of chromium and cobalt in human serum by neutron activation analysis. Clin Chem. 24(2):303–308. 10.1093/clinchem/24.2.303 627061
Visuri T, Borg H, Pulkkinen P, Paavolainen P, Pukkala E. 2010. A retrospective comparative study of mortality and causes of death among patients with metal-on-metal and metal-on-polyethylene total hip prostheses in primary osteoarthritis after a long-term follow-up. BMC Musculoskelet Disord. 11:78. 10.1186/1471-2474-11-78 20416065
Visuri T, Pukkala E, Paavolainen P, Pulkkinen P, Riska EB. 1996. Cancer risk after metal on metal and polyethylene on metal total hip arthroplasty. Clin Orthop Relat Res. 329(Suppl):S280–S289. 10.1097/00003086-199608001-00025 8769342
Visuri T, Pulkkinen P, Paavolainen P. 2006. Malignant tumors at the site of total hip prosthesis. Analytic review of 46 cases. J Arthroplasty. 21(3):311–323. 10.1016/j.arth.2005.03.046 16627137
Voroshilin SI, Plotko EG, Fink TV, Nikiforova V. 1978. [Cytogenetic effect of inorganic wolfram, zinc, cadmium and cobalt compounds on human and animal somatic cells]. Tsitol Genet. 12(3):241–243. 684833
Wan R, Mo Y, Feng L, Chien S, Tollerud DJ, Zhang Q. 2012. DNA damage caused by metal nanoparticles: Involvement of oxidative stress and activation of ATM. Chem Res Toxicol. 25(7):1402–1411. 10.1021/tx200513t 22559321
Wang D, Tian X, Jiang Y. 2012. NDRG1/Cap43 overexpression in tumor tissues and serum from lung cancer patients. J Cancer Res Clin Oncol. 138:1813–1820. 10.1007/s00432-012-1236-9 22722710
Wang G, Hazra TK, Mitra S, Lee HM, Englander EW. 2000. Mitochondrial DNA damage and a hypoxic response are induced by CoCl(2) in rat neuronal PC12 cells. Nucleic Acids Res. 28(10):2135–2140. 10.1093/nar/28.10.2135 10773083
Wang GL, Semenza GL. 1995. Purification and characterization of hypoxia-inducible factor 1. J Biol Chem. 270(3):1230–1237. 10.1074/jbc.270.3.1230 7836384
Wang T, Fu J, Wang Y, Liao C, Tao Y, Jiang G. 2009. Use of scalp hair as indicator of human exposure to heavy metals in an electronic waste recycling area. Environ Pollut. 157(8-9):2445–2451. 10.1016/j.envpol.2009.03.010 19346038
Wappelhorst O, Kuhn I, Heidenreich H, Markert B. 2002. Transfer of selected elements from food into human milk. Nutrition. 18(4):316–322. 10.1016/S0899-9007(01)00798-5 11934544
Webb M, Heath JC, Hopkins T. 1972. Intranuclear distribution of the inducing metal in primary rhabdomyosarcomata induced in the rat by nickel, cobalt and cadmium. Br J Cancer. 26(4):274–278. 10.1038/bjc.1972.37 5071189
Wedrychowski A, Schmidt WN, Hnilica LS. 1986. DNA-protein crosslinking by heavy metals in Novikoff hepatoma. Arch Biochem Biophys. 251(2):397–402. 10.1016/0003-9861(86)90345-0 3800374
Wehner AP, Busch RH, Olson RJ, Craig DK. 1977. Chronic inhalation of cobalt oxide and cigarette smoke by hamsters. Am Ind Hyg Assoc J. 38(7):338–346. 10.1080/0002889778507627 900017
Wehner AP, Craig DK. 1972. Toxicology of inhaled NiO and CoO in Syrian golden hamsters. Am Ind Hyg Assoc J. 33(3):146–155. 10.1080/0002889728506624 5074671
Wild P, Perdrix A, Romazini S, Moulin JJ, Pellet F. 2000. Lung cancer mortality in a site producing hard metals. Occup Environ Med. 57(8):568–573. 10.1136/oem.57.8.568 10896965
Witkiewicz-Kucharczyk A, Bal W. 2006. Damage of zinc fingers in DNA repair proteins, a novel molecular mechanism in carcinogenesis. Toxicol Lett. 162(1):29–42. 10.1016/j.toxlet.2005.10.018 16310985
Witzleb WC, Ziegler J, Krummenauer F, Neumeister V, Guenther KP. 2006. Exposure to chromium, cobalt and molybdenum from metal-on-metal total hip replacement and hip resurfacing arthroplasty. Acta Orthop. 77(5):697–705. 10.1080/17453670610012863 17068698
Wolff M, Jelkmann W, Dunst J, Depping R. 2013. The aryl hydrocarbon receptor nuclear translocator (ARNT/HIF-1β) is influenced by hypoxia and hypoxia-mimetics. Cell Physiol Biochem. 32(4):849–858. 10.1159/000354487 24081025
Wong PK. 1988. Mutagenicity of heavy metals. Bull Environ Contam Toxicol. 40(4):597–603. 10.1007/BF01688386 3285919
World Health Organization (WHO). 2006. Cobalt and inorganic cobalt compounds. Geneva, Switzerland: World Health Organization. Concise Int Chem Assess Doc. 69.
Wragg J, Cave M, Basta N, Brandon E, Casteel S, Denys S, Gron C, Oomen A, Reimer K, Tack K, et al. 2011. An inter-laboratory trial of the unified BARGE bioaccessibility method for arsenic, cadmium and lead in soil. Sci Total Environ. 409(19):4016–4030. 10.1016/j.scitotenv.2011.05.019 21703664
Xia M, Huang R, Sun Y, Semenza GL, Aldred SF, Witt KL, Inglese J, Tice RR, Austin CP. 2009. Identification of chemical compounds that induce HIF-1alpha activity. Toxicol Sci. 112(1):153–163. 10.1093/toxsci/kfp123 19502547
Yamada K. 2013. Cobalt: Its role in health and disease. Met Ions Life Sci. 13:295–320. 10.1007/978-94-007-7500-8_9 24470095
Yeşilada E. 2001. Genotoxicity testing of some metals in the Drosophila wing somatic mutation and recombination test. Bull Environ Contam Toxicol. 66(4):464–469. 10.1007/s001280029 11443308
Yıldız M, Cigerci IH, Konuk M, Fidan AF, Terzi H. 2009. Determination of genotoxic effects of copper sulphate and cobalt chloride in Allium cepa root cells by chromosome aberration and comet assays. Chemosphere. 75(7):934–938. 10.1016/j.chemosphere.2009.01.023 19201446
Yin DZ. 1990. [Comparison of serum trace element spectrum of liver cancer patients and healthy adults]. Zhonghua Zhong Liu Za Zhi. 12(3):200–202. 2249593
Yokoiyama A, Kada T, Kuroda Y. 1990. Antimutagenic action of cobaltous chloride on radiation-induced mutations in cultured Chinese hamster cells. Mutat Res. 245(2):99–105. 10.1016/0165-7992(90)90007-7 2215557
Zeh A, Becker C, Planert M, Lattke P, Wohlrab D. 2009. Time-dependent release of cobalt and chromium ions into the serum following implantation of the metal-on-metal Maverick type artificial lumbar disc (Medtronic Sofamor Danek). Arch Orthop Trauma Surg. 129(6):741–746. 10.1007/s00402-008-0677-8 18592257
Zeh A, Planert M, Siegert G, Lattke P, Held P, Hein W. 2007. Release of cobalt and chromium ions into the serum following implantation of the metal-on-metal maverick-type artificial lumbar disc (Medtronic Sofamor Danek). Spine. 32(3):348–352. 10.1097/01.brs.0000253599.89694.c0 17268267
Zeiger E, Anderson B, Haworth S, Lawlor T, Mortelmans K. 1992. Salmonella mutagenicity tests: V. Results from the testing of 311 chemicals. Environ Mol Mutagen. 19 Suppl 21:2–141. 10.1002/em.2850190603 1541260
Zeller WJ. 1975. [Investigation of the influence of copper and cobalt ions on the carcinogenesis by diethyl-nitrosamine (DENA) in Wistar rats (author's transl)]. Arch Geschwulstforsch. 45(7):634–636. 818977
Zey JN. 1985. Health hazard evaluation report: Wyoming High School, Wyoming, Ohio. Cincinnati, OH: National Institute for Occupational Health and Safety. HETA 85-085-1615.
Zhang H, Ji Z, Xia T, Meng H, Low-Kam C, Liu R, Pokhrel S, Lin S, Wang X, Liao YP, et al. 2012 a. Use of metal oxide nanoparticle band gap to develop a predictive paradigm for oxidative stress and acute pulmonary inflammation. ACS Nano. 6(5):4349–4368. 10.1021/nn3010087 22502734
Zhang L, Lv J, Sun S. 2012 b. Elements in lung tissues of patients from a high lung cancer incidence area of China. Biol Trace Elem Res. 148(1):7–10. 10.1007/s12011-012-9336-6 22274755
Zhang P, Yao Q, Lu L, Li Y, Chen PJ, Duan C. 2014. Hypoxia-inducible factor 3 is an oxygen-dependent transcription activator and regulates a distinct transcriptional response to hypoxia. Cell Rep. 6(6):1110–1121. 10.1016/j.celrep.2014.02.011 24613356
Zhang Q, Kusaka Y, Donaldson K. 2000. Comparative pulmonary responses caused by exposure to standard cobalt and ultrafine cobalt. J Occup Health. 42:179–184. 10.1539/joh.42.179
Zhu S, Zhang Y, Gao Y, Wang XJ, Chen T, Yang Y, Shi R, Jin P, Tian Y, Shen XM. 2011. [Correlation between level of metallic elements in urine and childhood acute leukemia]. Zhonghua Yu Fang Yi Xue Za Zhi. 45(2):146–149. 21426795
Zou W, Yan M, Xu W, Huo H, Sun L, Zheng Z, Liu X. 2001. Cobalt chloride induces PC12 cells apoptosis through reactive oxygen species and accompanied by AP-1 activation. J Neurosci Res. 64(6):646–653. 10.1002/jnr.1118 11398189