# Glossary

Ames assay: The Ames Salmonella/microsome mutagenicity assay is a short-term bacterial reverse mutation assay specifically designed to detect a wide range of chemical substances that can produce genetic damage that leads to gene mutations.
Analysis bias: A bias arising from inappropriate data assumptions, models, or statistical methods used to evaluate findings, exposure-response relationships, latency, or confounding.
Aneuploidy: An abnormality involving a chromosome number that is not an exact multiple of the haploid number (one chromosome set is incomplete).
Apoptosis: Cell deletion by fragmentation into membrane-bound particles, which are phagocytosed by other cells.
Arabinose resistance: The L-arabinose resistance test with Salmonella typhimurium (Ara test) is a forward mutation assay that selects a single phenotypic change (from L-arabinose sensitivity to L-arabinose resistance) in a unique tester strain (an araD mutant).
Aroclor 1254-induced liver: Liver tissue treated with the polychlorinated biphenyl mixture Aroclor 1254 used as a source of S9 fraction for mutagenic and genotoxic effects testing.
Ascertainment bias: Systematic failure to represent equally all classes of cases or persons supposed to be represented in a sample.
Attrition bias: Systematic differences between comparison groups in withdrawals or exclusions of participants from the results of a study.
Biexponential process: A process of drug (or xenobiotic) clearance with two phases with different rates. The first phase often involves rapid distribution of a drug to peripheral tissues, while the second phase represents clearance mechanisms that eliminate the drug from the body. (See “Two-compartment pharmacokinetic model.”)
Boiling point: The boiling point of the anhydrous substance at atmospheric pressure (101.3 kPa) unless a different pressure is stated. If the substance decomposes below or at the boiling point, this is noted (dec). The temperature is rounded off to the nearest °C.
Chemical Data Reporting Rule: Chemical Data Reporting (CDR) is the new name for Inventory Update Reporting (IUR). The purpose of Chemical Data Reporting is to collect quality screening-level, exposure-related information on chemical substances and to make that information available for use by the U.S. Environmental Protection Agency (EPA) and, to the extent possible, to the public. The IUR/CDR data are used to support risk screening, assessment, priority setting and management activities and constitute the most comprehensive source of basic screening-level, exposure-related information on chemicals available to EPA. The required frequency of reporting currently is once every four years.
Co-exposures: substances to which study participants are exposed that can potentially confound the relationship between the exposure and disease.
Cochran-Armitage trend test: A statistical test used in categorical data analysis when the aim is to assess for the presence of an association between a variable with two categories and a variable with k categories. It modifies the chi-square test to incorporate a suspected ordering in the effects of the k categories of the second variable.
Comet assay: The comet assay evaluates DNA damage by measuring DNA migration in single cells using gel electrophoresis. Migration of DNA is directly related to DNA strand length: the smaller the strands (produced by breaks in the DNA, i.e., damage), the further the DNA will migrate from the nucleus in an electric field.
Confounding bias and potential confounders: A bias arising when the comparison groups under study (e.g., exposed versus unexposed, or the cases versus controls) have different background risks of disease (Pearce et al. 2007), in effect mixing the association of interest with the effects of other factors. Potential confounders can include any co-exposures or risk factors associated with both the exposure and the disease, and that are not part of the disease pathway.
Conversion factor: A numerical factor used to multiply or divide a quantity when converting from one system of units to another.
Critical temperature: The temperature at and above which a gas cannot be liquefied, no matter how much pressure is applied.
Differential misclassification bias: A bias that arises when the probability of being misclassified differs across groups of study subjects. The effect(s) of such misclassification can vary from an overestimation to an underestimation of the true value.
Differential selection: Selective pressure for self-renewal. Gene mutations that confer a growth or survival advantage on the cells that express them will be selectively enriched in the genome of tumors.
Disposition: The description of absorption, distribution, metabolism, and excretion of a chemical in the body.
Dominant lethal mutation assay: The dominant lethal assay identifies germ cell mutagens by measuring the ability of a chemical to penetrate gonadal tissue and produce embryonic death due to chromosomal breakage in parent germ cells.
Ecological study: A study in which the units of analysis are populations or groups of people rather than individuals.
ELISA assay: Enzyme-linked immunosorbent assay; a sensitive immunoassay that uses an enzyme linked to an antibody or antigen as a marker for the detection of a specific protein, especially an antigen or antibody.
Epigenetic mechanisms: Changes in gene function that do not involve a change in DNA sequence but are nevertheless mitotically and/or meiotically heritable. Examples include DNA methylation, alternative splicing of gene transcripts, and assembly of immunoglobulin genes in cells of the immune system.
Exposure-response gradient: Describes the change in effect caused by differing levels of exposure (or doses) to a chemical or substance.
FDA Good Laboratory Practice Regulations: A quality system codified by the U.S. Food and Drug Administration that prescribes operating procedures for conducting nonclinical laboratory studies that support or are intended to support applications for research or marketing permits for products regulated by the Food and Drug Administration.
Fisher’s exact test: The test for association in a two-by-two table that is based on the exact hypergeometric distribution of the frequencies within the table.
Follow-up: Observation over a period of time of a person, group, or initially defined population whose appropriate characteristics have been assessed to observe changes in health status or health-related variables.
Genomic instability: An increased propensity for genomic alterations that often occurs in cancer cells. During the process of cell division (mitosis) the inaccurate duplication of the genome in parent cells or the improper distribution of genomic material between daughter cells can result from genomic instability.
Genotoxic: The property of a chemical or agent that can cause DNA or chromosomal damage.
Healthy worker hire effect: Initial selection of healthy individuals at time of hire so that their disease risks differ from the disease risks in the source (general) population.
Healthy worker survival effect: A continuing selection process such that those who remain employed tend to be healthier than those who leave employment.
Henry’s Law constant: The ratio of the aqueous-phase concentration of a chemical to its equilibrium partial pressure in the gas phase. The larger the Henry’s law constant the less soluble it is (i.e., greater tendency for vapor phase). The relationship is defined for a constant temperature, e.g., 25°C.
Information bias: A bias arising from measurement error. Information bias is also referred to as observational bias and misclassification (see differential and non-differential misclassification bias). When any exposure, covariate (http://en.wikipedia.org/wiki/Covariate), or outcome variable is subject to measurement error, a different quality or accuracy of information between comparison groups can occur.
Integration of scientific evidence across studies: The final step in the cancer assessment that assigns greater weight to the most informative studies to reach a preliminary listing recommendation.
Job exposure matrix (JEM): A tool used to assess exposure to potential health hazards in occupational epidemiologic studies by converting coded occupational data (usually job titles) into a matrix of possible levels of exposures to potentially harmful agents, reducing the need to assess each individual's exposure in detail.
Lagging: Statistical methods that weight exposure times in order to account for prolonged induction and latency periods, particularly in occupational epidemiology studies.
Latency and prolonged induction: The induction period is the time required for a cause to lead to the disease process (regardless of symptoms); the latent period is the time between the exposure and clinical manifestation of the disease. Especially important when considering cancer outcomes.
Left truncation: This bias can occur when workers hired before the start of the study, and thus exposed and at risk for disease, do not remain observable at the start of follow-up. The remaining prevalent workers may be healthier and not representative of all workers hired before the start of the study.
Melting point: The melting point of the substance at atmospheric pressure (101.3 kPa). When there is a significant difference between the melting point and the freezing point, a range is given. In case of hydrated substances (i.e., those with crystal water), the apparent melting point is given. If the substance decomposes at or below its melting point, this is noted (dec). The temperature is rounded off to the nearest °C.
Metaplasia: A change of cells to a form that does not normally occur in the tissue in which it is found.
Methemoglobin: A form of hemoglobin found in the blood in small amounts. Unlike normal hemoglobin, methemoglobin cannot carry oxygen. Injury or certain drugs, chemicals, or foods may cause a higher-than-normal amount of methemoglobin to be made. This causes a condition called methemoglobinemia.
Micronuclei: Small nuclear-like bodies separate from, and additional to, the main nucleus of a cell, produced during the telophase of mitosis or meiosis by lagging chromosomes or chromosome fragments derived from spontaneous or experimentally induced chromosomal structural changes.
Miscible: A physical characteristic of a liquid that forms one liquid phase with another liquid (e.g., water) when they are mixed in any proportion.
Molecular weight: The molecular weight of a substance is the weight in atomic mass units of all the atoms in a given formula. The value is rounded to the nearest tenth.
Mutagenic: Capable of inducing genetic mutation, e.g., a genotoxic substance or agent that can induce or increase the frequency of mutation in the DNA of an organism.
Mutations: A change in the structure of a gene, resulting from the alteration of single base units in DNA, or the deletion, insertion, or rearrangement of larger sections of genes or chromosomes. The genetic variant can be transmitted to subsequent generations.
National Health and Nutrition Examination Survey: A program of studies designed to assess the health and nutritional status of adults and children in the United States. The survey is unique in that it combines interviews and physical examinations.
Nondifferential misclassification bias: Arises when all classes, groups, or categories of a variable (whether exposure, outcome, or covariate) have the same error rate or probability of being misclassified for all study subjects. In the case of binary or dichotomous variables nondifferential misclassification would usually result in an ‘underestimation’ of the hypothesized relationship between exposure and outcome.
Normochromatic erythrocyte: A mature erythrocyte that lacks ribosomes and can be distinguished from immature, polychromatic erythrocytes by stains selective for RNA.
Octanol/water partition coefficient (log K_ow_): A measure of the equilibrium concentration of a compound between octanol and water.
One-compartment model: A pharmacokinetic modeling approach that models the entire body as a single compartment into which a drug is added by a rapid single dose, or bolus. It is assumed that the drug concentration is uniform in the body compartment at all times and is eliminated by a first order process that is described by a first order rate constant.
Personal breathing zone: A sampling area as close as practical to an employee’s nose and mouth, (i.e., in a hemisphere forward of the shoulders within a radius of approximately nine inches) so that it does not interfere with work performance or safety of the employee.
Personal protective equipment: Specialized clothing or equipment, worn by an employee to minimize exposure to a variety of hazards. Examples of PPE include such items as gloves, foot and eye protection, protective hearing devices (earplugs, muffs) hard hats, respirators, and full body suits.
Plate incorporation: A commonly used procedure for performing a bacterial reverse mutation test. Suspensions of bacterial cells are exposed to the test substance in the presence and in the absence of an exogenous metabolic activation system. In the plate-incorporation method, these suspensions are mixed with an overlay agar and plated immediately onto minimal medium. After two or three days of incubation, revertant colonies are counted and compared with the number of spontaneous revertant colonies on solvent control plates.
Point emission: A release that can be identified with a single discharge source or attributed to a specific physical location.
Poly-3 trend test: A survival-adjusted statistical test that takes survival differences into account by modifying the denominator in the numerical (quantal) estimate of lesion incidence to reflect more closely the total number of animal years at risk.
Proto-oncogene: A gene involved in normal cell growth. Mutations (changes) in a proto-oncogene may cause it to become an oncogene, which can cause the growth of cancer cells.
Proxy: A substitute authorized to act for the study participant. Often this is a spouse or other family member who may consent to be interviewed, offering information about the participant.
P_trend_: Level of statistical significance of a change over time in a group selected to represent a larger population.
QUOSA: A collection of scientific literature management software and services for researchers and information professionals in the life sciences and related scientific and medical areas designed to retrieve, organize, and analyze full-text articles and documents.
Recall bias: A bias arising from systematic error in the accuracy or completeness of “recalled” by study participants regarding past events, and usually arises in the context of retrospective case-control interviews or questionnaires. The concern is that those with the disease may search their memories more thoroughly than unaffected controls to try to recall exposure to various causal factors. This bias is often differential and biases towards an overestimate of effect.
Reverse causality: May arise in case-control studies when exposure is measured after disease diagnosis, as the concern is that symptoms or early manifestations of the disease may affect the measured exposure; this is particularly of concern in studies using biomarkers of effect.
Right truncation: For right truncated data, only participants or person-time under observation up to a given date are included. Right truncation results in limiting person-time to values that are limited below the given date. Truncation is similar to but distinct from the concept statistical censoring. A truncated sample is similar to an underlying sample with all values outside the bounds entirely omitted, with no count of participants or person-time omitted kept. Alternatively, with statistical censoring, the value of the bound exceeded is known and documented.
Selection bias: An error in choosing the individuals or groups to take part in a study. Ideally, the subjects in a study should be very similar to one another and to the larger population from which they are drawn (for example, all individuals with the same disease or condition). If there are important differences, the results of the study may not be valid, and bias can be introduced in either direction.
Selective reporting: Selective reporting occurs when the effect estimate for a measurement (of exposure or disease) was selected from among analyses using several measurement instruments, reflecting the most favorable result or subcategories.
Sensitivity: The proportion of truly diseased persons in the screened population who are identified as diseased by the screening test; or the probability of correctly diagnosing a true case with the test.
Sister-chromatid exchange: The exchange during mitosis of homologous genetic material between sister chromatids; increased as a result of inordinate chromosomal fragility due to genetic or environmental factors.
Solubility: The ability of a substance to dissolve in another substance and form a solution. The Report on Carcinogens uses the following definitions (and concentration ranges) for degrees of solubility: (1) miscible (see definition), (2) freely soluble- capable of being dissolved in a specified solvent to a high degree (>1,000 g/L), (3) soluble- capable of being dissolved in a specified solvent (10–1,000 g/L), (4) slightly soluble- capable of being dissolved in a specified solvent to a limited degree (1–10 g/L), and (5) practically insoluble- incapable of dissolving to any significant extent in a specified solvent (<1 g/L).
Specific gravity: The ratio of the density of a material to the density of a standard material, such as water at a specific temperature; when two temperatures are specified, the first is the temperature of the material and the second is the temperature of water.
Specificity: The proportion of truly nondiseased persons who are so identified by the screening test; or the probability of correctly identifying a non-diseased person with the test.
Spot test: Qualitative assay in which a small amount of test chemical is added directly to a selective agar medium plate seeded with the test organism, e.g., Salmonella. As the chemical diffuses into the agar, a concentration gradient is formed. A mutagenic chemical will give rise to a ring of revertant colonies surrounding the area where the chemical was applied; if the chemical is toxic, a zone of growth inhibition will also be observed.
Study sensitivity: The ability of a study to detect an effect (if it exists) which would include a large number of exposed cases; evidence of substantial exposure (e.g., level, duration, frequency, or probability) during an appropriate window; an adequate range in exposure levels or duration allowing for evaluation of exposure-response relationships; and an adequate length of follow-up.
Study utility: The overall utility of a study is based on consideration of the potential for bias (i.e., study quality) and study sensitivity. Serious concerns about study quality will result in lower utility of the study; a high-quality study with low sensitivity could also have low utility.
Surrogate exposure data: Ideally, a study would provide multiple quantitative metrics of each individual’s exposure to the substance of interest. However, a surrogate metric correlated with exposure may be used instead of, or in addition to exposure data.
Time-weighted average: The average exposure concentration of a chemical measured over a period of time (not an instantaneous concentration).
Toxicokinetics: The mathematical description (toxicokinetic models) of the time course of disposition of a chemical in the body.
Transitions: DNA nucleotide substitution mutation in which a purine base is substituted for another purine base (adenine → guanine or guanine → adenine) or a pyrimidine base for another pyrimidine base (cytosine → thymine or thymine → cytosine).
Transversions: DNA nucleotide substitution mutation in which a purine base (adenine or guanine) is substituted for a pyrimidine base (cytosine or thymine) or vice versa.
Two-compartment pharmacokinetic model: A two-compartment pharmacokinetic model resolves the body into a central compartment and a peripheral compartment. The central compartment generally comprises tissues that are highly perfused such as heart, lungs, kidneys, liver, and brain. The peripheral compartment comprises less well-perfused tissues such as muscle, fat, and skin. A two-compartment model assumes that, following drug administration into the central compartment, the drug distributes between that compartment and the peripheral compartment. However, the drug does not achieve instantaneous distribution (i.e., equilibrium), between the two compartments. After a time interval (t), distribution equilibrium is achieved between the central and peripheral compartments, and elimination of the drug is assumed to occur from the central compartment.
Type-I error: The error of rejecting a true null hypothesis, i.e., declaring that a difference exists when it does not.
Type-II error: The error of failing to reject a false null hypothesis, i.e., declaring that a difference does not exist when in fact it does.
Vapor density, relative: A value that indicates how many times a gas (or vapor) is heavier than air at the same temperature. If the substance is a liquid or solid, the value applies only to the vapor formed from the boiling liquid.
Vapor pressure: The pressure of the vapor over a liquid (and some solids) at equilibrium, usually expressed as mm Hg at a specific temperature (°C).