# Abbreviations

  ACGIH: American Conference of Governmental Industrial Hygienists
  ADME: absorption, distribution, metabolism, and excretion
  ANOVA: analysis of variance
  atm: atmosphere
  ATSDR: Agency for Toxic Substances and Disease Registry
  bw: body weight
  BDL: below detection limit
  CA: chromosomal aberration
  CASRN: Chemical Abstracts Service registry number
  CDC: Centers for Disease Control and Prevention
  CDR: Chemical Data Reporting Rule
  CI: confidence interval
  CIN: chromosomal instability
  cm^2^: centimeters squared
  cm^3^: centimeters cubed (mL)
  DLMI: dominant lethal mutation index
  DLMR: dominant lethal mutation rate
  DNA: deoxyribonucleic acid
  dw: drinking water
  EPA: Environmental Protection Agency
  EQ: exposure quartiles model
  EUSES: European Union System for the Evaluation of Substances
  Exp.: exposed
  F: female
  FDA: Food and Drug Administration
  FR: Federal Register
  ft: feet
  FTE: full-time equivalent
  FU: follow-up
  g: gram
  G: guanine
  GC/MS: gas chromatography/mass spectroscopy
  GI: gastrointestinal
  GM: geometric mean
  Hb: hemoglobin
  HETA: Health Hazard Evaluation and Technical Assistance
  HHE: Health Hazard Evaluation
  HHS: Department of Health and Human Services
  HIC: highest ineffective concentration
  HID: highest ineffective dose
  HPLC: high-performance liquid chromatography
  hr: hour
  HWE: healthy worker effect
  HWSE: healthy worker survival effect
  I: inconclusive
  i.m.: intramuscular
  i.p.: intraperitoneal
  i.v.: intravenous
  IARC: International Agency for Research on Cancer
  ICD-7, -8, -9: International Classification of Diseases, Seventh, Eighth or Ninth Revision
  ICD-O: International Classification of Diseases for Oncology
  IDLH: immediately dangerous to life and health
  in: inch
  inj.: injection
  JEM: job-exposure matrix
  kg: kilogram
  L: liter
  LEC: lowest effective concentration
  LED: lowest effective dose
  LOD: limit of detection
  Log K_ow_: logarithm of octanol/water partition coefficient
  M: male
  m^3^: cubic meter
  MCL: maximum contaminant level
  mg: milligram
  mL: milliliter
  MN: micronuclei
  mol: mole
  MS: mass spectrometry
  N: number
  NA: not available; not applicable
  NCE: normochromatic erythrocyte
  NCI: National Cancer Institute
  NCTR: National Center for Toxicological Research
  ND: not detected; not determined; not done
  ng: nanogram
  NHANES: National Health and Nutrition Examination Survey
  NI: no information
  NIEHS: National Institute of Environmental Health Sciences
  NIH: National Institutes of Health
  NIOSH: National Institute for Occupational Safety and Health
  NLM: National Library of Medicine
  NOES: National Occupational Exposure Survey
  NOS: not otherwise specified
  NPL: National Priorities List
  NR: not reported; none reported
  ns: not specified
  NS: not significant
  NT: not tested
  NTP: National Toxicology Program
  OHAT: Office of Health Assessment and Translation
  OR: odds ratio
  OSHA: Occupational Safety and Health Administration
  P: probability
  p value: the statistical probability that a given finding would occur by chance compared with the known distribution of possible findings
  p.o.: per os (oral administration)
  PBZ: personal breathing zone
  PCE: polychromatic erythrocyte
  PEL: permissible exposure limit
  ppm: parts per million
  ppt: parts per trillion
  QSAR: quantitative structure-activity relationship
  R: estimated daily production of adducts
  r: correlation coefficient
  RAHC: Reasonably anticipated to be a human carcinogen
  RBC: red blood cell
  REL: recommended exposure limit
  RNS: reactive nitrogen species
  RoC: Report on Carcinogens
  ROS: reactive oxygen species
  RQ: reportable quantity
  RR: relative risk
  RTG: relative total growth
  s.c.: subcutaneous
  SAFE: significance analysis of function and expression
  SCE: sister-chromatid exchange
  SD: standard deviation
  SEER: Surveillance, Epidemiology, and End Results Program, NCI
  SIC: Standard Industrial Classification
  SIR: standardized incidence ratio
  SMR: standardized mortality ratio
  SOCMI: synthetic organic chemical manufacturing industry
  SRR: standardized rate ratio, standardized relative risk
  SSB: single-strand break
  STS: soft tissue sarcoma
  TDS: Total Diet Study
  TLV-TWA: threshold limit value time-weighted average
  t_max_: time to maximum concentration in plasma
  TMD: tail moment dispersion coefficient
  TRI: Toxics Release Inventory
  TSCA: Toxic Substances Control Act
  TSFE: time since first employment
  UDS: unscheduled DNA synthesis
  UK: United Kingdom
  US: United States
  VOC: volatile organic compound
  WBC: white blood cell
  WHO: World Health Organization
  wk: week
  wt%: weight percent
  yr: year or years
  μg: microgram