# Introduction and Methods

Cobalt is a naturally occurring element that is present in several different forms. Elemental cobalt is a hard, silvery grey metal that can combine with other elements, e.g., with oxygen (cobalt oxide), sulfur (cobalt sulfate) or arsenic (cobalt arsenide). The most common oxidation states of cobalt are +2 and +3; for most simple cobalt compounds, the valence is +2, designated as cobalt(II). Cobalt compounds can be organic or inorganic as well as water-soluble or -insoluble. Cobalt compounds are used in a variety of industrial applications and as a colorant for glass, ceramics, and paint, and as catalysts, as driers for inks and paints, and in feed supplements and batteries. Cobalt is used in alloys or composites, such as cobalt-tungsten carbide, and in cobalt-containing prosthetics. Cobalt nanoparticles are used in medical tests and treatments as well as in the textile and electronics industries.

Cobalt and cobalt compounds that release cobalt ions in vivo (collectively referred to as cobalt) was selected for review for possible listing in the Report on Carcinogens (RoC) based on evidence of widespread exposure and an adequate database of cancer studies to evaluate the potential carcinogenicity of cobalt. The listing does not include cobalt as part of the vitamin B_12_ molecule because of the stability of that molecule in biological fluids. Cancer and toxicological studies of forms of cobalt that have confounding exposures, such as cobalt alloys and radioactive forms of cobalt, were not included in the review of the cobalt compounds. Two cobalt-containing substances, ‘cobalt sulfate’ and ‘cobalt-tungsten carbide: powders and hard metals,’ are currently listed in the Report on Carcinogens (RoC) as reasonably anticipated to be human carcinogens (NTP 2014a; 2014c). Cobalt sulfate, which has been listed since 2004 based on sufficient evidence of carcinogenicity from studies in experimental animals (NTP 2002), is included in the current review of cobalt as a class. Cobalt-tungsten carbide: powders and hard metals, which was first listed in 2011 based on limited evidence of carcinogenicity from studies in humans and supporting evidence from studies on mechanisms of carcinogenesis (NTP 2009) falls outside the review.

## Monograph Contents

This RoC monograph on cobalt consists of the following components: (Part 1) the cancer evaluation component that reviews the relevant scientific information and assesses its quality, applies the RoC listing criteria to the scientific information, and recommends an RoC listing status for cobalt, and (Part 2), the draft substance or cancer hazard profile containing the NTP’s preliminary listing recommendation, a summary of the scientific evidence considered key to reaching that recommendation, and data on properties, use, production, exposure, and Federal regulations and guidelines to reduce exposure to cobalt and cobalt compounds and cobalt compounds that release cobalt ions in vivo.

The methods for preparing the RoC monograph on cobalt are described in the “Cobalt Protocol” (NTP 2014b). The cancer evaluation component for cobalt provides information on the following topics that are relevant to understanding the relationship between exposure to cobalt compounds and cancer: Introduction and properties (Section 1), human exposure (Section 2), disposition and toxicokinetics (Section 3), human cancer studies (Section 4), studies in experimental animals (Section 5), mechanisms and other relevant effects (Section 6), and an overall cancer evaluation that provides a synthesis of Sections 1 through 6 and rationale for listing cobalt and cobalt compounds and cobalt compounds that release cobalt ions in vivo as a class (Section 7). The information reviewed in Sections 3 through 7 (except for information on exposure and properties) must come from publicly available, peer-reviewed sources. The appendices in the RoC Monograph contain important supplementary information, including the literature search strategy, exposure-related information and regulations, clinical study description and/or quality tables for cancer studies in humans or experimental animals, and a discussion of the results from the genotoxicity studies.

## Process for Preparation of the Cancer Hazard Evaluation Component

The process for preparing the cancer evaluation component of the monograph included approaches for obtaining public and scientific input and using systematic methods (e.g., standardized methods for identifying the literature [see Appendix A], inclusion/exclusion criteria, extraction of data and evaluation of study quality using specific guidelines, and assessment of the level of evidence for carcinogenicity using established criteria). [Links are provided within the document to the appendices, and specific tables or sections can be selected from the table of contents.]

The Office of the Report on Carcinogens (ORoC) followed the approaches outlined in the concept document, which discusses the scientific issues and questions relevant to the evaluation of the carcinogenicity of cobalt compounds, the scope and focus of the monograph, and the approaches to obtain scientific and public input to address the key scientific questions and issues for preparing the cancer evaluation component of the monograph. The ORoC presented the concept document for cobalt to the NTP Board of Scientific Counselors (BSC) at the April 17, 2014 meeting, which provided opportunity for written and oral public comments, after which the concept was finalized and cobalt was approved by the NTP Director as a candidate substance for review. The concept document is available on the RoC website (https://ntp.niehs.nih.gov/go/730697).

### Key Scientific Questions and Issues Relevant for the Cancer Evaluation

The scientific issues in this review concern the evaluation of the topics mentioned earlier, including human exposure, disposition and toxicokinetics, cancer studies in humans and experimental animals, and mechanistic data. The key questions for each topic are as follows:

#### Questions Related to the Evaluation of Human Exposure Information

- How are people in the United States exposed to cobalt?
- How do we measure exposure?
- What are the non-occupational sources and levels of exposure?
- What are the occupational settings and levels of exposure?
- Has exposure changed over time?
- What federal regulations and guidelines limit exposure to cobalt?
- Are a significant number of people residing in the United States exposed to cobalt?

#### Questions Related to the Evaluation of Disposition and Toxicokinetics

- How is cobalt absorbed, distributed, metabolized, and excreted (ADME)?
- What, if any, are the qualitative and/or quantitative species or sex differences for ADME?
- What is known about the form of cobalt (particulate, ion) from ADME studies in exposed tissue, particularly in the lung?
- How can toxicokinetic models (if any) inform biological plausibility, interspecies extrapolation, or other mechanistic questions for cobalt?

#### Questions Related to the Evaluation of Human Cancer Studies

- Which epidemiologic studies should be included in the review?
- What are the methodological strengths and limitations of these studies?
- What are the potential confounders for cancer risk for the tumor sites of interest in these studies?
- Is there a credible association between exposure to cobalt and cancer?
- If so, can the relationship between cancer endpoints and exposure to cobalt be explained by chance, bias, or confounding?

#### Questions Related to the Evaluation of Cancer Studies in Experimental Animals

- What is the level of evidence (sufficient or not sufficient) of carcinogenicity of cobalt from animal studies?
- What are the methodological strengths and limitations of the studies?
- What are the tissue sites?

#### Questions Related to the Evaluation of Mechanistic Data and Other Relevant Data

- What are the genotoxic effects due to cobalt exposure? Does genotoxicity vary by cobalt compound?
- What are the cytotoxic or toxic effects of cobalt exposure? Does cytotoxicity or toxicity vary by cobalt compound?
- What are the major mechanistic modes of action for the carcinogenicity of cobalt?
  - What are the common key steps or mode(s) of action of toxicity or carcinogenicity across different cobalt compounds? What role and contribution does cobalt ion play in the proposed mechanism? What are the effects from exposure to particulate cobalt?
  - What factors influence biological or carcinogenic effects? How do particle size, solubility, and cellular uptake of a cobalt compound affect biological or carcinogenic effects?
  - Is there evidence that supports grouping cobalt and cobalt compounds that release cobalt ions in vivo together in the assessment?

### Approach for Obtaining Scientific and Public Input

To help address the approach to identify a common mode of action involving the cobalt ion for cobalt compounds, additional scientific input was requested early in the review process to define the scope of the review, i.e., what cobalt compound(s) could reasonably be included in this evaluation? Based on input from several scientific experts at a Cobalt Information Group Meeting convened at NIEHS on October 7, 2014, the scope of the evaluation was recommended to include cobalt and cobalt compounds that release cobalt ions in vivo. Technical advisors for the review of cobalt are identified on the “CONTRIBUTORS” page.

Public comments on scientific issues were requested at several times prior to the development of the RoC monograph, including the request for information on the nomination, and the request for comment on the draft concept document, which outlined the rationale and approach for conducting the scientific review. In addition, the NTP posted its protocol for preparing the draft RoC monograph on cobalt for public input on the ORoC webpage for cobalt (https://ntp.niehs.nih.gov/go/730697) prior to the release of the draft monograph. Seven written public comments on cobalt have been received from the public as of the date on this document.

### Methods for Writing the Cancer Evaluation Component of the Monograph

The procedures by which relevant literature was identified, data were systematically extracted and summarized, and the monograph was written, together with the processes for scientific review, quality assurance, and assessment and synthesis of data, are described below.

The preparation of the RoC monograph for cobalt began with development of a literature search strategy to obtain information relevant to the topics listed above for Sections 1 through 6 using search terms developed in collaboration with a reference librarian (see Protocol). The approximately 7,500 citations identified from these searches were uploaded to web-based systematic review software for evaluation by two separate reviewers using inclusion/exclusion criteria, and 484 references were selected for final inclusion in the monograph using these criteria.

Information for the relevant cancer and mechanistic sections was systematically extracted in tabular format and/or summarized in the text from studies selected for inclusion in the monograph. All sections of the monograph underwent scientific review and quality assurance (QA, i.e., assuring that all the relevant data and factual information extracted from the publications have been reported accurately) by a separate reviewer. Any discrepancies between the writer and the reviewer were resolved by mutual discussion in reference to the original data source.

Strengths, weaknesses, and study quality of the cancer studies for cobalt compounds in humans (see Appendix C) and experimental animals (see Appendix D) were assessed based on a series of a priori considerations (questions and guidelines for answering the questions), which are available in the protocol (available at https://ntp.niehs.nih.gov/go/730697). Two reviewers evaluated the quality of each study. Any disagreements between the two reviewers were resolved by mutual discussion or consultation with a third reviewer in reference to the original data source. Relevant genotoxicity and mechanistic studies were also assessed for their strengths and weaknesses.

RoC listing criteria (see text box) were applied to the available database of carcinogenicity data to assess the level of evidence (sufficient, limited, or inadequate) for the carcinogenicity of cobalt from studies in humans and the level of evidence (sufficient, not sufficient) from studies in experimental animals. The approach for synthesizing the evidence across studies and reaching a level of evidence conclusion was outlined in the protocol. The evaluation of the mechanistic data included a complete discussion and assessment of the strength of evidence for potential modes of action for cobalt-induced neoplasia, including those involving, e.g., cytotoxicity, genotoxicity, and oxidative stress. Mechanistic data are discussed across cobalt compounds. The RoC listing criteria were then applied to the body of knowledge (cancer studies in humans and experimental animals and mechanistic data) for cobalt and cobalt compounds that release cobalt ions in vivo to reach a listing recommendation.

RoC Listing Criteria

##### Known to Be Human Carcinogen:

There is sufficient evidence of carcinogenicity from studies in humans*, which indicates a causal relationship between exposure to the agent, substance, or mixture, and human cancer.

##### Reasonably Anticipated to Be Human Carcinogen:

There is limited evidence of carcinogenicity from studies in humans*, which indicates that causal interpretation is credible, but that alternative explanations, such as chance, bias, or confounding factors, could not adequately b excluded, OR

there is sufficient evidence of carcinogenicity from studies in experimental animals, which indicates there is an increased incidence of malignant and/or a combination of malignant and benign tumors (1) in multiple species or at multiple tissue sites, or (2) by multiple routes of exposure, or (3) to an unusual degree with regard to incidence, site, or type of tumor, or age at onset, OR

there is less than sufficient evidence of carcinogenicity in humans or laboratory animals; however, the agent, substance, or mixture belongs to a well-defined, structurally related class of substances whose members are listed in a previous Report on Carcinogens as either known to be a human carcinogen or reasonably anticipated to be a human carcinogen, or there is convincing relevant information that the agent acts through mechanisms indicating it would likely cause cancer in humans.

Conclusions regarding carcinogenicity in humans or experimental animals are based on scientific judgment, with consideration given to all relevant information. Relevant information includes, but is not limited to, dose response, route of exposure, chemical structure, metabolism, pharmacokinetics, sensitive sub-populations, genetic effects, or other data relating to mechanism of action or factors that may be unique to a given substance. For example, there may be substances for which there is evidence of carcinogenicity in laboratory animals, but there are compelling data indicating that the agent acts through mechanisms which do not operate in humans and would therefore not reasonably be anticipated to cause cancer in humans.

*This evidence can include traditional cancer epidemiology studies, data from clinical studies, and/or data derived from the study of tissues or cells from humans exposed to the substance in question that can be useful for evaluating whether a relevant cancer mechanism is operating in people.