# Appendix E Genotoxicity and Cellular Transformation

This section describes the assessment of studies evaluating genetic and related effects from exposure to cobalt compounds and provides the background for the discussion of genotoxicity as a possible mode of action for cobalt-induced carcinogenicity (see Section 6). The genotoxicity data summarized in Section 6.2.1 and Table 6-2 are described more fully below.

Cobalt metal and several cobalt compounds have been tested in short-term assays to evaluate mutagenicity, DNA damage, and other potential genotoxic effects. These compounds include several forms of cobalt: (1) the water-soluble salts cobalt chloride (and its hexahydrate), cobalt sulfate (and its heptahydrate), and cobalt nitrate (and its hexahydrate); (2) a water-insoluble compound, cobalt oxide; (3) an organic water-soluble compound, cobalt acetate; (4) cobalt metal and (5) the cobalt particles: cobalt sulfide(s) and cobalt nanoparticles. Most of the genotoxicity studies identified reported on tests using cobalt chloride (or its hexahydrate). The specific cobalt compound form (i.e., hydrate) tested is indicated when provided by the study authors. The oxidation state of the cobalt salts, oxide and acetate compounds in this section is +2 (cobalt(II)), unless indicated otherwise.

A discussion of the genotoxic effects of certain cobalt compounds reported for in vitro and in vivo assays are presented below and a compilation of studies is provided in tabular form for each section. An overall summary call for genetic and related effects is provided for the compounds by endpoint in Table 6-2; the calls are based on the integration of the evidence from an authoritative review (namely IARC 2006) and several primary studies published since the IARC review.

## E.1 In Vitro Mutagenicity and DNA-damage Studies of Cobalt Compounds in Bacteria

Cobalt metal and two water-soluble cobalt salts (cobalt chloride and its hexahydrate, cobalt sulfate heptahydrate) were tested for mutagenicity in prokaryotic (bacterial) systems (see Table E-1 for study details and sources not provided in text). Results for mutagenicity are mostly negative for cobalt compounds in bacterial tester strains; however, there were some positive results in a few studies that detect mutations involving GC base pairs, although the evidence was not entirely consistent.

Cobalt chloride was reported to be mutagenic in only some of the studies in three Salmonella strains (TA97, TA98, and TA1537) (Pagano and Zeiger 1992; Wong 1988) but not in other strains (TA100, TA102, TA1535, TA1538, TA2637). It was also mutagenic in one of several studies in Escherichia coli (Ogawa et al. 1999) but not Bacillus subtilis. Cobalt sulfate heptahydrate was positive in TA100 but not in TA98 and TA1537. A growth inhibition assay for cobalt chloride in B. subtilis had mixed results in two studies; however, the test that showed growth inhibition (positive results) was conducted using preincubation, which is a more sensitive assay that the standard plate incorporation assay. Cobalt metal was positive in the Salmonella strains in which it was tested (TA98 and TA100) but not in E. coli.

Positive results in a particular set of Salmonella typhimurium and E. coli bacterial tester strains can suggest very specific types of mutations. Tester strains TA100, TA102 and TA1535 are generally considered indicators of base-pair substitution. The frameshift mutation detected by S. typhimurium strain TA98 is a disruption of a dinucleotide run of (CG)_4_ residues, while TA100 detects base-pair mutations in a codon for proline (GGG sequence) in the histidine G46 gene. Reverse mutations at the trpE ochre (TAA) codon can be identified by positive results in the E. coli WP2 uvrA/pKM101 strain. The results for these strains in the studies identified in this review are not strong; however, sequencing of the supF tRNA mutational reporter gene in bacteria exposed to cobalt chloride showed that both frameshift and base-pair substitution occurred at G:C base pairs (Ogawa et al. 1999).

Overall, the results for cobalt-induced bacterial mutagenicity are considered mostly negative without the addition of S9 and are completely negative in all assays with S9. The negative results for the assays that included the addition of S9 (and which were positive without S9) may be due to the presence of radical-scavenging enzymes in the mixture, which could eliminate a mutagenic effect; alternatively, proteins in the S9 mixture could bind the cobalt ions, rendering them ineffective as a mutagen.

Some studies reported anti-mutagenic effects. Potent anti-mutagenic effects were observed for cobalt chloride on reverse mutations induced by 3-amino-1,4-dimethyl-5H-pyrido[4,3-b]indole (Trp-P-1) in Salmonella strains TA98 and TA1538. Cobalt chloride hexahydrate showed an anti-mutagenic effect (inhibition of spontaneous mutation) when tested in B. subtilis (Inoue et al. 1981).

Table E-1 In Vitro Mutagenicity and DNA-damage Studies of Cobalt Compounds in Bacteria

Compound | Reference | LED/HID | Results | | Comments and Conclusions
Compound | Reference | LED/HID | −S9 | +S9 | Comments and Conclusions
Reverse mutation/ Salmonella typhimurium/TA100
Cobalt chloride | Ogawa et al. (1986)* | NR | − | | Negative −S9
Cobalt chloride hexahydrate | Tso and Fung (1981)* Arlauskas et al. (1985)* | 23,800 μg/mL NR | − − | | Negative −S9 in two studies
Cobalt sulfate heptahydrate | Zeiger et al. (1992), NTP (1998) | 100 μg/plate | + | (+) | Positive −S9; weak positive −+S9
Cobalt metal | NTP (2014d) | 500 μg/plate −S9 7,500 μg/plate +S9 | (+) | − | Weak positive −S9; negative +S9
Reverse mutation/Salmonella typhimurium/TA102
Cobalt chloride | Wong (1988)* | 40 μg/mL [approx. 100 μg/plate] | − | − | Negative ±S9
Reverse mutation/Salmonella typhimurium/TA1535
Cobalt chloride | Arlauskas et al. (1985)* Wong (1988)* | NR 40 μg/mL | − − | − | Negative −S9 in 2 of 2 studies; negative +S9
Cobalt sulfate heptahydrate | Zeiger et al. (1992) NTP (1998) | 10,000 μg/plate | − | − | Negative ±S9
Reverse mutation/Salmonella typhimurium/TA97
Cobalt chloride | Pagano and Zeiger (1992)* | 13 μg/mL [approx. 32 μg/plate] | + | | Positive −S9; Preincubation assay (generally more sensitive than standard plate incorporation assay)
Reverse mutation/Salmonella typhimurium/TA98
Cobalt chloride | Arlauskas et al. (1985)* Ogawa et al. (1986)* Wong (1988)* | NR NR 40 μg/mL [approx. 100 μg/plate] | − − + | − | Positive −S9 in 1 of 3 studies; negative +S9
Cobalt chloride hexahydrate | Mochizuki and Kada (1982)* | 20 μg/mL | − | | Anti-mutagenic effect on Trp-P-1-induced reverse mutations; same effect in TA1538, so independent of plasmid pKM101 (which is in TA98 but not TA1538).
Cobalt sulfate heptahydrate | Zeiger et al. (1992) NTP (1998) | 10,000 μg/plate | − | − | Negative ±S9
Cobalt metal | NTP (2014d) | 100 μg/plate −S9 7,500 μg/plate +S9 | + | − | Positive −S9 (weak effect, not well-correlated with dose); negative +S9
Reverse mutation/Salmonella typhimurium/TA1537
Cobalt chloride | Arlauskas et al. (1985)* Ogawa et al. (1986)* Wong (1988)* | NR 130,000 μg/plate 40 μg/mL [approx. 100 μg/plate] | − − + | − | Positive −S9 in 1 of 3 studies; negative +S9 [note: recommended maximum dose for assay is generally 5,000 to 6,000 μg/plate, depending on toxicity]
Reverse mutation/Salmonella typhimurium/TA1538
Cobalt chloride | Arlauskas et al. (1985)* | NR | − | | Negative −S9
Cobalt chloride hexahydrate | Mochizuki and Kada (1982)* | 20 μg/mL | − | | Anti-mutagenic effect on Trp-P-1-induced reverse mutations; same effect in both strains, independent of plasmid pKM101, which is in TA98 but not TA1538
Reverse mutation/Salmonella typhimurium/TA2637
Cobalt chloride | Ogawa et al. (1986)* | 130,000 μg/plate | − | | Negative −S9; strain detects bulky DNA adduct formation
Mutation/Escherichia coli strain WP2 uvrA/pKM101
Cobalt chloride hexahydrate | Arlauskas et al. (1985)* | NR | − | | Negative −S9
Cobalt chloride hexahydrate | Kada and Kanematsu (1978)* Leitão et al. (1993)* | 20 μg/mL 50 μg/mL | − − | | Negative −S9 Induced anti-mutagenic effect (inhibition of mutagenesis induced by N-methyl-N′-nitrosoguanidine) in two studies
Cobalt metal | NTP (2014d) | 450 μg/plate | − | − | Negative ±S9
Mutation/ Escherichia coli strain SY1032/pKY241 supF tRNA locus
Cobalt chloride | Ogawa et al. (1999)* | 2.6 μg/mL | + | | Positive −S9
Prophage induction/Escherichia coli
Cobalt chloride | Rossman et al. (1984)* | 415 μg/mL [approx. 1,037 μg/plate] | − | | Negative −S9
Reverse mutation/Bacillus subtilis strain NIG 1125
Cobalt chloride hexahydrate | Inoue et al. (1981)* | 30 μg/mL | − | | Anti-mutagenic effect (inhibition of spontaneous mutation)
Growth inhibition/Bacillus subtilis rec strain strains H17
Cobalt chloride | Nishioka (1975)* Kanematsu et al. (1980)* | 325 μg/plate 325 μg/plate | − + | | Positive −S9 in 1 of 2 studies; positive study used ‘cold preincubation’ procedure

* As cited by IARC (2006).

LED/HID = lowest effective dose/highest ineffective dose, NR = not reported, + = positive, (+) = weak positive, − = negative.

## E.2 Genotoxicity Studies of Cobalt Compounds in Non-mammalian Eukaryotes

Cobalt water-soluble compounds (cobalt chloride, cobalt nitrate, and cobalt sulfate) and nanoparticles were tested for mutations, DNA damage and chromosomal damage in numerous studies in non-mammalian eukaryotes. Mostly positive effects were observed in yeast, plants, insects, nematodes, and zebrafish, for genotoxic activity of a variety of cobalt compounds for the evaluated endpoints. These include mutation (cobalt chloride and cobalt nitrate hexahydrate), gene conversion (cobalt chloride), DNA damage (cobalt chloride, cobalt nitrate hexahydrate, and cobalt sulfate), chromosomal aberration (cobalt chloride and cobalt sulfate) and aneuploidy (cobalt sulfate). Recombination was reported as treatment-related in Drosophila studies on cobalt chloride, cobalt nitrate hexahydrate, and cobalt nanoparticles. None of these studies reported using the addition of a metabolic activation mixture (S9). The results of the genotoxicity studies of cobalt compounds tested in non-mammalian eukaryotes are described below and are summarized in Table E-2.

In fungi, cobalt chloride treatment resulted in induction of gene mutation and conversion in several assays. In the yeast Saccharomyces cerevisiae, cobalt chloride was at least weakly mutagenic in five of eight studies identified (Egilsson et al. 1979; Kharab and Singh 1985; 1987; Prazmo et al. 1975; Putrament et al. 1977), depending on the type of mutation. Respiratory deficiency mutations are consistently positive, while others, such as for the ilv gene, were negative; the significance of this difference is not clear. Gene conversion was observed as at least weakly positive at the trp locus in the yeast S. cerevisiae D7 in all three of the studies reported (Fukunaga et al. 1982; Kharab and Singh 1985; Singh 1983).

Studies on tissues from two plants reported DNA damage due to exposure to cobalt chloride for Allium cepa bulbs (Yıldız et al. 2009) and cobalt nitrate hexahydrate treatment of Zea mays seedlings (Erturk et al. 2013). Chromosomal aberrations were reported after cobalt chloride exposure in the Yıldız et al. (2009) study and also in an earlier A. cepa study with cobalt sulfate (Gori and Zucconi 1957), which also reported the induction of aneuploidy.

Cobalt soluble salts (cobalt chloride and cobalt nitrate hexahydrate) caused somatic mutation and/or recombination in Drosophila melanogaster fruit flies strain mwh/flr3 (Ogawa et al. 1994; Vales et al. 2013; Yesilada 2001). In the study of cobalt nanoparticles, Vales et al. (2013) used the somatic mutation wing spot assay with strain mwh/TM3 to distinguish somatic mutations from recombination that suggested that the genotoxic effect for the mwh/flr3 is not due to mutation (see study details in Table E-2).

Fish have been used to assess genotoxic effects of cobalt compounds. Direct DNA damage was reported in sperm from exposed male zebrafish (Danio rerio) for both cobalt chloride and cobalt sulfate, showing a dose-dependent increase for both compounds.

Table E-2 Genotoxicity Studies of Cobalt Compounds in Non-mammalian Eukaryotes

Compound | Reference | LED/HID | Results (−S9)^a^ | Comments and Conclusions
FUNGI (Yeast)
Mutation/Saccharomyces cerevisiae
Cobalt chloride | Prazmo et al. (1975)* Egilsson et al. (1979)* Putrament et al. (1977)* Putrament et al. (1977)* Fukunaga et al. (1982)* Singh (1983)* Kharab and Singh (1985)* Kharab and Singh (1987)* | ‘Petite’ mutation 260 μg/mL SBTD-2B, respiratory deficiency 640 μg/mL Respiratory deficiency 520 μg/mL Strain 197/2d 520 μg/mL Erythromycin-resistant mutation/ilv mutation DL7: 1,300 μg/mL 13,000 μg/ml 3,000 μg/mL ‘Petite’ mutation/DL7 respiratory deficiency: 750 μg/mL | + (+) + − − − (+) + | Some positive results for mutation in yeast, especially respiratory deficiency type
Gene conversion (trp)/Saccharomyces cerevisiae D7
Cobalt chloride | Fukunaga et al. (1982)* Singh (1983)* Kharab and Singh (1985)* | 1,300 μg/mL 13,000 μg/mL 1,500 μg/mL | + (+) (+) | Positive for 3 of 3 studies
PLANTS (Onion or corn)
DNA damage/Allium cepa or Zea mays
Cobalt chloride | Yıldız et al. (2009) | 5.5 ppm | + | Positive in comet assay in Allium cepa bulbs
Cobalt nitrate hexahydrate | Erturk et al. (2013) | 5 mM | + | Genomic template instability increases with cobalt exposure levels in Zea mays seedlings
Chromosomal aberrations/Allium cepa
Cobalt chloride | Yıldız et al. (2009) | 5.5 ppm | + | Positive in anaphase-telophase chromosome aberration assay in Allium cepa bulbs
Cobalt sulfate | Gori and Zucconi (1957)* | 3 μg/mL | + | Positive results
Aneuploidy/Allium cepa
Cobalt sulfate | Gori and Zucconi (1957)* | 15 μg/mL | + | Positive results/ dosed 5 d, then water 3d
INSECTS (Drosophila melanogaster; fruit fly)
Mutation or mitotic recombination/ wing spot test
Cobalt chloride | Ogawa et al. (1994)* Ogawa et al. (1994)* Vales et al. (2013) | mwh/flr 260 μg/mL mwh/TM3 1,040 μg/mL mwh/flr^3^ wings small spots 10 mM large spots 10 mM twin spots 10 mM total 10 mM | + − + i i + | Positive results for single and total mutant spots at high doses (10 mM) of ionic cobalt indicate CoCl2 is more genotoxic than nanoparticles in this assay (see below).
Cobalt nitrate hexahydrate | Yesilada (2001)* | Strain mwh/flr^3^ wings Mutations, chromosomal deletion, nondisjunction 291 μg/mL Mitotic recombination 2,910 μg/mL | + + | Positive effects; additional details were not provided in review paper
Cobalt nanoparticles | Vales et al. (2013) | mwh/flr^3^ wings small spots 1 mM large spots 10 mM twin spots 10 mM total 5 mM mwh/TM3 wings small spots 1 mM large spots 10 mM total 10 mM | + − i + i − i | Dose-dependent induction of small, but not large, spots indicates slow progression of nanoparticles to reach the wing imaginal disks. Single mutant spots result from both somatic mutation and somatic recombination; twin spots only result from somatic mutation. Results negative for this assay, suggesting that effect for experiment above is due to somatic recombination and [underlined: not] mutation.
FISH (Danio rerio; zebrafish)
DNA damage
Cobalt chloride | Reinardy et al. (2013) | 5 mg/L | + | Concentration-dependent increase in DNA strand breaks in sperm from exposed male zebra fish for 13 d in water
Cobalt sulfate | Reinardy et al. (2013) | 5 mg/L | + | Concentration-dependent increase in DNA strand breaks in sperm from exposed male zebra fish for 13 d in water

* As cited by IARC (2006).

LED/HID = lowest effective dose/highest ineffective dose, NR = not reported, + = positive, − = negative, i = inconclusive.

^a^ No studies reported testing with +S9.

## E.3 In Vitro Studies of Genotoxicity of Cobalt Compounds in Mammalian Cells

Cobalt compounds have been evaluated for genotoxic effects in mammalian cells in vitro in rodent (mouse, hamster, and rat) and human cells. In general, no major species differences (with one possible exception) were observed, albeit not all types of effects were tested in cells from all species. Although most studies tested cobalt chloride, a greater number of different cobalt compounds were tested compared to the other experimental systems including another soluble cobalt salt (cobalt sulfate), an organic water-soluble cobalt compound and insoluble cobalt forms including cobalt metal, cobalt nanoparticles, and cobalt sulfide particles.

Overall, there is strong evidence that all types of cobalt compounds are clastogenic and induced DNA damage in both human and animal cells and most of the compounds (except cobalt metal) caused cellular transformation in animal cell lines (see Section E.7). There is also some evidence that a soluble cobalt compound (cobalt chloride, which was the only compound tested for most of the endpoints) induces sister chromatid exchange and aneuploidy. However, mixed results were reported for mutagenicity in animal cells for a variety of cobalt compounds and chromosomal aberrations in human cells. Cobalt nanoparticles caused micronuclei in both rodent and human cells; however, findings for other compounds differ by species with positive findings for cobalt chloride and cobalt metal in human cells and negative findings for cobalt chloride in rodent cells.

All of the described studies in mammalian cells were performed without the addition of exogenous S9 metabolic activation mixture. Results for the in vitro studies in mammalian cells are discussed below and genotoxic and related effects are summarized in Table E-3 and Table E-4.

### E.3.1 Rodent Cells

Rodent cells were tested in vitro for genotoxicity (mutagenicity, DNA strand breaks, sister chromatid exchange, and micronuclei) and related effects (i.e., cellular transformation and apoptosis) with soluble cobalt salts (cobalt chloride) and some relatively insoluble forms or particles (cobalt oxide, cobalt sulfides and particles, cobalt metal and nanoparticles) (see Table E-3).

There is strong evidence that different types of cobalt compounds (both soluble and relatively insoluble forms) cause DNA damage. Positive results were reported for cobalt chloride, cobalt metal, and cobalt nanoparticles in BALB/3T3 cells (Anard et al. 1997; Ponti et al. 2009); cobalt chloride and cobalt sulfides in Chinese hamster ovary (CHO) cells (Hamilton-Koch et al. 1986; Robison et al. 1982), as well as in rat neuronal PC12 cell mitochondria (Wang et al. 2000). The only negative study reported using a different type of assay (nucleoid sedimentation) in CHO cells to test cobalt chloride (Hamilton-Koch et al. 1986).

Cobalt assays for mutagenicity generally gave negative results; conflicting results may be due in part to the type of loci evaluated in the various assays. Cobalt chloride and cobalt sulfide caused mutations in studies using V79 Chinese hamster fibroblast cells Hprt locus (Hartwig et al. 1990; Miyaki et al. 1979) and for the transgenic G12 Gpt, but not for the normal fibroblast Gpt locus (Kitahara et al. 1996). Both assays testing cobalt chloride hexahydrate were negative, but they tested different gene loci, one at the Tk locus of mouse lymphoma L5178Y cells (Amacher and Paillet 1980) and the 8AG locus of V79 cells (Yokoiyama et al. 1990). Thus, the disparity of results may be due to the specific locus tested in these assays; the Hprt locus was positive in the two studies where it was evaluated for cobalt chloride, while the other assays looked at different loci. Mixed results were also reported for cobalt sulfide tested in a Chinese hamster transgenic cell line; the Gpt locus for G10 was negative while the G12 strain tested positive. These cells lines have different Gpt locus insertion sites and differ in their response to clastogens. When compared with G10, the G12 strain has a lower spontaneous mutant frequency (30 compared with 100 per million cells) and is highly sensitive to insoluble metal (nickel) compounds, with mutant induction of 20 to 30 fold for G12, compared with only 2 to 3 times the number of spontaneous mutants induced for G10 (Klein et al. 1994).

In cytogenetic assays, cobalt chloride induced sister chromatid exchange (SCE) in mouse macrophage-like cells (Andersen 1983). SCE involves double-strand DNA breaks and is induced by agents that form DNA adducts or interfere with DNA replication and/or repair. Cobalt nanoparticles (Ponti et al. 2009), but not cobalt chloride (Ponti et al. 2009; Suzuki et al. 1993), caused micronucleus induction.

### E.3.2 Human Cells

Human cells were tested in vitro for genotoxicity (DNA strand breaks, sister chromatid exchange, micronuclei, chromosomal aberrations, and aneuploidy) with soluble cobalt salts (cobalt acetate, cobalt chloride, cobalt nitrate, and some relatively insoluble forms or particles (cobalt oxide, cobalt metal, and nanoparticles) (see Table E-3).

There is strong evidence that different types of cobalt compounds caused DNA damage after exposure in vitro in human cells, similar to that of the rodent cells described previously. DNA damage, such as strand breaks, was reported after cobalt chloride treatment in assays in several human cell lines including diploid fibroblasts, mononuclear leukocytes, HepG2 cells, H460 lung epithelial cells, and T-cells (Alarifi et al. 2013; Caicedo et al. 2007; Davies et al. 2005; De Boeck et al. 1998; Hamilton-Koch et al. 1986; Hartwig et al. 1990; McLean et al. 1982; Patel et al. 2012). Negative results were reported in studies that used different techniques like nucleoid sedimentation (Hamilton-Koch et al. 1986) or different cell types like peripheral blood leukocytes (Colognato et al. 2008). Interestingly, T-cells did not show DNA damage in the comet assay for cobalt chloride but did for cobalt nanoparticles in the same study (Jiang et al. 2012). Treatment with cobalt metal also gave very strong positive results for lymphocytes, mononuclear leukocytes, and normal fetal fibroblasts (Anard et al. 1997; De Boeck et al. 1998; De Boeck et al. 2003b; Qiao and Ma 2013; Van Goethem et al. 1997). Cobalt nanoparticles and cobalt oxide nanoparticles gave positive results in all identified studies for lymphocytes, HepG2 cells, A549 lung epithelial cells, and bronchial BEAS-2B bronchial cells (Alarifi et al. 2013; Cavallo et al. 2015; Colognato et al. 2008; Jiang et al. 2012; Kain et al. 2012; Wan et al. 2012).

Evidence that cobalt compounds cause chromosomal damage comes primarily from studies using human lymphocytes or lung fibroblast cells. Both soluble (cobalt chloride) and insoluble (cobalt metal and cobalt nanoparticles) cobalt forms induced micronucleus formation (Colognato et al. 2008; De Boeck et al. 2003b; Miller et al. 2001; Van Goethem et al. 1997). Chromosomal aberrations were evaluated after exposure to various forms of cobalt, with mixed results possibly related to cell type or exposure level and not compound solubility. Cobalt chloride hexahydrate and cobalt oxide were positive for aberrations in lung fibroblast cells (Figgitt et al. 2010; Smith et al. 2014); however, exposure to cobalt oxide, cobalt acetate tetrahydrate, and cobalt nitrate did not induce chromosomal aberrations in lymphocytes, diploid fibroblasts or mononuclear leukocytes (Paton and Allison 1972; Voroshilin et al. 1978). These results appear to be related to cell type but not compound solubility, although intracellular soluble cobalt has been shown to be more cytotoxic than particulate cobalt in human lung fibroblasts at levels above 1 mM. For example, the relative survival for 1.7 mM cobalt chloride treated cells was 29% but was 55% survival for the same concentration of cobalt oxide (Smith et al. 2014). Regarding the negative results in the study by Paton and Allison, the top dose of 0.015 μg/mL cobalt nitrate to treat fibroblasts may have been too low to see an effect in the assay.

Cobalt chloride induced sister chromatid exchange in lymphocytes (Andersen 1983) as well as aneuploidy in lymphocytes and primary fibroblasts (Figgitt et al. 2010; Resende de Souza Nazareth 1976).

Table E-3 In Vitro Studies of Genotoxic Effects of Cobalt Compounds in Mammalian Cells

Compound | Reference | Concentration (LED or HID) | Results (−S9)^a^ | Comments and Conclusions
RODENT CELLS
Mutation/V79 Chinese hamster lung fibroblasts (V79) or Mouse lymphoma (MOLY), hamster transgenic cell line or BALB/3T3 mouse cells
Cobalt chloride | Miyaki et al. (1979)* Hartwig et al. (1990)* Kitahara et al. (1996)* Kitahara et al. (1996)* | 26 μg/mL 13 μg/mL 13 μg/mL 6.5 μg/mL | (+) + − + | V79—mixed results Hprt locus Hprt locus Gpt locus Transgenic G12, Gpt locus
Cobalt chloride hexahydrate | Yokoiyama et al. (1990)* Amacher and Paillet (1980)* | 2 μg/mL 57.11 μg/mL | − − | V79-8AG locus, negative results MOLY L5178Y cells, Tk locus, negative results
Cobalt sulfide (CoS_2_ and CO_3_S_4_) particles | Kitahara et al. (1996)* | 1 μg/mL 0.5 μg/mL | − + | Chinese hamster transgenic cell lines (derived from V79) G10, Gpt locus, negative results G12, Gpt locus, positive results
DNA damage/strand breaks/alkaline elution, sucrose gradient, or Q-PCR/3T3 mouse cells, Chinese Hamster Ovary (CHO) cells, BALB/3T3 cells/neuronal cell mitochondria
Cobalt chloride | Hamilton-Koch et al. (1986)* Hamilton-Koch et al. (1986)* Ponti et al. (2009) Wang et al. (2000) | 260 μg/mL (ASG) 1,300 μg/mL (NS) 1 μM 100 μM | + − + + | CHO cells—positive using alkaline sucrose gradient but not nucleoid sedimentation in the same study Positive in BALB/3T3 cells—2 hr. exposure to sub-toxic dose Positive in rat neuronal PC12 cell mitochondria
Cobalt (metal) | Anard et al. (1997)* | 1 μg/mL | + | BALB/3T3 mouse cells—positive for alkaline elution; used purified DNA
Cobalt sulfides (CoS_2_ and CO_3_S_4_) particles | Robison et al. (1982)* | 10 μg/mL | + | CHO cells—Positive using sucrose gradient
Cobalt metal nanoparticles | Ponti et al. (2009) | 1 μM | + | Positive in BALB/3T3 cells—2 hr. exposure to sub-toxic dose
Micronucleus formation/mouse cells
Cobalt chloride | Ponti et al. (2009) | 10 μM | − | Negative for micronuclei induction (24 hr) in BALB/3T3 fibroblast cells
Cobalt chloride hexahydrate | Suzuki et al. (1993)* | 50 μg/mL | − | Negative for MN induction in BALB/c mouse bone marrow
Cobalt metal nanoparticles | Ponti et al. (2009) | 1 μM | + | Positive for micronuclei induction (24 hr) in BALB/3T3 fibroblast cells
Sister chromatid exchange/mouse macrophage-like cells P388D_1_
Cobalt chloride | Andersen (1983)* | 13 μg/mL | + | Positive for SCE induction
HUMAN CELLS
DNA damage - strand breaks/several cell types/alkaline elution, alkali-labile sites, or comet assay
Cobalt chloride | McLean et al. (1982)* Hamilton-Koch et al. (1986)* Hamilton-Koch et al. (1986)* Hamilton-Koch et al. (1986)* Hartwig et al. (1990)* De Boeck et al. (1998)* Alarifi et al. (2013) Colognato et al. (2008) Patel et al. (2012) Caicedo et al. (2007) Davies et al. (2005) Jiang et al. (2012) | 6.5 μg/mL 650 μg/mL 1,300 μg/mL 1,300 μg/mL 65 μg/mL 0.3 μg/mL 10 μg/mL 100 μM 150 μM 5 mM 0.84 μM 30 μM | + + + − + + + − + + + − | Mostly positive results White blood cells—fluorescence analysis of DNA unwinding Diploid fibroblasts Alkaline sucrose gradient Nick translation Nucleoid sedimentation Nucleoid sedimentation Mononuclear leukocytes—comet assay HepG2 hepatocarcinoma cells (24 hr)—comet assay Negative in peripheral blood leukocytes—comet assay Damage in H460 lung epithelial cells—comet assay Damage in CD4+ T-cells obtained from lymphoma Jurkat cell line Damage for artificial spiked fluids—comet assay Negative for DNA damage on T-cells—comet assay
Cobalt chloride hexahydrate | Anard et al. (1997)* | 25 μg/mL | − | Negative for lymphocytes using alkaline elution
Cobalt metal | Anard et al. (1997)* Anard et al. (1997)* Van Goethem et al. (1997)* De Boeck et al. (1998)* De Boeck et al. (2003b)* Qiao and Ma (2013) | 3.0 μg/mL 4.5 μg/mL 0.6 μg/mL 0.3 μg/mL 0.6 μg/mL 5 μM | + + + + + + | Positive for lymphocytes using alkaline elution Positive in several studies, for mononuclear leukocytes for DNA single-strand breaks and alkali-labile sites, and alkaline comet assay Positive for normal fetal fibroblast cells in single cell array assay
Cobalt nanoparticles | Colognato et al. (2008) Wan et al. (2012) Jiang et al. (2012) | 50 μM 5 μg/ml 3 μM | + + + | Positive in peripheral blood leukocytes—comet assay Positive in exposed A549 lung epithelial cells—comet assay Positive for DNA damage in T-cells—comet assay
Cobalt oxide (Co_3_O_4_) nanoparticles | Kain et al. (2012) Kain et al. (2012) Alarifi et al. (2013) Cavallo et al. (2015) | 20 μg/mL 20 μg/mL 5 μg/mL A549 20 μg/mL BEAS-2B 40 μg/mL (direct) 5 μg/mL (oxidative) | + + + + + + + | Positive in A549 lung cell line (DNA breaks) Positive in BEAS-2B lung cell (DNA breaks and oxidative damage) Positive in HepG2 hepatocarcinoma cells (24 hr)—comet assay Positive in alveolar A549 and bronchial BEAS-2B cells, for both direct and oxidative damage—comet assay
Micronucleus formation/ binucleates, cytochalasin-B assay/ lymphocytes or osteoblast-like cell line
Cobalt chloride | Colognato et al. (2008) | 40 μM | + | Positive in peripheral blood leukocytes, with clear trend for increase, high variability in response of donors
Cobalt metal | Van Goethem et al. (1997)* Miller et al. (2001)* De Boeck et al. (2003b)* | 0.6 μg/mL 0.75 μg/ml 3 μg/mL | + + + | Positive for micronuclei induction in three studies with different cell types
Cobalt nanoparticles | Colognato et al. (2008) | 40 μM | + | Increase in peripheral blood leukocytes, high variability among donors, less effective than cobalt chloride in same study
Chromosomal aberrations/ lung fibroblast cells or lymphocytes
Cobalt chloride hexahydrate | Fairhall et al. (1949) Smith et al. (2014) | 1.3 ppb 50 μM | + + | Induced significant increase of total aberrations in primary fibroblasts In WTHBF-lung fibroblast cells—soluble cobalt induces more cytotoxicity and cell cycle arrest than particulate (cobalt oxide, see below) but both produced similar levels of genotoxicity; chromosomal damage significant (p < 0.05).
Cobalt nitrate | Paton and Allison (1972)* | 0.015 μg/mL 0.15 μg/mL | − − | Negative in diploid fibroblasts WI38 (derived from embryonic lung tissue) and MRC-5 (derived from fetal lung tissue) toxic dose Negative in mononuclear leukocytes (toxic dose)
Cobalt oxide (CoO) | Smith et al. (2014) | 0.5 μg/mL | + | Lung fibroblast cells—significant chromosome damage at p < 0.05
Cobalt acetate tetrahydrate | Voroshilin et al. (1978)* | 0.6 μg/mL | − | Negative in lymphocytes
Sister chromatid exchange (SCE)/lymphocytes
Cobalt chloride | Andersen (1983)* | 1.3 μg/mL | + | Positive for SCE in lymphocytes
Aneuploidy/ lymphocytes
Cobalt chloride | Resende de Souza Nazareth (1976)* | 3.7 μg/mL | + | Positive for aneuploidy in lymphocytes
Cobalt chloride hexahydrate | Figgitt et al. (2010) | 25 ppb | + | Induced significant increase in aneuploidy in primary fibroblasts

* As cited by IARC (2006).

LED/HID = lowest effective dose/highest ineffective dose, NR = not reported, + = positive, (+) = weakly positive, − = negative.

^a^ No studies reported testing with +S9.

Table E-4 In Vitro Studies of Other (Genotoxic-related) Effects of Cobalt Compounds in Mammalian Cells

Compound | Reference | Concentration (LED or HID) | Results (−S9)^a^ | Comments and Conclusions
Cell transformation/C3H10T1/2 mouse fibroblasts, Syrian hamster embryo cells (SHE), or BALB/3T3 cells
Cobalt chloride | Doran et al. (1998)* Ponti et al. (2009) | 5 μg/mL 70 μM | + − | Positive in C3H10T1/2 mouse fibroblast cells Negative in BALB/3T3 cells (72 hr exposure)
Cobalt sulfate monohydrate | Kerckaert et al. (1996)* | 0.125 μg/mL | + | Positive in SHE cells
Cobalt acetate | Casto et al. (1979)* | 0.2 mM (approx. 35.4 μg/mL) | + | Positive for cell transformation enhancement by simian adenovirus SA7/ SHE cells
Cobalt metal | Doran et al. (1998)* | 500 μg/mL | − | Negative in C3H10T1/2 mouse fibroblast cells, even at high exposure
Cobalt metal nanoparticles | Ponti et al. (2009) Sighinolfi et al. (2014) Annangi et al. (2014) | 7 μM 10 μM 0.05 μg/ml | + + + | Positive in BALB/3T3 cells (72 hr exposure) Positive in BALB/3T3 cells (72 hr exposure) Cell transformation in mouse embryo fibroblasts after 12-wk exposure to sub-toxic dose; Ogg1^+/+^ and Ogg1^-/-^ with knockout cells more sensitive
Cobalt sulfide (CoS, amorphous) Cobalt sulfide (CoS_2_, crystalline) | Abbracchio et al. (1982)* and Costa et al. (1982)* Abbracchio et al. (1982)* and Costa et al. (1982)* | 10 μg/mL 1 μg/mL | (+) + | Positive in Syrian hamster embryo cells Positive in Syrian hamster embryo cells

* As cited by IARC (2006).

LED/HID = lowest effective dose/highest ineffective dose; + = positive; (+) = weakly positive; − = negative.

^a^ No studies reported testing with +S9.

## E.4 Protein Binding and DNA Repair Inhibition by Cobalt Compounds

Protein binding and DNA repair inhibition due to exposure to several cobalt compounds (including cobalt chloride, cobalt sulfate, cobalt nitrate, cobalt acetate, cobalt metal, and cobalt nanoparticles) have been evaluated; the available studies are summarized in Table E-5 and discussed in Section 6.3 on potential mechanisms of carcinogenesis. Protein binding is important in the consideration of genotoxicity assay results for cobalt compounds because cobalt binding in vivo, e.g., to serum proteins, could render it less effective than when tested in vitro for the same endpoint.

## E.5 In Vivo Genotoxicity Studies of Cobalt Compounds in Rodents

Several studies tested different type of cobalt compounds, including a water-soluble salt (cobalt chloride), cobalt acetate, and cobalt metal for genotoxic effects in vivo. The available data suggests that cobalt compounds are clastogenic and can induce DNA and chromosomal damage, i.e., micronucleus formation, chromosomal aberrations, and aneuploidy, as shown by results reported for in vitro assays. The results of the in vivo studies are discussed below and summarized in Table E-6.

DNA damage was observed after i.p. exposure to cobalt acetate in the Fischer rat, with strongest results observed for cells from the kidney, liver, then lung (Kasprzak et al. 1994). In two studies, cobalt chloride exposure in vivo induced micronucleus formation in mouse bone marrow after i.p. injection (Rasgele et al. 2013; Suzuki et al. 1993) but results were negative in a third study of cobalt metal in murine peripheral blood lymphocytes after inhalation exposure (NTP 2014d). Route of exposure and tissue type varied between these studies; one or both of these factors may be the cause of the disparate results. Dose-dependent increases in chromosomal breaks and aberrations were reported in Swiss mouse bone marrow after oral exposure to a single dose of cobalt chloride in the test animals (Palit et al. 1991a; Palit et al. 1991b; 1991c; 1991d; as cited in WHO 2006). Aneuploidy was observed in hamster bone marrow and testes after i.p. injection of either cobalt chloride or cobalt chloride hexahydrate (Farah 1983).

Table E-5 Studies of Nucleic Acid and Protein Binding and DNA Damage/Repair Inhibition of Cobalt Compounds

Compound | Reference | Concentration (LED or HID) | Results (−S9)^a^ | Comments and Conclusions
Binding/crosslinks
Cobalt chloride | Wedrychowski et al. (1986)* Paleček et al. (1999)* | 130 μg/mL >13 μg/mL 78 μg/mL | + + (full) + | Positive for DNA-protein crosslinks/ in rat Novikoff ascites hepatoma cells Inhibition of p53 protein-DNA binding for consensus sequence and supercoiled DNA
Cobalt chloride hexahydrate | Sabbioni et al. (2014b) | 10 μM | + | Radiolabeled cobalt binding to DNA (4 hr exposure) much lower (0.0019 ng/10^6^ cells) than for microparticles or nanoparticles (see below)
Cobalt sulfate | Lloyd et al. (1998) | 20 μM | + | Salmon sperm DNA generative cross-links, induced single (not double) strand DNA damage
Cobalt metal ion | Bal et al. (2013) | NTS 110 μM A 90 μM B 11 μM | + | Cobalt binds to human serum albumin at three sites: N-terminal site (NTS), A and B; they had different affinities—site B was the strongest
Cobalt nanoparticles | Sabbioni et al. (2014b) | 10 μM | + | Radiolabeled cobalt binding to DNA (4 hr exposure) Binding 1.7 ng/10^6^ cells
Cobalt microparticles | Sabbioni et al. (2014b) | 10 μM | + | Radiolabeled cobalt binding to DNA (4 hr exposure) Binding 9.2 ng/10^6^ cells
Cobalt ions (see comments) | Alipázaga et al. (2008) | 1.0 mM | + | Cobalt binds to O_2_ in presence of glycylglycylhistidine, directly forming adducts; cobalt was prepared from cobalt carbonate reaction with perchloric acid
Inhibition of DNA repair
Cobalt chloride hexahydrate | Hartwig et al. (1991) and Kasten et al. (1997)* | 12 μg/mL (incision and polymerization step) 48 μg/mL (ligation step) | + − | Positive for Inhibition of nucleotide excision repair of UV-induced DNA damage, alkaline unwinding/ repair VH16 fibroblasts; data shown for Kasten et al. (1997) (same research group, subsequent publication)
Cobalt chloride hexahydrate | Kasten et al. (1997)* | 86 μg/mL (incision step) | + | Inhibition of UV-induced cyclobutane pyrimidine dimers, alkaline unwinding + T4 endonuclease V/VH16 fibroblasts
Cobalt (metal) | De Boeck et al. (1998)* | 1.2 μg/mL (with 5.5 μg/mL MMS post-treatment) 1.2 μg/mL (with 5.5 μg/mL MMS co-exposure) | + + | Positive for DNA repair inhibition, alkaline Comet assay/ human mononuclear leukocytes
Cobalt acetate | Snyder et al. (1989)* | 100 μg/mL | + | Inhibition of repair of UV-induced pyrimidine dimers, nucleoid sedimentation in HeLa S-3 cells
Inhibition/inactivation of protein
Cobalt chloride | Asmuss et al. (2000)* | 6.5 μg/mL (XPA) 130 μg/mL (Fpg) | + − | Positive for inhibition of xeroderma pigmentosum group A (XPA) protein (with Zn finger domain) binding to UV-irradiated oligonucleotide [XPA is a zinc finger protein involved in nucleotide excision repair, but no effect on bacterial Fpg protein (Zn finger domain)]
Cobalt nitrate hexahydrate | Kopera et al. (2004) | 10 μM | + | Reported substitution for zinc in the zinc finger derived from the DNA report protein XPA

* As cited by IARC (2006).

LED/HID = lowest effective dose/highest ineffective dose, NR = not reported, + = positive, − = negative.

^a^ No studies reported testing with +S9.

Table E-6 In Vivo Genotoxicity Studies of Cobalt Compounds in Rodents

Compound | Species/Sex/# | Reference | Exposure | Results | Comments and Conclusions
DNA damage
Cobalt acetate | F344/CR rat male and female/12 per group | Kasprzak et al. (1994) | i.p. one dose 50 or 100 μmol 2 or 10 d | Kidney + Liver + Lung + | Damage in kidney > liver > lung cells; retention of cobalt in kidney and liver, less in lung
Micronucleus formation/peripheral blood lymphocytes
Cobalt metal | B6C3F1/N mouse/male and female | NTP (2014a) | Inhalation 3 months 10 mg/m^3^ | − | Negative for micronuclei induction in peripheral blood lymphocytes
Micronucleus formation/bone marrow
Cobalt chloride | Swiss albino mouse/male/5 per group | Rasgele et al. (2013) | i.p. 24 hr 22.5 mg/kg 48 hr 11.2 mg/kg | + + | Significant increase in micronucleated polychromatic erythrocytes; no toxicity observed; distilled water control
Cobalt chloride hexahydrate | BALB/c AnNCrj mouse/male | Suzuki et al. (1993)* | i.p. 50 mg/kg bw | +; also enhanced formation with other mutagens | Micronuclei enhanced, compared with other mutagens used (20 mg/kg DMH, 50 mg/kg benzo(a)pyrene, and 200 mg/kg 2-napthylamine)
Chromosomal breaks and chromosomal aberrations (bone marrow)
Cobalt chloride | Swiss mouse/male | Palit et al. (1991a; 1991b; 1991c; 1991d)** | Oral Single dose 4.96 to 19.8 mg/kg | + | Dose response increase in chromosomal damage
Aneuploidy, pseudodiploidy, and hyperploidy/bone marrow and testes (meiosis 1)
Cobalt chloride | Hamster | Farah (1983)* | i.p. 400 mg/kg bw total dose | + (bone marrow and testes) | Exposure is total dose over 9 days
Cobalt chloride hexahydrate | Hamster | Farah (1983)* | i.p. 400 mg/kg bw total dose | + (bone marrow and testes) | Exposure is total dose over 9 days

* As cited by IARC (2006), ** as cited by WHO (CICAD) (2006).

LED/HID = lowest effective dose/highest ineffective dose, NR = not reported, + = positive, − = negative.

## E.6 Genotoxicity Studies of Occupational Exposure to Cobalt

The available database for evaluating occupational exposure to cobalt and genetic effects is inadequate because of the paucity of studies, exposure to other genotoxic agents, or small numbers of exposed workers. Two studies reported by IARC are not reviewed because they were not specific for cobalt exposure and a more recent study of occupational exposure was identified; however, a study of Brazilian copper smelter workers is also not reviewed because blood cobalt levels were similar among unexposed controls (De Olivera et al. 2012). Two studies are reviewed below, only one of which is of cobalt workers (De Boeck et al. 2000); however, the second study is briefly reviewed (Hengstler et al. 2003) because it conducted multivariate analyses (see Table E-7).

De Boeck et al. (2000) measured 8-hydroxydeoxyguanosine, DNA damage (comet assay), and micronuclei in lymphocytes from workers at cobalt refinery facilities in Belgium, Norway, and Finland, cobalt hard workers, and unexposed controls from the same plants. All genetic markers were similar between the cobalt-exposed workers and non-exposed workers. Limitations of the study were small numbers of workers and the measurement of damage at least 40 hours after exposure.

In the second study, DNA strand breaks were measured in 78 German workers producing or recycling cadmium or cadmium products. In analysis considering only exposure to single metals, DNA single-strand breaks correlated better with cobalt concentrations (measured in air and urine) than cadmium concentrations (air and blood). Logistic analysis evaluating all variables as well as interactions between metals found that the increases in DNA strand breaks were explained by cobalt (air), cadmium (air), cadmium (blood), and interaction between lead and cobalt in the air (Hengstler et al. 2003).

Table E-7 Genotoxicity Studies of Occupational Exposure to Cobalt

Endpoint | Population | Reference | Exposure Assessment | | Results | Comments and Conclusions
DNA damage Cobalt in air and urine | Workers in 10 facilities producing or recycling cadmium or its products in Germany (N = 78; 62 men and 16 women) | Hengstler et al. (2003) | Cobalt meas in air (range): 0–10 μg/m^3^ Cobalt in urine – to air Cobalt in urine – to air (normalized to creatinine) | + R = 0.453 p = 0.000 R = 0.504 p = 0.000 | | Co-exposures to cadmium and lead contribute to DNA strand breaks in logistic regression models. DNA single strand breaks correlated with cobalt conc in air (p < 0.001, R = 0.401).
DNA damage 8-Hydroxy- deoxyguanosine (8-OHdG) Micronuclei | Refinery workers (three facilities—in Belgium, Norway, and Finland) exposed to cobalt (analysis = 24); workers exposed to hard metal plants in one plant (analysis = 29) and unexposed workers from the four facilitates (analysis = 27) Workers and exposed workers from one plant were excluded from the analysis because of older population and higher 8-OHdG | De Boeck et al. (2000) | Cobalt in urine (μg cobalt per gram creatinine) Level (SD; range): Controls: 1.7 (1.6; 0.6–5.5) Exposed: 21.5 (2.1 (5.0–82.5) | − (all three endpoints) | | Negative for DNA damage measured in lymphocytes—comet assay; cobalt levels were measured in urine Exposure equivalent to 20 μg/m^3^ of cobalt in air Exposure assessment from samples on Friday, and genetic damage assessed from samples the following Monday

R = correlation coefficient.

## E.7 Cell Transformation

Cobalt compounds caused cellular transformation, which may be related to genotoxicity but is not a genotoxic effect per se (see Table E-8). The Syrian hamster embryo (SHE) transformation assay identifies non-genotoxic carcinogens with 80% to 90% accuracy and detection for genotoxic carcinogens is even higher (Benigni et al. 2015). Cell-transformation assays in SHE and other cell lines were positive for three soluble cobalt compounds (cobalt chloride, cobalt sulfate monohydrate, and cobalt acetate) (Casto et al. 1979; Doran et al. 1998; Kerckaert et al. 1996; Ponti et al. 2009), cobalt nanoparticles (Annangi et al. 2014; Ponti et al. 2009; Sighinolfi et al. 2014), cobalt microparticles (Sabbioni et al. 2014a), and cobalt sulfide (Abbracchio et al. 1982; Costa et al. 1982), but negative for cobalt metal (Doran et al. 1998).

Table E-8 In Vitro Studies of Other (Genotoxic-related) Effects of Cobalt Compounds in Mammalian Cells

Compound | Reference | Concentration (LED or HID) | Results (−S9)^a^ | Comments and Conclusions
Cell transformation/C3H10T1/2 mouse fibroblasts, Syrian hamster embryo cells (SHE), BALB/3T3 cells
Cobalt chloride | Doran et al. (1998)* Ponti et al. (2009) | 5 μg/mL 70 μM | + − | Positive in C3H10T1/2 mouse fibroblast cells Negative in BALB/3T3 cells (72 hr exposure)
Cobalt sulfate monohydrate | Kerckaert et al. (1996)* | 0.125 μg/mL | + | Positive in SHE cells
Cobalt acetate | Casto et al. (1979)* | 0.2 mM (approx. 35.4 μg/mL) | + | Positive for cell transformation enhancement by simian adenovirus SA7/ SHE cells
Cobalt metal | Doran et al. (1998)* | 500 μg/mL | − | Negative in C3H10T1/2 mouse fibroblast cells, even at high exposure
Cobalt nanoparticles | Ponti et al. (2009) Sabbioni et al. (2014a) Sighinolfi et al. (2014) Annangi et al. (2014) | 7 μM 5 μM 10 μM 0.05 μg/ml | + + + + | Positive in BALB/3T3 cells (72 hr exposure) Positive in BALB/3T3 cells (72 hr exposure) Positive in BALB/3T3 cells (72 hr exposure) Cell transformation, mouse embryo fibroblasts, 12-wk exposure to sub-toxic dose; Ogg1^+/+^ and Ogg1^-/-^ with knockout cells more sensitive
Cobalt microparticles | Sabbioni et al. (2014a) | 1 μM | + | Positive in BALB/3T3 cells (72 hr exposure)
Cobalt sulfide (CoS, amorphous) Cobalt sulfide (CoS_2_, crystalline) | Abbracchio et al. (1982)* and Costa et al. (1982)* Abbracchio et al. (1982)* and Costa et al. (1982)* | 10 μg/mL 1 μg/mL | (+) + | Positive in Syrian hamster embryo cells Positive in Syrian hamster embryo cells

* As cited by IARC (2006).

LED/HID = lowest effective dose/highest ineffective dose; NR = not reported; + = positive; (+) = weakly positive; − = negative.

^a^ No studies reported testing with +S9.