# Appendix D Cancer Studies in Experimental Animals

## D.1 Study Quality

### D.1.1 Evaluation Methods

Each primary study was systematically evaluated for its ability to inform the cancer hazard evaluation using a series of signaling questions related to the following study performance elements: population, exposure conditions, outcome assessment, potential confounding, and statistics and reporting (see NTP 2014b). The response for answering the signaling question of whether there is a potential bias or limitation is based on a comparison of the study element with that of the “ideal” study for a specific endpoint and exposure to the candidate substance. Guidelines for the ideal study are provided in the protocol. Two reviewers evaluated each study and differences were resolved by reference to the original publication and consultation with a third reviewer.

### D.1.2 Study Quality and Sensitivity Questions and Responses

The following questions were used to evaluate study quality and sensitivity; the questions are grouped according to the study performance element. A short description (typically one to two words) of the questions is provided in the study quality tables in Section D.2 (e.g., controls for the question on concurrent controls below).

#### D.1.2.1 Population (Selection of Study Animals)

- Are there concerns that the concurrent control group was not adequate for evaluating the study?
- Are historical control data reported?
- Are there concerns that the study design did not include randomization of animals to dose groups or take appropriate steps to ensure that dose groups are identical except for dosing status?

#### D.1.2.2 Quality of the Exposure

- Are there concerns that the chemical characterization and dose formulations (e.g., confirmation, homogeneity, purity, solubility, and stability) and delivery of the chemical (actual vs. desired dose) are not adequate for attributing any neoplastic effects to the substance?
- Are there concerns that the dosing regimen (dose selection and dose groups, or other factors) or the exposure duration are either not (1) adequate for detecting a neoplastic effect or (2) for attributing any tumor effects to the substance?
- Are there concerns that survival or body weight change(s) over time for treatment and/or control groups could affect attributing the study findings to the exposure?

#### D.1.2.3 Quality of the Endpoint Assessment

- Are there concerns that the methods to assess tumor outcome and the pathology procedures (necropsy, histology, or diagnosis) are not adequate for attributing the effects to the exposure?

#### D.1.2.4 Potential for Confounding

- Are there concerns about the potential for confounding?

#### D.1.2.5 Analysis and Reporting

- Are there concerns that reporting of the data and statistical analysis are inadequate for evaluating the results? Are there concerns that different types of tumors are not accurately combined in the analysis?

#### D.1.2.6 Sensitivity

- Are there concerns about the animal model (source, species, strain, or sex) that could affect study interpretation?
- Are there concerns that the study does not have adequate statistical power (number of animals per exposure and control group) to detect a neoplastic effect, if present? Are there concerns that survival-related effects or high mortality due to poor husbandry conditions have decreased statistical power?
- Are there concerns that the study duration (observation period) is not adequate to detect a neoplastic effect, if present?

For each question, the following terms were used to rate the potential for bias and/or quality:

- Minimal concerns: Information from study designs and methodologies indicate that they are close to the ideal study characteristics and that the potential for bias is unlikely or minimal (+++).
- Some concerns: Study designs or methodologies are less than ideal, indicating possible bias (++).
- Major concerns: Study designs or methodologies suggest that the potential for a specific type of bias is likely (+).
- Inadequate: Study designs or methodologies suggest that the bias is critical and would make the study not informative for cancer hazard evaluation.
- No information: The information is inadequate to evaluate the level of concern.

## D.2 Overall Assessment of Study Utility

An overall assessment of study utility is based on consideration of both the potential for bias (i.e., limitations) and consideration of study sensitivity, and the studies are broadly grouped into the four categories below. Studies having critical concerns for important issues will generally be considered to be inadequate to inform the evaluation. It should also be noted that some concerns about a study element (such as inadequate observation and/or exposure period and statistical power) would decrease the sensitivity of a study to detect an effect; however, if despite these limitations positive findings were described, these studies would inform a cancer assessment. Some studies, such as co-carcinogen studies, have less utility for determining whether a substance is a cancer hazard but may provide utility regarding mechanism of action or other issues and thus utility would be rated based on the purpose of the study.

- High (low/minimal concerns for most potential biases)
- Moderate (low/minimal or some concerns for most potential biases)
- Low (major concerns for several potential biases)
- Inadequate (critical concerns for some potential bias)

## D.3 Study Quality Assessment and Study Quality Tables: Carcinogenicity Studies

The following tables contain the study quality assessment (rating and rationale for the rating) for each study. The studies are organized by study type, and then by metal type or compound, followed by route of exposure. For summary tables of study quality across all studies, see Table 5-2 (carcinogenicity) and Table D-24 (co-carcinogenicity).

Table D-1 NTP (2014d) (Rats): Cobalt Metal/Powder; Inhalation

Study Utility Domain Question | Rating Rationale
Selection of animals
Controls | +++ Concurrent controls were used.
Historical data | Yes Historical controls were reported.
Randomization | +++ Random allocation was done.
Exposure
Chemical purity | +++ The cobalt was 98% pure and tested for stability.
Dosing regimen | +++ Dose levels were based on the 3-month studies, and three dose levels were tested.
Survival | ++ A significant decrease in survival of females and significant decrease in body weight of both sexes was reported.
Pathology | +++ Full necropsies were performed and a quality assurance program was in place to verify the histopathological evaluations.
Confounding | +++ Little to no sources of confounding. Animal husbandry and disease surveillance were well conducted and chemical purity was tested by a third party.
Reporting and analysis | +++ Full details were reported.
Sensitivity
Animal model | +++ Both sexes of non-transgenic rats were used.
Statistical power | +++ Large number of animals used.
Study duration | +++ Near lifespan duration of 2 years was used. Although survival rates were low in both control and exposed groups at the end of the study, survival did not decline after ~80 weeks and there was ≥90% probability of survival at 75 weeks. Thus, there is minimal concern that the low survival rates at the end of the study limited the sensitivity to observed treatment-related cancer effects.

Overall utility: High

A well-designed study in all factors, but with a significant decrease in survival of female rats.

Table D-2 NTP (2014d) (Mice): Cobalt Metal/Powder; Inhalation

Study Utility Domain Question | Rating Rationale
Selection of animals
Controls | +++ Concurrent controls were used.
Historical data | Yes Historical controls were reported.
Randomization | +++ Random allocation was done.
Exposure
Chemical purity | +++ The cobalt was 98% pure and tested for stability.
Dosing regimen | +++ Dose levels were based on the 3-month studies, and three dose levels were tested.
Survival | ++ A significant decrease in survival of males and significant decrease in body weight of both sexes was seen.
Pathology | +++ Full necropsies were performed and a quality assurance program is in place to verify the histopathological evaluations.
Confounding | +++ Few to no sources of confounding. Animal husbandry and disease surveillance were well conducted and chemical purity was tested by a third party.
Reporting and analysis | +++ Full details were reported.
Sensitivity
Animal model | +++ Both sexes of non-transgenic mice were tested.
Statistical power | +++ Large number of animals used.
Study duration | +++ Near lifespan duration of 2 years was used.

Overall utility: High

A well-designed study in all factors, but with a significant decrease in survival of male mice.

Table D-3 Hansen et al. (2006): Cobalt Metal/Powder; Injection

Study Utility Domain Question | Rating Rationale
Selection of animals
Controls | +++ Untreated controls were not included but PVC particles, which are assumed to be inert, were used.
Historical data | No No historical controls were available.
Randomization | NR No information about randomization was provided.
Exposure
Chemical purity | NR No information on the chemical purity was reported, only information on the particle size of the bulk metal and the surface to mass ratios of the bulk metal and nanoparticles.
Dosing regimen | ++ Only a single dose and single dose level was given, but the dose level was not reported. Particles were reported to cover a specific area of tissue; continuous exposure to cobalt nanoparticles.
Survival | +++ Survival was lower than PVC controls after 8 months, but it was due to moribund tumor growth.
Pathology | +++ Complete necropsies were performed.
Confounding | ++ Details of animal husbandry were not reported and neither was chemical purity; however, it was stated that animals were looked after in accordance with European standard requirements and that animals were observed daily for clinical abnormalities. The negative controls underwent the same procedures of implanting particles.
Reporting and analysis | ++ Neither the chemical purity, dose level, age of rats, nor statistical analysis were reported.
Sensitivity
Animal model | ++ Only male rats were tested, so sex differences can't be determined.
Statistical power | + Few animals per group were tested. Two time points were used to sacrifice animals, which reduced the effective number of animals at each sacrifice and for each reported incidence, thus lowering the statistical power of each individual time point.
Study duration | + Treated animals were sacrified at 6 and 8 months; animal sacrificed at 8 rather than 12 months because of tumor growth from expousre to cobalt nanoparticles. Controls were sacrificed at 6 and 12 months. Duration may not be adquate for evaluating cobalt metal.

Overall utility: Moderate

The longest duration of observation was 8 months (due to tumors induced by cobalt nanoparticles) and two forms of cobalt metal were tested in the same individual rat, bulk metal particles and nanoparticles. Duration may not be adequate for evaluating cobalt metal. Complete necropsies were performed. Inert polyvinyl chloride particles were used as a negative control. Only a small number of males were tested with a single dose level, though dose was never fully reported. Poor reporting of chemical purity and animal husbandry.

Table D-4 Jasmin and Riopelle (1976): Cobalt Sulfide or Cobalt Metal; Injection

Study Utility Domain Question | Rating Rationale
Selection of animals
Controls | +++ Concurrent vehicle controls were used.
Historical data | No No historical controls were used.
Randomization | NR No information about randomization was provided.
Exposure
Chemical purity | ++ The chemical purity was reported as “reagent grade.”
Dosing regimen | + Only a single dose was given at one dose level without a reported basis for that level. Dose was lower than that used in other injection studies.
Survival | NR No survival information was reported.
Pathology | ++ The level of necropsy was not full: in addition to the kidney, study looked for metastases in the abdomen and thorax, but not the entire body.
Confounding | ++ No information about animal husbandry, including disease surveillance, was reported and chemical purity was only reported as “reagent grade.”
Reporting and analysis | ++ Details were not reported for animal husbandry or disease surveillance and chemical purity reported was limited as it was reported as “reagent grade.” Surival information was not reported and number of animals at sacrifice is unclear.
Sensitivity
Animal model | ++ Only non-transgenic female rats were tested.
Statistical power | ++ A moderate number of animals per group were used and survival was not reported.
Study duration | + 12 months.

Overall utility: Low

A moderate number of rats per group was used; however, sensitivity was limited by short observation period, use of only a single dose level, which was lower than that used in other studies and and testing in only females. No information on animal husbandry, including disease surveillance; chemical purity or stability, and number of animals at sacrifice were poorly reported. Full necropsies were not performed, though the abdominal and thoracic cavities were examined.

Table D-5 Heath and Daniel (1962): Cobalt Metal/Powder; Injection

Study Utility Domain Question | Rating Rationale
Selection of animals
Controls | + There was no concurrent control, but there was a historical control from Heath 1954, which was cited in the paper as the reason for not having a concurrent control.
Historical data | Yes (limited) Controls from an earlier studies were used in place of concurrent controls.
Randomization | NR No information about randomization was provided.
Exposure
Chemical purity | ++ Only stated as “spectroscopically pure.”
Dosing regimen | + Only one dose was given at one dose level and the number of injections was not reported but assumed to be single injection. Rationale for dose not provided.
Survival | NR Unable to determine if there were treatment-related survial effects since survival of controls from the 1956 study was not reported. Survival in exposed group was low, with 8 out of 20 rats dying only days after the injection; however, survival was good after initial deaths; deaths may have been due to technical difficulties with the intrapleural injections.
Pathology | ++ Only looked at the injection site; full necropsies were not reported.
Confounding | ++ No information regarding animal husbandry conditions and disease surveillance were reported, but chemical purity was reported as “spectroscopically” pure.
Reporting and analysis | + No animal husbandry or necropsy methods were reported and chemical purity was reported only as “spectroscopically pure.”
Sensitivity
Animal model | ++ Only non-transgenic female rats were tested.
Statistical power | + Small numbers of animals. Survival was low due to deaths caused within the first 3 days from difficulties with the intrapleural injection.
Study duration | +++ 28 months.

Overall utility: Low

The duration of observation was over two years long, but exposure was only a single dose. There was no concurrent control, but there was a historical control. No statistics were done, a low number of animals was used, and necropsies were not done; only skin tumors were histologically examined. No information was reported about chemical purity or stability, or animal husbandry.

Table D-6 Heath (1956): Cobalt Metal/Powder; Injection

Study Utility Domain Question | Rating Rationale
Selection of animals
Controls | ++ Untreated controls were used in the first series of experiments, but not in the second series; however, untreated controls from the first series could be used as historical or non-concurrent controls for the second series of studies. The survival of untreated controls was not reported.
Historical data | Yes (limited) The untreated controls from the first series of studies was used as a historical control for the second series of studies.
Randomization | NR No information about randomization was reported.
Exposure
Chemical purity | ++ Purity was reported as “spectroscopically pure.”
Dosing regimen | + Only one dose level was used with no explanation as to why that level was chosen. The duration of treatment was not reported, but was assumed to be a single dose.
Survival | NR No data reported for untreated controls; two of 10 males, 4 of 10 females (Series I) and 0/10 females (Series II) without tumors died before sacrificed.
Pathology | ++ No methods reported, but it was stated that no other tumors besides local tumors were found, though a metastasis to the lymph nodes were found, suggesting necropsies were performed, but the extent of the necropsies is not known.
Confounding | ++ No information regarding animal husbandry conditions and disease surveillance were reported, but chemical purity was reported as “spectroscopically” pure.
Reporting and analysis | + No reporting of animal husbandry, disease surveillance, randomization, treatment duration, necropsy methods, or survival for untreated controls.
Sensitivity
Animal model | ++ Both male and female rats were used in the first series of studies, but only females were tested in the second series.
Statistical power | + Small numbers of animals were tested.
Study duration | +++ Duration of observation was near the animals’ expected lifespan.

Overall utility: Low

Observation duration was sufficient and both sexes were tested. However, there was no reporting of animal husbandry, necropsy methods, or chemical stability. Only one dose level was tested, and a small number of male and female rats was used. Full necropsies were not reported to have been performed.

Table D-7 NTP (1998) (Rats): Cobalt Sulfate; Inhalation

Study Utility Domain Question | Rating Rationale
Selection of animals
Controls | +++ Concurrent controls were used.
Historical data | Yes Historical controls were reported.
Randomization | +++ Random allocation was done.
Exposure
Chemical purity | +++ The cobalt was 99% pure and tested for stability.
Dosing regimen | +++ Dose levels were based on 16-day and 13-week studies, and three dose levels were tested.
Survival | +++ Survival was high and not affected by cobalt exposure.
Pathology | +++ Full necropsies were performed and a quality assurance program was in place to verify the histopathological evaluations.
Confounding | +++ Little to no sources of confounding. Animal husbandry and disease surveillance were well conducted and chemical purity was tested by a third party.
Reporting and analysis | +++ Full details were reported.
Sensitivity
Animal model | +++ Both sexes of non-transgenic rats were used.
Statistical power | +++ Large number of animals used.
Study duration | +++ Near lifespan duration of 2 years was used.

Overall utility: High

A well-designed study in all factors and survival was similar to controls.

Table D-8 NTP (1998) (Mice): Cobalt Sulfate; Inhalation

Study Utility Domain Question | Rating Rationale
Selection of animals
Controls | +++ Concurrent controls were used.
Historical data | Yes Historical controls were reported.
Randomization | +++ Random allocation was done.
Exposure
Chemical purity | +++ The cobalt was 99% pure and tested for stability.
Dosing regimen | +++ Dose levels were based on 16-day and 13-week studies, and three dose levels were tested.
Survival | +++ Survival was high and not affected by cobalt exposure.
Pathology | +++ Full necropsies were performed and a quality assurence program is in place to verify the histopathological evaluations.
Confounding | +++ Little to no sources of confounding. Animal husbandry and disease survalence were well-conducted and chemical purity was tested by a third party.
Reporting and analysis | +++ Full details were reported.
Sensitivity
Animal model | +++ Both sexes of non-transgenic mice were tested.
Statistical power | +++ Large number of animals used.
Study duration | +++ Near lifespan duration of 2 years was used.

Overall utility: High

A well-designed study in all factors and survival was similar to controls.

Table D-9 Shabaan et al. (1977): Cobalt Chloride; Injection

Study Utility Domain Question | Rating Rationale
Selection of animals
Controls | ++ Untreated controls were not reported for the 8-month study, but were for the 12-month study and could be used for the 8-month study as a non-concurrent control.
Historical data | Yes (limited) There were untreated controls that were sacrificed at the 12-month time point that could serve as non-concurrent or historical controls for the 8-month study. Fewer neoplasms would be expected at 8 months than at 12 months and no neoplasms were found at 12 months, so using 12-month untreated controls seems justified.
Randomization | NR No information about randomization was provided.
Exposure
Chemical purity | NR No information about chemical purity, stability, or homogeneity was provided.
Dosing regimen | + Only one dose tested and no basis given for choosing that level. Animals were treated 19 days. Treated animals developed persisent hyperlipaemia
Survival | ++ Mortality of exposed rats was high compared to controls; 11/20 survived at 12 months and 16/20 survived at 8 months
Pathology | + Only survivors were necropsied; those that died before 8 months or 12 months were not examined.
Confounding | + No information about chemical purity or disease surveillance was reported and animal husbandry was poorly reported.
Reporting and analysis | + Untreated controls were not clearly reported, neither was animal husbandry. Chemical purity and the rationale for the single dose level used was not reported. Statistics were not calculated. The route of exposure was reported as s.c. injection, but the tumors developed in sites outside of the reported injection sites (central abdominal wall) and the authors didn't differentiate which sites were injection sites and which were non-injection sites.
Sensitivity
Animal model | ++ Only male non-transgenic rats were tested.
Statistical power | ++ A reasonable number of animals tested, but there was a significant decrease in survival of the exposed rats.
Study duration | + 8 months (experiment 1) or 12 months (experiment 2). The 8-month study would not normally meet inclusion criteria, but since tumors were induced it was included.

Overall utility: Low

Exposure was only for 19 days and animals that did not survive to the end of the experiments were not necropsied and there was a significant decrease in survival of exposed rats, so the studies may underestimate the true results. Only a single injection was given to male rats; females were not tested. The tumors and injection sites were not clearly reported and tumor sites were not designated as injection site or non-injection sites.

Table D-10 Steinhoff and Mohr (1991): Cobalt Oxide; Intratracheal

Study Utility Domain Question | Rating Rationale
Selection of animals
Controls | +++ Concurrent controls were used.
Historical data | No No historical controls were available.
Randomization | NR No information about randomization was provided.
Exposure
Chemical purity | ++ The method of manufacture of the cobalt was reported, but the purity was only stated at “chemically pure.” Dose levels were randomly verified by gravimetric measurements taken several times during the study.
Dosing regimen | ++ Two dose levels were given every 2 or 4 weeks for close to 2 years (39 doses).
Survival | ++ Data are not provided, but it was stated in the results that there were “no appreciable differences.”
Pathology | ++ Only the high-dose group was fully necropsied. Histological examinations were done on organs with gross lesions suspected of having tumors and all respiratory tracts in the low-dose group or controls.
Confounding | ++ The method of manufacture of the cobalt was reported, but the purity was only stated at “chemically pure.” Animal husbandry was described, but disease surveillance was not reported.
Reporting and analysis | ++ Methods were poorly reported and lacked details about the chemical purity, animal husbandry, and rationale for selecting the dose level. Survival was not reported.
Sensitivity
Animal model | +++ Both sexes of non-transgenic rats were used.
Statistical power | +++ Large number of animals were used; survival was reported as similar to controls.
Study duration | +++ Observation duration was for lifespan.

Overall utility: Moderate

Two dose levels were tested in a high number of both sexes of rats for two years, with treatment and observations for the lifespan without any significant difference in survival compared to untreated controls. However, only the high-dose group received full necropsies. Details of the chemical and animal husbandry were not reported.

Table D-11 Steinhoff and Mohr (1991): Cobalt Oxide; Injection (IP)

Study Utility Domain Question | Rating Rationale
Selection of animals
Controls | +++ Concurrent controls were used.
Historical data | No No historical controls were available.
Randomization | NR No information about randomization was provided.
Exposure
Chemical purity | ++ The method of manufacture of the cobalt was reported, but the purity was only stated as “chemically pure.”
Dosing regimen | + One dose level was given every 2 months for 6 months with no explanation as to what the dose level was based on.
Survival | NR No survival information was reported.
Pathology | ++ All organs and tissues suspected of having tumors and all tumors in the injection region were evaluated by histological examination.
Confounding | ++ The method of manufacture of the cobalt was reported, but the purity was only stated as “chemically pure.” Animal husbandry was described, but disease surveillance was not reported.
Reporting and analysis | ++ Methods were poorly reported and lacked details about the chemical purity, animal husbandry, and rationale for selecting the dose level. Survival was not reported.
Sensitivity
Animal model | +++ Both sexes of non-transgenic rats were used.
Statistical power | + There were only 10 animals per sex per group tested and survival was not reported.
Study duration | +++ Observation duration was for lifespan.

Overall utility: Moderate

Both sexes of rats were tested with a long duration of observation. However, reporting of animal husbandry, including disease surveillance and chemical purity was poor and survival was not reported. There was a small number of animals per group, only one dose level was tested, exposure was for less than one year and histological examination was only done on organs with gross tumors, all of which would limit the sensitivity to detect an effect.

Table D-12 Steinhoff and Mohr (1991): Cobalt Oxide; Injection (SC)

Study Utility Domain Question | Rating Rationale
Selection of animals
Controls | +++ Concurrent controls were used.
Historical data | No No historical controls were used.
Randomization | NR No information about randomization was provided.
Exposure
Chemical purity | ++ The method of manufacture of the cobalt was reported, but the purity was only stated as “chemically pure.”
Dosing regimen | ++ Only a single dose level was tested, but it was given at two intensities, either weekly or daily (1/5 the level) for 2 years. There was no reported basis for that dose level.
Survival | NR No survival information was reported.
Pathology | ++ All organs and tissues suspected of having tumors and all tumors in the injection region were evaluated by histological examination.
Confounding | ++ The method of manufacture of the cobalt was reported, but the purity was only stated at “chemically pure.” Animal husbandry was described, but disease surveillance was not reported.
Reporting and analysis | ++ Methods were poorly reported and lacked details about the chemical purity, animal husbandry, and rationale for selecting the dose level. Survival was not reported.
Sensitivity
Animal model | ++ Only male rats were tested.
Statistical power | + There were only 10 animals per group and survival was not reported.
Study duration | +++ Observation duration was for lifespan.

Overall utility: Moderate

Duration of exposure and observation were sufficient; one dose level was tested, but it was tested at two intensity levels. However, few animals per group were used and only included males; histological exam was only done on organs with gross tumors, which would limit the senstivity to detect an effect. Reporting of animal husbandry, including disease surveillance, and chemical purity were poor and no survival data was provided.

Table D-13 Gilman and Ruckerbauer (1962) (Rats): Cobalt Oxide; Injection

Study Utility Domain Question | Rating Rationale
Selection of animals
Controls | +++ Concurrent controls (vehicle-aqueous suspension of pencillin G procaine) were used.
Historical data | No No historical controls were available.
Randomization | NR No information about randomization was provided.
Exposure
Chemical purity | + No information provided on chemical purity, stability, or homogeneity, other than that the test material was “washed” to remove water soluble impurities and was <5 μm particle size. Cobalt was administered in an aqueous suspension of pencillin G procaine.
Dosing regimen | + Only a single dose given at one dose level, but preliminary tests using unwashed unwashed particles, which contained an unknown water-soluble toxin that had killed many mice. Rats tolerated dose.
Survival | ++ No survival-related effects at 90 days, only time period reported.
Pathology | ++ Necropsy was not reported, but metastasis was reported, suggesting that necropsies were done.
Confounding | + Animals and bedding periodically dusted with rotenone powder; not clear if the same rats were used from the preliminary experiment using unwashed cobalt.
Reporting and analysis | + Methods were poorly reported and lacked chemical purity or stability, animal husbandry, necropsy methods, or statistical analysis. Tumor incidences were reported as both sexes combined.
Sensitivity
Animal model | +++ Both sexes of non-transgenic rats were used.
Statistical power | + Only 10 animals were tested and they were reported as both sexes combined.
Study duration | ++ 1.3 years.

Overall utility: Low

The duration of observation was sufficient and both sexes were tested. However, only a single dose was given at one dose level with results reported as both sexes combined; few animals per group were tested. Reporting was poor and lacked information on chemical purity or stability, animal husbandry, and necropsy methods. Animal bedding was periodically dusted with rotenone powder and half of the exposed group had been administered unwashed cobalt, which was known to contain additional chemicals.

Table D-14 Gilman and Ruckerbauer (1962) (Mice): Cobalt Oxide; Injection

Study Utility Domain Question | Rating Rationale
Selection of animals
Controls | +++ Concurrent controls (vehicle-aqueuous suspension of pencillin G procaine) were used.
Historical data | No No historical controls were available.
Randomization | NR No information about randomization was provided.
Exposure
Chemical purity | + No information provided on chemical purity, stability, or homogeneity, other than that the test material was “washed” to remove water soluble impurities and was <5 μm particle size. Cobalt was administered in an aqueous suspension in pencillin G procaine.
Dosing regimen | + Only a single dose given at one dose level, but preliminary tests using unwashed particles, which contained an unknown water-soluble toxin that had killed many animals, was reported. Half the animals died in this study between 2nd and 6th day.
Survival | ++ No treatment-related survival effects at 90 days, only time period reported.
Pathology | ++ Necropsy was not reported, but metastasis was reported, suggesting that necropsies were done.
Confounding | + Animals and bedding periodically dusted with rotenone powder. Half of the animals were given washed particles and the other half were survivors of animals given unwashed particles in a preliminary experiment, which contained an unknown water-soluble toxin that had killed many animals.
Reporting and analysis | ++ Methods were poorly reported and lacked chemical purity or stability, animal husbandry, necropsy methods, or statistical analysis.
Sensitivity
Animal model | ++ Only non-transgenic female mice were tested.
Statistical power | ++ A large number of animals were tested; however, survival was only reported for 90 days.
Study duration | +++ 2 years.

Overall utility: Low

The duration of observation and the numbers of animals per group were sufficient. Survival was only reported for 90 days. However, only a single dose was given (without rationale for level), to females only; half of them received unwashed cobalt, which was known to contain other chemicals. Reporting was poor and lacked chemical purity or stability, animal husbandry, and necropsy methods, though metastasis was reported suggesting necropsies were performed. Bedding was periodically dusted with rotenone powder.

Table D-15 Wehner et al. (1977): Cobalt Oxide; Inhalation

Study Utility Domain Question | Rating Rationale
Selection of animals
Controls | +++ Concurrent untreated controls (sham-smoked) were used.
Historical data | No No historical controls were available.
Randomization | NR No information about randomization was provided.
Exposure
Chemical purity | ++ There was no information on chemical purity or stability of the cobalt.
Dosing regimen | ++ Single dose level with no justification for choosing that level, but administered for life.
Survival | +++ Cobalt had no significant effect on survival or body weight compared to untreated controls although surival was low in both groups.
Pathology | +++ Detailed necropsies were performed.
Confounding | ++ Animal conditions were partly reported, but chemical purity and disease surveillance were not reported.
Reporting and analysis | + Methods were not fully reported with no information on disease surveillance or chemical purity. Tumor sites were not always defined. Tumor incidence reported as “carcinoma” or “polyp” without saying what tissue they originated from is meaningless.
Sensitivity
Animal model | ++ Only male hamsters were tested. Hamsters are less senstive for evaluating lung tumors.
Statistical power | + A large number of animals was used; however, statstical power was reduced by poor survival (fewer than 10 animals were alive at 18 months) in both cobalt-exposed and the corresponding control animals (IARC 1991).
Study duration | +++ Duration of treatment and observation was for the animals' lifespans.

Overall utility: Moderate

Duration of exposure and observation were sufficient. However, methods and results were not fully reported; chemical purity or stability, animal husbandry, and randomized allocation into groups were not reported as well as the tissue sites of the tumors. Full necropsies were reported. Only a single dose level was tested (with no justification for choosing that dose level) in a large number of male hamsters. There was relatively poor survival in both exposed and control groups.

### D.3.1 Study Quality Tables: Co-carcinogen Studies

Table D-16 Finogenova (1973): Cobalt Chloride; Injection

Study Utility Domain Question | Rating Rationale
Selection of animals
Controls | +++ Known carcinogen alone control, which is appropriate for a co-carcinogen study.
Historical data | No No historical controls were used.
Randomization | NR No information about randomization was provided.
Exposure
Chemical purity | NR No information about chemical purity, stability, or homogeneity was provided.
Dosing regimen | ++ Two dose levels (10-fold apart from each other) of cobalt were tested and were given twice a week for only 8 weeks, but this is a co-carcinogen study.
Survival | NR No survival information was reported.
Pathology | ++ Only local skin tumors were reported and described as to histologic grade. Full necropsies were not conducted. Because it's a co-carcinogen study and tumors from the known carcinogen are what is of interest and the types of induced tumors are already known or expected, lack of a full necropsy is less critical than for a carcinogenicity study.
Confounding | NR No information about chemical purity or animal husbandry, including disease surveillance, was reported.
Reporting and analysis | + Very poor reporting. There is no chemical purity, stability, or homogeneity reported and no information on animal husbandry disease surveillance, duration of observation, extent of necropsy, survival, or tumor incidence (only tumor latency was reported).
Sensitivity
Animal model | ++ Only females of non-transgenic mice were tested.
Statistical power | +++ Large number of animals used, but survival was not reported.
Study duration | ++ The duration of observation was unreported, but was at least 24 weeks, however, this is a co-carcinogen study.
Assay utility | + Co-Carcinogen study

Overall utility: Low

All co-carcinogenicity studies were categorically restricted to being ranked no higher than low utility to account for their indirect measure of carcinogenicity. A large number of female animals per group were given two dose levels. However, there was very poor reporting. Incidence was not reported, only tumor latency and onset were reported. Survival, chemical purity or stability, animal husbandry, duration of observation, and extent of necropsy were not reported.

Table D-17 Kasirsky et al. (1965): Cobalt Chloride; Injection

Study Utility Domain Question | Rating Rationale
Selection of animals
Controls | +++ Known carcinogen alone control, which is appropriate for a co-carcinogen study.
Historical data | No No historical controls were used.
Randomization | NR No information about randomization was provided.
Exposure
Chemical purity | NR No information about chemical purity, stability, or homogeneity was provided.
Dosing regimen | ++ A single dose level of the known carcinogen and four dose levels of cobalt chloride were given for about 10 weeks, though the exact duration of exposure was not clearly reported.
Survival | + Survival was only reported for three dose levels of cobalt chloride in the first trial, but not in any groups of the second trial or the carcinogen alone control of the first trial. The high cobalt chloride dose level of the first trial reported conflicting survival between Table 1 and the summary at the end of the paper.
Pathology | + No necropsies were performed, just measurment of tumor size by external examination and histological exam of excised tumors.
Confounding | ++ Very few details were reported about animal husbandry and no information was reported about chemical purity.
Reporting and analysis | ++ Results were not reported per sex and the duration was not clearly reported. Survival for all groups, chemical purity, and animal husbandry were not reported.
Sensitivity
Animal model | +++ Both sexes of non-transgenic mice were tested.
Statistical power | ++ Sufficient number of animals of each sex, but results were not reported as per sex. Survival was not clearly reported.
Study duration | ++ It was not clearly reported, but is thought to have been at least 72 days, though this is a co-carcinogen study.
Assay utility | + Co-carcinogen study

Overall utility: Low

All co-carcinogenicity studies were categorically restricted to being ranked no higher than low utility to account for their indirect measure of carcinogenicity. Neither duration, survival, chemical purity, stability or animal hubandry were clearly reported. Results were not reported per sex. A full necropsy was not conducted, so this study is only relevant to skin tumors induced by the carcinogen.

Table D-18 O’Hara et al. (1971): Cobalt Chloride; Injection

Study Utility Domain Question | Rating Rationale
Selection of animals
Controls | +++ There was no untreated group and no cobalt alone group, but it's similar to a co-carcinogen study and did have a known carcinogen alone group.
Historical data | No No historical controls were used.
Randomization | NR No information about randomization was provided.
Exposure
Chemical purity | NR No information about chemical purity, stability, or homogeneity was provided.
Dosing regimen | Inadequate Cobalt was administered after tumors had already started to develop; this is more like a tumor treatment study. Only two very similar dose levels were tested: 50 and 60 mg/kg.
Survival | +++ The high dose level caused an increase in mortality, however low survival was caused by tumors. Statistical analysis was not done on survival.
Pathology | ++ No full necropsies were reported; only local skin tumors were reported.
Confounding | ++ Very few details reported about animal husbandry and no information reported about chemical characteristics.
Reporting and analysis | ++ Chemical purity or stability or disease surveillance methods were not reported and animal husbandry conditions were poorly reported.
Sensitivity
Animal model | +++ Both sexes of non-transgenic mice were tested.
Statistical power | +++ The high-dose level group had a decrease in survival, but statistics were not calculated for survival and the low survival was caused by tumors.
Study duration | ++ 17 weeks, but this is a co-carcinogen study and neoplasms were induced before cobalt exposure started.
Assay utility | Inadequate Co-carcinogen study

Overall utility: Inadequate

This study has little utility for evaluation because the cobalt was not administered until after tumors had developed. No necropsies were performed; it only looked at local tumors. Only two, closely spaced dose levels were tested. A good number of mice per group was used. Chemical purity or stability and animal husbandry or disease surveillance were not reported. All co-carcinogen studies were categorically restricted to being ranked no higher than low utility to account for their indirect measure of carcinogenicity.

Table D-19 Zeller (1975): Cobalt Chloride; Injection

Study Utility Domain Question | Rating Rationale
Selection of animals
Controls | +++ A cobalt chloride alone group was said to have been tested, but no results of that group were reported. The reported control was the known carcinogen alone, which is appropriate for a co-carcinogen study.
Historical data | No No historical controls were used.
Randomization | NR No information about randomization was provided.
Exposure
Chemical purity | NR No information about chemical purity, stability, or homogeneity was provided.
Dosing regimen | + Only one dose level of cobalt, given for 43 weeks, was tested with no rationale for choosing that dose level.
Survival | +++ There was no significant effect on survival from cobalt.
Pathology | ++ Pathology procedures not described but histopathological evaluations were done on the respiratory tract and the liver.
Confounding | NR No information on animal husbandry conditions, disease surveillance, or chemical purity were reported.
Reporting and analysis | + Poor reporting of chemical purity or stability, animal husbandry, or necropsy methods. Tumor incidences were reported as both sexes combined, making it impossible to examine sex differences.
Sensitivity
Animal model | ++ Both sexes of non-transgenic rats were tested; however, tumor incidences were reported as both sexes combined.
Statistical power | + Only 12 animals per group per sex were tested, but tumor incidences were reported as both sexes combined.
Study duration | +++ Duration of treatment was 43 weeks and duration of observation was for the animals' lifespan.
Assay utility | + Co-carcinogen study

Overall utility: Low

All co-carcinogen studies were categorically restricted to being ranked no higher than low utility to account for their indirect measure of carcinogenicity. The study had a long duration of observation. However, poor reporting of chemical purity/stability, animal husbandry, necropsy methods, or necropsy with histological descriptions only of the respiratory tract and liver. Only one dose level was tested, without a reported rationale, on a small number of males and females, with tumor incidences reported as both sexes combined.

Table D-20 Orzechowski et al. (1964): Sodium Cobaltinitrite; Injection

Study Utility Domain Question | Rating Rationale
Selection of animals
Controls | +++ There were no untreated controls or cobalt alone controls, but there was a known carcinogen alone group and this is a co-carcinogen study.
Historical data | No No historical controls were used.
Randomization | NR No information about randomization was provided.
Exposure
Chemical purity | NR No information about chemical purity, stability, or homogeneity was provided.
Dosing regimen | +++ Six dose levels were given over 72 days and maximum dose level was based on toxicity in preliminary studies.
Survival | +++ Survival was high and similar to known carcinogen only controls.
Pathology | + Necropsies were not done, only histological examination of tumors were done.
Confounding | ++ Very few details reported about animal husbandry and no information was reported about chemical purity.
Reporting and analysis | + No chemical purity or animal husbandry were reported. Tumor incidences were reported as both sexes combined.
Sensitivity
Animal model | ++ Both sexes of non-transgenic mice were used, though tumor incidence were only reported as both sexes combined.
Statistical power | +++ Large number of animals per group and experiments were conducted in triplicate and survival was high and similar to controls.
Study duration | ++ A very short duration of 75 days was used, but it's a co-carcinogenicity study and tumors were induced.
Assay utility | + Co-carcinogen study

Overall utility: Low

All co-carcinogen studies were categorically restricted to being ranked no higher than low utility to account for their indirect measure of carcinogenicity. Tumor incidences were reported as both sexes combined. No information on chemical purity or stability or animal husbandry were reported. Six dose levels were tested, which were based on preliminary studies and a high number of animals per group was used, with experiments conducted in triplicate. Necropsies were not performed; histological examination was conducted only on tumors.

Table D-21 Thompson et al. (1965): Sodium Cobaltinitrite; Drinking Water

Study Utility Domain Question | Rating Rationale
Selection of animals
Controls | +++ There were no untreated controls or cobalt alone controls, but there was a known carcinogen alone group and this is a co-carcinogen study.
Historical data | No No historical controls were used.
Randomization | NR No information about randomization was provided.
Exposure
Chemical purity | NR No information about chemical purity, stability, or homogeneity was provided.
Dosing regimen | +++ Three dose levels were tested. The duration of treatment was not reported, but assumed to be about 11 weeks, but this is a co-carcinogen study.
Survival | NR No survival information was reported.
Pathology | + No full necropsies were performed, just histology of the tumors and hematology measurements.
Confounding | ++ Very little information about animal husbandry and no information about chemical purity or disease surveillance.
Reporting and analysis | ++ Nothing was reported for chemical purity or stability, disease surveillance, survival, or duration of treatment. Dosing regimen and duration of observation were not clearly reported.
Sensitivity
Animal model | +++ Both sexes of non-transgenic mice were tested.
Statistical power | +++ Large number of animals per group, but survival was not reported.
Study duration | ++ Not clearly reported, assumed to be about 11 weeks, but this is a co-carcinogen study.
Assay utility | + Co-carcinogen study

Overall utility: Low

All co-carcinogen studies were categorically restricted to being ranked no higher than low utility to account for their indirect measure of carcinogenicity. Both sexes of mice were tested with three dose levels. Nothing was reported for chemical purity or stability, survival, duration of treatment, and animal husbandry and the dosing regimen were not clearly reported. Full necropsies were not done; histology was only performed on tumors.

Table D-22 Steinhoff and Mohr (1991): Cobalt Oxide; Intratracheal

Study Utility Domain Question | Rating Rationale
Selection of animals
Controls | +++ No untreated control was used, but a benzo[a]pyrene-only control was included, which is consistent with a co-carcinogenicity study.
Historical data | No No historical controls were used.
Randomization | NR No information about randomization was provided.
Exposure
Chemical purity | ++ The method of manufacture of the cobalt was reported, but the purity was only stated as “chemically pure.”
Dosing regimen | + Only a single dose level was used and given for 47 weeks for cobalt and 13 wk for benzo[a]pyrene.
Survival | NR No survival information was reported.
Pathology | ++ Only organs with gross lesions and the respiratory tract were examined histologically.
Confounding | ++ The method of manufacture of the cobalt was reported, but the purity was only stated as “chemically pure.” Animal husbandry was described, but disease surveillance was not reported.
Reporting and analysis | ++ Methods were poorly reported and lacked details about the chemical and animal husbandry.
Sensitivity
Animal model | ++ Only female rats were tested.
Statistical power | +++ A large number of animals were used and survival was similar to controls.
Study duration | ++ Treatment with cobalt was for 47 weeks, benzo[a]pyrene was given for 13 wk, while observation was lifespan.
Assay utility | + Co-carcinogen study

Overall utility: Low

All co-carcinogen studies were categorically restricted to being ranked no higher than low utility to account for their indirect measure of carcinogenicity. One dose level was tested on a high number of females for almost a year, with observations for their lifespan. However, only partial necropsies were performed. Details of the chemical, animal husbandry, and survival were not reported.

Table D-23 Wehner et al. (1977): Cobalt Oxide; Inhalation

Study Utility Domain Question | Rating Rationale
Selection of animals
Controls | +++ Controls were cigarette smoke alone.
Historical data | No No historical controls were used.
Randomization | NR No information about randomization was provided.
Exposure
Chemical purity | + There was no information on chemical purity or stability of the cobalt and the composition of the cigarettes is complex and variable. However, information on the type of research cigarette (Kentucky IRI research cigarettes) was provided.
Dosing regimen | ++ Single dose level with no justification for choosing that level, but administered for life.
Survival | +++ Cobalt had no significant effect on survival or body weight compared to untreated controls.
Pathology | +++ Detailed necropsies were performed.
Confounding | + Chemical purity and disease surveillance were not reported. The uncertainty of the composition of the cigarettes may contribute to confounding.
Reporting and analysis | + Methods were not fully reported with no information on disease surveillance or chemical purity. Tumor sites were not always defined. Tumor incidence reported as “carcinoma” or “polyp” without saying from which tissue they originated is meaningless.
Sensitivity
Animal model | ++ Only male hamsters were tested.
Statistical power | +++ A large number of animals were used and survival was similar to controls.
Study duration | +++ Duration of treatment and observation was for the animals' lifespan.
Assay utility | + Co-carcinogen study

Overall utility: Low

All co-carcinogen studies were categorically restricted to being ranked no higher than low utility to account for their indirect measure of carcinogenicity. Duration of exposure and observation were sufficient. However, methods and results were not fully reported; chemical purity or stability, animal husbandry, and randomized allocation into groups were not reported as well as the tissue sites of the tumors. Full necropsies were reported. Only a single dose level was tested (with no rationale for choosing that dose level).

Table D-24 Overview of Experimental Animal Co-carcinogenicity Study Quality Evaluations

Study | Metal | Controls | Historical Data | Random-ization | Purity | Dosing | Survival | Pathology | Con-founding | Reporting & Analysis | Animal Model | Stats | Duration | Assay Utility | Overall Utility
Finogenova (1973) | Cobalt chloride | +++ | No | NR | NR | ++ | NR | ++ | NR | + | ++ | +++ | ++ | + | Low
Kasirsky et al. (1965) | Cobalt chloride | +++ | No | NR | NR | ++ | + | + | ++ | ++ | +++ | ++ | ++ | + | Low
O’Hara et al. (1971) | Cobalt chloride Sodium cobaltinitrite | +++ | No | NR | NR | 0 | +++ | ++ | ++ | ++ | +++ | +++ | ++ | 0 | Inadequate
Zeller (1975) | Cobalt chloride | +++ | No | NR | NR | + | +++ | ++ | NR | + | ++ | + | +++ | + | Low
Orzechowski et al. (1964) | Sodium cobaltinitrite | +++ | No | NR | NR | +++ | +++ | + | ++ | + | ++ | +++ | ++ | + | Low
Thompson et al. (1965) | Sodium cobaltinitrite | +++ | No | NR | NR | +++ | NR | + | ++ | ++ | +++ | +++ | ++ | + | Low
Steinhoff and Mohr (1991) | Cobalt oxide | +++ | No | NR | ++ | + | NR | ++ | ++ | ++ | ++ | +++ | ++ | + | Low
Wehner et al. (1977) | Cobalt oxide | +++ | No | NR | + | ++ | +++ | +++ | + | + | ++ | +++ | +++ | + | Low

+ ++ = high quality/little to no concerns, ++ = moderate quality/moderate concerns, + = low quality/high concerns, 0 = inadequate, NR = not reported.