# Appendix C Human Cancer Study Tables

This appendix contains background information related to the cancer assessment on cobalt and certain cobalt compounds in humans including detailed (1) data information on study design, methods, and findings for human cancer studies (Table C-1 through Table C-9) and (2) detailed information on the quality assessment of the individual studies (Table C-10, Table C-11, and Table C-12).

## C.1 Methodologies and Study Characteristics

The data from several cohort studies, which include four nested case-control studies and two case-control studies on esophageal and head and neck cancers, were systematically extracted from relevant publications and are summarized in the tables below (Table C-1 through Table C-9). Some of the studies were conducted on overlapping populations. The cohort studies are organized by occupational group and listed in chronological order (earliest studies first) similar to Table 4-1.

Table C-1 Study Description and Methodologies of Cohort Studies: Tüchsen et al. (1996)

Field | Description
Reference | Tüchsen et al. (1996) Tüchsen F, Jensen MV, Villadsen E, Lynge E. Incidence of lung cancer among cobalt-exposed women. Scand J Work Environ Health. 1996 Dec;22(6):444–50. PubMed PMID: 9000312.
Study-design type | Cohort
Location and enrollment dates | Copenhagen, Denmark; Jan 1, 1943 (Factory 1) or Jan 1, 1962 (Factory 2) – Dec 31, 1992
Population description | Danish women porcelain plate workers.
Eligibility criteria | All women employed at any time in two underglaze porcelain plate departments (Factory 1 and Factory 2); and all female top glaze decorators in a department without cobalt exposure (Factory 1).
Cohort details | Population size: 1,394 total; 874 cobalt-exposed workers, 520 unexposed workers. Loss-to-follow-up: 13 (0.92%) Referent Group: External (SIR); also calculated SIR for unexposed workers.
Outcome data source | Followed for death and emigration using data in the Central Population Register and the municipal population registers. Cancer cases identified by linkage to Danish Cancer Register (ICD-7).
Exposure assessment | Company records
Exposure assessment notes | Exposure to cobalt-aluminate spinel and/or cobalt silicate at 2 factories. Detailed information on work history; exposure monitoring data was reported for air and urine from the 1980s which was not used in the exposure assessment; calendar period was adjusted for in analysis.
Exposure-level | Employment in factories/departments with or without cobalt
Co-exposures | Nickel, silica
Analysis methods and control for confounding | Analytical methods: Personnel files for permanently ill persons may have been removed in earlier years, potentially resulting in an underestimate of incidence. Covariates: Age Confounder consideration: Calculation of expected number of cancer cases took 5-year age groups and calendar periods in consideration. No HWE, no control for other variables; unclear if calendar period was controlled

Table C-2 Study Description and Methodologies of Cohort Studies: Mur et al. (1987)

Field | Description
Reference | Mur et al. (1987) Mur JM, Moulin JJ, Charruyer-Seinerra MP, Lafitte J. A cohort mortality study among cobalt and sodium workers in an electrochemical plant. Am J Ind Med. 1987;11(1):75–81. PubMed PMID: 3812499.
Study-design type | Cohort and nested case control study
Location and enrollment dates | France; 1950–1980
Population description | Male electrochemical workers including cobalt production workers
Eligibility criteria | N = 1,143. All men employed for at least one year at a cobalt production plant producing cobalt, cobalt salt and oxides, and sodium between 1950 and 1980; hired between 1900 and 1979.
Cohort details | Population size: N = 1,143; number of cobalt production workers not reported but ~25% of current staff at publication Loss-to-follow-up: 17.9% for cobalt production workers; 75% hired before 1975. Referent Group: Internal and external comparing cohort mortality to male mortality in France
Case-control description and eligibility criteria | | Population size | Response rates | Source
Case-control description and eligibility criteria | Cases | 9 | NR | All lung cancer cases from cohort
Case-control description and eligibility criteria | Controls | 18 | NR | Two controls/case were matched on year of birth and age at death and “smoking habits” (undefined); controls were selected from among those dying of conditions other than cancer.
Outcome data source | Vital status ascertained by registry offices in the birth places of Frenchmen, and at embassies and consulates for foreign-born. Cause of death (ICD-8) ascertained by physicians and medical records. 80% of causes of death determined and classified.
Exposure assessment | Company records
Exposure assessment notes | Job histories grouped according to employment in general service, maintenance, sodium or cobalt production. Only included those with exclusive employment in any of these departments. No Co levels reported, nor were prior measurements available.
Exposure-level | 60% worked greater than 10 years; 75% hired before 1975
Co-exposures | Arsenic, nickel
Analysis methods and control for confounding | Analytical methods: Covariates: age, year of death SMR all-cause mortality = 0.77 (p < 0.01); no methods to control HWE; all-cause mortality for cobalt production = SMR 1.29 (0.86–1.87). Analytical method: matched case-control study Covariates: None Confounder consideration: Cases (deaths from lung cancer) were matched to controls (deaths from cause other than cancer) for year of birth, age at death, and smoking habits

Table C-3 Study Description and Methodologies of Cohort Studies: Moulin et al. (1993)

Field | Description
Reference | Moulin et al. (1993) Moulin JJ, Wild P, Mur JM, Fournier-Betz M, Mercier-Gallay M. A mortality study of cobalt production workers: an extension of the follow-up. Am J Ind Med. 1993 Feb;23(2):281–8. PubMed PMID: 8427256.
Study-design type | Cohort
Location and enrollment dates | France; Extended follow-up of the Mur et al. (1987) study through 1988
Population description | Male electrochemical plant workers including cobalt production workers
Eligibility criteria | All men employed for at least one year at a cobalt production plant producing cobalt, cobalt salt and oxides, and sodium between 1950 and 1988; hired between 1900 and 1979. Cohort I included all workers excluding person years of foreign-born workers over 75 years of age; Cohort II included only French-born workers.
Cohort details | Population size: Cohort 1 – N = 1148; Cohort II – N = 870; number of cobalt workers NR Loss-to-follow-up: Unknown cause of death 1% for all French born workers; Overall, no cause of death for 11.7% Cohort I; 9.7% in Cohort II; or 11% unknown cause of death overall. Loss to follow-up for cobalt production workers was not reported. Referent Group: External comparison with French male mortality rates
Outcome data source | Used death certificates from the French National Institute for Medical Research and Health files for deaths 1968–1988 for French born; cause of death prior to 1968 was ascertained from physicians and hospital records; for foreigners, cause of death ascertained from embassies and consulates.
Exposure assessment | Company records
Exposure assessment notes | Job histories grouped according to employment in general service, maintenance, sodium or cobalt production. Either “ever” or “only” employment in any of these departments. No Co levels reported, nor were prior measurements available.
Exposure-level | NR, but likely similar to Mur et al. (1987)
Co-exposures | Nickel, arsenic
Analysis methods and control for confounding | Analytical methods: Restriction to French-born reduced the power to detect effect, yet mitigated concerns about attrition bias. Covariates: age Confounder consideration: No reported control for period effects, duration, or and time since first exposure

Table C-4 Study Description and Methodologies of Nested Case Control Studies: Moulin et al. (1998)

Field | Description
Reference | Moulin et al. (1998) Moulin JJ, Wild P, Romazini S, Lasfargues G, Peltier A, Bozec C, Deguerry P, Pellet F, Perdrix A. Lung cancer risk in hard-metal workers. Am J Epidemiol. 1998 Aug 1;148(3):241–8. PubMed PMID: 9690360.
Study-design type | Nested Case-Control
Location and enrollment dates | FRANCE; January 1, 1968–December 31, 1991.
Population description | Male and female French hard-metal workers
Case-control description and eligibility criteria | | Population size | Response rates | Source
Case-control description and eligibility criteria | Cases | 61 | 97% | All cohort workers who died of lung cancer
Case-control description and eligibility criteria | Controls | 180 | 98% | Three controls/case sampled from among those at risk - i.e., who were under FU and alive on the date the case died and had completed 3 mos of employment. Controls matched for gender and date of birth ±6 mos of the case.
Exposure assessment | JEM
Exposure assessment notes | Semi-quantitative (JEM) exposure assessment based on administrative records and interviews with colleagues; 320 job periods assigned estimates of exposure to cobalt and tungsten carbide - Intensity score from 0 (no exposure) to 9 (highest exposure level); frequency score of <10%, 10%–50%, and >50% of work time. 744 historical atmospheric concentrations of cobalt were used to validate matrix scores, but no concentrations were included from Co powder production area.
Exposure-level | NR
Co-exposures | Employment in maintenance shop, PAHs, asbestos, silica, certain chromium compounds, certain nickel compounds, arsenic compounds, cadmium compounds, nitrosamines, benzene, tungsten carbide
Analysis methods and control for confounding | Analytical methods: Covariates: unclear which variables were controlled in the multivariate analysis for cobalt alone Confounder consideration: mentioned the full list of IARC carcinogens, but did not indicate if these were controlled in the cobalt alone analyses

Table C-5 Study Description and Methodologies of Cohort Studies: Wild et al. (2000)

Field | Description
Reference | Wild et al. (2000) Wild P, Perdrix A, Romazini S, Moulin JJ, Pellet F. Lung cancer mortality in a site producing hard metals. Occup Environ Med. 2000 Aug;57(8):568–73. PubMed PMID: 10896965.
Study-design type | Cohort
Location and enrollment dates | France; January 1968–December 1992
Population description | Hard metal workers in the largest such factory in France (included in the Moulin et al. 1998 paper).
Eligibility criteria | Subjects who had worked at least 3 months between January 1, 1950 and June 30, 1992, and were still alive by January 1, 1968. 80% of cohort were hired prior to 1970. Mean follow-up 18.6 years
Cohort details | Population size: 2,216 men and 644 women Loss-to-follow-up: 20.2%; Foreign-born workers terminated before 1968 censored and considered lost to follow-up Referent Group: External analysis using “local death rates” as comparison.
Outcome data source | Vital status ascertained by registry offices of birthplaces and computer database of all deaths in France starting in 1978. Cause of death obtained by matching the file of dead subjects with the national file of causes of death from 1968, coded to ICD-8 of disease before 1978, and to ICD-9 for disease after 1978; 96% of causes could be retrieved.
Exposure assessment | JEM
Exposure assessment notes | Semi-quantitative (JEM) exposure assessment based on administrative records and interviews with colleagues; 320 job periods assigned estimates of exposure to cobalt and tungsten carbide - Intensity score from 0 (no exposure) to 9 (highest exposure level); frequency score of <10%, 10%–50%, and >50% of work time. Ever or only employment in the “powder production workshop” was also used as an indicator of potential exposure to cobalt.
Exposure-level | NR
Co-exposures | PAHs, certain chromium compounds, certain nickel compounds, silica, cobalt-tungsten carbide, asbestos, arsenic compounds, cadmium compounds, nitrosamines, benzene
Analysis methods and control for confounding | Analytical methods: Covariates: Age, unclear if these are crude estimates Confounder consideration: conducted separate smoking analyses

Table C-6 Study Description and Methodologies of Cohort Studies: Moulin et al. (2000a)

Field | Description
Reference | Moulin et al. (2000a) Moulin JJ, Clavel T, Roy D, Dananche B, Marquis N, Fevotte J, Fontana JM. 2000. Risk of lung cancer in workers producing stainless steel and metallic alloys. Int Arch Occup Environ Health 73(3): 171–180. PMID 10787132
Study-design type | Nested Case-Control
Location and enrollment dates | France; January 1, 1968–December 31, 1992
Population description | Male and female workers in a French factory producing stainless and alloyed steel.
Case-control description and eligibility criteria | | Population size | Response rates | Source
Case-control description and eligibility criteria | Cases | 54 (17 Co-exposed) | NR | All workers who died from lung cancer determined thru death certificate and medical record matching process.
Case-control description and eligibility criteria | Controls | 162 (67 Co-exposed) | NR | 3 controls / case sampled from those under follow-up at the date of death, had completed 1 year of employment, and known to be alive on this date, same gender, and DOB within 6 months of deceased case.
Exposure assessment | JEM
Exposure assessment notes | Semi-quantitative JEM had 5 levels of exposure no exposure, occasional, and low, medium, and high exposure. Frequency was coded as 10% to 100% of working time; low, medium, and high probability of accuracy of intensity and frequency codes was included. Increasing exposure levels, duration of exposure, and cumulative dose (frequency weighted and unweighted)
Exposure-level | NR
Co-exposures | Iron, acid mists, PAHs, asbestos, silica, chromium and/or nickel
Analysis methods and control for confounding | Analytical methods: Analyses were lagged. Covariates: PAHs, age, gender, silica, smoking ever/never Confounder consideration: Co correlated in a reported matrix with Chromium and/or Nickel, and Iron, but neither of these were included in the multivariate analysis

Table C-7 Study Description and Methodologies of Cohort Studies: Grimsrud et al. (2005)

Field | Description
Reference | Grimsrud et al. (2005) Grimsrud TK, Berge SR, Haldorsen T, Andersen A. Can lung cancer risk among nickel refinery workers be explained by occupational exposures other than nickel? Epidemiology. 2005 Mar;16(2):146–54. PubMed PMID: 15703528.
Study-design type | Nested Case-Control
Location and enrollment dates | Norway; 1910–1995
Population description | Norwegian nickel refinery workers
Case-control description and eligibility criteria | | Population size | Response rates | Source
Case-control description and eligibility criteria | Cases | 213 | NR | lung cancers diagnosed from 1952–1995 and in the Cancer Registry of Norway during this time.
Case-control description and eligibility criteria | Controls | 525 | NR | 3 controls / case randomly drawn among cohort members at risk at the time of dx (incidence density sampling), free of lung CA, and born within 24 months of the case’s DOB, and matched by gender. Controls drawn in a 1:1 ratio for cases diagnosed before 1970.
Exposure assessment | JEM
Exposure assessment notes | A semi-quantitative JEM was developed for various species of nickel based on 5,900 personal measurements; this was supplemented with 3,500 personal samples from the breathing zone for cobalt.
Exposure-level | In μg/m^3^: High (144–3,100); Medium (29.7–142); Low (0.31–29.5)
Co-exposures | Nickel, arsenic, asbestos, sulfuric acid mists
Analysis methods and control for confounding | Analytical methods: Covariates: smoking Confounder consideration: No multivariate estimates were possible due to collinearity with nickel.

Table C-8 Study Description and Methodologies of Case-control Studies: Rogers et al. (1993)

Field | Description
Reference | Rogers et al. (1993) Rogers MA, Thomas DB, Davis S, Vaughan TL, Nevissi AE. A case-control study of element levels and cancer of the upper aerodigestive tract. Cancer Epidemiol Biomarkers Prev. 1993 Jul-Aug;2(4):305–12. PubMed PMID: 8348053.
Study-design type | Case-Control
Location and enrollment dates | Western WA state, USA; 9/1/83–2/28/87
Population description | Population based randomly selected controls and cases from SEER
Case-control description and eligibility criteria | | Population size | Response rates | Source
Case-control description and eligibility criteria | Cases | N = 507; N = 153 laryngeal, N = 73 esophageal, N = 359 oral cavity cancers | 52.8% providing toenail samples | Laryngeal, esophageal, or oral cavity cancers of epithelial origin identified from local SEER registry with positive histological findings; some cases confirmed by cytology and followed with attending physician.
Case-control description and eligibility criteria | Controls | N = 434 | 66.4% providing toenail samples | Controls from same area as cases selected by random digit dialing and frequency matched by sex and age in 5-year intervals of cases.
Exposure assessment | Personal monitoring
Exposure assessment notes | Dietary sources of trace elements of cobalt, iron, calcium, zinc, chromium explored; toenails collected and cleaned; personnel blinded to case status; formation of nail matrix takes 8–24 mos; median time from dx to interview was 6.5 mos, so samples likely to represent prediagnostic levels; qx data on occupation collected but not reported.
Exposure-level | Tertiles of cobalt in toenails; highest level 0.17 ppm
Co-exposures | Iron, calcium, zinc, chromium
Analysis methods and control for confounding | Analytical methods: “Exposed cases” in this table refers to both cases and controls combined; exposed cases alone NR. Covariates: age, alcohol (drink years), ascorbic acid mg/day, beta-carotene, mg/day, energy intake, kcal/day, sex, smoking (pack-years). Correlations between cobalt and other measured metals not provided; and models for cobalt did not include other metal levels. Confounder consideration: Nutrients in the model did not greatly confound the relationship between exposure and disease, but inclusion resulted in ORs closer to the null. ORs for Esophageal cancer significantly elevated for iron and calcium.

Table C-9 Study Description and Methodologies of Case-control Studies: O’Rorke et al. (2012)

Field | Description
Reference | O’Rorke et al. (2012) O’Rorke MA, Cantwell MM, Abnet CC, Brockman AJ, Murray LJ, FINBAR Study Group. Toenail trace element status and risk of Barrett's oesophagus and oesophageal adenocarcinoma: results from the FINBAR study. Int J Cancer. 2012 Oct 15;131(8):1882–91. PubMed PMID: 22262413.
Study-design type | Case-control study
Location and enrollment dates | All Ireland (Republic and Northern); 3/2002–12/2004
Population description | Population based cases and controls
Case-control description and eligibility criteria | | Population size | Response rates | Source
Case-control description and eligibility criteria | Cases | N = 137 esophageal cancer; N = 182 Barrett’s esophagus | Esophageal CA = 38.6%; Barrett's esophagus = 66.9 | No. Ireland: Esophageal cases (≤85 yrs) identified from electronic path records from all path labs. Rep of Ireland: cases identified from the main referral hospitals diagnosing and treating esophageal CA. Pathology review and histologically confirmation; excluding in situ CA. Barrett's esophagus - pts with ≥3 cm of Barrett's mucosa at endoscopy or biopsy showed specialized intestinal metaplasia. Pts with dysplasia on histology excluded.
Case-control description and eligibility criteria | Controls | 221 | 35.5 | Adults (35 to 84) without history of esophageal or other gastrointestinal cancer or known diagnosis of Barrett's esophagus; frequency matched by sex and age (5 yrs). Selected at random from general practitioner (GP) list (No. Ireland) and from 4 GP practices (2 rural and 2 urban) in Dublin and Cork areas that reflected the distribution of the Rep. Ireland cases
Exposure assessment | Personal monitoring
Exposure assessment notes | Cobalt level in toenails; tertile cutpoints of log(e) transformed Co based on control distribution. Questionnaire for demographics, lifestyle habits, diet, manual/non-manual occupation, and medical history; anthropometric measurements; personnel blinded as to case status.
Exposure-level | Average (μg/g) ± SD: cases – 0.02 ± 0.06; controls – 0.02 ± 0.04. Range: cases 0.002–0.60; controls – 0.002–0.47
Co-exposures | Selenium, iron, chromium, zinc measured
Analysis methods and control for confounding | Analytical methods: Covariates: GI reflux, H. pylori infection, age, education, energy intake, location, sex, smoking, smoking habits Confounder consideration: Unadjusted model almost identical results to the age and sex adjusted model; other metals measured included selenium, chromium, zinc, mercury, cerium. No correlation with cobalt reported. Not in models.

## C.2 Assessment of Study Quality, Sensitivity, and Utility of Human Studies of Cobalt

This appendix provides (1) an assessment of the study quality, sensitivity, and utility of the human studies to inform the cancer hazard evaluation, and (2) study quality and utility summaries for cohort studies and for case-control studies. Each primary study was systematically evaluated for its utility to inform the cancer hazard identification using core, signaling and follow-up questions outlined in the protocol (NTP 2014b) for five domains of study quality (selection bias, methods to evaluate potential confounding, exposure misclassification, outcome misclassification, selective reporting, and quality of the analysis) and one domain for study sensitivity. Two reviewers evaluated study quality and utility and differences were resolved by reference to the original publication and discussion.

For each domain, the following terms were used to rate the potential for bias and/or quality:

- Low/minimal concerns: Information from study designs and methodologies indicate that they are close to the ideal study characteristics and that the potential for bias is unlikely or minimal, recognizing general limitations of observational studies. [+++ high quality]
- Some concerns: Study designs or methodologies are less than ideal, indicating possible bias. [++ medium quality]
- Major concerns: Study designs or methodologies suggest that the potential for a specific type of bias is likely albeit depending on the direction and distortion of the potential bias, the study may have some limited utility. [+ low quality]
- Critical concern: Distortion of bias would make study findings unreliable for cancer hazard identification. [0 rating]
- No information: The information in the study is inadequate to evaluate the level of concern for the domain.

In addition, when adequate information was available, an assessment was made whether a bias was likely to be differential (systematic) or non-differential and the predicted direction of the bias (towards or away from the null; over or underestimate of the effect estimate). The impact of the potential bias or confounding on the study findings is discussed in the cancer hazard assessment (see Sections 4.2.3, 4.3.3).

Based on the overall evaluation, studies were broadly grouped according to their ability to inform the cancer hazard evaluation based on the above characteristics, as follows:

- High (low/minimal concerns for most potential biases, high or moderate sensitivity rating)
- Moderate (low/minimal or some concerns for most potential biases, high or moderate sensitivity rating)
- Moderate/low (some to major concerns for several potential biases, sensitivity rating varies)
- Low (major concerns for several potential biases, sensitivity rating varies)
- Inadequate (critical concerns for any bias, sensitivity rating varies)

The overall study judgment is not meant to be an algorithm that sums up the ratings across domains. The quality of the exposure assessment and potential for exposure misclassification and potential confounding was given considerable weight in ranking the studies. In addition, studies with high probability of systematic (i.e., differential) biases were rated low.

Guidelines and characteristics of the ratings specific for each domain as well as the overall study utility are provided in the cobalt protocol. The assessment (rating and rationale for the rating) of the study quality and sensitivity domain for each study and the overall study evaluation are summarized in the following sections. The studies in each table are ordered by study design, with cohort and nested case-control studies first, followed by case-control studies, and then by publication date of the first study publication.

- Selection bias and evaluation of methods used to address potential confounding (Table C-10)
- Information bias: exposure and outcome misclassification (Table C-11)
- Selective reporting and analysis bias (Table C-12)
- Study sensitivity, quality and utility of cohort and nested case-control studies (Table 4-2)
- Study sensitivity, quality, and utility of case-control studies (Table 4-5)

### C.2.1 Selection Bias and Evaluation of Methods Used to Address Potential Confounding

#### C.2.1.1 Cohort and Nested Case-control Studies

In three of the four nested case-control studies in the lung cancer cohort studies, the potential for selection bias was thought to be low (Grimsrud et al. 2005; Moulin et al. 2000b; Moulin et al. 1998), as all studies appropriately selected and matched cases and controls on relevant variables. The fourth nested case-control study, i.e., the study of electrochemical workers by Mur et al. (1987), did not provide information on methods of selection and matching.

The loss to follow-up was large in the cohort studies of electrochemical and hard-metal workers (Moulin et al. 1993; Moulin et al. 1998; Mur et al. 1987; Wild et al. 2000), but there was no evidence presented to assess whether the loss was related to exposure. In these studies, the largest losses were due to the inability to find death records for foreign-born workers (15%–21%). Except for Mur et al. (1987), follow-up for these workers ended at the last date of employment (Moulin et al. 1998; Wild et al. 2000); or analyses were restricted to non-foreign-born workers (Moulin et al. 1993). Differential selection out of the porcelain workers cohort (Tüchsen et al. 1996) could have occurred as the authors mentioned that records of ill persons may have been removed potentially resulting in an underestimate of the true incidence of cancer.

Evidence of a healthy worker effect (HWE) based on external analyses showing statistically significant decreases in all-cause mortality rates was present in Moulin et al. (1998), Mur et al. (1987) and Moulin et al. (2000b) studies. Internal analyses, however, were conducted that have the effect of minimizing HWE, although no adjustment in any analysis was made for time since hire. In the electrochemical workers (Moulin et al. 1993; Mur et al. 1987) while HWE was evident in the full cohort, it was not apparent among cobalt only workers.

In the electrochemical workers cohort (Moulin et al. 1993) 46% of cohort members had been hired prior to the start of follow-up, with the likely effect of inducing a downward bias in the effect estimate. Such left censoring can result in a cohort with healthier prevalent hires who have remained working from earlier periods of exposure. The Moulin et al. (2000b) study indirectly addressed the healthy worker survival effect (HWSE) indicating that cases and controls in the nested study were matched on age and were reported to have similar distributions for the date of hire, suggesting there was little concern for HWSE.

#### C.2.1.2 Case-control Studies

Both of the population-based case-control studies of cobalt in toenails report sufficient information to evaluate whether selection of participants is related to exposure and disease. Selection bias is unlikely in the Rogers et al. (1993) study, which ascertained all cases of aerodigestive cancers (e.g., oral cavity, esophageal, and laryngeal cancer) from the Western Washington state SEER cancer registry and used random-digit dialing to identify controls in a defined area.

In the FINBAR study, there is some concern that selection bias may been operating in the selection of cases and controls from the Republic of Ireland in this study (O’Rorke et al. 2012). Cases were identified from the “main” hospitals involved in the diagnosis and treatment of esophageal cancer including the national referral center for esophageal cancer. In contrast, Republic of Ireland controls were selected at random from two urban and two rural general practices, purportedly reflecting the urban/rural distribution of esophageal cancer cases in the Republic. However, smoking rates among the controls suggest that participating controls may not be fully representative of the case population or of those who did not submit toenail samples. Current smoking was higher in the cases, as expected, but the level of smoking in the controls was lower than that of the general population (16% of controls returning toenail samples, and 17.7% in all controls; 23.6% of males 55 years and over). Among those not returning toenail samples, the proportion of current smokers was higher (27%).

Participation rates were low in both studies, especially when combined with the reduced percentage of those returning toenail samples. In the Rogers et al. (1993) study, the proportion of all eligible cases who returned usable toenails was 52.8%, and for controls 66.4%. This proportion was 36% for esophageal, 63.5% for laryngeal, and 54.5% for oral cancers. However, the distribution of risk factors (alcohol consumption and tobacco smoking) was consistent with what is known about risk factors for aerodigestive cancers and argues against systematic selection bias. In the O’Rorke et al. (2012) study, the participation rate (including those who submitted toenails) was 38.6% in cases and 35.5% in controls.

### C.2.2 Evaluation of Methods to Address Confounding

This section addresses whether the studies used appropriate methods to control confounding or provided relevant data to evaluate potential confounding. The final evaluation of whether confounding bias can explain the results of each study is discussed in the cancer assessment sections (Sections 4.2.2 and 4.3.2 and 4.4).

#### C.2.2.1 Cohort and Nested Case-control Studies

Most of the cohort and nested case-control studies conducted age-, sex-, and calendar year- or period-standardized comparisons in external analyses (SMR or SIR) and, in some cases, restricted internal analyses to men (when there were small numbers of women workers) in internal analyses. All studies provided information about or directly controlled for smoking; however, the quality of these data ranged widely. Some conducted sub-studies of smoking habits of some proportion of the workers (ranging from <30% to 70%) (Moulin et al. 1993; Mur et al. 1987; Tüchsen et al. 1996); others categorized workers as “ever-never” smokers (Moulin et al. 2000b), and others were able to incorporate detailed information on former and current smokers and their level of smoking (Grimsrud et al. 2005). While smoking is a strong risk factor for lung cancer, there was no evidence of smoking being strongly associated with cobalt exposure in any of the studies.

Regarding co-exposures, studies among the hard-metal workers (Moulin et al. 1998; Wild et al. 2000), stainless and alloyed steel workers (Moulin et al. 2000a) and nickel refinery workers (Grimsrud et al. 2005) assessed co-exposures to several known IARC carcinogens; however, in none was information on co-exposures either sufficiently reported, or controlled. Based on communications with the author (Dr. Wild) it is unlikely that co-exposures were controlled in the hard-metal studies. Furthermore, exposure to cobalt (not in the presence of tungsten carbide) ranged from exposure to pure cobalt in cobalt powder production workshops to mixed exposures, with potential exposure to lung carcinogens in the other production workshops. In the stainless and alloyed steel workers (Moulin et al. 2000a) no control was indicated for metals most closely correlated with cobalt. In the Grimsrud et al. (2005) study, data were available to evaluate the role of cobalt on lung cancer controlling for a number of other carcinogens. Their focus was to understand the confounding effect of co-exposures with nickel (correlation, r = 0.63); however, they were not able to separate the effects of cobalt from nickel as all nickel workers were exposed to cobalt. The electrochemical worker study (Moulin et al. 1993; Mur et al. 1987) and the porcelain painters (Tüchsen et al. 1996) did not collect information on co-exposures, although an earlier paper on this cohort provided information about low levels of nickel (<10% of Danish occupational limit of 0.1 mg/m^3^), silica (no detectable concentrations), and dust (average of 7.6 mg/m^3^) measured in 1981 prior to changes in practices that reduced air levels of cobalt somewhat. The electrochemical workers cohort may have been exposed to arsenic, which is added during the production process, and nickel and arsenic are contained in cobalt ore, but no measurements of these were taken.

#### C.2.2.2 Case-control Studies

Methods used to control for potential confounding in the two biomarker studies are adequate overall. While neither author reported correlations among the multiple metals analyzed in these studies, Rogers et al. (1993) also investigated the risk of cancer for iron, zinc, chromium, and calcium and provided ORs for each in relation to each cancer; however, these ORs were not controlled for presence of the other elements. Similarly, O’Rorke et al. (2012) also measured included selenium, chromium, zinc, mercury, and cerium; however, no correlation with cobalt was indicated, nor were these other metals included in the cobalt models. Both studies frequency matched controls to cases within 5-year age bands and sex strata; and both collected information on a wide range of risk factors and potential confounders. Both studies reported the distributions of potential confounders among cases and controls and provided clear descriptions of their process for multivariate analysis. Neither study reported on cobalt levels according to the occupational or dietary data collected.

Table C-10 Selection Bias and Evaluation of Methods Used to Address Potential Confounding in Human Studies of Cobalt

Study | Selection Bias | Methods Used to Address Potential Confounding
Tüchsen et al. (1996) | Rating: ++; Direction ↓ Rationale: No HWE was evident; only external analyses comparing cancer incidence in the Danish population. Differential selection out of the cohort could have occurred as the authors mentioned that records of ill persons may have been removed potentially resulting in an underestimate of the true incidence of cancer. | Rating; ++; ↑ Rationale: No internal or statistical analysis controlling for smoking or potential carcinogens; however, minimal exposure to occupational co-exposures indicated from measurements in 1981 and smoking data on subset of the population
Mur et al. (1987) Moulin et al. (1993) | Rating: ++ (Mur for case-control analysis); ++ (Moulin et al. 1993; French nationals analysis); ↓ Rationale: HWE present based on significant decreases in all-cause mortality rates (Mur et al. 1987) in the entire cohort, but not for workers exposed only to cobalt. High loss to follow-up in both studies due to foreign-born workers, with no information provided to assess if the loss was related to exposure. Moulin et al. (1993) provided a restricted analysis for French nationals in addition to a whole-cohort analysis, to mitigate a potential bias. However, 46% of the cohort was hired prior to the start of follow-up (left truncation), which could induce a downward bias in the effect estimate. | Rating; +; ↑ Rationale: Mur et al. (1987) reported smoking data from admin records available from 30% of the cohort (Mur et al. 1987), although cases and controls were reported as matched on smoking status with no report on methods of matching. Moulin et al. (1993) did not adjust for smoking. Potential exposure to nickel and arsenic from cobalt ore and/or processing methods, however, no analysis conducted controlling for potential carcinogens. Internal analysis (nested case-control) available in the Mur et al. (1987) study helps minimize potential confounding.
Moulin et al. (1998) | Rating: ++ for nested case-control analysis; ↓ Rationale: High loss to follow-up largely due to foreign-born workers who were right censored at the last date of employment; no g-methods or additional information provided to assess/mitigate potential HWSE. No indication that loss was related to exposure. Concerns with statistically significant decreases in all-cause mortality rates (HWE) mitigated by nested case-control analysis. Left truncation not an issue in this incidence cohort. | Rating; +; ↑ Rationale: Ever vs. never smoking data collected, and ever/never data on co-exposures in the JEM. Unlikely if models for cobalt alone included smoking and co-exposures (based on communication with author). Little information provided on cobalt co-exposures. Internal analyses may help reduce potential confounding from lifestyle factors. “Other cobalt exposures” were a mix of cobalt exposures from pure cobalt alone to other cobalt (not tungsten carbide) production activities with exposure to other carcinogens and not well defined.
Wild et al. (2000) | Rating: ++; ↓ Rationale: High loss to follow-up largely due to foreign-born workers who were censored at the last date of employment; no g-methods or additional information provided to assess/mitigate potential HWSE. No indication that the loss was related to exposure. No case-control analysis of cobalt alone provided. Left truncation not an issue in this incidence cohort. | Rating; +; ↑ Rationale: Smoking data abstracted from factory health records and for earlier smoking from former colleagues. Co-exposures to several IARC carcinogens likely (no correlations provided) and assessed (ever/never) from JEM exposure. Unlikely that smoking and co-exposures were included in estimate for cobalt alone exposure. See Moulin et al. (1998) also.
Moulin et al. (2000a) | Rating: +++ Rationale: HWE effect based on significant decreases in all-cause mortality rates in external analysis; cross-sectional cohort, internal analyses may have mitigated potential HWE bias. Nested case-control study of living controls matched on age at selection with the case; similar as to their distribution of year of hire, suggesting that it is unlikely that the HWSE was operating. | Rating: ++; ↑ Rationale: Statistical analysis controlled for smoking (ever-never) for 71% of subjects and some co-exposures (levels assigned from JEM). However, the models did not control for co-exposure to other metals (nickel/chromium and iron), which were correlated with exposure to cobalt, although not to lung cancer in these data.
Grimsrud et al. (2005) | Rating: +++ Rationale: No information about whether HWE was present in the original cohort, but only cases who were identified from 1970 onwards were included; controls were matched to cases by gender and age and at risk at the time of the case diagnosis and were similar with respect to year of first employment, reducing the concern with HWSE. However, some concern remains given that sick workers hired at the same dates as healthy workers could move from higher to lower exposure groups. No analysis was conducted to account for this possibility. Participation rates were 94% for both cases and controls. | Rating: ++; ↑ Statistical analyses controlled for smoking (5 categories) and exposure to lung carcinogens (arsenic, asbestos, sulfuric acid mists and nickel). Due to the high correlation between cobalt and nickel exposure, categorical levels of cobalt variable could not be retained in the fully adjusted model. Only smoking adjusted exposure response estimates were available.
Rogers et al. (1993) | Rating: +++ Rationale: Ascertained all cases of aerodigestive cancer from the Western Washington State SEER cancer registry and used random digit dialing to identify controls in the same defined area as controls. | Rating: +++ Rationale: Frequency matched controls to cases within 5-year age bands and sex strata; collected and reported information on a wide range of risk factors and potential confounders including past dietary data, alcohol and tobacco use among cases and controls. Differences in education, not occupation reported. Food frequency questionnaire based on usual dietary habits 10 years prior to the interview. Other metals measured included zinc, chromium, iron, and calcium; however, no correlations were shown with cobalt, nor were these metals included in models.
O’Rorke et al. (2012) | Rating: ++ Rationale: Methods for case and control selection vary by location. Northern Ireland cases identified systematically from electronic pathology records across the country; cases in the Republic were identified from “main” hospitals involved in the diagnosis and treatment of esophageal cancer. Potential for cases not referred to the major referral centers to be excluded. Very low participation rates and lower smoking rates in controls suggests the potential for selection bias is present due to lifestyle factors related to esophageal cancer. | Rating: +++ Rationale: Frequency matched controls to cases within 5-year age bands and sex strata; collected and reported information on a wide range of risk factors and potential confounders including past dietary data, alcohol, manual labor, and tobacco use among cases and controls. Dietary intake based on food frequency questionnaire assessing diet and alcohol use 5 years previously. Other metals measured included selenium, chromium, zinc, mercury, and cerium; however, no correlation with cobalt was indicated, nor were these other metals included in the models for cobalt.

### C.2.3 Information Bias: Exposure Assessment and Disease Endpoints

#### C.2.3.1 Cohort and Nested Case-control Studies

The exposure assessment evoking the most confidence is that of Grimsrud et al. (2005), which incorporated 3,500 personal breathing zone samples of cobalt air concentrations into the JEM which had been developed for an analysis of exposure to types of nickel using time- and department-specific exposure estimates. Non-differential misclassification may be possible for earlier decades of exposure based on limited data for those years. The study of nickel workers is followed by the hard-metal studies in which semi-quantitative assessments were conducted with validation for cobalt in non-production areas (Moulin et al. 1998; Wild et al. 2000), and then by the stainless and alloyed steel workers cohort (Moulin et al. 2000a), which also used a non-validated semi-quantitative JEM. Studies using only qualitative assessments warranted the lowest confidence in the exposure assessment (Moulin et al. 1993; Mur et al. 1987; Tüchsen et al. 1996).

Semi-quantitative categories of exposure based on job-exposure or job-task exposure matrices with estimates of exposure ranks or levels, which do not allow for the estimation of the risk per unit of exposure, were used in the hard-metal (Moulin et al. 1998; Wild et al. 2000) and stainless and alloyed steel worker studies (Moulin et al. 2000a). Strengths of the assessments are that they were based on expert opinion, were job-period specific, and incorporated information on frequency, intensity, duration, or probability. The hard-metal exposure assessment was considered to be somewhat higher quality than that used in the stainless and alloyed steel cohort, as their JEM was validated by historical exposure measurements, but these were not specific for cobalt (the focus of these studies was for exposure to cobalt-tungsten carbide hard metals thus less information is available for cobalt alone.) While the Moulin et al. (2000a) study was specifically designed to measure cobalt and other co-exposures in the JEM, there was little information provided on past cobalt exposure.

The most concern about exposure misclassification existed primarily for studies in which cobalt exposure was simply defined as employment in particular workshops (Moulin et al. 1993; Mur et al. 1987), or in factory departments (Tüchsen et al. 1996). Previously published data from the porcelain painters (Raffn et al. 1988) indicated an overlap of cobalt levels in referents and exposed individuals, suggesting that the referents in the Tüchsen et al. (1996) paper may not have been “unexposed.” In addition, exposure assessment in these studies did not differentiate workers according to exposure level. Potential misclassification of exposure would arise from lack of information on job tasks, use, and exposure conditions.

None of these occupational cohort studies provided information on the use of protective measures in workplace, nor was there any indication that such measures were taken into consideration in the job exposure matrices, nor were changes in hygiene practices over time when reported (e.g., Tüchsen et al. 1996) incorporated into the analyses as proxies for such changes.

In all the studies, the potential for exposure misclassification was generally considered to be non-differential, and would most likely bias towards the null, reducing the power to detect an effect. In subgroup and trend analyses, (specifically, in the Grimsrud et al. (2005), Moulin et al. (1998), and Moulin et al. (2000a) studies) exposure misclassification between exposure groups would most likely attenuate any exposure-response relationships.

#### C.2.3.2 Case-control Studies

Both population-based studies were conducted to determine the relationship of low levels of metals derived primarily from dietary sources to esophageal cancer, Barrett’s esophagus, and other aero-digestive cancers. However, a major concern about information bias in exposure assessment exists for both studies because the window of exposure implied by measuring metals in nails for cancer outcomes may not be appropriate. Nail samples were collected a median of 6.5 months after diagnosis in the Rogers et al. (1993) study, at or near the time of study enrollment in both studies. O’Rorke et al. (2012) reported that 76.7% of esophageal cancer cases had habitually clipped their toenails prior to admission to hospital. Toenail clippings likely reflect an integrated exposure that occurred 12 to 18 months prior to clipping (Fleckman 1985). Given that Barrett’s esophagus, esophageal and aerodigestive cancers have long latency periods, clippings that reflect at most an exposure window 12 months prior to diagnosis may or may not reflect ongoing exposure related to the development of cancer. In addition, several known factors can influence nail growth and possibly affect the time window of exposure represented by the sample. For example, nail growth is faster during pregnancy, and in warmer climates (Fleckman 1997). Certain medical conditions have been shown to increase or decrease the rate of nail growth, and age and sex affect nail growth with faster nail growth in men, and declining rates with increasing age (Dawber and Baran 1987; Fleckman 1985). Trace element deposition in nails may be influenced by several factors including those that are correlated with cancer (e.g., immobilization, decreased circulation, malnutrition, weight loss, age, gender, changes in diet and smoking and alcohol consumption) (Hunter et al. 1990; Slotnick and Nriagu 2006). Furthermore, reproducibility of cobalt specifically, in toenails from multiple samples over time has been reported to have intermediate to high within-person variability suggesting that sampling at any one point in time may not reflect long-term exposure (Garland et al. 1993). Another concern is whether the cancer process itself could alter deposition of cobalt in the nails, resulting in reverse causality. Two studies of cobalt levels by cancer stage in patients with lung cancer (Benderli Cihan et al. 2011; Kuo et al. 2006) and one with laryngeal cancer (Klatka et al. 2011) show contradictory findings, with no difference, increasing, and decreasing cobalt levels with increasing stage of disease. Rogers stratified cases by stage at diagnosis (in situ, localized versus regional, and distant), and by the time from diagnosis to interview (which was either <7 months or >7 months); there were no significant differences by stage or by time from diagnosis to interview, suggesting that reverse causality was not operating in this study.

### C.2.4 Information Bias – Disease Endpoints

#### C.2.4.1 Cohort and Nested Case-control Studies

Overall, the incidence and mortality measures used in the cohort studies were likely to distinguish between the presence and absence of cancer and reliably distinguish one cancer from another. Two cohorts, the Danish porcelain painters cohort (Tüchsen et al. 1996) and the Norwegian nickel refinery workers nested case-control study (Grimsrud et al. 2005), were based on incident cases of lung cancer obtained through linkage with the Danish Cancer Registry and the Norwegian Cancer Registry, respectively.

The remaining cohorts, with the exception of the first analysis of the electrochemical workers (Mur et al. 1987) were based on mortality data obtained primarily from death certificates (Moulin et al. 2000a; Moulin et al. 1993; Moulin et al. 1998; Wild et al. 2000). For lung cancer results and cancers with similarly low survival rates (lung and esophageal cancer 5-year survival rates, 16.8% and 17.8%, respectively), mortality data adequately reflect incidence.

Concerns regarding disease misclassification primarily existed in the cobalt production worker studies (Moulin et al. 1993; Mur et al. 1987). In the Mur et al. (1987) study, the cause of death was ascertained by physician interviews and medical records; in the Moulin et al. (1993) update, a decision had been made a priori to use the cause of death indicated on the death certificate, regardless of whether lung cancer was indicated in the medical record. As a result, one of the four exposed cases of lung cancer was dropped. While death certificate data are usually preferred over medical records, they are more likely to result in both missing cases and misclassification as compared to cancer registry data used in incidence studies, in which cancers are histologically confirmed. In neither of these studies was cancer histologically confirmed.

#### C.2.4.2 Case-control Studies

Both of the biomarker studies appear to be able to reliably distinguish between the presence and absence of the cancer outcome, suggesting low/minimal concern for information bias of the disease endpoints. Cancer diagnoses were based on histological findings in both studies with follow-up cytology for some cases (Rogers et al. 1993) or review by study pathologists (O’Rorke et al. 2012).

Table C-11 Information Bias – Exposure Assessment and Disease Endpoints in Human Studies of Cobalt

Study | Exposure Misclassification | Outcome Misclassification
Tüchsen et al. (1996) | Rating: ++, Direction ↓ Rationale: Exposure designated by employment in a department considered to include exposure to cobalt or not; calendar periods of different exposures not incorporated into analysis; no information on intensity, frequency, level, or duration | Rating; +++ Rationale: Incident cases of lung cancer obtained through linkage with the Danish Cancer Registry
Mur et al. (1987) Moulin et al. (1993) | Rating: ++, ↓ Rationale: Exposure was assigned based on job location in various workshops including cobalt production, calendar periods of different exposures not incorporated into analysis; no information on intensity, frequency, level, or duration. | Rating; ++ Some evidence that lung cancer cases may have been missed. Cause of death ascertained by physician interviews and medical records (Mur et al. 1987), and only by death certificates in the re-analysis (Moulin et al. 1993), resulting in one of four cases being dropped. Mortality may have missed cases certain cases with better survival (e.g., laryngeal, oral cavity and pharyngeal cancers), which were first reported by Mur et al. (1987), but not by Moulin et al. (1993).
Moulin et al. (1998) | Rating: ++ to +++, ↓ Rationale: JEM based on expert judgment and limited data from records. Intensity scores (0–9), and frequency of work time exposed (<10%, 10%–50%, >50%). JEM exposure scores for cobalt validated but did not include cobalt powder production areas. | Rating; +++ Rationale: Mortality data are adequate for lung cancer, which has a low survival rate.
(Wild et al. 2000) | Rating: ++ to +++, ↓ Rationale: Similar JEM as Moulin et al. (1998). As the focus of the study was on hard metals, exposures within other workshops (i.e., cobalt powder production) were assessed in less detail or were not precise as those for cobalt-tungsten carbide. | Rating; +++ Rationale: Mortality data are adequate for lung cancer, which has a low survival rate.
Moulin et al. (2000a) | Rating: ++, ↓ Rationale: JEM for specific job periods based on expert’s subjective quantification which was based on interviews with former and current workers in each workplace and on measurements in other French factories and published results from the literature. No airborne exposure level measurements used to validate these judgments and little information on past exposures. Categories of exposure were based on frequency, intensity, duration, and probability. | Rating; +++ Rationale: Mortality data, which is adequate for lung cancer that has a low survival rate
Grimsrud et al. (2005) | Rating: +++, ↓ Rationale: Quantitative JEM developed for nickel analysis using time- and department-specific exposure estimates plus a cobalt surrogate intensity measurement based on estimated levels of time- and department-specific periods from 3,500 personal samples of cobalt air concentrations from the breathing zone. Low level of concern for non-differential exposure misclassification as monitoring did not begin until 1973 and personnel files carried some degree of uncertainty concerning the earlier decades. | Rating; +++ Rationale: Incident cases of lung cancer obtained through linkage with the Norwegian Cancer Registry.
Rogers et al. (1993) | Rating: +; direction not known Rationale: Unlike other elements investigated, cobalt levels in food measured by a food frequency questionnaire were not available from USDA, Window of exposure implied by a single measurement of cobalt in nails (12–18 months exposure) for cancer outcomes may not be valid for induction of esophageal cancer. Single sample of toenails shown to have low to intermediate reproducibility for cobalt (Garland et al. 1993). | Rating; +++ Rationale: Cases identified through the local SEER cancer registry; diagnosis based on a positive histological finding or a positive cytology with follow-up to the attending physician to confirm the diagnosis. Potential controls with a history of any cancer were excluded.
O’Rorke et al. (2012) | Rating: +; direction not known Rationale: Window of exposure implied by a single measurement of cobalt in nails (12–18 months exposure) for cancer outcomes may not be valid for cancer induction of esophageal cancer or Barrett’s esophagus; single sample of toenails shown to have low to intermediate reproducibility for cobalt (Garland et al. 1993). | Rating; +++ Rationale: Esophageal adenocarcinoma cases had a histologic confirmation of adenocarcinoma within the esophagus and excluded in situ cancers. Available clinical and histologic records (surgical and radiological reports) were reviewed by 3 authors and a pathologist to confirm location of the tumor in the esophagus. Potential controls had no history of esophageal or any gastrointestinal cancer or Barrett’s esophagus.

### C.2.5 Selective Reporting and Analysis Bias in Human Studies of Cobalt

#### C.2.5.1 Cohort and Nested Case-control Studies of Cobalt

There is little evidence of selective reporting in any of the cohort studies. For the hard-metal studies, the focus of the analysis was not on cobalt alone; thus, few analyses were presented. For the porcelain painter and electrochemical worker studies, additional information regarding exposure and the cohort might have been reported, but this is more a problem of reduced quality of reporting than of selective reporting.

The analysis of the nickel refinery workers (Grimsrud et al. 2005) is the strongest in terms of its methods, assumptions, and statistical analysis, using categorical and continuous variables were reported and methods of model fitting described. The nested case-control analyses of stainless-steel workers (Moulin et al. 2000a) and hard-metal workers (Moulin et al. 1998) were also considered adequate and used appropriate models to evaluate exposure-response relationships.

For the hard-metal cohorts, both Moulin et al. (1998) and Wild et al. (2000) lagged exposure indices 10 years to account for disease latency. However, in contrast to Moulin et al. (1998), Wild et al. (2000) did not report detailed analyses for cobalt without hard metal, and lagged exposure indices only for the workshop analysis of hard metals, but not the analysis based on the JEM, on which the cobalt SMR was based.

#### C.2.5.2 Case-control Studies

In both the Rogers et al. (1993) and the O’Rorke et al. (2012) studies, concerns are low/minimal that the study does not provide results for all relevant measures and participants that would bias its interpretation.

Concerns with analysis bias were low/minimal in both of these studies, although O’Rorke et al. (2012) provided somewhat more detail about the assumptions and methods of their analyses. The O’Rorke et al. (2012) study, after log transforming the toenail element concentrations, used a backwards elimination approach using multivariate logistic regression investigating the association between tertiles of toenail trace element concentrations and the risk of esophageal cancer. Rogers et al. (1993) reported a categorical analysis using unconditional logistic regression to calculate ORs as estimates of the relative risk for each cancer, adjusting for the effects of potentially confounding factors. The primary table in the Rogers et al. (1993) study combined cases and controls, so it was not possible to ascertain the distribution of cases and controls across tertiles of cobalt.

Table C-12 Selective Reporting and Analysis Bias in Human Studies of Cobalt

Study | Selective Reporting | Analysis
Tüchsen et al. (1996) | Rating: +++ Rationale: No evidence that reporting of the data or analyses were limited to only a subset of the data that were collected. | Rating: ++ Rationale: SMR external analysis only conducted; no internal analyses conducted to account for potential confounding, or induction period. No exposure-response analyses.
Mur et al. (1987) Moulin et al. (1993) | Rating: +++ Rationale: No evidence that reporting of the data or analyses were limited to only a subset of the data that were collected. | Rating: +++ Rationale: Conducted cobalt-specific external and internal analyses and did not report exposure-response analyses or particular methods for analysis of the data (Mur); Moulin restricted analyses to French-born workers exposed to cobalt exclusively, to minimize bias from selection or confounding. Unclear whether adjustments for censoring or recent exposures (lagging) were considered to address the large number of electrochemical workers who worked fewer than 10 years, which would address potential bias from inclusion of short-term workers with potentially lower exposures.
Moulin et al. (1998) | Rating: +++ Rationale: No evidence that reporting of the data or analyses were limited to only a subset of the data that were collected. | Rating: +++ Rationale: Conducted internal cobalt analysis with trend analyses for exposure to cobalt alone by levels of intensity, duration, and cumulative (weighted or unweighted) doses using a fit of the ranks of the recoded variables as a test for trend.
Wild et al. (2000) | Rating: +++ Rationale: No evidence that reporting of the data or analyses were limited to only a subset of the data that were collected. | Rating: ++ Rationale: Conducted external SMR analysis only for cobalt alone with little documentation of what the models included
Moulin et al. (2000b) | Rating: +++ Rationale: No evidence that reporting of the data or analyses were limited to only a subset of the data that were collected. | Rating: +++ Rationale: Methods, assumptions, and statistical analysis are described in detail. Analyses using categorical and continuous variables were reported and methods of model fitting described
Grimsrud et al. (2005) | Rating: +++ Rationale: No evidence that reporting of the data or analyses were limited to only a subset of the data that were collected. | Rating: +++ Rationale: Methods, assumptions, and statistical analysis are described in detail. Analyses using categorical and continuous variables were reported and methods of model fitting described; and an indicator variable was included to denote first employment prior to 1930 when exposure assessments were not as reliable
Rogers et al. (1993) | Rating: +++ Rationale: No evidence that reporting of the data or analyses were limited to only a subset of the data that were collected. | Rating: +++ Rationale: Categorical analyses using unconditional logistic regression to calculate ORs as estimates of the relative risk of each cancer, adjusting for the effects of potentially confounding factors.
O’Rorke et al. (2012) | Rating: +++ Rationale: No evidence that reporting of the data or analyses were limited to only a subset of the data that were collected. | Rating: +++ Rationale: Backwards elimination approach using multivariate logistic regression investigating the association between tertiles of toenail trace element concentrations (log transformed) and the risk of esophageal cancer

### C.2.6 Study Sensitivity, Quality, and Utility of Cohort and Nested Case-control Studies

#### C.2.6.1 Cohort and Nested Case-control Studies

Factors that influence the ability of a study to detect an effect (if present) include the sample size; the exposure prevalence; the range, level, duration, window, or route of exposure; and the length of follow-up in cohort studies. Studies with greater sensitivity to detect an effect are more informative for the evaluation, and an investigation of study sensitivity can help explain heterogeneity across studies. All studies with the exception of the nickel refinery workers (Grimsrud et al. 2005) study (204 workers) observed small numbers of exposed cases of lung cancer: 3 and 4 among the electrochemical workers (Moulin et al. 1993); 15 among hard-metal workers (Moulin et al. 1998; Wild et al. 2000); 8 among porcelain painters (Tüchsen et al. 1996) and 17 among the stainless and alloyed steel workers (Moulin et al. 2000b).

Except for Grimsrud et al. (2005), all of the studies are limited with regards to the level or range of exposures, either because these were not reported nor included in the analyses (Moulin et al. 1993; Moulin et al. 1998; Mur et al. 1987; Tüchsen et al. 1996; Wild et al. 2000).

The sensitivity of the porcelain painters study to detect any effect may have been limited by potentially combining workers with high and low exposures together, diluting any effect. Tüchsen et al. (1996) reported that high levels of cobalt aluminate-spinel dust were measured in 1954 (170 particles (0.5 to 5 μg/cm^-3^) and in 1967 (150 particles); and that levels of cobalt silicate, which began to be used in both factories in 1981, initially exceeded the hygienic standard for all measurements in the range from 1.3 to 172 times (as reported by Tüchsen et al. 1996). While there were no analyses to differentiate high and low exposure levels of the two types of cobalt compounds, overall, there is information that levels of any cobalt compound changed from high to low from 1982 to 1984 and leveled off through 1990. Thus, combining low- and high-exposure workers could decrease the ability to detect an effect.

No information on exposure levels was reported for the electrochemical workers (Moulin et al. 1993; Mur et al. 1987), hard-metal workers (Moulin et al. 1998; Wild et al. 2000), or the stainless and alloyed steel workers (Moulin et al. 2000a). Moulin et al. (1998) (hard-metal workers) and Moulin et al. (2000a) (stainless and alloyed steel workers) analyzed trends across duration of exposure and un-weighted and frequency-weighted cumulative dose information, but did not provide the numbers of exposed cases across categories of these variables. Thus, it is difficult to know how many workers were exposed to higher levels or longer durations of exposure.

Most studies had sufficient follow-up time to allow for a cancer induction period. The hard-metal, stainless and alloyed steel, and nickel refinery studies (Grimsrud et al. 2005; Moulin et al. 2000b; Moulin et al. 1998; Wild et al. 2000) lagged analyses to discount years after initial exposure and prior to diagnosis.

#### C.2.6.2 Case-control Studies

The sensitivity of these case-control studies to detect effects at high and low levels is somewhat limited, given the likely low levels of cobalt in these “non-exposed” populations. Both case-control studies report low levels of cobalt in toenails, reported as categorical variables with tertile cut points (μg/g) of cobalt concentrations: O’Rorke et al. (2012) (Ireland): <0.004, 0.004 to <0.011, and ≥0.011; Rogers et al. (1993) (Western Washington state U.S.A.): <0.05, 0.05 to 0.17, and >0.17 μg/g. The range of levels in the O’Rorke et al. (2012) study are 0.002 to 0.60 μg/g (mean = 0.02 ± 0.06); Rogers et al. (1993) did not report ranges, means, or SDs. Cobalt levels in toenails from a general population sample (the Nurses’ Health Study (Garland et al. 1993)) were comparable to these levels (mean ± SD = 0.042 ± 0.023).

With respect to the differences between the levels of cobalt reported in these two papers, a U.S. Geologic Survey professional paper (Shacklette and Boerngen 1984) reported that soils of the Pacific Northwest generally have high concentrations of cobalt; however, studies of soils in Ireland and the United Kingdom have reported low or deficient soil cobalt levels in several areas (Lark et al. 2013). These studies support the differences seen in exposure distributions for these two populations and suggest that environmental exposures in different geographical areas with different metal composition may influence population levels of cobalt.