# Appendix B Chemical Properties and Exposure-related Information, Clinical Surveys and Studies, and Regulations

This appendix reports chemical properties for cobalt compounds not included in Table 1-1 because they did not meet either of the criteria for inclusion in the table (i.e., no animal or genotoxicity testing data are available and they are in commercial use greater than 100,000 pounds per year in the United States (per EPA Chemical Data Reporting rule) exposure information for cobalt levels in urine and blood (Table B-1), in hair and nails (Table B-2), and in tissues from cancer patients (Table B-3). The regulations and guidelines that are likely to decrease human exposure to cobalt and cobalt compounds are reported in Section B.3.

## B.1 Chemical Properties

The chemical forms of cobalt listed in Table B-1 below were not included in Table 1-1 because they did not meet either of the two criteria for inclusion in that table (i.e., availability of animal or genotoxicity testing data for these compounds or in commercial use greater than 100,000 pounds per year in the United States (per the EPA Chemical Data Reporting rule)). For many of these cobalt compounds listed in the table below, solubility in water and bioaccessibility (based on % solubility in gastric/lysosomal fluids) are not particularly correlated. Most of the compounds are fairly bioaccessible but not always soluble in water. For example, as shown in Table B-1, cobalt trihydroxide and cobalt borate propionate are both bioaccessible but the trioxide is insoluble in water while the borate propionate is water soluble.

Table B-1 Physical and Chemical Properties for Additional Chemical Forms of Cobalt

Name | CAS No. | Formula | Molecular Weight | Physical Form | Solubility (Grams per 100 cc Cold Water) | Bioaccessibility (% Solubility in Gastric/Lysosomal Fluids)
Hydroxide oxide | 12016-80-7 | CoOOH | 91.9 | Solid | 0.00007 | 21/42
Trihydroxide | 1307-86-4 | Co(OH)_3_ | 110.0 | Pasty liquid | 0.00013 | 65/80
Lithium dioxide | 12190-79-3 | CoO_2_Li | 97.9 | Solid | 0.00003 | 26/4
Isononanoate | 84255-52-7 | Co(C_9_H_17_O_2_)_2_ | 373.4 | Liquid | 0.705 | 91/89
Neodecanoate | 27253-31-2 | Co(C_10_H_19_O_2_)_2_ | 401.5 | Liquid | 0.0772 | 83/72
Acetyl acetonate | 14024-48-7 | Co(C_5_H_7_O_2_)_2_ | 257.2 | Solid | 0.516 | 100/96
Borate propionate | 91782-61-5 | BO_3_(CoC_3_H_5_O_2_) _3_ | 454.8 | Solid | 3.33 | 89/88
Borate 2-ethylhexanoate | 91782-60-4 | BO_3_(CoC_8_H_15_O_2_) _3_ | 665.3 | Solid | 0.994 | 88/92
Borate neodecanoate | 68457-13-6 | BO_3_(CoC_10_H_19_O_2_) _3_ | 749.5 | Pasty liquid | 0.190 | 100/87
Tallate | 61789-52-4 | – | – | Pasty liquid | – | 62/48
Resinate | 68956-82-1 | – | – | Solid | 0.00335 | 9/14

## B.2 Exposure

The values for urine cobalt listed below are in Table B-2 are also illustrated in Figure 2-1 in Section 2. Values identified for the following exposure groups are listed in the table for: (1) general population, (2) environmental exposure, (3) occupational exposure, (4) medical (hip) implants functioning normally, and (5) medical (hip) implants that have failed. Values for cobalt in hair and nails are reported in Table B-3 and also illustrated in Figure 2-2 for (1) the general population, (2) environmental exposure, (3) occupational exposure, and (4) hip implants.

Table B-2 Values for Urine and Blood Cobalt Levels (Means or Medians) in the United States and Other Countries^a^

Reference Location | Study Population | Exposure Group (# People or Samples) | Urine Cobalt (μg/L)^a^ | | Serum Plasma, or Blood Cobalt (μg/L)^a^
General Public
Bibi et al. (2016) Pakistan | Control group that never drank arsenic-contaminated water from 48 total subjects, including children (10–15 yr) and 2 groups of adults (25–35 yr; 40–50 yr) | Control (N not reported) | Mean (SE) Units NR^h^ 0.07 ± 0.01 | | Blood Mean (SE) Units NR 0.08 ± 0.03
Bradberry et al. (2014) United Kingdom | Normal ranges for UK | – | – | | Blood or serum <0.6
Centers for Disease Control and Prevention (CDC) and National Center for Health Statistics (NCHS) (2011) United States | – | (2,504) | 0.326 ^b,c^ GM | | –
Dunstan et al. (2005) England | Controls for patients receiving a hip implant | Controls (4) | Mean (95% CI) 0.6 (0.40–0.74) | | Blood Mean (95% CI) 0.69 (0.43–0.89)
De Boeck et al. (2000) Belgium, Norway, Finland (cobalt refineries), Sweden, England (hard-metal plants) | Matched controls from 2 cobalt refineries and two hard metal-producing plants | Controls (27) | GM ± SD 1.7 ± 1.6 | | –
Nemery et al. (1992) Belgium | Workers in workshops in the diamond polishing industry (sawing diamonds or drawing jewelry) not thought to be exposed to cobalt (controls for occupational study) | (48) | 2.3 ± 1.8 | | –
Angerer (1989) (as reported in IARC 1991) Germany | NR | (NR) | 0.01 (NR) | | Blood (range) 0.2–1.3
Alexandersson (1988) Sweden | Workers not exposed to cobalt (controls for occupation study) | (25) | [0.4 (0.1–2.2)] | | Blood [0.5 (0.1–1.2)]
Christensen and Mikkelsen (1986) Not specified | Porcelain workers without exposure to cobalt (controls for occupational study) | (46) | μg/g creatinine^e,f^ [0.8 (0.04–10.7)] | | Blood 0.24 (0.05–0.6)
Hartung (1986) (as reported in IARC 1991) Not specified | – | (NR) | – | | Serum 0.1 (NR)
Ichikawa et al. (1985) Not specified Japan | Office workers (controls for occupational study) | (20) | 2.0 ± 1.0 | | Blood 1.9 ± 1.1
Lewis et al. (1985) (as reported in IARC 1991) Not specified | – | – | – | | Serum 0.28 (NR)
Scansetti et al. (1985) Italy | “White collar” workers (control for occupational study) | (NR) | 0.41 ± 0.22 | | –
Andersen and Høgetveit (1984) (as reported in IARC 1991) Not specified | NR | (NR) | – | | Plasma 0.15 ± 0.07
Mikkelsen et al. (1984) (as cited in IARC 1991) Not specified | – | (NR) | 0.94 (0.05–13.8) | | –
Ostapczuk et al. (1983) (as reported in IARC 1991) Not specified | NR | (NR) | – | | Blood 0.09 ± 0.02
Kasperek et al. (1981) (as reported in IARC 1991) Not specified | NR | (NR) | – | | Plasma 0.195 ± 0.015
Schumacher-Wittkopf and Angerer (1981) (as reported in IARC 1991) Not specified | NR | (NR) | 0.38 (0.1–0.75) | | –
Alexandersson and Swensson (1979) (as reported in IARC 1991) Not specified | NR | (NR) | – | | Blood 0.5 ± 0.1
Versieck et al. (1978) (as reported in IARC 1991) Not specified | NR | (NR) | – | | Serum 0.108 ± 0.06
Hip Implants (stable)
Savarino et al. (2014) Not reported; authors from Italy | Metal on metal hip resurfacing (HR, 2013 and 2014 studies) and total hip replacement patients (THR, 2013 study) Not clear if HR patients overlap in the two studies | Controls (48) THR mean 121 mo (16) HR mean 105 mo (25) HR follow-up 2 yr (14) 5 yr (19) 9 yr (22) | – | | 0.3 (0.1–0.5) 0.7 (0.3–1.6) 1.2 (0.3–2.5) 1.2 ± 0.6 1.1 ± 0.3 0.90 ± 0.12
Sidaginamale et al. (2013) United Kingdom | Metal on metal hip arthroplasty (total hip or articulating surface replacement) patients; tested for cobalt levels at various times after implant (mean times reported) | Controls (3,042) Implant #1 32 mo (416) Implant #2 55.4 mo (165) Implant #2 66 mo (467) | – | | Serum^d^ 0.5 (0.3–6.7) 2.99 (0.20–228) 2.29 (0.65–190) 2.63 (0.37–204)
Zeh et al. (2007); Zeh et al. (2009) Not reported; prostheses from Germany and procedure carried out in Germany | Metal-on-metal artificial lumbar disc implant patients followed up at different times post operation | Controls (5) Patients; avg.; range follow-up (10) 14.8; 11–22 mo 36.7; 32–43.1 mo | – | | Serum 0.72 ± 0.76 4.75 ± 2.71 1.89 ± 1.54
Witzleb et al. (2006) Not reported; replacements were from UK and Switzerland | Hip resurfacing arthroplasty and metal on metal total hip replacement (THR) patients | Controls (130) Hip resurfacing 3 mo (56) 24 mo (23) THR (24 mo) bilateral (3) unilateral (34) | – | | Serum^d^ 0.25 (NR) 2.17 (NR) 4.28 (NR) 3.18 (NR) 1.70 (NR)
Dunstan et al. (2005) England | Patients receiving a metal-on-metal hip implant because of bone cancer; 10 survivors with samples, 5 of which retained their original implants (3 metal-on-metal, 2 metal-on-polypropylene); 5 converted to metal-on-polyethylene | Type of stable implant Metal-on-polyethylene (2) Metal-on-metal (3) Converted from metal-on-metal to metal-on-polypropylene (5) | Mean (95% CI) 1.0 (NR) 12.2 (3.6–18.0) 2.88 (1.3–7.8) | | Blood Mean (95% CI) 0.48 (0.5–0.5) 1.97 (1.1–2.4) 0.65 (0.3–1.1)
Adami et al. (2003) Italy | Metal-on-metal total hip replacement patients | Controls (15) Patients (15) | – | | Blood 0.3 ± 0.1 4.1 ± 1.5
Lhotka et al. (2003) Not reported; hip manufacturers are European | Metal-on-metal hip replacement patients 131 implant #1 128 implant # 2 Patients divided into 5 groups and sampled at different time periods (mo) post operations | Controls (31) Implant #1 Immediate PO (24) 3–6 mo (27) 12–15 mo (27)) 35–38 mo (28) 42–48 mo (25) Implant #2 Immediate PO (24) 3–6 mo (25) 12–15 mo (27) 35–38 mo (26) 42–48 mo (26) | – | | Blood 0.7 ± 0.45 3.23 ± 2.0 10.9 ± 3.2 23.3 ± 6.9 36.6 ± 10.2 17.0 ± 15.7 8.1 ± 4.9 14.8 ± 6.4 33.6 ± 17.1 17.4 ± 7.4 27.7 ± 18.0
Schaffer et al. (1999) Not reported; authors from Austria and prostheses from Austria | Metal-on-metal total hip replacement (76 patients). Cobalt measured at different times in subsets of the population post operation | Controls (26) Patients 1-yr PO (22) 2-yr PO (25) 3-yr PO (29) | 0.4^d^ (0.1–1.1) 5.5^d^ (0.2–13.2) 5.7 (estimated from graph) 10.3 (estimated from graph) | | Blood^d^ 1.1 (0.6–2.0) 1.5 (0.3–5.5) 2.1 (estimated from graph) 2.0 (estimated from graph)
Hennig et al. (1992) (as cited in Schaffer et al. 1999) Not specified | Metal-on-metal total hip replacement patients | (10) | 3.8^d^ (2.1–286.2) | | –
Sunderman et al. (1989) United States | Metal-on-polyethylene hip (N = 21) Pre and post implantation NB: The pre-operative group included patients receiving either Ti-Al-V or Co-Cr prostheses and knee implants | Controls (42) Patients (Time sampled) 6–120 wk PO (NR) | μg/g creatinine^e^ 0.5 ± 0.4 (SE) 0.7 ± 0.3 | | Serum 0.05 ± 0.01 (SE) 0.13 ± 0.05
Medical implants (unstable)
Bradberry et al. (2014) Not reported; authors from UK | Failed hip replacement patients (18) with systemic toxicity (e.g., neuro-ocular toxicity, cardiotoxicity, thyroid toxicity) | Total with levels (17) Metal-on metal (8) Ceramic (9) | – | | Median peak 398 (14–6,521) 34.5 (13.6–399) 506 (353–6,521)
Rodriguez de la Flor et al. (2013) Spain | Hip implants requiring revision surgery | Before revision (11) After revision (11) | 205.6 ± 310.6 44.3 ± 94.9 | | Serum 25.8 ± 40.6 13.1 ± 29.3
Dunstan et al. (2005) England | Patients receiving a metal-on-metal hip implant because of bone cancer; 10 survivors with samples, 5 of which retained their original implants | Radiologically loose hip implants (2) | Mean (95% CI) 205 (140, 270) | | Mean (95% CI) 35.5 (19, 52)
Environmental exposure
Cheyns et al. (2014) D.R. Congo | Adults and children (<14 yrs) living in urban and rural communities close to metal mining and/or refining plants or villages near a lake receiving effluents from metal refining plants | Controls Children (24) Adults (57) Lake Children (13) Adults (47) Polluted communities Children (32) Adults (79) | μg/g creatinine^e^ Mean^b^ (25%–75% CI) 4.2 (2.6–7.2) 2.7 (1.3–5.3) 14.0 (7.5–21.0) 9.4 (4.0–19.8) 27.9 (13.4–62.7) 11.7 (7.1–22.0) | | –
Moreno et al. (2010) Mexico | Urine cobalt levels in children in the Taxco mining area of Southern Mexico Reference values were reported in the literature for children from other countries | Reference Children (35) | 2.2 (NR) 18^d^ (3–47) | | –
Occupational exposure
Cobalt production: Refining
Lantin et al. (2011) Belgium | Cobalt refinery workers | Cobalt production (249) | | μg/g creatinine^f^ 3.90^e^ (0.3–204) | Blood 1.0 (<0.5–32.0)
De Boeck et al. (2000) Belgium, Norway, Finland (cobalt refineries), Sweden, England (hard metal plants) | Workers exposed to cobalt dust from 2 refineries and hard metal dust from two hard metal-producing plants, location not specified | Co refinery workers (24) Hard metal workers (29) | | GM ± SD 21.5 ± 2.1 19.9 ± 2.4 | –
Thomassen et al. (1999) Russia | Nickel refinery workers | Roasting (25) Anode casting [old] (20) Anode casting [new] (11) Electrorefining [old] (23) Electrorefining [new] (10) Rinsing [old] (18) Rinsing [new] (12)) | | 5.8 ± 5.7 8.4 ± 9.0 14 ± 37 2.9 ± 4.8 2.7 ± 2.4 8.7 ± 11 16 ± 19 | –
Cobalt production: Cobalt salts or oxide
Coombs (1996) South Africa | Cobalt oxide workers, pre- and post-environmental and exposure controls (plant converts cobalt metal to cobalt oxide) | Pre-controls (43 samples across 8 job titles) Post-controls (91 samples across 12 job titles) | | 454.6 μg/g creatinine^e^ 68.5^i^ | –
Swennen et al. (1993) Belgium | Production of cobalt powder, oxides, and salts | Day and shift Mon; pre-shift (82) Mon; post-shift (82) Fri; pre-shift (82) Fri; post-shift (82) | | μg/g creatinine^b,f^ 21.1 (0.3–488) 52.9 (2.7–2245) 40.6 (0.9–1288) 69.8 (1.6–2038) | Blood 9.7 (2.0–120) 11.0 (2.0–120) 11.2 (2.0–110) 12.7 (2.0–120)
Angerer et al. (1985) Germany | Foundry workers using cobalt as a powder (4 groups) or salt (3 groups) | All 7 groups (40) | | Range of means 18.9–438.4 | Blood 4.9–47.9
Metallurgical
Beaucham et al. (2014) (State NR), United States | Metallurgical workers at an orthopedic implant manufacturing company | (21) | 0.6^d^ (0.3–2.0) | | –
Deng et al. (1990) Michigan, United States | Metallurgical Site visit; 261 urine samples from 39 workers; up to 7 specimens /person per day | Monday Pre-shift (33) Post-shift (32) Tuesday Pre-shift (34) Post-shift (34) Wednesday Pre-shift (36) Post-shift (36) Thursday Pre-shift (35) Post-shift (0) | μg Co/mg creatinine^g^ 21.3 ± 28.6 44.3 ± 65.7 26.4 ± 32.1 50.4 ± 71.7 36.3 ± 56.7 50.2 ± 78.0 40.8 ± 58.6 ND | | –
Cemented carbides (hard meals) and bonded diamonds (diamond abrasives)
Sahakian et al. (2009) Alabama, United States | Cemented carbides and bonded diamonds Site visit at three cemented tungsten manufacturing facilities; urine collected post shift near end of work week | All plants (84) Areas with air levels > recommended exposure limits Reclamation (7) Powder mixing (5) Milling (5) Spray drying (2) Pressing (10) Shaping (4) | | μg Co/g creatinine GM^b^ (95% CI) 9.6 (7.1–12.8) 25.2 (8.7–73.2) 14.5 (2.5–84.9) 134.7 (96–189) 20.0 (0.9–438) 30.3 (14.9–61.8) 25.7 (5.0–133.5) | Blood GM^b^ (95% CI) 2.0 (1.5–2.5) 4.0 (1.2–13.2) 3.7 (0.6–23.6) 15.6 (11.2–22) 3.2 (1.8–5.8) 3.7 (2.6–5.2) 3.3 (2.2–5.1)
Kraus et al. (2001) Germany | Hard-metals production workers (87) in different workshops | Forming (23) Pressing (30) Heavy alloy production (3) Powder processing (14) WC production (4) Sintering (6) Grinding (5) Maintenance (2) | | μg/g creatinine^e^ 13.5 (0.8–106.4) 5.5 (0.4–35.9) 1.6 (1.1–2.2) 28.5 (0.8–227.8) 2.1 (0.3–5.7) 4.1 (0.3–9.6) 2.2 (0.2–6.0) 3.0 (1.3–4.7) | –
Linnainmaa and Kiilunen (1997) Finland | Hard metal workers; manufacturing or sharpening blades at 16 workplaces | (131) | | 14.2 (0.5–160) | –
Ferdenzi et al. (1994) Italy | Production of diamond cutting wheels workers (20) | Pre- & post-workplace modifications (Friday end of shift) 1988 (NR) 1991 (15) | | 550 85 | –
Mosconi et al. (1994a) Province of Bergamo, Italy | Diamond abrasive production and hard metal production | People exposed (314; numbers not reported for subgroups) Diamond abrasive production Mold-filling Sintering Grinding Mechanical-working Hard-metals exposures Grinding Tool production Hard metal alloy filling Other | | 587 (39–2,100) 193 (102–390) 151 (34–520) 67.2 (14–165) 31.5 (0.8–730) 19.4 (0.8–100) 4.8 (0.8–18) 2.85 (0.8–72) | –
Sabbioni et al. (1994a) Italy | Hard metal workers (251) in four locations; three were hard metal mfg/tool production; Pavia produced diamond wheels | Bergamo (88) Milan (24 urine, 20 blood) Pavia- powder mixing (23) Turin (28) | | 303.6 ± 837.5 13.9 ± 9.7 61.1 ± 58.2 32.5 ± 35.7 | Blood 45.6 ± 66.9 5.06 ± 4.37 NR NR
Suardi et al. (1994) Italy | Diamond abrasive production and grinding activities workers (159) | Producer (6) Grinder (87) Hard-metal form grinder (9) Others (76) Total (178) | | μg/g creatinine^f^ 50.17 ± 24.30 10.89 ± 15.23 7.67 ± 5.94 4.55 ± 7.31 9.17 ± 14.79 | –
Nemery et al. (1992) Belgium | Diamond polishers using cobalt-containing disks workers in 10 workshops (194); 5 with low Co exposure and 5 with high exposure | Exposure category Low (73) High (86) | | 9.0 ± 7.2 25.2 ± 23.8 | –
Burr and Sinks (1988) Michigan, United States | Cemented carbides and bonded diamonds Site visit; 149 urine samples from 24 tool manufacturing workers (up to 7 specimens/person per day) | Monday Pre-shift (19) Post-shift (20) Tuesday Pre-shift (21) Post-shift (23) Wednesday Pre-shift (20) Post-shift (23) Thursday Pre-shift (21) Post-shift (0) | | Creatinine adjusted 10.8 ± 7.0 19.0 ± 14.8 18.3 ± 20.3 25.1 ± 21.4 15.0 ± 15.4 27.0 ± 21.9 22.1 ± 26.2 ND | –
NIOSH (1987) South Carolina, United States | Cemented carbides and bonded diamonds Site visit for grinding of tungsten carbide tools (post-sintering process) | Pre-shift (10) Post-shift (10) Change from pre-to post-shift (10) | | μg/g creatinine^e^ [10.5] (4.7–19.0) [18.1] (8.4–27.7) [7.6] (1.4–15.1) | –
Kusaka (1996); Kusaka et al. (1986) Asia | Hard metal asthma patients (8) | (4) | | (1–29) | Blood (2.8–4.2)
Posma and Dijstelberger (1985) The Netherlands | Hard metal production workers | 6 subgroups (27) Sawing (3) Pressing/mixing (4) Grinding (10) Sintering (3) | | μg/g creatinine^e^ 64.3 (45–102) 45.1 (31–56) 25.5 (5.8–39) 6.4 (2.5–11.1) | Blood 18.3 (9.6–32) 11.5 (10.4–12.9) 8.6 (4.0–14.6) 2.0 (<0.3–4.4)
Pellet et al. (1984) (reported in IARC 1991) Not specified | Hard metal production workers | Co powder production (6) Pre-sintered WC (15) Hard metal use (7) | | 35.1 9.6 11.7 | –
Chemicals and pigments: Pottery or plate painting or cloisonné
Christensen and Poulsen (1994); Raffn et al. (1988); Christensen and Mikkelsen (1986) Denmark | Adult female pottery painters at two factories | 10 yr surveillance date 1982 (46) 1984 (49) 1989 (145) 1991 (107) Type of Co exposure soluble cobalt (46) slightly soluble cobalt (15) Exposure timing/1982 (46) After 6 wk vacation 4 wk after returning to work | | μg/g creatinine^e,f^ [69.5] [21.7] [12.7] [9.8] [4.8 (<0.1–26.2)] [77.0 (2.2–848.0)] | Blood^g^ 2.16 ± 3.72 0.63 ± 0.27 [0.5 ± 0.3] [2.2 ± 3.7]
Arai et al. (1994) Japan | Cloisonne workers | Glaze workers (49) | | 1.75 ± 2.81 | Blood 1.5 ± 0.9
Other or unspecified
Afridi et al. (2009) Pakistan | Steel mill workers | Non-exposed (75) Quality control (35) Production (56) | | 1.5 ± 0.4 2.3 ± 0.4 3.6 ± 0.6 | 1.2 ± 0.3 2.4 ± 0.6 3.9 ± 0.8
Scansetti et al. (1998) Italy | Not specified | Monday (6) Thursday (6) | | 13.2 ± 9.8 30.9 ± 21.9 | –
Chadwick et al. (1997) United Kingdom | Thermal spraying workers (34) at 6 worksites in the industrial processes | Grit blasting (5) Plasma spraying (89) Detonation gun spraying (27) | | μg/g creatinine^d,e,f^ 6.6 (0.16–11.0) 0.5 (0.16–139) 8.9 (0.73–34.1) | –
Meecham and Humphrey (1991) Not reported; authors from UK | Unspecified occupational exposure to Co | (1) | | NA | 234

Urine values are plotted in Figure 2-1; values plotted for the general public or unexposed controls are shown in bold italic while those for other exposures are in bold).

Co = cobalt; NF = no studies found, NR = not reported in IARC or primary reference; PO = post-operation; WC = tungsten carbide.

^a^ Mean ± standard deviation or range () unless stated otherwise. Studies are arranged within groups by most recent to oldest by publication date.

^b^ Geometric mean.

^c^ Reported urinary cobalt concentration is the geometric mean for the most recent (2011-2012) National Health and Nutrition Examination (NHANES) survey year for which data are available. Urinary cobalt data ranged from 0.316 to 0.379 μg/L for 1999 to 2012 (CDC 2015).

^d^ Median.

^e^ It is generally accepted that 1 L of urine contains 1 g creatinine.

^f^ Value reported by authors as μg/mmol creatinine or μmol/mmol creatinine; converted to μg/g creatinine using the following conversion factor: 1 mol creatinine = 113.1 g creatinine; nmol/L blood converted to μg/L using the MW of cobalt = 58.9.

^g^ Values were reported in units of μg/mg creatinine; however, μg/mg creatinine appears to be a typographical error. All other HHEs reported urine values in either μg/L or μg/g creatinine.

^h^ Not graphed because units not reported by authors.

^i^ Values reported are weighted means across the 8 or 12 job titles.

Table B-3 Values for Hair and Nail Cobalt Levels in the United States and Other Countries^a^

Reference Location | Study Population | Exposure Group, Number of People or Samples (N) | Hair Concentration, μg/g^b^ | Nails Concentration, μg/g^b^
General Population
Carneiro et al. (2011) Brazil | Healthy male and female urban students 12–18 years of age from 9 public schools in Porto Alegre | (126) | 0.008 ± 0.007 | 0.08 ± 0.1
Dongarrà et al. (2011) Sicily | Students 11–13 years of age | Overall (136) Males (38) Females (98) | 0.19 ± 0.33 0.26 ± 0.51 0.16 ± 0.22 | –
Elenge et al. (2011) Province of Katanga, Congo | General, non-industrialized population (medical students with no occupational history of exposure to metals) in the copper-belt. | 109 | Mean (5 to 95 percentile) 1.67 (0.8–2.02) | –
González-Muñoz et al. (2010) Spain | Normotensive and hypertensive postmenopausal women | Normotensive (12) Hypertensive (14) | Median 0.02 (0.01–0.03) 0.03 (0.02–0.3) | –
Bergomi et al. (2002) Emilia-Romagna region, No. Italy | Randomly sampled controls for an ALS study enrolled in the Italian National Health Service | Controls (40) | – | Median (25–75 percentile) 0.018 (0.009–0.041)
Campbell et al. (1988) UK | Healthy controls (hospital staff, volunteers) on no medication | Controls (160) | μg/mL 0.07 ± 0.02 | –
Kanabrocki et al. (1979) Unknown—U.S. institutions | General population - details NR | Females (9) Males (11) | – | 0.07 (0.02–0.15) 0.04 (0.01–0.15)
Environmental
Bibi et al. (2016) Lahore district, Punjab province, Pakistan | Persons of various ages from 3 sites near industrial areas used for agricultural purposes ranked as high, medium, and low exposure and controls living far from arsenic-contaminated regions | Risk area Low risk (12) Medium risk (12) High risk (12) Control (12) | – | 0.59 ± 0.02^c^ 0.53 ± 0.04 0.32 ± 0.07 0.22 ± 0.07 p = 0.00
Occupational
Afridi et al. (2009) Pakistan | Steel mill workers and non-exposed males 25–55 years of age | Production (56) Quality control (35) Control (75) | 4.67 ± 0.8 2.48 ± 0.5 1.1 ± 0.2 | –
Sabbioni et al. (1994a) Bergamo, Milan, Pavia, and Turin, Italy | Hard metal workers (male and female) from four plants; three were hard metal manufacturing/tool production; hair and nail data not available from the diamond workers | Bergamo; hair (90); toenails (92) Milan; hair (22); toenails (23) Turin; hair (28); toenails (NR) | 49.09 ± 114.2 9.6 ± 10.7 13.4 ± 25.3 | 53.8 ± 107.2 18.9 ± 27.3
Bencko et al. (1986) Czech Republic | Nickel (Ni) and Co production workers, and age-matched healthy workers unexposed to Co | Exposed to Co (30) Exposed to Ni (33) Unexposed (27) | 96.8 ± 59.7 3.3 ± 2.0 0.38 ± 0.27 | –
Hip Implants
Rodriguez de la Flor et al. (2013) Spain | Patients with metal-on-metal resurfacing arthroplasty before and after revision surgery | Before revision surgery (i.e., unstable) (11) After revision surgery (11) | 147.4 ± 233.3 47.11 ± 74.20 p = 0.249 | –
Liu et al. (2011) China | Patients with metal-on- metal hip resurfacing arthroplasty Compared with patients with metal-on-polyethylene hip arthroplasty | Metal-on-metal (22) Preop 6 mos post-op 12 mos post-op | 4.4 ± 2.13 53.3 ± 11.84 47.4 ± 10.0 p = 0.0000 | –
| | Polyethylene bearings (22) Preop 6 mo post-op 12 mo post-op | 3.2 ± 2.42 3.4 ± 1.69 4.2 ± 2.46 p = 0.3371 | –

Hair values are plotted in Figure 2-2; values plotted for the general public or unexposed controls are shown in bold italic while those for other exposures are in bold.

NR = not reported.

^a^ Reported values are means ± standard deviations or ranges () except where noted (e.g., medians or percentiles). Studies are arranged from most recent to oldest by publication date.

^b^ Other units noted in table.

^c^ No units were reported by the authors in this paper, but Bibi et al. (2016) reported results for arsenic for the same population as μg/g hair and nails.

## B.3 Clinical Surveys and Studies

Several publications were identified that measured trace metals (such as heavy metals and essential metals) in tissue (such as tumors of different stages or normal tissue) or surrogates (e.g., hair, nails, blood) from cancer patients with a referent group (e.g., healthy humans, other diseases) or referent tissue (e.g., non-tumor from the same or different subjects). Because this information may inform several other sections (such as exposure, disposition, and toxicokinetics), these studies are discussed in below and are cross-referenced in the other sections.

For most studies, the source of the exposure is unknown with the exception of the study (reported in a series of publications) of copper smelter workers exposed to cobalt and other metals (Gerhardsson et al. 1985; Gerhardsson and Nordberg 1993; Gerhardsson et al. 1984). The studies varied in design and reporting quality. The source (i.e., underlying population) and methods for selecting the “cases” and “controls” were unclear. Three studies were hospital-based case-control studies with defined populations (Benderli Cihan et al. 2011; Kuo et al. 2006; Zhu et al. 2011), one of which included patients with other lung diseases as the referent group (Kuo et al. 2006); however, none calculated a risk estimate for exposure to cobalt and cancer. Most studies were conducted in Asia or in countries in the Middle East; few studies were conducted in Europe.

Findings from the studies are briefly discussed below: Section B.3.1 discusses the studies of patients with cancers of the lung and larynx, which have been identified as cancer sites of interest, and Section B.3.2 discusses studies of patients with cancer or tumors at other tissue sites (breast, brain, colon, leukemia, and thyroid).

### B.3.1 Studies of Lung or Laryngeal Cancer Patients

Table B-4 describes the findings from five studies that measured cobalt in lung tissues and two studies that measured cobalt in non-target (e.g., surrogate) tissues of lung cancer patients (living or deceased) and referents (healthy controls or living or deceased patients with lung disease or other cancers). In the only study of workers likely to be highly exposed to metals, Gerhardsson et al. (1993; 1985; 1984) reported cobalt levels in lung tissue from deceased copper smelter workers. Cobalt levels were higher (although not significantly so) in lung tissue from workers who died of lung cancer compared to rural referents who died of other causes (primarily cardiovascular disease). However, cobalt levels were also significantly higher among all workers who died of other cancers compared to the referents, and similar relationships were reported between workers exposed to other metals and referents. Thus, this study can only provide evidence to support exposure to cobalt and not whether exposure to cobalt was associated with lung cancer.

Of the two clinic or hospital-based studies that measured cobalt in lung tissues from cases with lung cancer and referents, lung-tissue cobalt levels were similar between the two groups in the study using referents who died of other cancers (Adachi et al. 1991) but were significantly lower in the study using living patients with lung disease as the referents (De Palma et al. 2008). Cobalt levels did not differ significantly between tumor and non-tumor tissues from the same patients in two studies (De Palma et al. 2008; Zhang et al. 2012a) or by stage of lung cancer (I/II vs. III) in a study by Kuo et al. (2006). Due to the choice of diseased referents in all of these studies, each had limited sensitivity to detect effects of cobalt on lung cancer.

The two lung cancer studies measuring cobalt in surrogate tissues of cases and non-diseased referents, a hospital-based case-control study in Turkey (Benderli Cihan et al. 2011) and a case-referent study in Pakistan (Qayyum and Shah 2014), had more defined methods for participant selection. Both studies found significantly higher levels of cobalt in hair and/or nails among cases compared to matched controls (Benderli Cihan et al. 2011) or volunteer referents (Qayyum and Shah 2014). Benderli Cihan et al. (2011) reported that cobalt levels in both nails and hair decreased with increasing cancer stage.

There were two small studies of laryngeal cancer, a Polish study investigating cobalt in normal and laryngeal tissue in cases (Klatka et al. 2011), and an Italian study measuring cobalt in tissue and plasma in cases and plasma in “normal males” (Collecchi et al. 1986). Both studies found higher cobalt levels in the laryngeal tumor tissue than the non-tumor tissues in the same patient. In addition, Klatka et al. (2011) reported higher cobalt levels in stage 4 tumors compared to stage 3 tumors. The findings by stage and by tissue type suggest that the carcinogenesis process may alter metal balances. Levels were significantly higher in laryngeal tissues among Polish patients from rural regions compared to those from urban areas suggesting the possibility of a role for environmental exposure to cobalt (Klatka et al. 2011). The Italian study found significantly higher levels of cobalt in the plasma from laryngeal cancer patients compared to the non-diseased referent group; however, selection of the cases and healthy subjects was not defined. No association between laryngeal cancer and cobalt concentration in toenails was found in a population-based case-control study of aerodigestive cancers from Washington state, United States (see Human Cancer Studies, Section 4).

### B.3.2 Other Cancers

Nine clinical studies were identified that measured cobalt level in target tissues (N = 3) (e.g., same organ as cancer) or surrogate tissue (N = 6) (e.g., serum, urine, and nails) of cancer patients and referents (see Table B-5). In addition to these studies, the occupational study of copper smelter workers discussed above for lung cancer (Gerhardsson et al. 1993; Gerhardsson et al. 1985; Gerhardsson et al. 1984), measured cobalt in liver and kidney tissues. In contrast to the findings for lung tissues, cobalt concentrations in liver and kidney tissue were similar among deceased workers as the rural referents (Gerhardsson et al. 1984).

Two clinical studies measured cobalt in target tissues in tumor and non-tumor tissues; compared to non-tumor tissue, one small study (4 individuals) found levels higher in the tumor tissue (thyroid, Reddy et al. 2002)and the other study found lower levels in the tumor tissue (colon polyps, Alimonti et al. 2008). In the latter study, cobalt levels were similar in tissues from controls as the non-tumor tissue from the lung cancer patients. In a study using breast biopsies (Kanias et al. 1994), cobalt levels were two-fold higher (although not statistically significant) in individuals with fibroadenoma than with fibrocystic disease.

Three of the six studies that measured cobalt in surrogate tissue (hair, urine, serum) found statistically higher levels in cancer patients than “healthy” or “normal” subjects; two studies measuring hair in either all cancer patients (Pasha et al. 2007) or stage III breast cancer (Benderli Cihan et al. 2011) and one study measuring serum in liver cancer cases (Yin 1990). Two studies of leukemia found non-significantly higher levels of cobalt compared to healthy subjects, one measuring cobalt in serum in acute leukemia patients (Demir et al. 2011) and the other measuring cobalt in urine of childhood leukemia patients (Zhu et al. 2011). In the sixth study, cobalt concentrations were similar from brain cancer patients and “healthy humans” (Arslan et al. 2011).

### B.3.3 Synthesis

Overall, several studies found statistically significantly higher levels of cobalt in surrogate tissues (hair, nails, urine, or serum) from patients with several different types of cancer including all cancers (Pasha et al. 2007), cancer of the lung (Benderli Cihan et al. 2011; Qayyum and Shah 2014), larynx (Collecchi et al. 1986), liver (Yin 1990), or breast (Benderli Cihan et al. 2011) compared to healthy controls. However, except for lung cancer, there was only one study per specific cancer site. Findings were less consistent in studies measuring cobalt levels in target tissues, as the referent groups included people with or who had died from other cancers or diseases rather than healthy controls, which complicates their interpretation. In other studies of lung or breast cancer, there were no significant differences in cobalt levels between the cancer patient and referent group (lung cancer, Adachi et al. 1991; De Palma et al. 2008); breast cancer (Kanias et al. 1994) or levels were higher in the referent group (lung disease) compared to lung cancer patients (Kuo et al. 2006). In a series of studies (Gerhardsson et al. 1993; Gerhardsson et al. 1985; Gerhardsson et al. 1984), cobalt levels were higher in lung tissues (but not liver or kidney) from cancer cases from deceased cobalt-exposed workers compared to the same type of tissue from the rural referent group who died from other causes.

Studies comparing cobalt levels in tumor and non-tumor tissue (from the same or different subjects) or by cancer stage were conflicting and were limited by only one or two studies available for each type of cancer. Higher levels of cobalt were found in tumors of the larynx (Collecchi et al. 1986; Klatka et al. 2011) and thyroid (Reddy et al. (2002) than non-tumor tissue; however, lower levels of cobalt were found in colon polyps (significant Alimonti et al. 2008) or lung tumors (Zhang et al. 2012b) although not significantly so) than the corresponding normal tissue. For cancer stage, higher levels of cobalt were found in tissues in more advanced cancers for laryngeal cancer; while for lung cancer, cobalt levels were similar across stage when measured in lung tissue but decreased with increasing cancer stage when measured in nails and hair.

None of the studies were able to distinguish whether metal levels could be a cause of cancer or whether the cancer process itself affects metal balances, although the focus of some studies was on this latter concern. There are several limitations of these studies that make interpretation of results difficult. Co-exposures with cobalt are present, and cobalt concentrations are correlated with other metals in the positive studies; most studies include very few subjects; and there is inadequate information on how cases and referents were selected. In general, more information was provided on cases than referents, although whether certain cases were selected by convenience, or according to a systematic protocol was not clear.

Table B-4 Findings from Studies That Measured Cobalt in Tissues (Means or Medians) of Lung and Larynx Cancer Patients and Referents

Reference | Population | Cancer Tissue | Number of Subjects | Category | Co Levels (μg/g Dry Tissue) | Exposure Methods | Comments
Adachi et al. (1991) | Japanese clinical survey | Lung cancer Lung tissue | 224 | Lung cancer | 0.33 ± 1.49 | Dried and digested; atomic absorption spectrophotometer (AAS) | NS
Adachi et al. (1991) | Japanese clinical survey | Lung cancer Lung tissue | 1,715 | Other cases | 0.27 ± 0.41 | Dried and digested; atomic absorption spectrophotometer (AAS) | NS
Benderli Cihan and Öztürk Yildirim (2011) | Turkish hospital-based case-control study Male non-small cell lung cancer (NSCLC; stage IIIB) and controls from the same geographical region using similar inclusion/criteria; similar age and ethnic background; all smokers | Lung cancer Hair | 67 | NSCLC | [0.0031 ± 0.011]* | 3 g; inductively coupled plasma mass spectrometry (ICP-MS) | p < 0.05
Benderli Cihan and Öztürk Yildirim (2011) | | Lung cancer Hair | 74 | Controls | [0.0004 ± 0.0005] | 3 g; inductively coupled plasma mass spectrometry (ICP-MS) | p < 0.05
De Palma et al. (2008) | Italian clinical study NSCLC and controls (men and women) undergoing pulmonary resection (lung metastasis from other cancers and lung disease) from the same hospital; smoking higher in cases | Lung cancer Lung biopsies | 45 | NSCLC (non-tumor tissue) | 0.07 (0.05–0.11) | Dried and digested; ICP-MS; standard | NS No differences in cobalt levels in non-tumor tissue in occupationally exposed (to metals) vs. non-exposed subjects and in smokers vs. non-smokers
De Palma et al. (2008) | Italian clinical study NSCLC and controls (men and women) undergoing pulmonary resection (lung metastasis from other cancers and lung disease) from the same hospital; smoking higher in cases | Lung cancer Lung biopsies | 45 | NSCLC (tumor) | 0.05 (0.01–0.10) | Dried and digested; ICP-MS; standard | NS No differences in cobalt levels in non-tumor tissue in occupationally exposed (to metals) vs. non-exposed subjects and in smokers vs. non-smokers
De Palma et al. (2008) | Italian clinical study NSCLC and controls (men and women) undergoing pulmonary resection (lung metastasis from other cancers and lung disease) from the same hospital; smoking higher in cases | Lung cancer Lung biopsies | 8 | Controls | 0.04 (0.02–0.18) | Dried and digested; ICP-MS; standard | NS No differences in cobalt levels in non-tumor tissue in occupationally exposed (to metals) vs. non-exposed subjects and in smokers vs. non-smokers
Gerhardsson et al. (1985); Gerhardsson and Nordberg (1993); Gerhardsson et al. (1984) | Swedish male smelter workers and rural and urban referents (deaths) | Lung and other cancers Lung tissue | 7 | workers/lung Cancer | [0.015] | Freeze dried; irradiated; neutron activation analysis (NAA) | Mean exposure duration 31.2 ± 8.4 yr Metal concentrations did not differ in smokers vs. non-smokers Authors state cobalt levels did not decline with time after exposure had ceased
Gerhardsson et al. (1985); Gerhardsson and Nordberg (1993); Gerhardsson et al. (1984) | Swedish male smelter workers and rural and urban referents (deaths) | Lung and other cancers Lung tissue | 24 | Workers/all cancer | [0.016]** | Freeze dried; irradiated; neutron activation analysis (NAA) | Mean exposure duration 31.2 ± 8.4 yr Metal concentrations did not differ in smokers vs. non-smokers Authors state cobalt levels did not decline with time after exposure had ceased
Gerhardsson et al. (1985); Gerhardsson and Nordberg (1993); Gerhardsson et al. (1984) | Swedish male smelter workers and rural and urban referents (deaths) | Lung and other cancers Lung tissue | 29 | Workers/ cardiovascular | [0.016]*** | Freeze dried; irradiated; neutron activation analysis (NAA) | Mean exposure duration 31.2 ± 8.4 yr Metal concentrations did not differ in smokers vs. non-smokers Authors state cobalt levels did not decline with time after exposure had ceased
Gerhardsson et al. (1985); Gerhardsson and Nordberg (1993); Gerhardsson et al. (1984) | Swedish male smelter workers and rural and urban referents (deaths) | Lung and other cancers Lung tissue | 12 | Workers/other causes | [0.016]* | Freeze dried; irradiated; neutron activation analysis (NAA) | Mean exposure duration 31.2 ± 8.4 yr Metal concentrations did not differ in smokers vs. non-smokers Authors state cobalt levels did not decline with time after exposure had ceased
Gerhardsson et al. (1985); Gerhardsson and Nordberg (1993); Gerhardsson et al. (1984) | Swedish male smelter workers and rural and urban referents (deaths) | Lung and other cancers Lung tissue | 65 | All workers | [0.015]*** | Freeze dried; irradiated; neutron activation analysis (NAA) | Mean exposure duration 31.2 ± 8.4 yr Metal concentrations did not differ in smokers vs. non-smokers Authors state cobalt levels did not decline with time after exposure had ceased
Gerhardsson et al. (1985); Gerhardsson and Nordberg (1993); Gerhardsson et al. (1984) | Swedish male smelter workers and rural and urban referents (deaths) | Lung and other cancers Lung tissue | 14 | Rural referents | [0.007] | Freeze dried; irradiated; neutron activation analysis (NAA) | Mean exposure duration 31.2 ± 8.4 yr Metal concentrations did not differ in smokers vs. non-smokers Authors state cobalt levels did not decline with time after exposure had ceased
Kuo et al. (2006) | Taiwanese hospital-based case-control study; 1994–1998 Cases (82% men) had primary lung cancer presenting at a veteran’s hospital. Controls (81% men) had lung disease presenting at the veteran’s hospital and 2 other teaching hospitals. | Lung cancer Lung tissue | 57 | Lung cancer cases | 0.18 ± 0.03* | Dried and digested; AAS; standard references | Cases were older and smoked more than controls Cobalt levels were similar in non-smokers and smokers
Kuo et al. (2006) | | Lung cancer Lung tissue | 40 | Controls (lung disease) | 0.25 ± 0.06 | Dried and digested; AAS; standard references | Cases were older and smoked more than controls Cobalt levels were similar in non-smokers and smokers
Kuo et al. (2006) | | Lung cancer Lung tissue | 25 | Adenocarcinoma | 0.11 ± 0.01 | Dried and digested; AAS; standard references | Cases were older and smoked more than controls Cobalt levels were similar in non-smokers and smokers
Kuo et al. (2006) | | Lung cancer Lung tissue | 35 | Squamous-cell carcinoma | 0.23 ± 0.04 | Dried and digested; AAS; standard references | Cases were older and smoked more than controls Cobalt levels were similar in non-smokers and smokers
Kuo et al. (2006) | | Lung cancer Lung tissue | 39 | Stage I/II | 0.20 ± 0.04 | Dried and digested; AAS; standard references | Cases were older and smoked more than controls Cobalt levels were similar in non-smokers and smokers
Kuo et al. (2006) | | Lung cancer Lung tissue | 21 | Stage I/III | 0.15 ± 0.02 | Dried and digested; AAS; standard references | Cases were older and smoked more than controls Cobalt levels were similar in non-smokers and smokers
Qayyum and Shah (2014) | Pakistan case-referent study: lung patients and controls Newly diagnosed patients from medical center and matched volunteer controls from same localities | Lung cancer Scalp hair | 56 | Cases | 10.77 ± 1.599* | Hair (3g); nails (1g) dried; flame atomic absorption spectrophotometry (FAAS); 3 subsamples/ sample; standard references | Cases were more likely to be male and smoked more than controls Cobalt levels and variables- stage (nails & hair): decreasing 1 to 3 Inconsistent patterns between nails and hair for other variables such as sex, location, smoking
Qayyum and Shah (2014) | Pakistan case-referent study: lung patients and controls Newly diagnosed patients from medical center and matched volunteer controls from same localities | Lung cancer Scalp hair | 54 | controls | 6.787 ± 0.873 | Hair (3g); nails (1g) dried; flame atomic absorption spectrophotometry (FAAS); 3 subsamples/ sample; standard references
Qayyum and Shah (2014) | Pakistan case-referent study: lung patients and controls Newly diagnosed patients from medical center and matched volunteer controls from same localities | Lung cancer Scalp hair | 56 | Cases | 51.36 ± 10.47* | Hair (3g); nails (1g) dried; flame atomic absorption spectrophotometry (FAAS); 3 subsamples/ sample; standard references
Qayyum and Shah (2014) | Pakistan case-referent study: lung patients and controls Newly diagnosed patients from medical center and matched volunteer controls from same localities | Lung cancer Scalp hair | 54 | Controls | 45.38 ± 7.491 | Hair (3g); nails (1g) dried; flame atomic absorption spectrophotometry (FAAS); 3 subsamples/ sample; standard references
Zhang et al. (2012b) | Chinese case-series (clinical) Malignant and normal tissue from lung cancer patients in regions with high lung cancer incidence | Lung cancer Lung tissue and tumor | 30 | Malignant tumor/lung cancer | [0.00012 ± 0.00005] | Dried, powder and digested; ICP-MS; standard references, spiked entire process; blanks to test for contamination | Number of subjects and whether the tumor and non-tumor tissue is from same subject not clear p = 0.051
Zhang et al. (2012b) | Chinese case-series (clinical) Malignant and normal tissue from lung cancer patients in regions with high lung cancer incidence | Lung cancer Lung tissue and tumor | 30 | Normal tissue/lung cancer | [0.00025 ± 0.00016] | Dried, powder and digested; ICP-MS; standard references, spiked entire process; blanks to test for contamination | Number of subjects and whether the tumor and non-tumor tissue is from same subject not clear p = 0.051
Collecchi et al. (1986) | Italian clinical study Males without known exposure to arsenic and cobalt with laryngeal carcinoma and “normal males” | Larynx cancer Larynx tissue | 15 | Malignant tissue/laryngeal cancer | 0.069 ± 0.007** | Radioactive NAA; standard references | Population undefined; spiked samples
Collecchi et al. (1986) | Italian clinical study Males without known exposure to arsenic and cobalt with laryngeal carcinoma and “normal males” | Larynx cancer Larynx tissue | 15 | Non-malignant tissue/laryngeal cancer | 0.040 ± 0.007 | Radioactive NAA; standard references | Population undefined; spiked samples
Collecchi et al. (1986) | Italian clinical study Males without known exposure to arsenic and cobalt with laryngeal carcinoma and “normal males” | Plasma | 15 | Laryngeal cancer | 18.27 ± 2.10*** ng/mL | Radioactive NAA; standard references | Population undefined; spiked samples
Collecchi et al. (1986) | Italian clinical study Males without known exposure to arsenic and cobalt with laryngeal carcinoma and “normal males” | Plasma | 11 | Controls | 0.73 ± 0.10 | Radioactive NAA; standard references | Population undefined; spiked samples
Klatka et al. (2011) | Polish clinical survey Male laryngeal cancer patients: tumor and normal tissue from the same patient | Larynx cancer Larynx tissue | 43 | Laryngeal carcinoma | 0.031 ± 0.0375 | Digested; plasma optical emission spectrometry (ICP-OES); separate tissue dried for calibration validated with reference material | –
Klatka et al. (2011) | Polish clinical survey Male laryngeal cancer patients: tumor and normal tissue from the same patient | Larynx cancer Larynx tissue | 43 | Non-tumor tissue | 0.017 ± 0.013 | Digested; plasma optical emission spectrometry (ICP-OES); separate tissue dried for calibration validated with reference material | –
Klatka et al. (2011) | Polish clinical survey Male laryngeal cancer patients: tumor and normal tissue from the same patient | Larynx cancer Larynx tissue | 29 | Stage 3 tumor | 0.025 ± 0.034* | Digested; plasma optical emission spectrometry (ICP-OES); separate tissue dried for calibration validated with reference material | –
Klatka et al. (2011) | Polish clinical survey Male laryngeal cancer patients: tumor and normal tissue from the same patient | Larynx cancer Larynx tissue | 14 | Stage 4 tumor | 0.044 ± 0.043 | Digested; plasma optical emission spectrometry (ICP-OES); separate tissue dried for calibration validated with reference material | –
Klatka et al. (2011) | Polish clinical survey Male laryngeal cancer patients: tumor and normal tissue from the same patient | Larynx cancer Larynx tissue | 19 | Rural regions | 0.046 ± 0.050* | Digested; plasma optical emission spectrometry (ICP-OES); separate tissue dried for calibration validated with reference material | –
Klatka et al. (2011) | Polish clinical survey Male laryngeal cancer patients: tumor and normal tissue from the same patient | Larynx cancer Larynx tissue | 24 | Urban regions | 0.019 ± 0.017 | Digested; plasma optical emission spectrometry (ICP-OES); separate tissue dried for calibration validated with reference material | –

Table B-5 Findings from Studies That Measured Cobalt in Tissues (Means or Medians) of Cancer Patients and Referents

Reference | Population | Cancer Tissue | Number of Subjects | Category | Co Levels (μg/g Dry Tissue) | Exposure Methods | Comments
Pasha et al. (2007) | Pakistan clinical survey; 2001 to 2003 Men and women cancer patients from two hospitals (15 to 93 yr) and normal donors from same region | All cancers Hair | 111 | Cancer patients | 24.6 ± 1.5* | Flame atomic absorption spectrophotometry (FAAS); 3 samples/person; reference | Normal donors matched for age group. Types of cancer not reported Cobalt levels correlated with other metals such as cadmium and chromium
Pasha et al. (2007) | Pakistan clinical survey; 2001 to 2003 Men and women cancer patients from two hospitals (15 to 93 yr) and normal donors from same region | All cancers Hair | 113 | Normal donors | 6.10 ± 0.36 | Flame atomic absorption spectrophotometry (FAAS); 3 samples/person; reference | Normal donors matched for age group. Types of cancer not reported Cobalt levels correlated with other metals such as cadmium and chromium
Gerhardsson et al. (1993); Gerhardsson et al. (1985); Gerhardsson et al. (1984) | Swedish retried copper smelter workers and 8 rural referents Tissue from deceased subjects who died of cancer and other causes | All cancers Liver | 10 | Workers/cancer | [0.012] | Freeze dried; irradiated; neutron activation analysis (NAA) | 47 workers were retired for 0 to 10 years and 18 workers were retired for 11 to 23 years; mean retirement = 7.2 ± 5.9 yr Mean exposure duration 31.2 ± 8.4 yr Metal concentrations did not differ in smokers vs. non-smokers
Gerhardsson et al. (1993); Gerhardsson et al. (1985); Gerhardsson et al. (1984) | Swedish retried copper smelter workers and 8 rural referents Tissue from deceased subjects who died of cancer and other causes | All cancers Liver | 8 | Workers/ cardiovascular | [0.011] | Freeze dried; irradiated; neutron activation analysis (NAA)
Gerhardsson et al. (1993); Gerhardsson et al. (1985); Gerhardsson et al. (1984) | Swedish retried copper smelter workers and 8 rural referents Tissue from deceased subjects who died of cancer and other causes | All cancers Liver | 2 | Workers/other causes | [0.015] | Freeze dried; irradiated; neutron activation analysis (NAA)
Gerhardsson et al. (1993); Gerhardsson et al. (1985); Gerhardsson et al. (1984) | Swedish retried copper smelter workers and 8 rural referents Tissue from deceased subjects who died of cancer and other causes | All cancers Liver | 20 | All workers | [0.011] | Freeze dried; irradiated; neutron activation analysis (NAA)
Gerhardsson et al. (1993); Gerhardsson et al. (1985); Gerhardsson et al. (1984) | Swedish retried copper smelter workers and 8 rural referents Tissue from deceased subjects who died of cancer and other causes | All cancers Liver | 8 | Rural referents | [0.016] | Freeze dried; irradiated; neutron activation analysis (NAA)
Gerhardsson et al. (1993); Gerhardsson et al. (1985); Gerhardsson et al. (1984) | Swedish retried copper smelter workers and 8 rural referents Tissue from deceased subjects who died of cancer and other causes | All cancers Kidney | 10 | Workers/cancer | [0.003] | Freeze dried; irradiated; neutron activation analysis (NAA)
Gerhardsson et al. (1993); Gerhardsson et al. (1985); Gerhardsson et al. (1984) | Swedish retried copper smelter workers and 8 rural referents Tissue from deceased subjects who died of cancer and other causes | All cancers Kidney | 8 | Workers/ cardiovascular | [0.003] | Freeze dried; irradiated; neutron activation analysis (NAA)
Gerhardsson et al. (1993); Gerhardsson et al. (1985); Gerhardsson et al. (1984) | Swedish retried copper smelter workers and 8 rural referents Tissue from deceased subjects who died of cancer and other causes | All cancers Kidney | 3 | Workers/other causes | [0.006] | Freeze dried; irradiated; neutron activation analysis (NAA)
Gerhardsson et al. (1993); Gerhardsson et al. (1985); Gerhardsson et al. (1984) | Swedish retried copper smelter workers and 8 rural referents Tissue from deceased subjects who died of cancer and other causes | All cancers Kidney | 21 | All workers | [0.003] | Freeze dried; irradiated; neutron activation analysis (NAA)
Gerhardsson et al. (1993); Gerhardsson et al. (1985); Gerhardsson et al. (1984) | Swedish retried copper smelter workers and 8 rural referents Tissue from deceased subjects who died of cancer and other causes | All cancers Kidney | 8 | Rural referents | [0.001] | Freeze dried; irradiated; neutron activation analysis (NAA)
Kanias et al. (1994) | Greek clinical survey Women (23) undergoing biopsy because of mammography or clinical findings with fibrocystic disease or fibroadenoma tumor | Breast breast tissue | 17 | Fibrocystic disease | 0.051 ± 0.045 | Samples and standards irradiated; radioactive count Corresponding to standards | Differences in cobalt levels between disease groups not Significant Correlation of cobalt with scandium in fibroadenoma and with zinc in combined fibroadenoma & fibrocystic disease
Kanias et al. (1994) | Greek clinical survey Women (23) undergoing biopsy because of mammography or clinical findings with fibrocystic disease or fibroadenoma tumor | Breast breast tissue | 6 | Fibroadenoma | 0.10 ± 0.17 | Samples and standards irradiated; radioactive count Corresponding to standards | Differences in cobalt levels between disease groups not Significant Correlation of cobalt with scandium in fibroadenoma and with zinc in combined fibroadenoma & fibrocystic disease
Kanias et al. (1994) | Greek clinical survey Women (23) undergoing biopsy because of mammography or clinical findings with fibrocystic disease or fibroadenoma tumor | Breast breast tissue | NR | Fibroadenoma & fibrocystic disease (same sample) | 0.027 ± 0.025 | Samples and standards irradiated; radioactive count Corresponding to standards | Differences in cobalt levels between disease groups not Significant Correlation of cobalt with scandium in fibroadenoma and with zinc in combined fibroadenoma & fibrocystic disease
Benderli Cihan et al. (2011) | Turkish clinical study Breast cancer from one hospital and volunteers or employees at the hospital (same age) | Breast (stage III) Hair | 52 | Cancer patients | 0.664 ± 0.566* | 3 g; ICP-MS | Cobalt was correlated with several other heavy metals in cancer patients
Benderli Cihan et al. (2011) | Turkish clinical study Breast cancer from one hospital and volunteers or employees at the hospital (same age) | Breast (stage III) Hair | 52 | Healthy humans | 0.269 ± 0.390 | 3 g; ICP-MS | Cobalt was correlated with several other heavy metals in cancer patients
Arslan et al. (2011) | Turkey clinical survey Patient with malignant glial tumors operated from one clinical center and healthy humans. | Brain Serum | 22 | Cancer patients | 0.04 ± 0.03 (μg/dL) | Frozen; atomic absorption spectrophotometer (AAS) | No information on healthy humans NS
Arslan et al. (2011) | Turkey clinical survey Patient with malignant glial tumors operated from one clinical center and healthy humans. | Brain Serum | 22 | Healthy humans | 0.03 ± 0.03 (μg/dL) | Frozen; atomic absorption spectrophotometer (AAS) | No information on healthy humans NS
Alimonti et al. (2008) | Italian clinical survey Male and female patients with colorectal polyps and control group from same hospital | Colorectal polyps Colorectal tissue | 17 | Tumor/polyps | [0.019 ± 0.016]* | Dried; digested samples, mass spectrometry; internal standards | No information about control group Sign differences between normal vs. polyps sign but not controls vs. normal or polyps
Alimonti et al. (2008) | Italian clinical survey Male and female patients with colorectal polyps and control group from same hospital | Colorectal polyps Colorectal tissue | 17 | Normal tissue/polyps | [0.04 ± 0.02] | Dried; digested samples, mass spectrometry; internal standards | No information about control group Sign differences between normal vs. polyps sign but not controls vs. normal or polyps
Alimonti et al. (2008) | Italian clinical survey Male and female patients with colorectal polyps and control group from same hospital | Colorectal polyps Colorectal tissue | 15 | Normal tissue/controls | [0.03 ± 0.016] | Dried; digested samples, mass spectrometry; internal standards | No information about control group Sign differences between normal vs. polyps sign but not controls vs. normal or polyps
Demir et al. (2011) | Turkey case-referent study Male and female newly diagnosed cases of acute leukemia from one clinical center and healthy subjects with similar distribution of sex, socioeconomics, and food habits | Acute leukemia (AML/ALL) Serum | 42 | Leukemia cases | 0.20 ± 0.17 (μg/dL) | Frozen; AAS | No information on source of controls. Not statistically Significant
Demir et al. (2011) | Turkey case-referent study Male and female newly diagnosed cases of acute leukemia from one clinical center and healthy subjects with similar distribution of sex, socioeconomics, and food habits | Acute leukemia (AML/ALL) Serum | 40 | Controls | 0.11 ± 0.06 | Frozen; AAS | No information on source of controls. Not statistically Significant
Zhu et al. (2011) | Chinese case-control; 2007–2008 Newly diagnosed male and female cases (71) of childhood leukemia (15 yr or less) at a hospital and sex- and age-matched controls | Childhood leukemia Urine | 71 | Childhood leukemia cases | 0.98 (0.57–2.28) ng/mg creatinine | Inductively coupled plasma mass spectrometry (ICP-MS) | NS
Zhu et al. (2011) | Chinese case-control; 2007–2008 Newly diagnosed male and female cases (71) of childhood leukemia (15 yr or less) at a hospital and sex- and age-matched controls | Childhood leukemia Urine | 113 | Controls | 0.77 (0.44–1.44) ng/mg | Inductively coupled plasma mass spectrometry (ICP-MS) | NS
Yin (1990) | Chinese clinical survey Male and female liver cancer cases (930) and age-matched healthy adults selected from the same hospital | Liver cancer Serum | 30 | Liver cancer cases | 0.0085 ± 0.0017 ppm* | ICP-AES | Cobalt levels correlated with other metals
Yin (1990) | Chinese clinical survey Male and female liver cancer cases (930) and age-matched healthy adults selected from the same hospital | Liver cancer Serum | 30 | Healthy adults | 0.0035 ± 0.0012 ppm | ICP-AES | Cobalt levels correlated with other metals
Reddy et al. (2002) | Indian thyroid samples Normal thyroid, adenoma, carcinoma samples from four subjects from pathology dept. | Thyroid cancer Thyroid tissue | NR | Carcinoma | 17.9 ± 2 | Freeze-dried converted to powder with standards, particle induced X-ray emission technique (PIXE) | No information on subjects. Not clear if different types of tissues are from same person
Reddy et al. (2002) | Indian thyroid samples Normal thyroid, adenoma, carcinoma samples from four subjects from pathology dept. | Thyroid cancer Thyroid tissue | NR | Adenoma | 11.6 ± 1.2 | Freeze-dried converted to powder with standards, particle induced X-ray emission technique (PIXE) | No information on subjects. Not clear if different types of tissues are from same person
Reddy et al. (2002) | Indian thyroid samples Normal thyroid, adenoma, carcinoma samples from four subjects from pathology dept. | Thyroid cancer Thyroid tissue | NR | Normal thyroid | 11.3 ± 1.2 | Freeze-dried converted to powder with standards, particle induced X-ray emission technique (PIXE) | No information on subjects. Not clear if different types of tissues are from same person

## B.4 Regulations and Guidelines

### B.4.1 Regulations

#### B.4.1.1 Coast Guard, Department of Homeland Security

Minimum requirements have been established for safe transport of cobalt naphthenate in solvent naphtha on ships and barges.

#### B.4.1.2 Department of Transportation (DOT)

Numerous cobalt compounds are considered hazardous materials, and special requirements have been set for marking, labeling, and transporting these materials.

#### B.4.1.3 Environmental Protection Agency (EPA)

##### B.4.1.3.1 Clean Air Act

National Emission Standards for Hazardous Air Pollutants: Cobalt compounds are listed as hazardous air pollutants.

##### B.4.1.3.2 Clean Water Act

Cobalt discharge limits are imposed for numerous processes during the production of cobalt at secondary cobalt facilities processing tungsten carbide scrap raw materials.

Discharge limits for cobalt are imposed for numerous processes during the production of cobalt at primary cobalt facilities; for numerous processes during the production of batteries; and for numerous processes during the production of cobalt salts.

Discharge limits for cobalt are imposed for wastewater discharges from centralized waste treatment facilities except discharges and activities exempted in 40 CFR 437.1(b), (c), and 40 CFR 421, Subpart AC.

Cobaltous bromide, formate, and sulfamate are designated as hazardous substances.

##### B.4.1.3.3 Comprehensive Environmental Response, Compensation, and Liability Act

Reportable quantity (RQ) = 1,000 lb. for cobaltous bromide, formate, and sulfamate.

##### B.4.1.3.4 Emergency Planning and Community Right-to-Know Act

Toxics Release Inventory: Cobalt and cobalt compounds are listed substances subject to reporting requirements.

Reportable quantity (RQ) = 100 lb. for cobalt, ((2,2′-(1,2-ethanediylbis (nitrilomethylidyne)) bis(6-fluorophenolato))(2-)-N,N′,O,O′)- (also called fluomine); = 10 lb. for cobalt carbonyl.

Threshold planning quantity (TPQ) = 100 lb. for fluomine (solids in powder form with particle size <100 μm or solution or molten form); = 10,000 lb. for all other forms of fluomine; = 10 lb. for cobalt carbonyl (solids in powder form with particle size <100 μm or solution or molten form); = 10,000 lb. for all other forms of cobalt carbonyl.

##### B.4.1.3.5 Federal Insecticide, Fungicide, and Rodenticide Act

Boiled linseed oil (containing no more than 0.33% manganese naphthenate and no more than 0.33% cobalt naphthenate) is exempt from the requirement of a tolerance when used as a coating agent for S-ethyl hexahydro-1H-azepine-1-carbothioate. No more than 15% of the pesticide formulation may consist of boiled linseed oil, and this exemption is limited to use on rice before edible parts form.

#### B.4.1.4 Food and Drug Administration (FDA)

Cobaltous salts are prohibited from use in human food.

All drugs containing cobalt salts (except radioactive forms of cobalt and its salts and cobalamin and its derivatives) have been withdrawn from the market because they were found to be unsafe or not effective, and they may not be compounded.

Chromium-cobalt-aluminum oxide used as a color additive for linear polyethylene surgical sutures used in general surgery must comprise no more than 2% by weight of the suture material, not migrate to surrounding tissue, and conform to labeling requirements in 21 CFR 70.25.

Chromium cobalt-aluminum oxide may be used as a color additive in contact lenses in amounts not to exceed the minimum reasonably required to accomplish the intended coloring effect.

Ferric ammonium ferrocyanide and ferric ferrocyanide used to color externally applied drugs (including those for use in the area of the eye) must not contain more than 200 ppm cobalt (as Co) and conform to labeling requirements in 21 CFR 70.25.

21 CFR 369 contains recommended drug labeling statements for over-the-counter cobalt preparations containing ≥0.5 mg cobalt as a cobalt salt per dosage unit and which recommend administration rates of ≥0.5 mg per dose and ≥2 mg per 24-hour period.

An approved new drug application is required for marketing cobalt preparations intended for use by man.

21 CFR 872, 874, and 888 identify class designations (Class I, II, or III) of various cobalt-containing dental prosthetic device alloys, cobalt-chromium-alloy-based facial prosthetics, and cobalt-chromium-molybdenum orthopedic devices that determine the type of premarketing submission or application required for FDA clearance to market.

Cobalt naphthenate may be used in quantities that do not exceed those reasonably required as an accelerator in the production of cross-linked polyester resins used as articles or components of articles intended for repeated use in contact with food.

Cobalt aluminate may be safely used as a colorant in the manufacture of articles or components of articles intended for use in producing, manufacturing, packing, processing, preparing, treating, packaging, transporting, or holding of food at levels not to exceed 5% by weight of all polymers except in resinous and polymeric coatings complying with 21 CFR 175.300, melamine-formaldehyde resins in molded articles complying with 21 CFR 177.1460, xylene-formaldehyde resins complying with 21 CFR 175.380, ethylene-vinyl acetate copolymers complying with 21 CFR 177.1350, and urea-formaldehyde resins in molded articles complying with 21 CFR 177.1900.

#### B.4.1.5 Occupational Safety and Health Administration (OSHA)

This legally enforceable PEL was adopted from the 1968 ACGIH TLV-TWA shortly after OSHA was established; it may not reflect the most recent scientific evidence and may not adequately protect worker health.

Permissible exposure limit (PEL) (8-h TWA) = 0.1 mg/m^3^ for cobalt metal, dust, and fume (as Co).

### B.4.2 Guidelines

#### B.4.2.1 American Conference of Governmental Industrial Hygienists (ACGIH)

Threshold limit value-time-weighted average (TLV-TWA) = 0.02 mg/m^3^ for cobalt and inorganic compounds; = 0.1 mg/m^3^ for cobalt carbonyl and cobalt hydrocarbonyl.

Biological exposure index (BEI) = 15 μg/L for cobalt in urine for cobalt and inorganic compounds, including cobalt oxides but not combined with tungsten carbide for end of shift at end of workweek.

#### B.4.2.2 Consumer Product Safety Commission (CPSC)

The CPSC has issued guidance regarding the potential hazards of specific cobalt- or cobalt-compound-containing art and craft materials (e.g., glazes, glass colorants, paints, toners, pigments, and dyes) and specific precautions to take when using them.

#### B.4.2.3 Environmental Protection Agency (EPA)

Regional Screening Levels (formerly Preliminary Remediation Goals): residential soil = 23 mg/kg; industrial soil = 350 mg/kg; residential air = 0.00031 μg/m^3^; industrial air = 0.0014 μg/m^3^; tap water = 6 μg/L.

#### B.4.2.4 National Institute for Occupational Safety and Health (NIOSH)

Recommended exposure limit (REL) (10-h TWA) = 0.05 mg/m^3^ for cemented tungsten carbide containing >2% Co (as Co); = 0.05 mg/m^3^ for cobalt metal dust and fume (as Co); = 0.1 mg/m^3^ for cobalt carbonyl (as Co) and cobalt hydrocarbonyl (as Co).

Immediately dangerous to life and health (IDLH) limit = 20 mg/m^3^ for cobalt metal dust and fume (as Co).