# Appendix A Literature Search Strategy

This document identifies the data sources, search terms, and search strategies that were used to identify literature for the draft monograph on cobalt and certain cobalt compounds (hereafter referred to as ‘cobalt’). The literature search strategy used for cobalt involved several approaches designed to identify potentially useful information for the broad range of topics covered by a Report on Carcinogens (RoC) monograph, as listed below.

- Properties and Human Exposure (focusing on the U.S. population)
- Disposition (ADME) and Toxicokinetics
- Human Cancer Studies
- Studies of Cancer in Experimental Animals
- Mechanistic Data and Other Relevant Effects
  - Genetic and Related Effects
  - Mechanistic Considerations

The methods for identifying the relevant literature for the draft cobalt monograph including (1) the search strategy, (2) updating the literature search, and (3) review of citations using web-based systematic review software are illustrated in Figure A-1 and discussed below. The detailed literature search strategy, including all database sources, and exclusion/inclusion criteria, are available at https://ntp.niehs.nih.gov/go/730697.

## A.1 Search Strategies

Relevant literature is identified using search terms, data sources, and strategies as discussed below.

1. General data search: This search covers a broad range of general data sources for information relevant to many or all of the wide range of monograph topics pertaining to cobalt.
2. Exposure-related data search: This search covers a broad range of potential sources for exposure-related information and physical-chemical properties.
3. Database searches in PubMed, Scopus, and Web of Science: The majority of the primary literature used to draft the cobalt monograph was identified from searches of these three extensive databases available through the NIEHS Library. Searches for cobalt were combined with the search terms for each of the monograph topics listed above to create the specific literature searches.
4. Searches for human cancer studies are somewhat unique because they involve the identification of search terms for exposure scenarios that might result in exposure of people to cobalt. For cobalt, these exposure-related search terms were based on uses of cobalt identified from the EPA’s TRI database and the Chemical Data Report rule website.
5. QUOSA library of occupational case-control studies search of the QUOSA-based library of more than 6,000 occupational case-control studies, approximately 95% of which are currently available as searchable full-text pdfs, was conducted using the “cobalt.”
6. Secondary sources: Citations identified from authoritative reviews or from primary references located by literature search, together with publications citing key papers identified using the Web of Science, “Cited Reference Search,” were also added.

## A.2 Updating the Literature Search

The literature searches will be updated prior to submitting the draft monograph for peer review and prior to finalizing the monograph. Monthly search alerts for cobalt searches were created in PubMed, Scopus, and Web of Science, and the results of these searches from the closing date of the initial search will be downloaded for review.

## A.3 Review of Citations Using Web-based Systematic Review Software

Citations retrieved from literature searches were uploaded to web-based systematic review software and screened using inclusion and exclusion criteria. Multi-level reviews of the literature were conducted, with initial reviews (Level 1) based on titles and abstracts only to identify citations that could be excluded and to assign the included literature to one or more monograph topics; subsequent reviews (Level 2) for literature assigned to the various monograph topics (Exposure, ADME & TK, Human cancer studies, etc.) were based on full-text (i.e., PDFs) of the papers and were carried out by the writer and scientific reviewer for each monograph section. Two reviewers, at least one of whom is a member of the ORoC at NIEHS, participated at each level of review.

Figure A-1

Literature Search Strategy and Review