# 7 NTP Listing Recommendation

Trichloroethylene is currently listed in the RoC as reasonably anticipated to be a human carcinogen. Since it was first listed in the RoC, additional cancer studies have been published. This monograph focuses on the potential for trichloroethylene exposure to cause kidney cancer, non-Hodgkin lymphoma (NHL), or liver cancer. This section brings forward and integrates the evaluations of the human and mechanistic data for each of these cancers (Sections 4, 5, and 6), other relevant data (Sections 1 and 2), and the level of evidence for carcinogenicity in experimental animals (current listing in the RoC), and reaches an NTP listing recommendation for trichloroethylene. The conclusions are based on applying the RoC listing criteria to the evidence across studies.

Overall Listing Recommendation

Trichloroethylene is known to be a human carcinogen based on sufficient evidence of carcinogenicity from humans. This conclusion is based on epidemiological studies showing that it causes kidney cancer in humans, together with supporting evidence from toxicological, toxicokinetic, and mechanistic studies demonstrating the biological plausibility of its carcinogenicity in humans. Epidemiological studies also provide limited evidence for a causal association for non-Hodgkin lymphoma (NHL) in humans. Supporting evidence is provided by studies in experimental animals demonstrating that trichloroethylene causes cancer at several tissue sites, including some of the same sites as seen in humans—kidney tumors in male rats, liver tumors in mice of both sexes, and lymphoma in female mice—as well as tumors at other sites, including testicular tumors in male rats and lung tumors in mice of both sexes.

The epidemiological, toxicological, toxicokinetic, and mechanistic evidence for kidney cancer, NHL and related cancers, and liver cancer is summarized below.

## 7.1 Kidney Cancer

Epidemiological studies have demonstrated a causal relationship between trichloroethylene exposure and kidney cancer based on consistent evidence of increased risk across studies with different study designs, in different geographical areas, and in different occupational settings; evidence of increasing cancer risk with increasing level or duration of exposure; and statistically significant increased risks of kidney cancer across studies combined in two meta-analyses.

Overall, increased risks of kidney cancer were found among individuals with the highest exposure in the most informative studies (i.e., studies with higher levels of exposure to trichloroethylene and better assessments of exposure and disease; see Figure 4-2 and Figure 4-3). Although several studies did not find an association between kidney cancer and trichloroethylene exposure, non-differential misclassification and lower sensitivity to detect an association (e.g., because of low exposure levels or small numbers of subjects) were concerns in these studies. The meta-analyses also provide strong evidence for an association with kidney cancer. A sensitivity analysis of one meta-analysis found that the meta-relative risk was robust and not sensitive to removal of individual studies or use of alternative risk estimates. Finally, biases or confounding by known or suspected occupational co-exposures, smoking, or other lifestyle factors are unlikely to explain the positive findings across studies (see Section 4.1.4 for a detailed discussion of the evidence).

Toxicokinetic and mechanistic data in both humans and animals provide credible evidence for the biological plausibility of the proposed mechanisms of trichloroethylene’s carcinogenicity in humans. The key events most likely contributing to tumorigenicity include (1) GSH-conjugation-derived metabolites produced in situ or delivered systemically to the kidneys and (2) mutagenic, genotoxic, and cytotoxic effects induced by these metabolites in the kidneys. Metabolism of trichloroethylene is qualitatively similar in humans and experimental animals. In vitro studies in kidney and liver cells from humans and animals have demonstrated the formation of several GSH-conjugation-derived metabolites, some of which (NAcDCVC and DCVG) have been detected in the urine or blood of trichloroethylene-exposed humans and experimental animals. The finding of a significantly elevated risk of renal-cell cancer among trichloroethylene-exposed individuals with a functionally active GSTT1 genotype but not among subjects with a GST-null genotype provides support for the importance of the GSH-conjugation pathway in the carcinogenicity of trichloroethylene in humans.

The available mechanistic data support a mutagenic and cytogenetic mode of action mediated by GSH-conjugation-derived metabolites. These metabolites have been shown to be mutagenic in vitro and genotoxic both in vitro and in vivo, most notably causing damage to human and animal kidney cells in vitro, cellular transformation of rat kidney cells in vitro, and DNA damage and micronucleus formation in kidney cells from rats exposed in vivo. A mechanism potentially contributing to trichloroethylene’s carcinogenicity is cytotoxicity and associated regenerative proliferation. Studies in humans also provide evidence that trichloroethylene causes nephrotoxicity, supporting the role of this mechanism in humans. Thus, the mode of action for kidney carcinogenicity may involve a combination of mutagenicity and cytotoxicity.

## 7.2 NHL and Related Cancers

Epidemiological studies provide limited evidence for a causal association between trichloroethylene exposure and NHL, based on positive associations in several studies and evidence for increased risk of NHL across studies combined in two meta-analyses. The evidence across studies is less consistent than for kidney cancer, and alternative explanations such as chance or confounding cannot reasonably be ruled out.

The strongest evidence for an association between trichloroethylene exposure and NHL comes from the InterLymph pooled analysis (p for Fisher’s combined probability = 0.004), supported by modest increases in risk in several cohort and case-control studies. The risk of NHL increased with increasing level or duration of exposure in the pooled InterLymph study, one of its component studies, and another case-control study, but evidence for an exposure-response relationship was lacking in several cohort studies. No evidence was found for confounding by lifestyle factors; however, potential confounding by exposure to other solvents, including chlorinated solvents, may have been possible in the aircraft-manufacturing studies.

The mechanisms by which trichloroethylene could cause lymphoma are largely unknown. Immunomodulation, including autoimmunity and immunosuppression, are strongly linked to NHL. There is evidence that trichloroethylene causes immunomodulation in both people and animals, suggesting a biologically plausible role for immunomodulation in induction of NHL by trichloroethylene. It has been proposed that lymphomas can develop from errors arising during the somatic hypermutation phase of B-cell activation, resulting from either chronic antigenic stimulation (autoimmunity) or from impaired pathogen control (immunosuppression). However, the results of some studies in humans and animals that measured immune biomarkers (such as those for B-cell activation) were not entirely consistent with this model. The mechanisms of immunomodulation and lymphomagenesis are not completely understood, and neither the proposed model nor the potential association between trichloroethylene-induced immune effects and lymphoma has been directly tested in either humans or animals.

## 7.3 Liver Cancer

The data available from studies in humans are inadequate to evaluate the relationship between trichloroethylene exposure and liver cancer. A few studies, including two meta-analyses, found modest increases in the risk of liver cancer; however, the findings are inconsistent across studies, and there was little evidence for exposure-response relationships in the individual studies or the meta-analyses. The evidence from recent studies, published since the latest meta-analysis (USEPA 2011a), appears to be weaker. Most of the studies (both recent and older) had limited ability to detect an association between trichloroethylene exposure and rare cancers such as liver cancer. In addition, the role of chance or confounding by one or more of the common occupational co-exposures or lifestyle factors cannot be completely ruled out.

The mode of action for trichloroethylene-induced liver cancer in mice is unknown but likely is complex, involving key events in several pathways. Studies in experimental animals provide evidence for several potential modes of action resulting primarily from oxidative stress, such as genotoxicity, oxidative damage, peroxisome proliferation, epigenetic events, and autoimmunity (hepatitis). Oxidative metabolites are considered to be more important than GSH-pathway metabolites in liver carcinogenicity because trichloroethylene, trichloroacetic acid, dichloroacetic acid, and chloral hydrate have similar hepatotoxic and hepatocarcinogenic effects. These metabolites are found in humans, and chloral or chloral hydrate is genotoxic in several in vitro and in vivo test systems. Although species differences in sensitivity to the proposed modes of action are likely, no data suggest that trichloroethylene causes liver tumors in mice solely by mechanisms that are not relevant to humans.

## 7.4 Other Cancer Sites

Although this evaluation focused on kidney cancer, NHL, and liver cancer, authoritative evaluations of the carcinogenicity of trichloroethylene are available for other tissue sites. IARC concluded that although cancer incidence was increased at several other tissue sites, the data were insufficient for an evaluation. Of some interest is cervical cancer, for which statistically significant increased risks were found among women in two of the Nordic cohort studies (the pooled biomonitoring study and the study of blue-collar workers). Excesses of cervical cancer, though not statistically significant, were also observed in the Utah aircraft-manufacturing study and in a case-control study in the Arve Valley area of France, where the screw-cutting industry was prevalent (Charbotel et al. 2013). However, the latter study found no association of cervical cancer with cumulative trichloroethylene exposure level or exposure duration. The database for this tissue site is limited by the small number of studies reporting on cervical cancer and the potential for confounding by smoking or human papilloma virus infection.

## 7.5 Toxicological Considerations across End Points

The available evidence indicates that trichloroethylene causes genotoxicity, toxicity, and cancer via its metabolic activation to reactive metabolites. Two distinct metabolic pathways for trichloroethylene have been identified that are common to all mammalian species studied: CYP oxidation and GSH conjugation. As discussed above, kidney cancer is most likely mediated through the GSH-conjugation pathway, whereas liver cancer (and toxicity) is thought to be mediated through the CYP-oxidation pathway. The oxidative pathway, primarily through CYP2E1, predominates in all species studied. However, the balance between oxidation and GSH conjugation of trichloroethylene can be altered by genetic polymorphisms or exposure to CYP inducers, and the impacts may be more substantial at higher substrate concentrations; this is consistent with the findings of increased risk of kidney cancer primarily among workers with high exposure to trichloroethylene. Differences among study populations in co-exposures or genetic susceptibility factors, both of which could affect the flux through the two metabolic pathways, may explain some of the heterogeneity across studies and cancer end points. Potentially sensitive subpopulations include individuals with GST, CYP2E1, or alcohol dehydrogenase polymorphisms. The frequencies of GSTT1 and GSTM1 polymorphisms vary among ethnic groups, with 40% to 85% of the population having GSTM1- or GSTT1-active genotypes and thus possibly a higher risk of developing cancer from trichloroethylene exposure. (A higher percentage and larger range of GST polymorphisms are found in African populations.) In addition, sex differences in human cancer risk are unclear. Only a few human cancer studies reported risk estimates for specific tissue sites separately for men and women, and several studies included fewer women than men (see Sections 4, 5, and 6), limiting the evaluation of potential patterns of sex differences in cancer risk.