# 6 Liver Cancer

The previous sections of the cancer evaluation component contain relevant information—ADME (Section 1), genetic and related effects (Section 2), and overview and assessment of the quality of the human cancer studies—that are important for several of the three cancer endpoints of interest (Section 3). This section builds on that information and evaluates the human cancer studies (Section 6.1), mechanistic data, including immune effects of trichloroethylene (Section 6.2), specifically for liver cancer.

## 6.1 Human Cancer Studies

Liver cancer is considered to be rare, with higher rates observed among males; the U.S. age-adjusted rates per 100,000 per year (2007 to 2011) are 12.4 (male) and 4.1 (female) for incidence and 8.5 (male) and 3.4 (female) for mortality (SEER 2014b). The 5-year survival rate is 16.6%, suggesting that mortality and incidence data are likely to be broadly comparable, at least for recent years. U.S. rates have been increasing at about 4% per year for the past decade with an overall incidence rate in 1975 of approximately 2.8 per 100,000. Incidence rates in European countries, from which the remaining studies in the evaluation are drawn, appear to be broadly comparable: for example, age-standardized U.K. incidence rates per 100,000 (2011) are approximately 7.0 (male) and 3.1 (female). The overall rate was 1.5 in 1975, with an increase of approximately 4% per year over the past decade (Cancer Research U.K. 2014a)[underlined: .] As noted, latencies of solid tumors such as liver cancer are generally considered to be longer than for most lymphohematopoietic cancers (e.g., >20 years), although a shorter latency has been reported in association with some exposures (see Howard 2013). Incidence rates start to increase steeply at a somewhat earlier age (40 to 44 years) than for kidney cancer, particularly among men. Liver cancer is reported in some studies as cancer of the liver and intrahepatic bile ducts (ICD-9 155, ICD-10 22) and in others as combined cancers of the liver and intrahepatic and extrahepatic bile ducts and gallbladder (ICD-9 155+156, ICD-10 22-24); some papers report primary liver cancer (ICD-9 155.1) separately. Approximately 75% of primary liver cancers are hepatocellular carcinomas, with cholangiocarcinomas forming the bulk of the remainder.

For each of the reviewed studies, summary data on study design, methods, and findings, systematically extracted from relevant publications as described in the study protocol, are presented in Table D-1. The evaluation of study quality, including study design, methods of exposure and cancer endpoint assessment, analysis and other relevant elements (such as study sensitivity) data, is reported in Table D-4 and Table D-5. Section 3 provided an overview of the study population characteristics and methods and a discussion of study quality and other elements across studies. Figure 6-1 (below) provides an overview of the studies broadly grouped according to their utility to inform the cancer evaluation.

Figure 6-1

Study Utility Ranking: Liver Cancer

E/R = exposure response.

Gray shading (left-hand column): Utility to inform hazard evaluation; light shading = highest utility; dark shading = lowest utility. Blue shading (right-hand column): Potential bias and study sensitivity; light shading = least biased or most sensitive; dark shading = overall potential biases towards the null or lower sensitivity.

^a^(Tan shading): Multiple limitations; overall direction of potential biases is unknown or 1 exposed case [for Christensen et al. (2013)].

^b^(Peach shading): Most potential biases away from the null.

### 6.1.1 Study Findings

This section summarizes and interprets the findings for liver cancer from the individual epidemiological studies brought forward for evaluation (see Table 6-1), and integrates the evidence across studies, applies the RoC listing criteria to the body of evidence, and reaches an NTP recommendation for the level of evidence for liver cancer using the same criteria as described for the evaluation of kidney cancer in Section 4 and NHL in Section 5.

Table 6-1 Findings for Trichloroethylene and Cancers of the Liver, Biliary Tract, or Gallbladder

Reference | Study Size (N) Exposure Assessment | Exposure Groups | External Analysis SMR, SIR (95% CI) # Exposed Cases/Deaths | Internal Analysis RR (95% CI)^a^ # Exposed Cases/Deaths or Cases/Controls | Interpretation
Nordic studies
Vlaanderen et al. (2013) | 5 Nordic countries Record linkage of cancer registry with census questionnaire Semi-quantitative JEM M: 14,702 cases, 73,510 controls F: 9,194 cases, 45,970 controls | Cumulative exp.(unit-yr) 0 0.04 0.13 0.72 High-exposure group [underlined: Cumulative] Men Women [underlined: Intensity × prevalence] Men Women | | ICD-7 155 HR (Incidence) 1.00 1.03 (0.91–1.16); 340 0.99 (0.90–1.09); 508 1.00 (0.90–1.11); 422 1.01 (0.78–1.31); 69 1.02 (0.72–1.46); 37 1.07 (0.86–1.33); 99 1.12 (0.79–1.59); 38 | Low prevalence of exposure (TCE) and exposure levels likely to be low Strengths; long follow-up, large numbers of cases Limitations: Misclassification of exposure likely; JEM had poor sensitivity and did not account for heterogeneity within jobs and over time; TCE exposure correlated with tetrachloroethylene exposure Null: No evidence for an association but limited utility
Hansen et al. (2013) (potential overlap with Raaschou-Nielsen et al. (2003)) | Pooled and updated Nordic cohorts Axelson et al. (1994), Anttila et al. (1995), Hansen et al. (2001) 5,553 (3,776 M, 1,777 F) Biomonitoring (U-TCA) | All exposed subjects 0-yr lag 10-yr lag 20-yr lag U-TCA (mg/L) <5 5–25 25–50 >50 p_trend_ | ICD-7 155: liver + biliary SIR 1.77 (1.24–2.45); 36 1.83 (1.24–2.56); 32 2.09 (1.34–3.11); 24 | ICD-7 155: liver + biliary HR incidence (no lag) 1.00; 16 0.66 (0.31–1.42); 12 0.45 (0.13–1.54); 5 0.63 (0.22–1.68); 3 0.20 | Low exposure levels (only 20% exposed to ≥20 ppm) and short duration of employment Covariates: Age, sex, calendar period; indirect consideration of smoking and alcohol consumption Strengths: Biomonitoring data; large numbers of workers ever exposed Limitations: Only 2 or 3 U-TCA measurements per individual and unlikely to estimate lifetime or cumulative exposure; low statistical power for evaluating modest risks; limited ability to evaluate exposure-response relationship Evidence for a positive association: Statistically significant, moderately elevated effect estimate for ever exposure; risks increase with increasing lag but not exposure level
Raaschou-Nielsen et al. (2003) (Potential overlap with Hansen et al. (2013)) | Danish blue-collar workers 40,049 M+F (approx. 70% M) Working at TCE company; size of company surrogate for TCE exposure prevalence | Men (588,047 p-yr) Primary liver (ICD-7 155) Other liver (ICD-7 156) Women (118,270 p-yr) Primary liver (ICD-7 155) Other liver (ICD-7 156) Men and women Yr. of 1st employment [underlined: Women] Before 1970 1970–1979 1980 and later [underlined: Men] Before 1970 1970–1979 1980 and later Duration employment (yr) Men <1 1 to 4 ≥5 [underlined: Women] <1 1 to 4 ≥5 | SIR (Total cohort) 1.1 (0.74–1.64); 27 1.2 (0.73–1.77); 22 2.8 (1.13–5.80); 7 1.1 (0.22–3.23); 3 Primary liver 1.28 (0.89–1.8)^c^ 2.5 (0.5–7.3); 3 2.1 (0.2–7.7); 2 5.9 (0.7–21.2); 2 1.5 (0.9–2.4); 17 0.8 (0.3–1.6); 7 0.9 (0.2–2.6); 3 1.3 (0.6–2.5); 9 1.0 (0.5–1.9); 9 1.1 (0.5–2.1); 9 2.8 (0.3–10.0); 2 4.1 (1.1–10.5); 4 1.3 (0.0–7.1); 1 No exposure-response pattern for lagged exposure, | NR | Higher levels of TCE prior to 1970 (40–60 ppm); low levels of exposure after that time Covariates: age, sex, calendar year Strengths: Large numbers of exposed cases; subcohort of subjects with higher exposure potential Limitations: Young cohort, possible selection bias of difference in SES, external analysis only Potential for confounding by smoking among women Limited evidence for a positive association: Statistically significant elevated risk of primary liver cancer among women; little evidence of exposure-response relationship
Aerospace and aircraft manufacturing workers
Lipworth et al. (2011) (update of Boice et al. (1999)) | Burbank (USA) aircraft manufacturing workers 5,443 (approx. 80% M) Qualitative JEM Individual work histories | TCE Ever exposed TCE: years exposed 0 <1 1–4 5+ p_trend_ | SMR (ICD-9 155+156) 0.89 (0.57–1.33); 24 | RR mortality 1.00; 32 0.67 (0.32–1.42); 10 0.69 (0.28–1.71); 6 0.83 (0.36–1.91); 8 0.20 | Exposure levels not reported; short exposure duration Covariates: age, date of birth, date of hire, termination date, sex, and race Strengths: Long follow-up Limitations: Evidence of HWE, few exposed deaths in subgroup analysis; likely exposure misclassification; no evaluation of exposure intensity, 70% had exposure to mixed solvents Null: No evidence for a positive association but limited utility (limitations mainly towards the null)
Radican et al. (2008) (mortality to 2000) Blair et al. (1998) (incidence 1973–1990) | Utah (USA) aircraft maintenance workers N = 7,204 (5,153 M, 1,051 F) Semi-quantitative JEM, individual work histories | Radican et al.: Ever-exposed 155 + 156 Primary liver: 155.0 [underlined: Cum. exp. (unit-yr]) Men^b^ All 0–5 5–25 >25 All 0–5 5–25 >25 Blair et al. (1998) Cumulative Exp Men No TCE exposure <5 units-yr 5–25 units-yr ≥25 units-yr | NR | ICD-9 HR mortality 1.12 (0.57–2.19); 31 1.25 (0.31–4.97); 8 ICD-9 155+156) 1.36 (0.59–3.11); 28 1.17 (0.45–3.09); 10 1.16 (0.39–3.46); 6 1.72 (0.68–4.38); 12 Primary liver 2.72 (0.34–21.88); 8 3.28 (0.37–29.45); 4 0 4.05 (0.45–36.41); 4 RR (incidence) (ICD-9 155+156) 0.2 (0.1–2.4); 1 0.6 (0.1–3.1); 3 0.6 (0.1–3.8); 2 1.1 (0.2–4.8); 4 | Estimated exposure: Most workers exposed to low levels (~10 ppm), modest number of workers exposed to higher levels (~100 ppm) Covariates: age, calendar year, and sex Strengths: Adequate semi-quantitative JEM, long follow-up, adequate statistical power for ever exposure Limitations: Potential for exposure misclassification because of missing information for some workers; limited power due to low numbers of higher exposed workers; long follow-up time (45 years) may be past induction time; cannot rule out confounding from other co-exposures Limited evidence for a positive association: Statistically non-significant elevated effect estimates for primary liver cancer; some evidence (not significant) for an exposure-response gradient
Boice et al. (2006) (overlap with Zhao et al. (2005)) | Los Angeles (USA) Rocket engine testing workers 1,111 Men Qualitative JEM; Individual work histories | Ever exposed | SMR (ICD-9 155+156) 1.28 (0.35–3.27); 4 | | Exposure occurred during test engine flush, which is likely to be high Covariates: Date of birth, year of hire, pay type (surrogate for SES), and exposure to hydrazine Strengths: Adequate follow up Limitations: Qualitative exposure assessment; few exposed cases Null: Small increase in risk but limited utility
Morgan et al. (1998) | Arizona (USA) aircraft manufacturing workers N = 4,733 (2,555 M, 2,178 F) Semi-quantitative JEM; individual work history | Ever exposed Cumulative exp. score Low (2,357) High (2,376) Peak (med/high) vs. low/no | SMR (liver & biliary) 0.98 (0.36–2.13); 6 1.32 (0.27–3.85); 3 0.78 (0.16–2.28); 3 | RR (mortality) 1.48 (0.56–3.91); 6^c^ 2.12 (0.59–7.66); 3 1.19 (0.34–4.16); 3 0.98 (0.29–3.35); 3 | High-exposure jobs were considered to be ≥50 ppm Covariates: age at hire, gender (decade of hire considered but no effect) Strengths: Long follow-up and semi-quantitative exposure Limitations: Evidence of an HWE; potential exposure misclassification among low/medium exposure groups; mortality analysis and few exposed cases Limited evidence of a positive association: Statistically non-significant, elevated effect estimate (internal analysis); no evidence for exposure-response relationship; based on few exposed subjects
Other studies of occupational exposure (cohort and case-control)
Silver et al. (2014) | New York State (USA) micro-electronics manufacturing workers cohort mortality 3,113 TCE exposed Semi-qualitative JEM | 5 modified exposure years (exposure duration modified by exposure potential); 10-yr lag | | “liver, biliary and gallbladder” HR (at 5 years) 0.99 (0.50–1.95); NR | Exposure levels NR; only 13.9% of cohort exposed Covariates: Paycode and sex, age, Variables considered in analyses but did not change risk estimate were birth cohort, time since last exposure (healthy worker survival), hire era, and employment duration prior to 1966 Limitations: Evidence of HWE, Exposure classification based on potential exposure and duration; only one cumulative exposure variable reported in analysis. Limited information on comparison and # of exposed cases NR. Young cohort with only 17% deaths Null: No evidence for a positive association but limited utility
Bahr et al. (2011) | Kentucky (USA) uranium processing workers (gaseous diffusion plant) 5,535 Men | Exp level (rank-ordered) 1 2 3 All | | “Liver & biliary” SRR (mortality) 1.00 0.34 (0.05–2.07); NR 0.39 (0.08–1.94); NR 0.43 (0.10–1.84); NR | No information on exposure level or number of workers in each exposure category Limitations: Unclear descriptions of methods and findings; limited statistical power; evidence of HWE and survival effect Null: No evidence for a positive association but limited utility
Ritz (1999) | Ohio (USA) uranium processing workers 2,971 (M) | Low exp. no lag >2 years >5 years Moderate exp. no lag >2 years >5 years Low exp. 15-yr lag >2 years >5 years Moderate exp. 15-yr lag >2 years >5 years | NR | ICD-9 155+156 RR (mortality) 0.93 (0.19–4.53); 3 1.90 (0.35–10.3); 3 4.97 (0.48–51.1); 1 8.82 (0.79–98.6); 1 1.16 (0.24–5.60); 3 2.86 (0.48–17.3); 3 5.53 (0.54–56.9); 1 12.1 (1.03–144); 1 | 96% workers with low exposure Covariates: Time since 1st hire, pay type, internal radiation, & same chemical at a different level Strengths: Follow-up adequate Limitations: Low exposure, limited power; selection bias possible Possible residual confounding by radiation Limited evidence for a positive association: Pattern of increasing risk with increasing exposure and lag but based on small numbers
Greenland et al. (1994) (nested case-control study) | Massachusetts (USA) electrical manufacturers N = 12 cases (exposed controls NR) | Ever exposure | | ICD-8 155+156 OR (mortality) 0.54 (0.11–2.63); NR | Limited statistical power; only 10% of jobs had exposure to TCE, most of which were from indirect exposure Covariates: Age, date of death, covariates that changed risk estimate by 20% Limitations: Small numbers of cases and controls and short follow-up, possible selection bias, low quality exposure assessment Null: No evidence for a positive association but limited utility
Christensen et al. (2013) (case-control) | Montreal (Canada) Population- and hospital-exposure | Ever exposure Substantial exposure | | Liver, presume ICD 155 OR (incidence) 1.1 (0.1–8.5); 1 2.1 (0.2–18); 1 | Number of cases inadequate for evaluation
Environmental exposure
Bove et al. (2014) | North Carolina (USA) (Camp Lejeune) Drinking water contamination Ecological exposure assessment 154,932 men and women | TCE in drinking water (μg/L-month) ≤1 >1–3,100 >3,100–7,700 >7,700–39,745 | | “Liver and biliary” HR (mortality); 10-yr lag 1.0 (19) 1.02 (0.48–2.15); 12 1.04 (0.47–2.27); 11 0.86 (0.37–1.97); 9 | Estimated mean levels (μg/L-month) TCE from water supply = 358.7; overall cumulative exposure = 6,369 (median) and 5,289 (mean); 20% were exposed to levels between 7,700 and 39,745 Covariates: sex, race, rank, and education; other variables considered in the model (did not change risk estimates by 10%) include marital status, birth cohort, date of death, duty occupation. Strengths: Large cohort and adequate modeling of exposure Limitations: Young cohort; no information on individual water consumption; potential confounding from other contaminants e.g., tetrachloroethylene Null: No evidence for a positive association but limited utility

Studies reported one or more of primary liver, liver plus intrahepatic biliary ducts, or liver, intrahepatic and extrahepatic biliary ducts and gallbladder combined (as noted). Not all studies reported ICD diagnostic codes used.

CI = confidence interval; HR = hazard ratio; OR = odds ratio, p-yr = people years; RR = relative risk; SIR = standardized incidence ratio, SMR = standardized mortality ratio, SRR = standardized rate ratio.

^a^ HR, OR, RR, or SRR.

^b^ Study also report risk by exposure patterns (continuous and peak). Among men, HR > 1 for both primary liver and liver + biliary cancer in all exposure categories with no clear exposure-response relationships. Few cases of liver + biliary cancer were reported for women: HR < 1.0 for all cumulative exposure and exposure pattern categories except for peak, infrequent, HR = 4.30 (0.87–21.33); 2.

^c^ Reported by Scott and Jinot (2011): combined risk for men and women in Raaschou-Nielsen et al. (2003), and RR adjusted for age and sex for Morgan et al. (1998).

The cancer evaluation reports on the latest update of a cohort study unless there are additional relevant data (e.g., analyses or exposure information) in previous publications. The available studies that reported on liver cancer and trichloroethylene exposure and were considered for inclusion in the cancer evaluation include 12 cohort or nested case-control studies and 1 population-based case-control study (Christensen et al. 2013). The cohort studies include three studies of occupationally exposed subjects from Nordic countries (Hansen et al. 2013; Raaschou-Nielsen et al. 2003; Vlaanderen et al. 2013), four studies of U.S. aerospace or aircraft manufacturing workers (Blair et al. 1998; Boice et al. 2006; Lipworth et al. 2011; Morgan et al. 1998; Radican et al. 2008), two studies of U.S. uranium processing workers (Bahr et al. 2011; Ritz 1999), one nested case-control study (Greenland et al. 1994) and one cohort study (Silver et al. 2014) of U.S. electronic workers, and a cohort of military personnel exposed to trichloroethylene in drinking water (Bove et al. 2014). Two meta-analyses were also identified that contributed to the evaluation.

Although the available database consists of several well-conducted studies, liver cancer is rare, and few workers were exposed to high levels of trichloroethylene with reasonable confidence of exposure. Thus, the major overall limitation across studies is low statistical power to evaluate a modest risk of liver cancer from exposure to trichloroethylene and exposure-response relationships. In addition, some of the studies report findings for both liver and biliary cancer combined and others for primary liver cancer only, making cross comparisons more difficult. Similar to kidney cancer, meta-analyses may be informative, although heterogeneity of findings, if considerable, can reduce their utility and should be noted. The findings of the individual studies are discussed below and presented in Figure 6-1.

#### 6.1.1.1 Nordic Studies

These three studies include subjects with occupational exposure to trichloroethylene from diverse industries and workers identified from a broad occupational or a broad population-based database. Two studies reported an association with potential trichloroethylene exposure and liver cancer, with the strongest evidence from the pooled analyses of biomonitored workers (Hansen et al. 2013), in which a statistically significant increase in risk was observed among men and women combined (SIR = 1.77, 95% CI = 1.24 to 2.45, 36 cases). Risks increased with increasing latency (as assessed by lag time), which partly reflect the longer average latencies of liver cancer (Manton et al. 2009), and provides support for an association between trichloroethylene exposure and liver cancer in this population. However, in internal analyses, which examined exposure-response relationships, risks were less than one and the highest risk (with the largest number of cases) was in the lowest exposure group, the referent group in this analysis, which complicates the interpretation of the study. Few U-TCA samples were available for each subject, and thus U-TCA, which is a measure of short-term exposure, may not have accurately captured exposure intensity from the past or in the future.

Increases in liver cancer risk were observed among women (total trichloroethylene-exposed cohort) in the Danish study of Raaschou-Nielsen et al. (2003) (SIR = 2.8, 95% CI = 1.13 to 5.80, 7 cases for ever exposed) and a SIR of 4.1 (95% CI = 1.1 to 10.5, 4 cases) was observed among workers with 1 to 4 years employment duration. A higher risk occurred among women with later years of first employment, when exposures were reportedly lower than the earlier years; however, the number of cases is small. In contrast, among men (with more overall cases than women), the highest risk was found among men employed before 1970 (SIR = 1.5, 95% CI = 0.9 to 2.4, 17 cases). It is important to note that the authors only conducted analyses for liver in the total cohort and not among the subcohort of workers considered to have higher exposure (as they did for kidney cancer). Some misclassification of exposure is likely as only a portion of the cohort was exposed to trichloroethylene. There was little evidence of an association with liver cancer in the large population-based study (Vlaanderen et al. 2013), although, as noted previously, exposure misclassification is likely to be substantial and estimated exposures were low.

#### 6.1.1.2 Aerospace and Aircraft Workers

The evidence for an increase in liver cancer risk among the group of U.S. studies of aerospace and aircraft workers (Blair et al. 1998; Boice et al. 2006; Lipworth et al. 2011; Morgan et al. 1998; Radican et al. 2008) is limited. In most of the studies, there were few exposed cases, especially in subgroup analyses, if reported, and the studies had limited ability to evaluate exposure-response relationships. In the Radican et al. (2008) cohort, which evaluated primary liver separately from liver and biliary combined, non-statistically significant increases were observed for both cancer categories in analyses of cumulative exposure for all workers and workers with the highest exposure. There is some evidence of a weak exposure response for cumulative exposure and primary liver cancer among male workers, but confidence intervals are wide. Findings from the other studies were null. Two mortality studies (Boice et al. 2006; Morgan et al. 1998) observed non-statistically significant, small increases in liver cancer, but were based on small numbers of exposed cases; no exposure gradient was observed in the Morgan study. The mortality study by Lipworth et al. (2011) observed a decrease in liver cancer by employment duration, a poor surrogate for cumulative exposure. It is not clear how many workers were exposed to trichloroethylene in the different categories of exposure duration, since exposure duration was short, so that exposure misclassification is likely. In addition, there is evidence of a healthy worker effect in this study, all of which limit the study’s ability to inform the cancer hazard evaluation.

#### 6.1.1.3 Other Studies

The remaining studies are of more limited utility for informing the cancer hazard evaluation. Ritz (1999) found an increased risk of liver cancer among uranium processing workers; risks increased with increasing lag time, exposure duration, and exposure level in analyses controlling for radiation exposure, which suggests a positive relationship between trichloroethylene exposure and cancer risk; however, the numbers are based on small numbers of workers, most with low exposure to trichloroethylene. In addition, there is the potential for selection bias and residual confounding, possibly by radiation exposure. The electronics worker cohort (Silver et al. 2014) and the drinking water study (Bove et al. 2014) reported no increases in risk but both studies had limited exposure assessment, and were relatively young cohorts. Overall, these limitations would tend to bias findings towards the null. The cohort study of uranium workers by Bahr et al. (2011) and the nested case-control study (Greenland et al. 1994), both of which have a number of methodological limitations, report decreases in risk, and neither study reported numbers of deaths. Finally, while the Montreal study (Christensen et al. 2013) had adequate exposure assessment and analytical methods, only one case of liver cancer was observed in the substantially exposed group, so this study is uninformative for this endpoint.

### 6.1.2 Meta-analyses

Two meta-analyses have been conducted on the cohort studies of liver cancer, by the EPA (Scott and Jinot 2011; USEPA 2011a) and by Alexander et al. (2007) (see Table 6-2). The inclusion and exclusion criteria, systematic data extraction, and methods of analysis used in the EPA meta-analysis were identical to those used for meta-analyses of kidney cancer and NHL and have been described in Sections 4 and 5, respectively. (See Table D-10 for a list of the studies included in these meta-analyses.) Studies included in this review that are not part of the meta-analyses include the pooled analyses by Hansen et al. (2013) (which includes the populations reported on by Axelson et al. (1994), Anttila et al. (1995), and Hansen et al. (2001), the population-based cancer registry study of Nordic countries by Vlaanderen et al. (2013), two studies of uranium processing workers (Bahr et al. 2011; Ritz 1999), the microelectronics workers study by Silver et al. (2014), and the drinking water study by Bove et al. (2014).

Table 6-2 Meta-analyses of Liver Cancer (Including Gall Bladder and Biliary Passages) and Trichloroethylene Exposure

Reference | Study Design (Number of Studies) | mRR (95% CI) All | mRR (95% CI) Highest Exposure | Comments
EPA (2011a)/Scott and Jinot (2011) | Cohort studies (8) and nested case-control study (1) | 1.29 (1.07–1.56) | 1.28 (0.93–1.77) | Random and fixed effects models; little evidence of heterogeneity or publication bias
Alexander et al. (2007) | Cohort studies (8) | 1.30 (1.09–1.55) | NR | Random effects model; some evidence of heterogeneity

mRR = meta-relative risk; NR = not reported; RR = relative risk.

The two meta-analyses are broadly comparable in terms of the studies included and the method of analysis. Scott and Jinot (2011) considered each of the studies up to and including 2011 listed in Table 6-1, with the exception of Bahr et al. (2011), Lipworth et al. (2011), and Ritz (1999). They did, however, include Boice et al. (1999), the earlier study followed up by Lipworth et al. (2011). Alexander et al. (2007) included each of the studies listed in Table 6-1 up to 2007 except for Zhao et al. (2005). The meta-analysis by Scott and Jinot (2011) suggests an overall statistically significant increase in the mRR for combined liver and biliary cancers, but a slight decrease in the mRR for the highest exposed groups was observed. Alexander et al. (2007) reported a comparable mRR. These authors also calculated mRRs for studies that reported primary liver cancer and biliary tract cancers separately and reported closely comparable risk estimates.

In the EPA meta-analysis, the mRR was elevated but less precise and no longer statistically significant (OR = 1.22, 95% CI = 0.93 to 1.61) with the removal of Raaschou-Nielsen et al. (2003), which was the largest study in that analysis, contributing 53% of the weight, and reporting twice the number of events as the other contributing studies. Differences in exposure metrics used in the component studies, and small numbers of cases or deaths place limitations on analyses by exposure intensity or duration. In the EPA analysis, the lower mRR observed among the highest exposed groups primarily reflects the inverse exposure-duration response relationship for exposure duration reported in the largest study by Raaschou-Nielsen et al. (2003) (Scott and Jinot 2011). Studies conducted since 2011 have not observed overall increases in risks or are of limited utility due to limited statistical power or exposure assessments, or other concerns.

#### 6.1.2.1 Occupational Co-exposures

With respect to occupational carcinogens, IARC and/or the Report on Carcinogens (Cogliano et al. 2011; NTP 2011) have identified some types of radiation (plutonium, thorium and its decay products), vinyl chloride and polychlorinated biphenyls as known human liver carcinogens, and concluded that there was limited evidence of human carcinogenicity for inorganic arsenic, and X- and gamma-radiation. Trichloroethylene-exposed workers in some studies may have been exposed to a range of other chemical or physical agents, primarily (1) chlorinated solvents (primarily tetrachloroethylene and 1,1,1-trichloroethane) in the Nordic studies, the studies of aircraft manufacturing and aerospace workers, and the drinking water study, (2) cutting fluids such as mineral and petroleum oils, organic solvents, hydrazine, benzene, chromates, and PAHs in the aerospace and aircraft industries, and (3) radiation (Ritz 1999), or cutting oils and metals in the studies of uranium processing workers (Bahr et al. 2011), and (4) vinyl chloride in the drinking water study (Bove et al. 2014). The co-exposure with the strongest potential for confounding is ionizing radiation in the study of uranium workers by Ritz (1999). A positive association was observed for liver cancer in this study after adjusting for exposure to radiation, which helps to reduce concern that confounding occurred, although residual confounding cannot be ruled out. In addition, there is limited evidence of exposure-response patterns with trichloroethylene intensity and duration in this study; however, few workers were exposed to moderate levels of trichloroethylene. Vinyl chloride is not a concern because no association with trichloroethylene was found in the drinking water study.

The other principal co-exposures identified in these studies have not been classified as known or suspected liver carcinogens in humans; however, there is some or sufficient evidence in animal studies for the liver carcinogenicity of several chlorinated and non-chlorinated solvents, including tetrachloroethylene, 1,1,2,2- and 1,1,1,2-tetrachloroethane, carbon tetrachloride, methylene chloride, and hydrazine. The chlorinated solvents tetrachloroethylene and 1,1,1-trichloroethane are probably common co-exposures in the aircraft manufacturing studies and possibly in the Nordic studies. In addition, the strength of the association with trichloroethylene was limited in these studies. Thus, confounding, especially in the aircraft manufacturing studies, cannot be reasonably ruled out.

#### 6.1.2.2 Lifestyle and Other Potential Confounders

Non-occupational risk factors include alcohol consumption, aflatoxins, estrogen-progestogen contraceptives, tobacco smoking, betel quid use without tobacco, viral infections (hepatitis B and C and human immunodeficiency virus type 1), parasites (liver flukes and Schistosoma), long-term use of anabolic steroids, and ionizing radiation (Cogliano et al. 2011; NTP 2011). Some of these factors, such as smoking, alcohol consumption, and possibly biological infections, may be related to socioeconomic status and could possibly vary by trichloroethylene exposure status.

The majority of cohort and nested case-control studies conducted age-, sex-, race- and calendar-year or period-standardized comparisons in external analyses (SMR or SIR) where appropriate and age-, sex-, race- and in some cases calendar period-adjusted comparisons in internal analyses. In addition, all of the studies, except for the Danish blue-collar worker study, conducted internal analyses, which would mitigate potential confounding from lifestyle factors. Although none of the cohort studies adjusted for smoking, tobacco smoking is a weaker risk factor for liver cancer than other cancers (meta-risk estimate approximately 1.5, (Lee et al. 2009)) and as noted in Section 4 for kidney cancer, there was little evidence for an association of trichloroethylene and lung cancer, which suggests that confounding from smoking is not a concern.

While none of the studies directly addressed alcohol consumption, incidence rates of cancers of the oral cavity, pharynx, or esophagus, or of cirrhosis (where reported) may provide indirect evidence of alcohol consumption relative to the reference population. While these rates are unremarkable in most of the studies, approximately 2-fold, statistically non-significant increases in incidence rates were observed for oropharyngeal and esophageal cancers among women in the Danish blue-collar workers cohort (Raaschou-Nielsen et al. 2003). Smoking- and alcohol-related diseases were not statistically significantly increased in the pooled analysis reported by Hansen et al. (2013). Overall, there is no strong indirect evidence for potential confounding by alcohol use in most of the cohorts, with the possible exception of the Danish cohort of trichloroethylene-exposed women workers (Raaschou-Nielsen et al. 2003).

### 6.1.3 Integration

Several individual cohort studies with moderate or low to moderate utility found modest increases in risk of liver cancer (Hansen et al. 2013; Morgan et al. 1998; Raaschou-Nielsen et al. 2003; Radican et al. 2008); the strongest evidence was from the external analysis in the updated and pooled analysis of biomonitored workers in Nordic countries (Hansen et al. 2013). (See Figure 6-2 for a plot of risk estimates for groups ever exposed to trichloroethylene grouped according to study utility.) However, no exposure-response relationship was observed in the internal analysis in this study and there was little evidence of an exposure-response relationship in any study with the possible exception of the Utah aircraft-manufacturing workers in analyses specific for primary liver cancer (Radican et al. 2008).

Figure 6-2

Forest Plot: Liver Cancer and Ever Exposure to Trichloroethylene

Relative risk and 95% CI for ever exposure to trichloroethylene and liver cancer according to study utility category (see Figure 6-1) and overall prediction of direction of any bias for low utility studies as described in Section 4.1.3. The effect estimate for Christensen et al. (2013) is based on only one liver case observed. Studies by Bove et al. (2014), Vlaanderen et al. (2013), and Ritz et al. (1999) are not graphed because they did not report relative risk for ever exposure. Findings for these studies are reported in Table 6-1. For studies reporting multiple risk estimates, preference was given to studies with longer lag (Hansen et al. (2013) [20 years]) and internal analysis. Risk estimates for Raaschou-Nielsen et al. (2003) (combined men and women) and internal analysis for Morgan et al. (1998) were reported by Scott and Jinot (2011).

The database is inadequate to evaluate the effect of latency, as few cohort studies conducted lagged vs. unlagged or time since first exposure analyses and data are generally sparse due to limited numbers of cases. SIRs increased with increasing lagged time (no lagged, 10 year lagged, and 20-year lagged) in the Nordic study of biomonitored workers and (Hansen et al. 2013). However, no relationship between risk of liver cancer and lagging was observed in two other studies (Raaschou-Nielsen et al. 2003; Vlaanderen et al. 2013). The rest of the studies did not conduct lagged analyses (Bahr et al. 2011; Boice et al. 2006; Christensen et al. 2013; Lipworth et al. 2011; Morgan et al. 1998; Radican et al. 2008) or only reported effect estimates for one lagging period (Bove et al. 2014; Greenland et al. 1994; Silver et al. 2014).

No or little evidence of an association of trichloroethylene exposure (for either ever exposed groups or among the highest exposed) and liver cancer risk was found in other studies, most of which were considered to be of low to low/moderate utility because of inadequate sensitivity to detect rare cancers such as liver cancer, concerns about non-differential exposure misclassification (Boice et al. 2006; Bove et al. 2014; Greenland et al. 1994; Lipworth et al. 2011; Silver et al. 2014; Vlaanderen et al. 2013) and/or other methodological concerns (Bahr et al. 2011). The only case-control study (Christensen et al. 2013) had too few exposed cases (one) to be informative. Ritz (1999) reported a positive association among uranium processing workers; however, this should be viewed with some caution because of potential residual confounding from exposure to radiation and small numbers of exposed cases. Two meta-analyses based on either nine or eight studies suggest a modest but statistically significant increase in liver cancer risk (Alexander et al. 2007; Scott and Jinot 2011), although they did not include some recent studies. Confounding by one or more of the common co-exposures, or chance, cannot be completely ruled out in some studies.

## 6.2 Mechanistic Data for Liver Carcinogenicity

Trichloroethylene metabolites produced by P450 oxidation, primarily CYP2E1, (see Section 1.3) are most likely responsible for liver toxicity and cancer (USEPA 2011a). Support for this hypothesis includes the following: trichloroethylene and its oxidative metabolites have similar hepatotoxic and hepatocarcinogenic effects, pretreatment with CYP inducers enhances hepatotoxicity, and treatment with CYP inhibitors decreases hepatotoxicity. In addition, liver tumor analyses based on immunostaining for c-Jun show that neither trichloroacetic acid nor dichloroacetic acid alone can account for the full characteristics of trichloroethylene-induced liver tumors (Bull et al. 2002).

This section reviews the hypothesized modes of action for liver carcinogenicity and is divided into two subsections: modes of action with limited experimental support and modes of action that are inadequately defined or have little to no experimental support. As with the previous mechanistic sections for kidney cancer and non-Hodgkin lymphoma, the discussion relies on recent comprehensive reviews by EPA (2011a; 2011b) and IARC (2014). The findings from these reviews are supplemented with primary literature that was not included in the reviews or as needed for clarity.

### 6.2.1 Hypothesized Modes of Action with Limited Experimental Support

Modes of action proposed for trichloroethylene-induced liver cancer that are perhaps the most biologically plausible include the following: genotoxicity from oxidative metabolites, PPARα activation, oxidative stress, and hypomethylation and gene expression changes (IARC 2014; USEPA 2011a; 2011b). Another possible mode of action is autoimmune hepatitis (Czaja 2013; Wang et al. 2013).

There are several similarities between the hypothesized modes of action in trichloroethylene-induced liver tumors in mice and some of the known characteristics of human hepatocellular carcinoma (USEPA 2011a). The mode of action for trichloroethylene-induced liver tumors is complex and likely involves key events from several pathways. Overall, a role for many of the key events could not be ruled out. Although the level of evidence varied for the different modes of action, the data were inadequate to support a definite conclusion that any of the proposed modes of action is operant. The key events associated with the proposed modes of action with the most experimental support are listed in Table 6-3 and are discussed below.

Table 6-3 Possible Modes of Action and Key Events for Trichlorethylene-induced Liver Cancer

Mode of Action | Key Events
Genotoxicity | 1. One or more oxidative metabolites are produced in situ or delivered systemically to the liver 2. Genotoxicity induced by oxidative metabolites advances acquisition of the multiple critical traits contributing to carcinogenesis
PPARα activation | 1. Oxidative metabolites activate PPARα in the liver 2. PPARα activation leads to alterations in cell proliferation and apoptosis 3. Alterations in cell proliferation and apoptosis cause clonal expansion of initiated cells 4. Clonal expansion of initiated cells leads to tumor formation
Oxidative stress | 1. Trichloroethylene or its metabolites induce oxidative stress 2. Oxidative stress leads to chronic inflammation, mutations, and damage to proteins, lipids, and DNA 3. Mutations and damage to macromolecules activates cell-signaling pathways, induces genomic instability and cell transformation, and leads to cancer
Epigenetic changes | 1. Epigenetic changes, particularly DNA methylation, are induced by one or more metabolites 2. These changes advance acquisition of multiple critical traits contributing to carcinogenesis
Autoimmune hepatitis | 1. Reactive metabolites form protein adducts and/or induce oxidative stress leading to lipid peroxidation and oxidative modifications to proteins in the liver (neoantigens) 2. Activation and hepatic infiltration of CD4^+^ T cells and secretion of inflammatory cytokines 3. Inhibition of apoptosis in self-reactive CD4^+^ T cells 4. Formation of anti-malondialdehyde- and anti-hydroxynonenal-protein adduct antibodies in association with increases in anti-nuclear antibodies 5. Hepatocyte damage/autoimmune hepatitis 6. Autoimmune hepatitis/cirrhosis contributes to hepatocarcinogenesis

Sources: Czaja (2013), EPA (2011a). Gilbert et al. (2006), Griffin et al. (2000c), Wang et al. (2013).

#### 6.2.1.1 Genotoxicity

Since genotoxicity is a well-established cause of carcinogenicity, one hypothesis is that trichloroethylene causes liver cancer by a genotoxic/mutagenic mode of action, presumably through formation of reactive oxidative metabolites that cause direct alterations in hepatocyte DNA (e.g., mutations, DNA damage, and/or clastogenic effects) (USEPA 2011a). The genotoxic effects of trichloroethylene and its metabolites were presented in Section 2. Chloral hydrate appears to have the greatest genotoxic potential among the oxidative metabolites. Genotoxic effects associated with chloral hydrate included mutagenicity in the Ames test; micronucleus formation, chromosome aberrations, aneuploidy, and cell transformation in mammalian cell cultures; and in vivo studies reported DNA single-strand breaks and micronucleus induction in mice. Some have argued that chloral hydrate is unlikely to be the cause of trichloroethylene carcinogenicity because it is a short-lived intermediate metabolite that is rapidly converted to trichloroacetic acid and trichloroethanol in the liver. Furthermore, doses used in the in vitro genotoxic studies were generally much higher than the reported peak concentrations achieved in the liver of rodents administered hepatocarcinogenic doses of trichloroethylene. However, it is uncertain if a direct comparison between concentrations in culture media used in genotoxicity assays in vitro and concentrations in whole-liver homogenates achieved in vivo is appropriate. Furthermore, some in vivo genotoxicity assays with chloral hydrate reported positive results at doses similar to those that induced a carcinogenic response in chronic bioassays.

Several studies investigated the frequency and spectra of H-ras mutations in liver tumors induced by trichloroethylene, trichloroacetic acid, or dichloroacetic acid (Bull 2000; Bull et al. 2002). Although there were some differences in the H-ras mutation frequencies reported among the studies, the data indicate that trichloroethylene, dichloroacetic acid, and trichloroacetic acid activate mutations in codon 61 of the H-ras protooncogene in liver carcinomas of male B6C3F_1_ mice at a frequency similar to that observed in spontaneous liver tumors. Trichloroacetic acid-induced tumors showed the same mutational spectrum as spontaneous liver tumors; however, trichloroethylene- and dichloroacetic acid-induced tumors had a significant decrease in AAA mutations and a significant increase in CTA mutations compared to spontaneous- or trichloroacetic acid-induced liver tumors. The similarity in frequency and types of H-ras mutations in liver tumors induced by trichloroacetic acid compared with spontaneous tumors suggests that trichloroacetic acid may act as a promoter of spontaneous tumors (Eastmond 2012). H-ras mutations appeared to be a late event because the frequency of H-ras mutations increased with time and was higher in hepatocellular carcinomas compared with adenomas (Bull et al. 2002). The effects of dichloroacetic acid and trichloroacetic acid were not typical of genotoxic agents and suggested that these compounds promoted clonal expansion of initiated cells while DNA damage accumulated with tumor growth. The data also suggest that both trichloroacetic acid and dichloroacetic acid may be involved in trichloroethylene-induced liver tumors through activation of the H-ras protooncogene. However, the mechanisms do not appear to be the same for dichloroacetic acid and trichloroacetic acid (Ferreira-Gonzalez et al. 1995).

It is clear that human and rodent livers are exposed to the oxidative metabolites of trichloroethylene. Chloral hydrate is the most genotoxic oxidative metabolite but is rapidly converted to trichloroacetic acid and trichloroethanol. The data are insufficient to assess the genotoxic contributions from the nongenotoxic contributions of chloral hydrate or other oxidative metabolites. Although the data are inadequate to conclude that a genotoxic mode of action is responsible for trichloroethylene-induced liver tumors, a genotoxic mode of action mediated by the oxidative metabolites is biologically plausible and cannot be ruled out.

#### 6.2.1.2 PPARα Activation

Trichloroethylene, trichloroacetic acid, and dichloroacetic acid induce peroxisome proliferation in mice but are relatively weak PPARα agonists requiring mM concentrations (Corton 2008; Keshava and Caldwell 2006). The peroxisome-related effects of trichloroethylene are most likely mediated through trichloroacetic acid because it is a primary oxidative metabolite of trichloroethylene and is a stronger PPARα agonist than dichloroacetic acid. The data linking trichloroethylene-induced liver tumors to a PPARα-dependent mechanism include the following: (1) there is a relatively good correlation between trichloroethylene- and trichloroacetic acid-induced liver tumors and induction of markers of PPARα activation in the mouse but not in the rat, (2) transactivation assays show that trichloroacetic acid activates mouse and human PPARα, (3) markers of PPARα activation are elevated at trichloroethylene or trichloroacetic acid doses below or coincident with doses that induce mouse liver tumors in a manner similar to other peroxisome proliferators, (4) trichloroethylene increases hepatocyte proliferation and peroxisome proliferator-associated genes in wild-type but not PPARα-null mice (93% of the altered genes in wild-type mice were PPARα dependent), and (5) trichloroacetic acid-induced mouse liver tumors have properties similar to those induced by classic peroxisome proliferators in rat liver (Corton 2008; Laughter et al. 2004).

However, it is unlikely that trichloroethylene induces liver tumors solely through metabolism to trichloroacetic acid and PPARα activation. The dose-response for liver weight increases were different for the two compounds, and liver weight increases did not correlate with peroxisomal enzyme activity or changes in peroxisomal number or volume (USEPA 2011a). Bull et al. (2002) also reported differences in tumor phenotypes (based on c-Jun expression) between trichloroethylene and trichloroacetic-acid-induced liver tumors. The H-ras mutation frequency in trichloroethylene-induced liver tumors was more similar to spontaneous or dichloroacetic acid-induced tumors than to trichloroacetic acid-induced tumors (discussed above in the Genotoxicity subsection) (Bull 2000; Bull et al. 2002). The H-ras mutation frequency pattern in trichloroacetic acid-induced liver tumors also was opposite that observed with other peroxisome proliferators. Furthermore, recent studies have demonstrated that PPARα activation is not the sole mode-of-action of hepatocarcinogenesis for known PPARα agonists (Guyton et al. 2009; USEPA 2011a).

Although trichloroethylene activates PPARα and other key events in the hypothesized mode of action, most of the proposed key events are nonspecific and may be caused by multiple mechanisms. A causal linkage between trichloroethylene exposure and alterations in gene expression and DNA synthesis with PPARα has not been established. Together, these data suggest that multiple mechanisms and cell types are likely involved in the hepatocarcinogenicity of PPARα agonists. It is biologically plausible that PPARα agonism mediated by trichloroacetic acid is operant; however, it is unlikely that it is the sole or predominant mode of action for trichloroethylene-induced hepatocarcinogenicity in mice.

#### 6.2.1.3 Oxidative Stress

Oxidative stress is an important factor in a number of human diseases, including cancer, and occurs when the concentration of reactive oxygen species (ROS) generated exceeds the antioxidant capacity of the cell (Klaunig et al. 1998). It can be induced by exposure to drugs or other chemicals, but also is part of normal cellular respiration and cell signaling. The consequences of oxidative stress may include damage to critical cellular macromolecules including DNA, lipids, and proteins. One of the most common forms of damage is the generation of 8-hydroxy-2'-deoxyguanosine (8-OHdG), a highly mutagenic adduct capable of causing cellular DNA damage. Other common biomarkers of oxidative stress include thiobarbituric acid-reactive substances (TBARS, an index of lipid peroxidation) and superoxide anion production.

Several studies reported evidence of oxidative stress in the liver of mice or rats following acute, subacute, or subchronic exposure to trichloroethylene, trichloroacetic acid, or dichloroacetic acid (Austin et al. 1996; Channel et al. 1998; Larson and Bull 1992; Parrish et al. 1996; Tabrez and Ahmad 2009; Toraason et al. 1999). EPA (2011a; 2011b) identified several issues in most of these studies (i.e., lack of appropriate controls, incomplete reporting, marked toxicity, and possible confounding by vehicle or route of administration effects) that limited interpretation of the data. However, a series of more recent studies show that dichloroacetic acid and trichloroacetic acid induce oxidative stress and macrophage activation in B6C3F_1_ mice (Hassoun and Cearfoss 2011; Hassoun et al. 2013; Hassoun et al. 2010a; Hassoun and Dey 2008; Hassoun and Ray 2003; Hassoun et al. 2010b). These studies were not reviewed by EPA (2011a; 2011b) and are briefly reviewed below.

In vitro studies using murine macrophage J774A.1 cells exposed to dichloroacetic acid or trichloroacetic acid showed dose- and time-dependent increases in superoxide anion production, cellular death, and lactate dehydrogenase (LDH) release (a marker of cell death) (Hassoun and Ray 2003). In contrast to in vivo studies (discussed below), there were no significant differences in the effects of these two compounds.

A series of in vivo studies were conducted to investigate oxidative stress in male B6C3F_1_ mice exposed to dichloroacetic acid and trichloroacetic acid (Cearfoss and Hassoun 2012; Hassoun and Cearfoss 2011; Hassoun et al. 2013; Hassoun et al. 2010a; Hassoun and Dey 2008; Hassoun et al. 2010b). Data from these studies are summarized in Appendix F and include the following: superoxide anion production in liver and peritoneal lavage cells (Table F-1), lipid peroxidation and DNA single-strand breaks in liver cells (Table F-2), phagocyte activation and superoxide dismutase (SOD) in peritoneal lavage cells (Table F-3), and antioxidant enzymes in liver cells (Table F-4).

Overall, these data show that both dichloroacetic acid and trichloroacetic acid induced dose- and time-dependent increases in superoxide anion production, lipid peroxidation, and DNA single-strand breaks. The data also indicated that antioxidant enzymes (e.g., SOD, catalase, and glutathione peroxidase) were involved in cellular resistance to oxidative stress. In most cases, dichloroacetic acid had a greater effect than trichloroacetic acid. These data suggest that superoxide anion production contributes to lipid peroxidation and DNA damage in the liver. There also was a strong correlation between superoxide anion production in peritoneal lavage cells (considered as a surrogate for Kupffer cells) and hepatic tissues that suggested phagocytic activation may contribute to oxidative stress in the liver.

Hepatocyte oxidative stress also was identified as a key event associated with other modes of action. These include PPARα activation (Klaunig et al. 2003), GST-zeta inhibition (Blackburn et al. 2006), and autoimmunity (see Section 2.2) (Wang et al. 2007a; Wang et al. 2007b; Wang et al. 2012b; Wang et al. 2013; Wang et al. 2009a; Wang et al. 2012c). Parrish et al. (1996) showed that markers of peroxisome proliferation and 8-OHdG levels were not significantly different from controls in mice exposed to dichloroacetic acid and concluded that oxidative damage did not play an important role in the chronic hepatotoxicity of peroxisome proliferators. Blackburn et al. (2006) reported that GST-zeta deficiency results in a constant level of oxidative stress due to the accumulation of maleylacetone and maleylacetoacetate. As discussed below, dichloroacetic acid is an inhibitor of GST-zeta, thus, dichloroacetic acid could cause oxidative stress by diminishing GST-zeta levels. Finally, Wang et al. (2013) reported that N-acetylcysteine supplementation protected against trichloroethylene-induced autoimmunity by attenuating oxidative stress.

There is evidence that oxidative metabolites of trichloroethylene can cause oxidative stress in the liver and it is biologically plausible that oxidative stress can contribute to hepatotoxicity and hepatocarcinogenicity. However, the key events for this mode of action have not been fully specified and the data are insufficient to determine the necessity or sufficiency of oxidative stress in trichloroethylene-induced hepatocarcinogenicity.

#### 6.2.1.4 Epigenetic Changes (Altered Gene Expression/Hypomethylation)

Altered gene expression, whether through global DNA hypomethylation or other mechanisms, can contribute to carcinogenesis by affecting genes identified with cell growth and differentiation, tissue remodeling, signal transduction, metabolism, apoptosis, cancer progression, and other processes (Caldwell and Keshava 2006; USEPA 2011a). Genetic expression studies and studies of changes in methylation status induced by trichloroethylene and its metabolites are reviewed below.

A limited number of in vitro and in vivo studies in experimental animals have investigated gene expression changes in liver induced by trichloroethylene or its oxidative metabolites (Caldwell and Keshava 2006; USEPA 2011a; 2011b). These studies reported that trichloroethylene alters expression of various stress-response, xenobiotic metabolizing, and homeostatic genes. Mice exposed to dichloroacetic acid also showed altered expression patterns in genes associated with cell growth, tissue remodeling, apoptosis, cancer progression, and xenobiotic metabolism in normal liver tissue and liver tumors.

Sano et al. (2009) investigated differences in gene expression profiles of liver in mice and rats exposed to acute and subacute oral doses of trichloroethylene. These differences included suppression of TGF-β signaling, activation of MAPK signaling, and alteration of the ubiquitin-proteasome system in mice but not rats and may play a role in the species-specific biochemical effects of trichloroethylene-induced liver carcinogenesis. Bradford et al. (2011) analyzed whole liver gene expression profiles in male mice from 15 inbred strains exposed to a single oral dose of trichloroethylene. PPARα-mediated molecular networks, primarily consisting of upregulation of lipid and drug metabolism genes, were the most pronounced effects that were dependent on genetic background. Gene expression changes that were significantly affected by treatment but not genotype included cell death, liver necrosis, and inflammatory-mediated response networks; however, there was little observable liver toxicity in this study. Transcription factor analysis of these genes revealed several inflammation-related regulatory proteins that are associated with activation of macrophages and lymphocytes and suggested that trichloroethylene may affect Kupffer cells. Recent in vitro studies using human hepatic L-02 cells reported that exposure to trichloroethylene induced alterations in the expression, distribution, and interactions of SET-associated proteins (Hong et al. 2012; Hong et al. 2013). SET (also known as protein phosphatase 2A inhibitor, I2PP2A, or template-activating factor-1, TAF-1) is a nuclear protein with roles in histone modification, gene transcription, DNA replication, nucleosome assembly, phosphatase activity, and kinase activity. Trichloroethylene also induced over-expression of several SET-binding proteins, including eukaryotic translation elongation factor 1 alpha 1 and 1 alpha 2 (eEF1A1 and eEF1A2), in a dose-dependent manner. Over-expression of eEF1A1 and eEF1A2 are associated with a variety of human tumors. Endogenous SET is known to decrease in the nucleus and increase in the cytoplasm upon cell death induced by toxic stress. eEF1A is primarily localized in the cytoplasm, but redistribution to the nucleus has been associated with cell proliferation and tumor development. Cytoplasmic translocation of SET and nuclear translocation of eEF1A also were observed in L-02 cells exposed to trichloroethylene. These results suggest that the translocation and over-expression of SET and eEF1A1/eEF1A2 are involved in trichloroethylene-induced liver cancer.

EPA (2011a; 2011b) also reviewed several studies that investigated the effects of trichloroethylene, trichloroacetic acid, and dichloroacetic acid on DNA methylation status in mice. Aberrant DNA methylation is a common hallmark of all types of cancer; however, it has not yet been determined whether altered DNA methylation is a consequence or cause of cancer. Rats and mice fed diets that induce hypomethylation (deficient in choline and methionine) develop liver tumors. A high dose of methionine (8 g/kg) was reported to decrease the number of dichloroacetic acid-induced liver foci and adenomas; however, mice fed a lower level of methionine (4 g/kg) had a higher incidence of foci. Although the authors believed their data indicated that methionine supplementation slowed the progression of tumors, the study did not demonstrate that enhanced tumor progression is a key event for the mode of action for dichloroacetic acid-induced liver carcinogenicity. Other studies reported that female B6C3F_1_ mice administered subacute oral doses of trichloroethylene (1,000 mg/kg), trichloroacetic acid (500 mg/kg), or dichloroacetic acid (500 mg/kg) had increased cell proliferation and hypomethylation of the promoter regions of c-Jun and c-Myc in the liver. Methionine treatment was reported to eliminate this effect in one study, but low doses of methionine had no effect. Hypomethylation also was reported in total liver and liver tumor DNA in mice initiated with N-methyl-N-nitrosourea and exposed to trichloroacetic acid or dichloroacetic acid for 46 weeks.

A few studies have reported altered gene expression and/or hypomethylation of liver DNA in mice exposed to high doses of trichloroethylene, trichloroacetic acid, and dichloroacetic acid; thus, it is biologically plausible that these events could contribute to trichloroethylene-induced liver carcinogenesis. Although there is evidence that hypomethylation is sufficient for carcinogenesis, it is uncertain if it is necessary for trichloroethylene-induced liver carcinogenesis. The doses of trichloroacetic acid and dichloroacetic acid tested for hypomethylation were higher than those used to induce liver tumors in mice. It is not known if hypomethylation also occurs at doses relevant to trichloroethylene carcinogenicity.

#### 6.2.1.5 Autoimmune Hepatitis

Hepatocellular carcinoma is recognized as a life-threatening complication in the course of autoimmune hepatitis in humans, (Arslan et al. 2011; Czaja 2013; Nishiyama et al. 2004; Watanabe et al. 2009). The primary risk factors for malignant transformation include the presence of cirrhosis at presentation or during treatment and long-term immunosuppressive therapy (Czaja 2013). Although the overall frequency of hepatocellular carcinoma in patients with autoimmune hepatitis and cirrhosis ranges from about 1% to 9%, recent clinical data in the United States suggests that the frequency of malignancy in autoimmune hepatitis is comparable with that reported for other types of cirrhosis. Wang and Czaja (1988) reported that the probability of hepatocellular carcinoma in corticosteroid-treated cases of severe autoimmune hepatitis with cirrhosis was 29% after 13 years.

Trichloroethylene exposure had been linked to non-viral (toxic) hepatitis (usually in association with idiosyncratic generalized hypersensitivity skin diseases), liver dysfunction, and liver cancer in humans (Hansen et al. 2013; Kamijima et al. 2007; Kamijima et al. 2008; Kim and Kim 2010) and autoimmune hepatitis in MRL+/+ mice (Gilbert et al. 2009; Gilbert et al. 2006; Griffin et al. 2000c). Autoimmune hepatitis in mice exposed to trichloroethylene was indicated by immune responses to protein adducts and liver inflammation. Inflammation of the liver in mice was induced by exposure to trichloroethylene and preformed metabolite protein adducts (Cai et al. 2008; Cai et al. 2007b; Gilbert et al. 2009; Kaneko et al. 2000; Kondraganti et al. 2012; Ramdhan et al. 2010; Tang et al. 2008). Autoantibodies were formed against “self” antigens of normal tissue, neoimmunogens of trichloroethylene-induced protein adducts, and the concomitant non-adducted proteins. Liver cirrhosis was not reported; however, cirrhosis, like cancer, takes time to develop (Meza-Junco et al. 2007). The longest study that looked at liver inflammation was 48 weeks, which might not have been long enough to allow for cirrhosis to develop. Nevertheless, these studies suggest that trichloroethylene exposure can initiate an autoimmune response, possibly resulting in B-cell activation and autoimmune hepatitis.

The underlying mechanisms of trichloroethylene-induced autoimmunity are not completely understood; however, the studies in MRL+/+ mice suggest that oxidative stress, formation of protein adducts, stimulation of CD4^+^ T cells and release of inflammatory cytokines, and autoantibody formation may be involved (Gilbert et al. 2012; Gilbert et al. 2009; Gilbert et al. 2006; Griffin et al. 2000a; Griffin et al. 2000c; Khan et al. 1995; Khan et al. 2001; Wang et al. 2007a; Wang et al. 2007b; Wang et al. 2013). None of the MRL+/+ mice developed hepatocellular carcinoma; however, as noted above, the maximum study duration was 48 weeks with most studies lasting only 4 to 32 weeks. There also was no evidence of hepatitis or liver cirrhosis in exposed B6C3F_1_ mice in the NTP (1990) study. The cases of non-viral hepatitis in humans were not evaluated for an immune component and the cases of liver cancer in humans did not report on hepatitis. Although the epidemiological and experimental data are not inconsistent with trichloroethylene promoting liver cancer via autoimmune hepatitis, the data are insufficient to determine if this proposed mode of action is operative.

### 6.2.2 Hypothesized Modes of Action with Inadequate Support

Several other modes of action have been proposed for trichloroethylene-induced liver cancer that are incompletely defined or have inadequate experimental support. These include increased liver weight or liver/body weight ratios, negative selection, glycogen accumulation, inactivation of GST-zeta, and cytotoxicity and regenerative hyperplasia (IARC 2014; USEPA 2011a; 2011b). These modes of action are briefly discussed below.

Increased liver weight: Although increased liver weight or increased liver/body weight ratios are associated with an increased liver cancer risk, these effects are nonspecific and may be caused by a number of factors (USEPA 2011a). Liver weight increases have been reported in rodents exposed to trichloroethylene, trichloroacetic acid, or dichloroacetic acid. However, no studies have evaluated the necessity of liver weight changes in trichloroethylene-induced liver carcinogenesis. Further, a mode of action hypothesis based on liver weight changes has not been adequately characterized and cannot be fully evaluated.

Negative selection: Negative selection refers to circumstances that convey a growth advantage to initiated cells relative to normal hepatocytes. This hypothesis suggests that the oxidative metabolites of trichloroethylene may contribute to liver tumor formation by several processes including the following: (1) downregulation of mitogenic stimulation in normal hepatocytes while initiated cells are refractory to this downregulation, (2) direct growth enhancement of certain populations of initiated cells, or (3) altered apoptosis (Bull 2000; USEPA 2011a). Bull (2000) suggested that data showing that trichloroethylene and its oxidative metabolites induced a transient increase in DNA synthesis in the liver of mice were consistent with a “negative selection” mode of action. However, the transient increases in cellular proliferation were confined to small populations of hepatocytes, and liver weight changes were associated with hypertrophy from increased glycogen storage and polyploidy rather than hyperplasia. Thus, mitogenic stimulation does not appear to play a significant role in trichloroethylene-induced liver cancer, and a mechanism for downregulation of mitogenic stimulation in normal hepatocytes has not been identified. Selective clonal expansion of initiated cells is a general feature of carcinogenesis and is not specific to trichloroethylene or its oxidative metabolites. Finally, trichloroethylene either does not affect apoptosis or causes only a slight increase at high doses. Although dichloroacetic acid has been reported to decrease apoptosis in mice, the data are inadequate to determine its relevance to liver cancer considering that mice have a very low background rate of apoptosis (Carter et al. 1995; USEPA 2011a). Therefore, the data are currently inadequate to properly define a mode of action based on negative selection. In addition, some of the data are inconsistent with this hypothesis.

Polyploidization: Tetraploidy has been associated with chromosome instability (CIN) that might persist or give way to a stably propagating aneuploid karyotype (Ganem et al. 2007). Both CIN and stable aneuploidy are common features of neoplasms, and tetraploidy is known to promote chromosomal aberrations and tumorigenesis in vivo. There is considerable experimental evidence that supports the theory that tetraploid cells are an important intermediate in the route to aneuploidy and cancer (Storchova and Kuffer 2008). Several chemicals, including trichloroethylene and dichloroacetic acid, that induce liver cancer in experimental animals also shift the hepatocyte ploidy distribution toward a greater percentage of diploid or polyploid cells (USEPA 2011a). Although polyploidization may be an important key event in tumor induction, the mechanisms are not well understood. Although it is biologically plausible that polyploidy can contribute to hepatocarcinogenicity, it is not known if polyploidization is necessary for trichloroethylene-induced liver tumors. Therefore, the data are inadequate to support polyploidization as operant in trichloroethylene-induced mouse liver tumors.

Glycogen storage: Several studies reviewed by EPA (2011a) reported that mice and rats exposed to dichloroacetic acid developed hepatomegaly that was partially attributable to accumulation of glycogen. Glycogen accumulation was observed as early as 1 week in normal liver while liver tumors were consistently glycogen-poor. However, rodent studies with trichloroethylene or trichloroacetic acid have reported either no change or a slight decrease in liver glycogen content or have not addressed this endpoint. Several studies have shown that glycogen accumulation can be pathogenic and that glycogen storage disease or poorly controlled diabetes is associated with an increased risk of liver cancer in humans (Lingohr et al. 2002; USEPA 2011a). Although it is biologically plausible that hepatocyte glycogen content may be affected by the apparent opposing actions of the trichloroethylene metabolites, dichloroacetic acid and trichloroacetic acid, the effects on glycogen content due to trichloroethylene exposure have not been adequately studied. Therefore, the data are inadequate to determine if this hypothesized mode of action contributes to trichloroethylene-induced hepatocarcinogenesis.

Inactivation of GST-zeta: Dichloroacetic acid inhibits its own metabolism through inactivation of GST-zeta (Board and Anders 2005; 2011). Successive doses of dichloroacetic acid have been reported to increase its plasma half-life in humans and mice and reduce its biotransformation in rat liver (Board and Anders 2005; Schultz et al. 2002). Several polymorphic variants of GST-zeta also have been identified that differ in their susceptibility to inactivation (Board and Anders 2011; Fang et al. 2006; Li et al. 2012). GST-zeta also is known as maleylacetoacetate isomerase (MMAI) and is part of the tyrosine catabolism pathway and metabolizes maleylacetoacetate and maleylacetone to fumarylacetoacetate and fumarylacetone, respectively (Board and Anders 2011; Stacpoole et al. 2008). Inhibition of GST-zeta by exposure to dichloroacetic acid results in the accumulation of maleylacetoacetate, maleylacetone, and succinylacetone and lower concentrations of fumarylacetoacetate (Blackburn et al. 2006; USEPA 2011a). Hereditary tyrosinemia type 1 is a metabolic disease caused by a deficiency of an enzyme involved in the last step of tyrosine catabolism. Individuals with this disease develop hepatocellular carcinoma at a young age (Stacpoole 2011; Tanguay et al. 1996). The increased cancer risk may be caused by the accumulation of one or more reactive tyrosine metabolites; however, it is not known which of these metabolites poses the greatest risk. Schultz et al. (2002) concluded that reduced MMAI activity is unlikely to be the sole carcinogenic mode of action for dichloroacetic acid and may be important only during the early stages of exposure. This conclusion is further supported by observations that GST-zeta knockout mice do not spontaneously develop hepatocellular carcinoma. Thus, the available data are insufficient to fully define the key events associated with this mode of action or to determine their necessity or sufficiency for carcinogenicity.

Cytotoxicity and regenerative hyperplasia: Cytotoxicity and regenerative hyperplasia have been recognized as key events in the mode of action of some chlorinated solvents (e.g., carbon tetrachloride, chloroform); however, trichloroethylene, trichloroacetic acid, and dichloroacetic acid induce liver carcinogenicity at doses that do not produce cytotoxicity (Bull et al. 2004; NTP 1976; 1990; USEPA 2011a). Further, there is no evidence that the transient increases in DNA synthesis in mouse liver are related to reparative hyperplasia. Thus, it is unlikely that cytotoxicity and reparative hyperplasia play a significant role in trichloroethylene-induced liver carcinogenicity.

### 6.2.3 Summary

Although species differences in sensitivity to the proposed modes of action are likely, no data suggest that trichloroethylene causes liver tumors in mice by mechanisms that are irrelevant to humans. Most of the hypothesized modes of action for liver tumors have some experimental support and are biologically plausible in humans and rodents. However, the data currently are inadequate to support the conclusion that any of the particular mode-of-action hypotheses are operant because a collection of key events sufficient to induce liver tumors has not been identified or demonstrated. It is likely that the oxidative metabolites (e.g., trichloroacetic acid, dichloroacetic acid, chloral hydrate) are involved in liver carcinogenicity because they induce hepatotoxic and hepatocarcinogenic effects that are similar to trichloroethylene. Liver tumor phenotype (e.g., immunostaining for c-Jun) and genotype (e.g., H-ras mutation frequency and spectrum) analyses support a role for both dichloroacetic acid and trichloroacetic acid and show that neither metabolite alone can account for the full characteristics of trichloroethylene-induced liver tumors. The data suggest that the mode of action is complex and likely involves key events from several pathways.