# 5 Non-Hodgkin Lymphoma (NHL)

Previous sections of the cancer hazard evaluation component contain relevant information—ADME (Section 1), genetic and related effects (Section 2), and overview and assessment of the quality of the human cancer studies (Section 3)—that are important for several of the three cancer endpoints of interest. This section builds on that information and evaluates the human cancer studies (Section 5.1) and mechanistic data (Section 5.2) specifically for non-Hodgkin lymphoma (NHL) and other related B-cell lymphohematopoietic cancers.

## 5.1 Human Cancer Studies

This review of NHL includes other B-cell lymphohematopoietic cancers thought to be related to NHL, including multiple myeloma (now renamed plasma-cell lymphoma), chronic lymphocytic leukemia (CLL), and hairy-cell leukemia (HCL). Other subtypes, such as diffuse large B-cell lymphoma (DLBCL) and follicular lymphoma, have also been studied in large cohorts.

NHL and its related subtypes are relatively uncommon, with NHL constituting about 4.3% of all new cancer cases per year in the United States. The U.S. age-adjusted incidence rate for NHL is approximately 24 and 16 cases per 100,000 per year in men and women, respectively (2007 to 2011 rates; SEER (2014d)) compared with approximately 8 and 5 per 100,000 deaths per year in men and women, respectively, due to a 70% 5-year survival rate, an increase from approximately 46% in 1975. NHL rates in other European countries (see e.g., Clarke and Glaser (2002), Muller et al. (2005), Adamson et al. (2007), Ferlay et al. (2014); Ferlay et al. (2013)), from which the studies included in the evaluation are drawn, appear to be broadly similar, but with some variations. For example, U.K. age-standardized incidence rates (2011) are approximately 18 and 13 per 100,000 per year in men and women, respectively, with a similar 5-year survival rate of approximately 63% (Cancer Research U.K. 2014b) although diagnosed incidence was approximately half that of the United States in 1975. Studies reporting incidence are generally more informative than mortality studies. The latencies of lymphohematopoietic cancers such as NHL are generally less than for solid tumors, but vary widely; they may be as low as 1 or 2 years in association with some exposures (Howard 2013). Incidence rates generally increase steeply after approximately 50 years of age.

Multiple myeloma is a rare cancer, constituting approximately 0.8% of all cancers. U.S. incidence and mortality rates for multiple myeloma are approximately 6 per 100,000 and 3.4 per 100,000 per year (2007 to 2011), respectively (SEER 2014c), again suggesting that the studies reporting incidence rates are more informative than those reporting only mortality rates. For CLL, incidence and mortality are approximately 16,000 cases and 4,600 deaths per year, respectively, in the United States, and the onset of disease increases markedly with age, with an average age at diagnosis of 72 years. (No comparable data for these specific subtypes was identified for the United Kingdom and other European countries.)

The incidence rate for NHL in Europe and the Nordic countries has roughly quadrupled from the 1950s to the late 1990s and doubled from the 1970s to the 1990s (Adamson et al. 2007) but has then stabilized in the past decade or more. A broadly similar pattern has been observed in the United States (Clarke and Glaser 2002), with increases in incidence in the United States now slowing to approximately 0.5% per year over the past decade (see U.S. SEER rates). However, no study has yet adequately examined to what extent observed changes in temporal trends are attributable to changes in classification systems, or diagnostic improvements or changes in registration methods rather than true changes in incidence (Adamson et al. 2007), particularly as variations in these trends are observed among different age and racial subgroups (e.g., Clarke and Glaser (2002)). As noted in Section 3, classification and coding systems for NHL and its subtypes have changed considerably over the past 20 years, so that comparisons of incidence rates across different studies conducted over different calendar periods should be interpreted with caution. In addition, earlier studies of NHL generally do not report subtypes, which do not reflect the histological and possibly biologically distinct heterogeneity of the disease (Clarke and Glaser 2002) and differences in rates and trends for subtypes, e.g., follicular lymphoma. In the available studies in the present evaluation, NHL was classified by ICD-7, 8, 9 or 10, ICD-O-2 or 3, or the InterLymph classification (Cocco et al. 2013), with some studies, using more recent classifications, reporting on B-cell lymphoma subtypes, primarily DLBCL, follicular lymphoma, multiple myeloma, CLL, or HCL.

Details on the study design, methods, and findings are available in Table D-1 and Table D-3. The evaluation of study quality, including study design, methods of exposure and cancer endpoint assessment, analyses and other elements related to the utility to inform the hazard evaluation (such as study sensitivity) is reported in Table D-4, Table D-5, Table D-8, and Table D-9) and discussed in Section 3. Figure 5-1 provides an overview of the conclusions from that evaluation and identifies the most informative studies based on the overall utility of the study. This section summarizes and interprets the findings for NHL and related B-cell lymphomas from the individual epidemiological studies brought forward for evaluation, and integrates the evidence across studies, applies the RoC listing criteria to the body of evidence, and reaches an NTP recommendation for the level of evidence for NHL and related B-cell lymphomas using the same criteria as described for the evaluation of kidney cancer in Section 4.

Figure 5-1

Study Utility Ranking: NHL

E/R = exposure response.

Gray shading (left-hand column): Utility to inform hazard evaluation; light shading = highest utility; dark shading = lowest utility. Blue shading (right-hand column): Potential bias and study sensitivity; light shading = least biased or most sensitive; dark shading = overall potential biases towards the null or lower sensitivity. Morgan et al. (1998) was rated somewhat lower for NHL than for kidney or liver cancer because of fewer expected and exposed cases.

^a^(Tan shading): Multiple limitations; overall direction of potential biases is unknown.

*Selection bias possible for external but not internal analysis.

### 5.1.1 Study Findings

The available studies reporting on trichloroethylene exposure in association with NHL and related cancers that were considered for inclusion in the cancer evaluation include 11 cohort or nested case-control studies and 7 case-control studies (of independent populations). Two meta-analyses were also identified and contributed to the evaluation.

The database consists of many reasonably well-conducted studies; however, similar to kidney cancer, NHL is a relatively uncommon cancer, and the majority of the cohort studies had limited statistical power to evaluate a modest risk from exposure to trichloroethylene and to evaluate exposure-response relationships.

The findings of the individual studies are discussed below and presented in Table 5-1, Table 5-2, and Table 5-3.

Table 5-1 Cohort and Nested Case-control Studies and Trichloroethylene Exposure: Findings for NHL^a^

Reference | Study Name Population # Exposure Assessment | Exposure Groups | External or Additional Analyses SMR, SIR (95% CI) # Cases/Deaths | Internal Analysis RR, SRR, HR or OR (95% CI) # Exposed Cases/Deaths or Cases/Controls | Interpretation
Nordic studies
Vlaanderen et al. (2013) | Population-based of 5 Nordic countries, linkage of cancer registry with census questionnaire M: 44,708 cases, 223,540 controls F: 31,422 cases, 157,110 controls Semi-quantitative JEM | Cumulative exp. (median unit-yr) 0 0.04 0.13 0.72 High exposure group (median) Cumulative (0.83 unit-yr) Intensity × prevalence (0.04 unit) | | ICD-7: 200, 202 HR incidence 1.00 1.01 (0.95–1.07); 1,213 0.93 (0.88–1.00); 1,183 0.97 (0.91–1.03); 1,211 0.95 (0.84–1.06); 353 0.96 (0.84–1.09); 269 | Low prevalence of exposure (TCE) and exposure levels likely to be low Covariates: Age, sex, country Strengths: Long follow-up, large numbers of cases Limitations: Misclassification of exposure likely; JEM had poor sensitivity and did not account for heterogeneity within jobs and over time; TCE exposure correlated with tetrachloroethylene exposure Null: No evidence for a positive association but limited utility due to low TCE levels and exposure misclassification
Hansen et al. (2013) (Potential overlap with Raaschou-Nielsen et al. (2003)) | Pooled and updated Nordic cohorts Axelson et al. (1994), Anttila et al. (1995), Hansen et al. (2001) 5,553 (3,776 M, 1,777 F) Biomonitoring (U-TCA) | Hansen et al. (2013) Men Women Men & women [underlined: Lag analysis (yr)] 0 10 20 [underlined: U-TCA (mg/L)] <5 5–25 25–50 >50 p_trend_ | ICD-7: 200, 202 SIR 1.55 (1.06–2.20); 32 0.63 (0.23–1.37); 6 1.26 (0.89–1.73); 38 1.21 (0.83–1.71); 32 1.11 (0.68–1.72); 20 | ICD-7: 200, 202 HRR incidence (no lag) 1.0; 12 1.16 (0.53–3.09); 14 1.56 (0.63–3.81); 8 0.66 (0.21–2.03); 4 0.79 | Low exposure levels (only 20% exposed to ≥20 ppm) and short duration of employment Covariates: Age, sex, calendar period; indirect consideration of smoking and alcohol consumption Strengths: Biomonitoring data; large numbers of workers ever exposed Limitations: Only 2 or 3 U-TCA measurements per individual and unlikely to estimate lifetime or cumulative exposure; low statistical power for evaluating modest risks; limited ability to evaluate exposure-response relationship Limited evidence for a positive association: Statistically significant, moderately elevated effect estimate among men only; decreased risk with increasing exposure
Raaschou-Nielsen et al. (2003) (Potential overlap with Hansen et al. (2013)) | Danish blue-collar workers 40,049 M+F (approx. 70% M) Working at a company using TCE | Higher TCE exposure subcohort Ever exposed [underlined: Lag time (yr)] 0–9 10–19 ≥20 [underlined: Duration employment (yr]) 1–4 ≥5 [underlined: Year of 1st employment] Before 1970 1970–1979 | ICD-7: 200, 202 SIR 1.5 (1.0–2.0) 65 1.8 (0.9–3.1); 12 1.3 (0.8–2.0); 22 1.7 (1.1–2.4); 31 1.5 (1.1–2.1); 35 1.6 (1.1–2.2); 30 1.6 (1.1–2.3); 35 1.5 (1.0–2.1); 30 | NR | Higher levels of TCE prior to 1970 (40–60 ppm); low levels of exposure after that time Covariates: Age, sex, calendar year Strengths: Large numbers of exposed cases; subcohort of subjects with higher exposure potential Limitations: Young cohort; possible selection bias for difference in SES; external analysis only; possible exposure misclassification Evidence for an association: Statistically significant, moderate elevated effect estimates but little evidence of an exposure response
Aerospace and aircraft workers
Lipworth et al. (2011) (update Boice et al. (1999)) | Burbank, CA (USA) aircraft manufacturing workers N = 5,443 (approx. 80% M) Individual work histories (JEM) | TCE cohort (ever exposed) TCE: years exposed 0 <1 1–4 5+ p_trend_ | ICD (time of death) SMR 1.31 (0.97–1.73); 50 | ICD (time of death) RR mortality 1.00; 50 0.84 (0.48–1.47); 18 1.10 (0.59–2.04); 14 1.02 (0.55–1.90); 15 >0.20 | Exposure levels not reported; short exposure duration Covariates: Age, date of birth, date of hire, termination date, sex, and race Strengths: Long follow-up, adequate number of cases and controls for ever exposure Limitations: Evidence of HWE, few exposed deaths in subgroup analysis; exposure misclassification is a concern; no evaluation of exposure intensity, 70% had exposure to mixed solvents Limited evidence for a positive association: Elevated effect estimate (approaching statistical significance) for ever exposure; no evidence of an exposure-response relationship
Radican et al. (2008) (mortality to 2000) Blair et al. (1998) (incidence 1973–1990) Note: mortality only updated by Radican) | Utah (USA) aircraft maintenance workers N = 7,204 (5,153 M, 1,051 F) Individual work histories (JEM) | Ever-exposed (M & F) 1990 follow-up: mortality 2000 follow-up: mortality Mortality; 2000 follow-up [underlined: Cumulative exp. (unit-yr)^a^] All 0–5 2–25 >25 [underlined: Exposure category] Low intermittent Low continuous Peak infrequent Peak frequent Incidence (1990) follow-up [underlined: Cumulative exp (unit-yr)] None 0–5 2–25 >25 | ICDA-8, ICD-9, 10 200, 202, or C82-8 Internal analysis HR mortality [underlined: Women] 1.18 (0.49–2.85); 9 1.48 (0.47–4.66); 4 0 1.30 (0.45–3.77); 5 1.39 (0.48–4.03); 5 1.03 (0.23–4.68); 2 3.45 (0.96–12.37); 3 1.27 (0.47–3.45); 6 Fewer than 3 exposed cases | ICDA-8, ICD-9, 10: 200, 202, or C82-85 HR mortality 2.0 (0.9–4.5); 28 1.36 (0.77–2.39); 46 Internal analysis HR mortality [underlined: Men] 1.56 (0.72–3.35); 37 1.83 (0.79–4.21); 18 1.17 (0.42–3.24); 7 1.50 (0.61–3.69); 12 1.50 (0.67–3.34); 25 1.74 (0.76–3.97); 20 1.90 (0.69–5.24); 7 1.57 (0.67–3.69); 16 RR incidence 0.5 (0.2–1.7); 5 0.9 (0.3–2.6); 8 0.7 (0.2–2.6); 4 1.0 (0.4–2.9); 7 | Estimated exposure: Most workers exposed to low levels (~10 ppm), modest number of workers exposed to higher levels (~100 ppm) Covariates: Age, calendar year and sex Strengths: Adequate semi-quantitative JEM, long follow-up, adequate statistical power for ever exposure Limitations: Potential for exposure misclassification because of missing information for some workers; limited power due to low numbers of higher exposed workers; long follow-up time (45 years) may be past induction time; cannot rule out confounding from other co-exposures Limited evidence for a positive association: Statistically non-significant elevated effect estimates for ever exposure and some subgroup analyses
Boice et al. (2006) (Overlaps with Zhao et al. (2005)) | Los Angeles (USA) Rocket engine testing workers 1,111 Men Qualitative JEM; Individual work histories | Ever exposed to TCE | ICD-9; 200-2010 SMR 0.21 (0.01–1.18); 1 | | Exposure occurs during text engine flush, which is likely to be high Covariates: Date of birth, year of hire, pay type (surrogate for SES) and exposure to hydrazine Strengths: Adequate follow up Limitations: Qualitative exposure assessment; one exposed death Null: Limited utility (only 1 exposed death)
Morgan et al. (1998) | Arizona aircraft manufacturing workers N = 4,733 (2,555 M, 2,178 F) Semi-quantitative JEM; individual work history | All TCE exposed workers Cumulative exp. score Low (2,357) High (2,376) Peak (med/high) vs. low/no | ICD 7-9: 200 SMR 0.96 (0.20–2.81); 3 1.79 (0.22–6.46); 2 0.50 (0.01–2.79); 1 | ICD 7-9: 200 RR mortality 1.36 (0.35–5.21) 3 2.25 (0.46–11.09); 2 0.81 (0.10–6.49); 1 1.31 (0.28–6.08); 2 | High-exposure jobs were considered to be ≥50 ppm Covariates: age at hire, gender (decade at high exposure considered but no effect) Limitations: Evidence of an HWE; potential exposure misclassification among low/medium exposure groups; mortality analysis and few exposed cases; inadequate statistical power because of few cases and ICD for NHL does not include 202 Limited evidence for a positive association: Elevated, but imprecise, effect estimate based on few cases and no consistent patterns
Other occupational studies
Silver et al. (2014) | New York State (USA) micro-electronics manufacturing workers 3,113 TCE exposed Semi-quantitative JEM | 5 modified exposure years (exposure duration modified by exposure potential) | NR | ICD time of death HR 0.87 (0.57–1.35) NR | Exposure levels NR. Only 13.9% of cohort exposed Covariates: Paycode and sex, age; variables considered in analyses but did not change risk estimate were birth cohort, time since last exposure (healthy worker survival), hire era, and employment duration prior to 1966 Limitations: Evidence of HWE. Exposure classification based on potential exposure and duration and only one cumulative exposure variable reported in analysis. Young cohort with only 17% deaths Null: No evidence for a positive association but limited utility based on limited exposure assessment and limited study sensitivity
Bahr et al. (2011) | Kentucky (USA) Uranium enrichment workers 5,535 (M) Generic JEM | TCE exposure probability category 0 0–1 2–3 0–3 4–5 Total TCE exposure category 1 2 3 Total | ICD NR SMR 3.20 (0.39–11.57); 2 1.85 (0.85–3.52); 9 1.70 (0.88–2.97); 12 1.76 (1.09–2.69); 21 1.05 (0.52–1.88); 11 1.49 (1.02–2.10); 32 | ICD NR SRR mortality 1.0 1.31 (0.47–3.65) 0.75 (0.27–2.12) 0.99 (0.40–2.46) | No information on exposure levels Covariates: Age, sex, race (unclear) Limitations: Unclear descriptions of methods and findings; limited statistical power; evidence of HWE hire and survival bias Null: No evidence for an association (internal analysis) but limited utility
Environmental exposure
Bove et al. (2014) | North Carolina (USA) (Camp Lejeune) 154,932 Drinking water contamination Ecological assessment | Cumulative TCE (μg/L-months) ≤1 >1–3,100 >3,100–7,700 >7,700–39,745 | | ICD NR HR mortality; 10-yr lag 1.0 (27) 0.90 (0.42–1.92); 10 0.75 (0.33–1.70); 8 1.15 (0.56–2.34); 13 | Estimated mean levels (μg/L-month) TCE from water supply = 358.7; overall cumulative exposure = 6,369 (median) and 5,289 (mean); 20% were exposed to levels between 7,700 and 39,745 Covariates: Sex, race, rank, and education; other variables considered in the model (did not change risk estimates by 10%) include marital status, birth cohort, date of death, duty occupation Strengths: Large cohort; adequate modeling of exposures Limitations: Young cohort; no information on individual water consumption; potential confounding from other contaminants e.g., tetrachloroethylene Null: Small increase in effect estimate but limited utility based on limited study sensitivity and exposure assessment

HR = hazard ratio; ICD = International Classification of Diseases; JEM = job-exposure matrix; NHL = non-Hodgkin lymphoma; NR = not reported; OR = odds ratio; ppm = parts per million; RR = relative risk; SIR = standardized incidence ratio; SMR = standardized mortality ratio; SRR = standardized rate ratio; TCE = trichloroethylene.

^a^ See Table 5-3 for NHL subtypes and related cancers.

Table 5-2 Case-control Studies of Trichloroethylene Exposure: Findings for NHL^a^

Reference | Study Size (N) Exposure Assessment | Exposure Groups | RR or OR (95% CI) # Exposed Cases/Controls | Interpretation
Christensen et al. (2013) | Montreal (Canada) Population- and hospital-based 1975–1985 NHL: 215 cases, 2,341 cancer controls Expert assessment of occupational data from interviews | Ever exposed Substantial exposure | ICD-9 200, 202 1.2 (0.5–2.9); 7/65^b^ 1.0 (0.3–3.5); 3/30^b^ | Exposure prevalence to TCE was very rare; ≤2% of cancer controls or population controls had substantial exposure and 3% had any exposure Covariates: age, census tract, median income, ethnicity, education, self vs. proxy respondent, smoking, alcohol assumption, coffee use Strengths: Adequate quality of exposure assessment Limitations: Low statistical power Null: Small increased risk for ever-exposed but limited utility based on low statistical power
Cocco et al. (2013) | 4 pooled multi-center studies (Italy, France, Europe “EPILYMPH” multi-center study, U.S. region 4 SEER study) Population-based NHL: 3,788 cases, 4,279 controls Questionnaires on occupational history, industrial hygiene reports, expert assessments | High probability exposure p for Fisher combined probability All exposed Duration (yr) No exposure 1–14 15–29 30–39 40+ p_trend_ Intensity (ppm) ≤5 5–75 >75 p_trend_ | NHL (all subtypes) InterLymph consortium classification^c^ 1.4 (0.9–2.1); 50/38 0.04 1.0; 3,453/3,903 0.7 (0.4–1.5); 15/23 1.9 (0.8–4.3); 17/9 2.8 (1.0–7.8); 15/5 3.3 (0.3–33); 3/1 0.009 1.1 (0.4–3.0); 8/8 1.3 (0.8–2.2); 33/25 2.2 (0.7–6.7); 9/5 0.059 | Exposure prevalence: 9% ever exposed; 1% high probability of exposure. Exposure levels not measured but high exposure categories are >75 ppm Covariates: age, sex, study location Strengths: Good exposure and disease assessment; analysis of NHL subtypes Limitations: Reduced statistical power in NHL subtype analysis, no adjustment for lifestyle factors or co-exposures Evidence for a positive association: Statistically significant association with NHL; Evidence for exposure-response relationship
Deng et al. (2013) Wang et al. (2009b) | Connecticut (USA) All NHL: 601 cases, 717 controls Questionnaire on occupational history. Linkage of occupation code to JEM | Wang et al. (2009b) Ever exposed Exposure intensity Low intensity Medium/high intensity p_trend_ Deng et al. (2013) polymorphism Ever exposed IL12A_07 genotype TT AA p interaction | ICD-O-2; OR 1.2 (0.9–1.8); 77/79 1.1 (0.8–1.6); 64/71 2.2 (0.9–5.4); 13/8 0.06 NHL (ICD-O-2) 0.70 (0.34–1.42); 14/26 2.09 (1.28–3.42); 51/31 0.009 | No cases or controls with high probability of exposure and medium/high exposure. Exposure prevalence 8% Covariates: Age, history of hematopoietic cancer, race, and alcohol consumption. Smoking, medical history of immune diseases, income, education level did not affect OR Strengths: Consideration of potential confounding from lifestyle factors, analyses by genotype & NHL subtype Limitations: Limited JEM (not calendar-year specific and based on occupations not job tasks), no control for co-exposures Evidence for a positive association: Statistically significant, moderate elevated effect estimate in genotype analysis; some evidence for an exposure-response relationship
Persson and Fredrikson (1999) | Sweden Population-based NHL: 199 cases, 479 controls Questionnaire on occupational history | Ever exposed | ICD-8 used in 2nd study, NR 1st study 1.2 (0.5–2.4); 16/32 | Exposure prevalence 1% in controls Covariates: Age, sex Limitations: Limited exposure assessment, potential for exposure misclassification is substantial Null: Small increase in risk but limited utility due to concern about exposure misclassification
Hardell et al. (1994) | Sweden Population-based NHL: 105 cases, 335 controls Questionnaire on occupational history and leisure activities | Ever exposed | Rappaport classification 7.2 (1.3–42); 4/4 | Exposure prevalence: 1% in controls Covariates: Age, vital status Limitations: Limited exposure assessment, and potential for exposure misclassification is substantial Limited evidence for an association: Statistically significant, high elevated effect estimate; methodological concerns and small numbers of exposed cases/controls may bias towards an overestimate of the risk estimate
Purdue et al. (2011a)^d^ incorporated in pooled analysis (Cocco et al. 2013) | U.S. SEER registry Population-based NHL: 1,189 cases, 982 controls Interviews on occupational histories and exposures; expert assessment by industrial hygienists based on questionnaire data and systematic industrial hygiene literature review | Exposure-response analyses Average exposure Per 90 ppm-hr/wk^e^ p_trend_ >360 ppm-hr/wk Average exp. intensity Per estimated 99 ppm p_trend_ Exposure duration (yr) Per 10 yr p_trend_ Cumulative exposure Per 65,520 ppm-hr p_trend_ >234,000 ppm-hr | ICD-O-2 OR (# cases NR) 1.11 (1.02–1.21) 0.02 7.9 (1.8–34.3) 1.18 (0.80–1.76) 0.41 1.13 (0.85–1.51) 0.40 1.10 (0.99–1.22) 0.08 3.3 (1.1–10.01) | Exposure not measured but high-exposure categories are >99 ppm, 360 ppm-hr-wk and 234,000 ppm-hr Covariates: Age, sex, race, education level, and study area Strengths: Good exposure and disease assessment, detailed analyses using multiple exposure metrics including analyses per estimated quantitative exposure, by intra-category high exposure and NHL subtype Limitations: Reduced statistical power in NHL subtype analysis, no adjustment for lifestyle factors or co-exposures Evidence for a positive association: Evidence for exposure-response relationship with multiple exposure metrics

ICD = International Classification of Diseases; JEM = job-exposure matrix; NHL = non-Hodgkin lymphoma; NR = not reported; OR = odds ratio; ppm = parts per million; RR = relative risk; SEER = Surveillance, Epidemiology and End Results program.

^a^ See Table 5-3 for findings on NHL subtypes and related cancers.

^b^ Cancer controls only reported.

^c^ The InterLymph Consortium classification (see Morton et al. (2007)) was harmonized with earlier WHO lymphoid neoplasms classification and the ICD-O-3.

^d^ Study findings presented that provide additional informative analyses that are not available in the pooled analyses. Findings from other studies are not presented in the tables since they did not have additional information thought to be informative.

^e^ Intracategory based on mean among controls.

Table 5-3 Cohort, Nested Case-control, and Population-based Case-control Studies of Trichloroethylene Exposure and NHL Subtypes

Reference | Exposure Group | DLBCL | Follicular Lymphoma | CLL | Multiple Myeloma
Cohort and nested case-control studies
Vlaanderen et al. (2013) | Cumulative exp. (unit-yr) 0 0.04 0.13 0.74 High-exposure group Cumulative (0.83 unit-yr) Intensity × prevalence (0.04 unit) | NR | NR | NR | ICD-7; HR (incidence) 1.00 0.93 (0.84–1.03); 468 0.92 (0.84–1.01); 574 0.96 (0.88–1.06); 541 1.01 (0.84–1.22); 132 1.03 (0.88–1.22); 134
Hansen et al. (2013) | Men Women Men & women | NR | NR | NR | ICD-7; SIR 0.47 (0.13–1.20); 4 1.04 (0.29–2.67); 4 0.65 (0.28–1.27); 8
Raaschou-Nielsen et al. (2003) | Entire cohort Men (588,047 p-yr) Women (118,270 p-yr) | NR | NR | NR | ICD-7; SIR 1.1 (0.70–1.52); 28 0.90 (0.18–2.56); 3
Lipworth et al. (2011) | Ever exposed TCE: years exposed 0 <1 1–4 5+ p_trend_ | NR | NR | 0.93 (0.40–1.83); 8 | ICD time of death: SMR 1.21 (0.76–1.81); 23 RR mortality 1.00 0.70 (0.31–1.58); 8 1.45 (0.68–3.09); 10 0.67 (0.25–1.83); 5 >0.20
Radican et al. (2008) Mortality | Ever exposed M & W Cumulative exp. (unit-yr) [underlined: Men^a^] All 0–5 2–25 >25 | NR | NR | NR | HR mortality (ICDA-8, ICD-9 and 10) 1.35 (0.62–2.93); 25 1.08 (0.43–2.71); 19 0.69 (0.21–2.27); 5 1.58 (0.53–4.71); 7 1.19 (0.40–3.54); 7
Blair et al. (1998) Incidence (RR) Same population as Radican et al. (2008) | Ever exposed M & W Cumulative exposure Men^b^ No exposure <5 5–25 >25 | NR | NR | NR | ICD NR RR (incidence) 1.3 (0.5–3.4); 14 1.7 (0.5–5.5); 10 1.0 (0.2–4.2); 4 0.8 (0.1–4.4); 2 1.2 (0.3–4.7); 4
Boice et al. (2006) | | | | ICD-9; SMR 0.21 (0.01–1.18) 1 | ICD-9; SMR 0.50 (0.01–2.77) 1
Silver et al. (2014) | 5 modified exposure duration yr (exposure duration modified by exposure potential) | | | | ICD time of death (HR mortality) 1.18 (0.70–1.99) NR
Yiin et al. (2009) Nested case-control study | Average cumulative TCE exposure score/100 | | | | OR (ICD-8) 1.02 (0.98–1.05) NR
Bove et al. (2014) | Cumulative (μg/L-mo) ≤1 >1–155 >155–380 >380–8,585 | NR | NR | NR | HR (ICD NR) 1.0; 6 2.09 (0.66–6.62); 7 1.29 (0.34–4.88); 4 0 cases
Case-control studies (OR)
Cocco et al. (2013) Pooled analysis | Intensity (ppm) ≤5 5–75 >75 p_trend_ | InterLymph classification^a^; OR 1.2 (0.3–4.4); 3/8 0.6 (0.2–1.6); 5/25 2.0 (0.5–8.7); 3/5 0.114 | InterLymph classification^a^; OR 1.1 (0.1–9.2); 1/8 1.7 (0.7–4.1); 7/25 1.5 (0.2–13); 1/5 0.10 | InterLymph classification^a^; OR 1.4 (0.3–7.0); 2/8 1.7 (0.7–4.0); 7/25 3.2 (0.6–18); 2/5 0.055 | NR
Purdue et al. (2011a) Incorporated into the pooled analysis | Average exposure Per 90 ppm-hr/week p_trend_ Cumulative exposure Per 65,520 ppm-hr p_trend_ | ICD-O-2; OR 1.11 (1.01–1.23) 0.03 1.07 (0.94–1.22) 0.29 | ICD-O-2; OR 1.15 (1.04–1.28) 0.005 1.17 (1.04–1.32) 0.01 | ICD-O-2; OR 1.09 (0.96–1.24) 0.16 1.11 (0.96–1.27) 0.16 | NR
Cocco et al. (2010) Incorporated into pooled analysis | Ever exposed Cumulative exposure Low exposure Medium exposure High exposure p_trend_ | 2001 WHO REAL classification; OR 0.7 (0.4–1.1); 17 0.7 (CI NR); 6/37 0.4 (CI NR); 4/43 0.9 (CI NR); 7/37 0.16 | 2001 WHO REAL classification; OR 1.2 (0.6–2.3); 11 2.4 (CI NR); 7/37 0.3 (CI NR); 1/43 1.0 (CI NR); 3/37 0.65 | 2001 WHO REAL classification; OR 0.9 (0.5–1.5); 18 1.0 (CI NR); 6/37 0.4 (CI NR); 3/43 1.2 (CI NR); 9/37 0.94 | 2001 WHO REAL classification; OR 0.6 (0.3–1) 0.2 (CI NR); 1/37 0.7 (CI NR); 4/43 0.8 (CI NR); 4/37 0.22
Deng et al. (2013)/Wang et al. (2009b) | Ever exposed IL12A_07 genotype TT AA p interaction | 2001 WHO REAL classification; OR 0.59 (0.19–1.85); 4 2.66 (1.42–4.96); 21 0.0119 | 2001 WHO REAL classification; OR 0.82 (0.25–2.72); 4 1.71 (0.78–3.77); 10 0.3498 | NR | NR
Gold et al. (2011) Seattle Region (SEER) | High confidence 10-yr lag Cumulative exposure No exposure 1–415 416–3,000 3,001–6,592 6,593–49,500 p_trend_ | NR | NR | NR | ICD-O-2/3; OR 1.0; 139/409 1.1 (0.4–2.9); 6/18 1.6 (0.7–3.5); 11/20 1.4 (0.5–3.8); 6/16 2.3 (1.1–5.0); 18/18 0.02
Costantini et al. (2008) Italy | Exposure intensity Very low/low Medium/high ≤15 years exposure >15 years exposure p_trend_ | | | ICD-9; OR 1.2 (0.5–2.7); 8/47 0.9 (0.3–2.6); 4/35 0.7 (0.1–3.4); 2/24 1.2 (0.2–6.2); 2/11 | ICD-9; OR 1.5 (0.7–3.5); 9/28 0.9 (0.3–2.4); 5/27 0.5 (0.1–2.3); 2/19 1.3 (0.3–5.9); 8/13 0.82
Nordström et al. (1998) | Ever exposed | | | HCL (ICD NR); OR 1.5 (0.7–3.3); 9/26

DLBCL = diffuse large B-cell lymphoma; CLL = chronic lymphocytic leukemia; HR = hazard ratio; ICD = International Classification of Diseases; JEM = job-exposure matrix; HCL = hairy cell leukemia; NHL = non-Hodgkin lymphoma; NR = not reported; OR = odds ratio; ppm = parts per million; RR = relative risk; SIR = standardized incidence ratio; SMR = standardized mortality ratio; SRR = standardized rate ratio; TCE = trichloroethylene; WHO REAL = World Health Organization Revised European American Classification of Lymphoid Neoplasms.

^a^ The InterLymph Consortium classification (see Morton et al. (2007)) was harmonized with the earlier WHO lymphoid neoplasms classification and the ICD-O-3. It combines chronic lymphocytic leukemia (CLL) with small lymphocytic lymphoma (SLL).

### 5.1.2 Cohort and Nested Case-control Studies

The available cohort studies and nested case-control studies reporting on NHL, multiple myeloma, or CLL include the following:

- Three studies conducted in Nordic countries (Hansen et al. 2013; Raaschou-Nielsen et al. 2003; Vlaanderen et al. 2013),
- Four studies of U.S. aircraft workers (Blair et al. 1998; Boice et al. 2006; Lipworth et al. 2011; Morgan et al. 1998; Radican et al. 2008),
- Two studies of uranium processing workers (Bahr et al. 2011; Yiin et al. 2009),
- One study of micro-electronic workers (Silver et al. 2014), and
- One study of U.S. military personnel exposed to trichloroethylene in drinking water (Bove et al. 2014).

Several of these studies also reported data for multiple myeloma (Blair et al. 1998; Boice et al. 2006; Hansen et al. 2013; Lipworth et al. 2011; Raaschou-Nielsen et al. 2003; Radican et al. 2008; Silver et al. 2014) or specifically for CLL (Boice et al. 2006; Lipworth et al. 2011). Several studies reported only on combined categories of NHL and leukemia (Zhao et al. 2005) or lymphoma (Greenland et al. 1994), and Ritz (1999) only reported data for all lymphohematopoietic cancers combined, and so these studies are excluded from this section.

#### 5.1.2.1 Nordic Studies

As discussed previously, workers and exposed subjects in these incidence studies (Hansen et al. 2013; Raaschou-Nielsen et al. 2003; Vlaanderen et al. 2013) were identified from broad occupational or population-based databases and with a wide range of occupations and likely co-exposures. All of these studies reported cancer incidence. Modest increases in overall risk for NHL in external analyses were observed among men (SIR = 1.55, 95% CI = 1.06 to 2.20; 32 cases) in the biomonitoring study (Hansen et al. 2013) and among those considered to have higher exposure in the blue-collar workers study (SIR = 1.7, 95% CI = 1.1 to 2.4, 31 exposed cases, 20-year lagged) (Raaschou-Nielsen et al. 2003). In internal analyses by Hansen et al. (2013), the highest risk was found among workers in the second highest exposure group but the risk estimate was lower in the highest exposure group. This study had limited ability to evaluate exposure-response relationships because of lack of information on lifetime exposures and possible misclassification of exposure intensity. Among blue-collar workers (Raaschou-Nielsen et al. 2003), risks did not increase by employment duration or presumed exposure level (as assessed by date of first employment). No increases in NHL risk were observed in the population-based study by Vlaanderen et al. (2013), which might have included subjects with a broader range of exposures and with a greater probability of exposure misclassification. It is not clear whether a linear exposure-response pattern would be predicted if the proposed mechanism involves immunomodulation.

No increases in the risks of multiple myeloma were observed in all three Nordic studies (Hansen et al. 2013; Raaschou-Nielsen et al. 2003; Vlaanderen et al. 2013).

#### 5.1.2.2 Aircraft Manufacturing Workers

Four mortality studies of aircraft manufacturing workers (Boice et al. 2006; Lipworth et al. 2011; Morgan et al. 1998; Radican et al. 2008) reported findings for NHL. The study of Utah aircraft workers (Radican et al. 2008) also included incidence data in an earlier update (Blair et al. 1998). The mortality study by Radican et al. (2008) had a 10-year longer follow-up and reported about two times as many NHL deaths as cases reported in the incidence study. There is some evidence of modest statistically non-significant increases in mortality for NHL (approximately 30%) and multiple myeloma among workers ever exposed to trichloroethylene in two studies (Lipworth et al. 2011; Radican et al. 2008); however, no clear patterns of increasing risk with cumulative exposure or exposure pattern (Radican et al. 2008) or exposure duration (Lipworth et al. 2011) were reported. Most of the exposed cases were in the low-exposure group in the latter study. No association between trichloroethylene exposure and NHL was found in the smaller study by Morgan et al. (1998) based on three deaths, in the study of aerospace workers (Boice et al. 2006) based on only one death, or with cancer incidence in the earlier update of the Utah aircraft manufacturing worker cohort (Blair et al. 1998).

#### 5.1.2.3 Other Studies

The remaining four studies had more limited sensitivity for informing these endpoints. Bahr et al. (2011) reported a statistically significant increase in mortality in external analyses but these were inversely related to higher exposure categories in internal analyses. In the study of micro-electronic workers, hazard ratios (HRs) for 5-modified exposure years were 0.87 (95% CI = 0.57 to 1.35) for NHL and 1.18 (95% CI = 0.70 to 1.99) for multiple myeloma (Silver et al. 2014), but this study had a limited exposure assessment and was a relatively young cohort. No association was found for multiple myeloma and trichloroethylene exposure in the nested case-control study of Tennessee uranium enrichment workers (Yiin et al. 2009). Lastly, small increases in NHL and multiple myeloma were observed in some exposure categories in the drinking water mortality study (Bove et al. 2014), which was also a young cohort and was limited by indirect measures of trichloroethylene exposure.

### 5.1.3 Population-based Case-control Studies

Table 5-2 reports findings for NHL and Table 5-3 reports findings on NHL-related subtypes. Four population-based case-control studies in different geographical locations, including one each in Montreal (Christensen et al. 2013) and Connecticut (Deng et al. 2013; Wang et al. 2009b), and two in Sweden (Hardell et al. 1994; Persson and Fredrikson 1999), and one pooled analysis, the InterLymph study (Cocco et al. 2013), reported data on NHL. Two of these studies (Cocco et al. 2013; Deng et al. 2013; Wang et al. 2009b) also reported on the NHL subtypes DLBCL and follicular lymphoma. Three other case-control studies reported on multiple myeloma (Gold et al. (2011), Costantini et al. (2008), and Cocco et al. (2010), one of the constituent studies of the pooled analysis), and two studies reported on CLL (Cocco et al. 2013; Costantini et al. 2008). One study reported on the NHL subtype HCL (Nordström et al. 1998).

The InterLymph study included pooled cases and controls from four large multi-center studies: the EPILYMPH study in Europe (Cocco et al. 2010), the ENGELA study in France (Orsi et al. 2010), the MIS study in Italy (Miligi et al. 2006), and the NCI-SEER study in the United States (Purdue et al. 2011a). Because the pooled analysis included all the subjects of the individual studies and harmonized the exposure and disease assessment, this evaluation primarily reviews the pooled analysis. Importantly, the authors did not observe between-study heterogeneity. Findings from analyses on different exposure metrics from the NCI-SEER study (Purdue et al. 2011a), as well as findings for multiple myeloma from the EPILYMPH study (Cocco et al. 2010), are also included in the evaluation.

The major advantage of the recent case-control studies was greater statistical power, especially for evaluating NHL histological subtypes. The pooled InterLymph study (Cocco et al. 2013) and the SEER study on multiple myeloma (Gold et al. 2011) were considered to be the most informative studies because of the quality of the exposure and disease assessments, evaluation of multiple metrics of exposure, and larger numbers of exposed cases and controls, especially among individuals with higher probability or intensity of exposure. The other studies were more limited in their ability to inform cancer evaluation (Christensen et al. 2013; Costantini et al. 2008; Deng et al. 2013; Wang et al. 2009b), especially the three Swedish case-control studies (Hardell et al. 1994; Nordström et al. 1998; Persson and Fredrikson 1999) because of small numbers of exposed cases and controls, lower quality exposure assessments, and concerns for exposure misclassification or the use of older disease classifications (see Figure 5-1, Section 3, and Appendix D).

#### NHL

The InterLymph pooled analyses (Cocco et al. 2013) found a moderate increase in NHL risk for all exposed subjects (OR = 1.4, 95% CI = 0.9 to 2.1, 50 exposed cases vs. 38 exposed controls); Fisher combined probability test, p = 0.004. Among subjects with a high probability of exposure, there was evidence of an exposure-response relationship with duration (p_trend_ = 0.009) and intensity (p_trend_ = 0.059) of trichloroethylene exposure; risk estimates in the highest exposed categories were approximately two- to three-fold higher than in the lowest categories but were not statistically significant. The most informative of the constituent studies, the U.S. SEER analysis (Purdue et al. 2011a), had the advantage of a high-quality and detailed exposure assessment and reported on additional exposure metrics. Increased risks were observed with multiple metrics, but most notably a positive trend with average exposure (p_trend_ = 0.02, OR = 1.1, 95% CI = 1.02 to 1.21 for each 99 ppm-hr per week increase, and 7.9, 95% CI = 1.8 to 34.3 for >360 ppm-hour per week) and for cumulative exposure (p_trend_ = 0.08, OR = 1.10, 95% CI = 0.99 to 1.22 per each 65,520 ppm-hour and 3.3, 95% CI = 1.1 to 10.01 for >234,000 ppm-hour). Estimated (not measured) exposures for a proportion of the workers were high (>234,000 ppm-hour cumulative exposure and 99-ppm average intensity of exposure), which increased the ability of the study to detect an effect.

Findings in the remaining case-control studies were somewhat inconsistent. The U.S. study of women (Deng et al. 2013; Wang et al. 2009b) reported increases in NHL risk for women with medium or high intensity of exposure (OR = 2.2, 95% CI = 0.9 to 5.4, 13 exposed cases). In addition, the risk associated with trichloroethylene exposure was higher (and statistically significant) among women with the AT or AA polymorphism of the IL2A_07 genotype than the TT polymorphism; most of this difference was observed in the DLBCL subtype rather than the follicular lymphoma subtype. Hardell et al. (1994) reported a high risk for NHL among trichloroethylene-exposed subjects (OR = 7.2, 95% CI = 1.3 to 42, 4 exposed cases); however, this study’s limitations include potential for exposure misclassification, including recall bias, use of proxy as controls, the minimum requirement to be classified as exposed was <1 week of continuous exposure in this study, potential confounding from exposure to other agents including other organic solvents, and small numbers of cases and controls. The other Swedish study by Persson and Fredrikson (1999) found an OR of 1.2 (95% CI = 0.5 to 2.4, 16 exposed cases) for ever exposure to trichloroethylene. In the Montreal study (Christensen et al. 2013), ORs were 1.0 (95% CI = 0.3 to 3.5, 3 exposed cases) for substantial exposure and 1.2 (95% CI = 0.5 to 2.9, 7 exposed cases) for ever exposed.

#### Multiple Myeloma, Follicular-cell Lymphoma, Chronic Lymphocytic Leukemia, Diffuse Large B-cell Lymphoma, and Hairy-cell Leukemia

The most informative of the three studies reporting on multiple myeloma, a case-control study using SEER cancer registry data (Gold et al. 2011), found a statistically significant exposure-response relationship for multiple myeloma (p_trend_ = 0.02), with a risk of 2.3 (95% CI = 1.1 to 5.0, 18 exposed cases) in the highest cumulative exposure category. The estimated highest cumulative exposure category was 6,593 to 49,500 ppm-hour. This study used the same detailed exposure assessment as Purdue et al. (2011a). There was little evidence of an association with multiple myeloma in the other two studies, the EPILYMPH study (Cocco et al. 2010), and the Italian multi-center study by Costantini et al. (2008).

The InterLymph analysis found evidence of statistically significant association with two NHL subtypes, follicular lymphoma and CLL; Fisher combined probability tests were 0.015 for follicular cell lymphoma and 0.005 for CLL. No association was found for any NHL subtypes in the EPILYMPH study (Cocco et al. 2010) but positive associations were found for CLL in the NCI-SEER study (Purdue et al. 2011a). In the case-control study among Connecticut women (Deng et al. 2013; Wang et al. 2009b), elevated risks were found for both DLBCL among genetically susceptible women, and an exposure-response relationship was found for DLBCL but not follicular-cell lymphoma. The Swedish study of HCL (Nordström et al. 1998) using similar methodologies as Hardell et al. (1994) observed a small (1.5) increase in this endpoint, based on 9 cases.

#### 5.1.3.1 Meta-analyses of Trichloroethylene Exposure and NHL and Related Subtypes

Several recent meta-analyses of NHL and trichloroethylene exposure have been conducted (Karami et al. 2013; Mandel et al. 2006; Scott and Jinot 2011; USEPA 2011a; Wartenberg et al. 2000). This evaluation is limited to the recent meta-analyses by the EPA (Scott and Jinot 2011; USEPA 2011a), Karami et al. (2012) and Kelsh et al. (2010) because many studies have been published since the older evaluations. Both meta-analyses were conducted prior to the publication of studies by Hansen et al. (2013), Vlaanderen et al. (2013), Christensen et al. (2013) and Bove et al. (2014) or the InterLymph study by Cocco et al. (2013)), all of which are included in our review. The individual studies contributing to the two pooled studies (Cocco et al. 2013; Hansen et al. 2013) were included in the meta-analysis; however, the pooled study by Hansen also updated their constituent cohorts.

The EPA meta-analyses included systematic data extraction of nine cohort and eight case-control studies in which potential trichloroethylene exposure was documented and risk estimates for NHL and trichloroethylene exposure were calculated. Studies with evidence of a low potential for exposure to trichloroethylene were excluded. Fixed and random-effects models, tests for heterogeneity and publication bias, and sensitivity analyses (to examine the impact of individual studies and selection of alternative relative risk selections on meta-relative risk estimates) were used to calculate summary meta-relative risks, using, where provided, adjusted or crude risk estimates from internal analyses rather than external (SMR or SIR) estimates. In addition, separate meta-analyses were conducted for the highest exposure groups (either by duration and/or intensity) within trichloroethylene-exposed populations (reported in 17 of the 19 constituent studies). Low to moderate heterogeneity among risk estimates was observed and there was some evidence of publication bias.

Karami et al. (2013) used similar exclusion criteria and methods of analysis to the EPA analysis and considered a closely overlapping body of 10 cohort and 9 case-control studies (see Table B-1 and Table D-10). Low to moderate heterogeneity but little evidence of publication bias was observed. Slightly higher mRRs were observed among the four European cohorts (mRR = 1.66, 95% CI = 1.29 to 2.14) than among the 6 U.S. cohorts (mRR = 1.41, 95% CI = 1.11 to 1.78), and among studies reporting NHL incidence compared with combined incidence and mortality.

In the EPA analysis, mRRs for the highest exposure groups within studies (where reported) were used to calculate mRRs for the highest exposure (intensity and/or duration) group(s) within studies. In contrast, Karami et al. calculated mRRs by high or low intensity of exposure and separately by high and low duration of exposure, based on a subset of studies that reported these metrics, thus yielding somewhat different mRR estimates from those in the EPA analysis. The summary mRRs for NHL are given in Table 5-4 below.

Table 5-4 Meta-analyses of Trichloroethylene Exposure and NHL and Related Subtypes^a^

Reference | Study Design (Number of Studies) | mRR (95% CI) All | mRR (95% CI) Highest Exposure | Comments
EPA (2011a)/Scott and Jinot (2011) | Combined cohort and case-control studies Any exposure (17) High exposure (13) | 1.23 (1.07–1.42)^b^ | 1.43 (1.13–1.82) | Random-effects model Low sensitivity to removal of individual studies or selection of alternative RRs Low to moderate heterogeneity; some evidence of publication bias
EPA (2011a)/Scott and Jinot (2011) | Cohorts (9) | 1.33 (1.13–1.58) | 1.60 (1.24–2.08) | No sig. diff. between cohort and case-control mRRs (any or highest exposure); lower heterogeneity for highest exposure groups
EPA (2011a)/Scott and Jinot (2011) | Case-control (8) | 1.11 (0.89–1.38) | 1.29 (0.76–2.20) | No sig. diff. between cohort and case-control mRRs (any or highest exposure); lower heterogeneity for highest exposure groups
Karami et al. (2013) | TCE-exposed cohort + case-control studies (19) | 1.32 (1.14–1.54) | NR | Random-effects model Little evidence of heterogeneity and publication bias
Karami et al. (2013) | TCE-exposed cohorts (10) Exp-response: Long duration Short duration High intensity^c^ Low intensity Subset of U-TCA studies (3) | 1.52 (1.29–1.79) 2.15 (1.34–3.45) | 1.56 (1.02–2.40) 1.30 (0.92–1.84) 1.27 (0.83–1.96) 1.68 (1.14–2.46) | Some evidence of positive exposure response among a total of 4 studies using measures of duration Negative exposure response observed among 5^b^ studies using measures of intensity (excluding 3 Nordic studies of U-TCA)
Karami et al. (2013) | TCE-exposed case-control (9) Exp-response: Long duration Short duration High intensity Low intensity | 1.14 (0.93–1.40) | 1.18 (0.60–2.34) 1.46 (0.78–2.73) 1.42 (0.86–2.33) 1.06 (0.79–1.42) | Some evidence of publication bias No association between exposure duration among 2 studies or intensity among 3 studies

mRR = meta-relative risk; NR = not reported; RR = relative risk; U-TCA = urine trichloroacetic acid.

^a^ See Table D-10 for a list of studies in each meta-analysis.

^b^ Adjustment for publication bias yielded mRR = 1.15 (95% CI = 0.97–1.36).

^c^ 6 studies cited in text, 5 in table.

The overall results of both meta-analyses (Karami et al. 2013; Scott and Jinot 2011; USEPA 2011a), are broadly comparable. Both show statistically significant mRRs for cohort and case-control studies combined and the body of cohort studies. The mRR for case-control studies was lower, but not significantly different, than the mRR for cohort studies (Scott and Jinot 2011). Importantly, the mRR was robust and not sensitive to the removal of individual studies or selection of alternative RRs. Overall, there was evidence from the EPA meta-analysis, among the body of cohort studies, and to a somewhat lesser extent among the case-control studies, that the risk of NHL is greater in the subgroups with the highest exposure compared with the overall exposure groups. In the analysis by Karami et al. (2013), associations between intensity or duration of exposure were less clear; the differences may be attributable to the smaller number of studies, the use of separate analyses of intensity and duration, less comparability between high- and low-exposure groups, or some differences in the included studies. The highest mRR was observed among the three Nordic studies using biomonitoring of urine TCA (Karami et al. 2013), which was not observed in the later pooled and updated study by Hansen et al. (2013). Neither meta-analysis included the InterLymph pooled analyses, although they included three of the component studies, two of which were null. Substitution of the component studies with the InterLymph study could possibly strengthen the association with trichloroethylene exposure in the meta-analysis of case-control studies (higher risk, less heterogeneity). The more recent meta-analysis (Karami et al. 2013) found a stronger association among studies that specifically assessed trichloroethylene than among studies of broadly assessed chlorinated solvents, in which effects from trichloroethylene would be diluted. They also calculated meta-relative risks among studies conducted across two different calendar time periods (divided by the median year of publication) and observed no differences for cohort studies of NHL and kidney cancer (but an increase in mRR for case-control studies of kidney cancer conducted since 1995). The latter finding, according to the authors, suggested “possible improvements” in the validity and reliability of exposure assessment methods in case-control studies (Karami et al. 2013).

Meta-analyses for other NHL subtypes have been largely inconclusive and were based on a small number of studies. Karami et al. (2013) conducted an analysis of multiple myeloma and CLL among the studies reporting for these endpoints that were included in their NHL meta-analysis and found no significant increases in risk. However, this meta-analysis did not include recent studies reporting on one or other of these endpoints (Bove et al. 2014; Cocco et al. 2013; Costantini et al. 2008; Gold et al. 2011; Hansen et al. 2013; Vlaanderen et al. 2013).

### 5.1.4 Evaluation of Potential Confounding by Occupational Co-exposures or Other Risk Factors

Section 3 discussed the adequacy of the methods used in the cohort (Section 3.2) and case-control studies (Sections 3.3 and 3.4) for evaluating potential confounding from occupational co-exposures and non-occupational factors. However, that assessment was not specific for NHL. This section builds on that assessment, integrating it with other relevant information and evaluating whether confounding can explain the increased risks of NHL and its related subtypes observed in a number of the studies.

#### 5.1.4.1 Occupational Co-exposures

The major occupational risk factors that have been associated with NHL (with limited evidence) include benzene, ethylene oxide, 2,3,7,8-TCDD, polychlorinated biphenyls, phenoxy herbicides, styrene, and ionizing radiation by IARC and the Report on Carcinogens (Cogliano et al. 2011; NTP 2011). Organic solvents may be potential risk factors and have been the focus of the recent EPILYMPH study (Cocco et al. 2010). The most common co-exposures in the cohort studies are the chlorinated and possible other organic solvents and cutting oils such as mineral and petroleum oils. Radiation is a possible co-exposure in the two studies of uranium workers (Bahr et al. 2011; Yiin et al. 2009). Other organic solvents, and possibly other exposures, may be co-exposures in two of the Swedish studies (Hardell et al. 1994; Nordström et al. 1998). Benzene was also a potential co-exposure in the InterLymph study (Cocco et al. 2013). Tetrachloroethylene exposure was correlated with trichloroethylene exposure in the Nordic population-based cohort; exposure to tetrachloroethylene but not to trichloroethylene was associated with increased risks of NHL.

None of the cohort and most of the case-control studies that reported NHL findings attempted to examine or control for potential confounding by co-exposures. The InterLymph study conducted sensitivity analyses that excluded subjects with benzene exposure; risks were elevated for both high probability (OR = 1.4, 95% CI = 0.8 to 2.6) and high intensity of exposure (OR = 1.9, 95% CI = 1.2 to 3.0) in the total cohort and analyses restricted to subjects with high probability of exposure (OR not reported), but trends were no longer apparent.

Several lines of evidence argue against a major impact from confounding of potential co-exposures across studies. None of the documented co-exposures are identified risk factors for NHL and the types and co-exposures of other agents are likely to vary in the patterns and levels across the various industries and time periods, especially in the studies of mixed occupation groups. In addition, an exposure-response relationship for NHL and exposure intensity was observed in the InterLymph study (considered to be the most informative study) and there was no evidence that other potential co-exposures were highly correlated with trichloroethylene exposure in that study. However, potential confounding by other solvents or chlorinated solvents may be possible, especially in the aircraft-manufacturing studies.

#### 5.1.4.2 Lifestyle and Other Potential Confounders

Of the non-occupational risk factors for NHL, which include viral infections, immunosuppressive disorders, autoimmune diseases, and exposure to immunosuppressive drugs or chemotherapy drugs (Cogliano et al. 2011; Hardell and Axelson 1998), there is little a priori reason to suspect that most of these would vary by trichloroethylene-exposure status in the cohort or nested case-control studies. Smoking is not considered to be a risk factor for NHL but may be a risk factor for follicular lymphoma. Each case-control study matched or adjusted for age, sex, birth year, or race, using conditional or unconditional logistic regression, as appropriate. Some studies (Christensen et al. 2013; Costantini et al. 2008; Deng et al. 2013; Wang et al. 2009b), and some of the constituent studies of the pooled analysis (Cocco et al. 2010; Miligi et al. 2006; Purdue et al. 2011a) also considered or adjusted for smoking, other lifestyle factors, and surrogates of socioeconomic status. Thus, confounding by these factors across studies seems unlikely.

### 5.1.5 Integration across Studies

Overall, there is some evidence of an association between exposure to trichloroethylene and NHL based on findings of a modest increase in risk of NHL in several studies with different study designs and in different populations, although the strength of the evidence varied (see Figure 5-1). The strongest evidence of an association between exposure to trichloroethylene and NHL comes from the InterLymph pooled analysis (p for Fisher combined probability = 0.004), which was considered to be the most informative study and is supported by findings of relatively small, mostly statistically non-significant increases (>20%) in NHL risk among workers exposed to trichloroethylene in most studies of moderate (Hansen et al. 2013; Radican et al. 2008) or low to moderate utility (Deng et al. 2013; Lipworth et al. 2011; Morgan et al. 1998; Raaschou-Nielsen et al. 2003; Wang et al. 2009b). Limitations in studies would primarily bias findings toward the null. The high increased risk reported by Hardell et al. (1994) should be viewed with caution because it was based on small numbers of exposed cases and controls and this study had several methodological limitations. There was little evidence (≤20%) (Bove et al. 2014; Persson and Fredrikson 1999) to no evidence (OR ≤ 1.0) (Bahr et al. 2011; Silver et al. 2014; Vlaanderen et al. 2013) for an association in most studies considered to be of lower utility, primarily because of low sensitivity to detect an effect. (Only 1 case of NHL was reported by Boice et al. (2006).)

Statistically significant increases in NHL risk were found in two recent meta-analyses (mRR = 1.23, 95% CI = 1.07 to 1.42, Scott and Jinot (2011); mRR = 1.23, 95% CI = 1.07 to 1.42, (Karami et al. 2013) for combined cohort and case-control studies). In the meta-analysis by Scott and Jinot, the mRR was robust and not sensitive to removal of individual studies or use of alternative risk estimates. In the most recent meta-analysis, there was little evidence of heterogeneity or publication bias (for the analysis of the combined cohort and case-control studies); however, there was some evidence for both publication bias and low to moderate heterogeneity in the EPA meta-analysis.

Some, but not all, studies found evidence for exposure-response relationships. The InterLymph study (Cocco et al. 2013) found that the risk of NHL increased with longer duration and higher intensity of exposure, and its constituent study by Purdue et al. (2011a) also found exposure-response relationships with other exposure metrics, including average weekly exposure and cumulative exposure. The study of Connecticut women (Deng et al. 2013; Wang et al. 2009b) found higher risks among women with the medium-high exposure intensity compared with women with low exposure. However, evidence for an exposure-response relationship was lacking among cohort studies (Hansen et al. 2013; Lipworth et al. 2011; Raaschou-Nielsen et al. 2003; Radican et al. 2008) and in some cases risks were lower among the higher exposed compared with the lowest exposed. These studies had limited ability to evaluate exposure-response relationships because of low statistical power or concerns about exposure misclassification. The EPA meta-analyses found a somewhat higher risk in analyses of high exposure than ever exposure; however, the latest meta-analysis found some evidence for exposure response with duration but not intensity. This pattern could possibly change with the inclusion of the InterLymph study.

No biases (such as selection) were identified that would bias towards a positive association, although the direction of the biases were not known in the studies by Hardell et al. (1994) and Persson and Fredrikson (1999) (see Figure 5-2). Confounding by other co-exposures can be ruled out reasonably in most of the large case-control studies and the Nordic studies of workers in diverse industries because the co-exposures to other agents are likely to vary in pattern and levels across the various industries and different time periods. Confounding by other solvents or chlorinated solvents may be possible in the aircraft-manufacturing studies. No evidence for confounding by lifestyle factors was found.

Figure 5-2

Forest Plot: NHL and Ever Exposure to Trichloroethylene

Effect estimate and 95% CI for ever exposure to trichloroethylene and NHL (see Figure 5-1) and overall prediction of direction of any bias (if possible) for low utility studies as described in Section 4.1.3 according to utility of the studies to inform the cancer hazard evaluation (see Section 3, Appendix D, and Figure 5-1). The effect estimate for Boice et al. (2006) is based on one NHL case. Studies by Bove et al. (2014) and Vlaanderen et al. (2013) are not graphed because they did not report relative risk for ever exposure. Findings for these studies are reported in Table 5-1. For studies reporting multiple effect estimates, a preference was given to internal analysis; the effect estimate using internal analysis (RR) for Morgan et al. (1998) was reported by Scott and Jinot (2011).

No association between NHL and exposure was found in some cohort studies with more limited designs or limited statistical power (Bahr et al. 2011; Bove et al. 2014; Morgan et al. 1998) and the recent, large population-based Nordic cohort study (Vlaanderen et al. 2013) in which exposures were likely low and non-differential exposure misclassification was likely. The studies by Vlaanderen et al. and Bove et al. were not included in the most recent meta-analyses.

With respect to related subtypes of NHL, the strongest evidence of an association for follicular lymphoma and CLL is based on positive associations in the InterLymph study (Cocco et al. 2013) and its constituent study, the NCI-SEER study by Purdue et al. (2011a). The most informative study on multiple myeloma (Gold et al. 2011) reported a statistically significant increase in incidence with increasing cumulative exposure. Weaker associations were found in some of the cohort studies. The meta-analysis on trichloroethylene exposure and NHL and related subtypes by Karami et al. (2013) also reported a meta-risk of 1.05 (95% CI = 0.88 to 1.27) for multiple myeloma and 0.98 (95% CI = 0.69 to 1.41) for combined chronic/small cell leukemia.

## 5.2 Mechanistic Data for NHL and Related Neoplasms

An increased risk of NHL and related neoplasms (e.g., follicular lymphoma, multiple myeloma, chronic lymphocytic leukemia) was identified in some epidemiological studies of humans exposed to trichloroethylene (see Section 5.1). In addition, increased incidences of lymphoma (female mice) and leukemia (female rats) were reported in experimental animals exposed to trichloroethylene (NTP 2011). Although the modes of action of trichloroethylene-induced NHL and related neoplasms are unknown, the key events may be related to effects of trichloroethylene on the immune system. There are also studies in humans and experimental animals that have evaluated the relationship between trichloroethylene and immunotoxicity or markers of immunomodulation. The following sections include a brief review of risk factors for NHL (Section 5.2.1) the immune effects of trichloroethylene in humans and experimental animals (Section 5.2.2), possible modes of action for trichloroethylene-induced immune modulation and NHL (Section 5.2.3). Section 5.2.4 summarizes the information.

### 5.2.1 Risk Factors for NHL

Many known risk factors for NHL are related to mechanisms involving chronic antigenic stimulation due to immunomodulation, including autoimmunity and/or immunosupression (Grulich et al. 2007; Hardell et al. 1998; Ponce et al. 2014). Both clinical and experimental data clearly show that chronic inflammation mediated by immunoglobulins and immune complexes contributes to cancer development (Balkwill et al. 2005; Coussens and Werb 2002; de Visser et al. 2006; Tan and Coussens 2007). Increased incidences of NHL have been reported among patients with congenital immune deficiency, autoimmune disease, or virus infection (e.g., HIV, human T-cell leukemia/lymphoma virus, Epstein-Barr virus); patients receiving immunosuppressive therapy following bone marrow or organ transplants; or as a late complication of certain chemotherapy and radiotherapy regimens for Hodgkin lymphoma (Aligo et al. 2014; Bernatsky et al. 2006; Besson et al. 2006; Hardell et al. 1998; Ponce et al. 2014).

Autoimmune disorders associated with an increased risk of NHL and related neoplasms include rheumatoid arthritis, systemic lupus erythematosus, Sjögren syndrome, sarcoidosis, and systemic sclerosis (scleroderma) (Ponce et al. 2014). NHL (predominantly B cell) accounts for about half the cancers observed in patients with primary immunodeficiencies and increases to about 75% in patients diagnosed with severe combined immunodeficiency (Ponce et al. 2014). Lymphoma risk also appears to increase with autoimmune disease severity. In addition, exposure to various immunotoxic industrial chemicals and pesticides (e.g., phenoxyacetic acids, chlorophenols, dioxins, organic solvents, DDT, PCBs, toxaphene, and chlordane) are recognized risk factors for NHL (Cantor et al. 1992; Hardell et al. 1998).

Although NHL includes many subtypes (e.g., diffuse large B cell lymphoma, T cell NHL, follicular lymphoma, chronic lymphocytic leukemia, and others), diffuse large B cell lymphoma is the most common among patients with autoimmune disorders. Autoimmune disorders are characterized by B cell hyperactivity and chronic inflammation. Lymphomas can develop from errors arising during the hypermutable stages of B cell development and can arise from either chronic antigenic stimulation (inflammation or autoimmunity) or from impaired pathogen control (immunosuppression). B cells initiate autoimmunity through several mechanisms including enhanced production of autoantibodies and immune complexes, dendritic and T cell activation, and cytokine production (Tan and Coussens 2007). The susceptibility of mature B cells to oncogenic transformation is due to DNA hypermutation and recombination during immunogen-induced activation and differentiation and results from the increased risk of genetic damage (e.g., double-strand breaks and chromosomal translocations) resulting from these processes during B cell maturation (Baecklund et al. 2014; Ponce et al. 2014).

Markers that may be important indicators for NHL risk include autoantibodies, lymphocyte subsets and activated lymphocytes, immunoglobulins, serum cytokines, and natural killer (NK) cell cytotoxicity. Several studies have reported an association between immune biomarkers and risk of NHL. Case-control studies using pre-diagnostic blood or serum and cohort studies of several immune biomarkers have reported predictive value for some lymphocyte subsets or immune markers and NHL. Several biomarkers or cytokines (such as sCD27, sCD30, sCD44, CXCL13, CD30, TNF-R1, sTNF2, BCA-1, vascular endothelial growth factor receptor, intercellular adhesion molecule (ICAM), IL-2, IL-10) are associated with NHL (Conroy et al. 2013; De Roos et al. 2012; Hosnijeh et al. 2010; Purdue et al. 2011b; Vermeulen et al. 2011).

Most malignancies, as well as pre-malignant tissues associated with chronic inflammatory diseases, have an altered immune cell status (Dalgleish and O'Byrne 2002; Tan and Coussens 2007). These alterations frequently include suppressed cell-mediated immunity and enhanced humoral immunity marked by a decrease in Th1 T helper cells and an increase in Th2 T helper cells (Tan and Coussens 2007) and the cytokines, i.e., interleukins or interferon, that they produce. A number of case-control studies have reported that polymorphisms in genes coding for immunoregulatory cytokines that mediate inflammation, apoptosis, and Th1/Th2 balance influence susceptibility to NHL (Bel Hadj Jrad et al. 2006; Deng et al. 2013; Hosnijeh et al. 2010; Lan et al. 2006; Purdue et al. 2007; Rothman et al. 2006; Wang et al. 2007c).

### 5.2.2 Immune Effects of Trichloroethylene

The effects of trichloroethylene on the immune system have been investigated in humans (Section 5.2.2.1) and experimental animals (Section 5.2.2.2). In addition, some studies have looked at biomarkers for immunomodulation. Of interest is whether changes in these biomarkers are consistent with proposed pathways for lymphoma development.

#### 5.2.2.1 Studies of Immunomodulation in Humans

This section summarizes the findings of studies (1) reporting risk estimates for autoimmune diseases and trichloroethylene exposure, (2) of trichloroethylene-induced skin hypersensitivity and (3) evaluating the relationship of trichloroethylene and biomarkers of immunomodulation. None of the studies evaluated phenotypic markers that would directly demonstrate immune suppression. The major limitation is they did not examine NHL or other disease.

Studies of trichloroethylene exposure and autoimmune diseases consisted of four case-control studies of systemic sclerosis (sclerodoma) (Diot et al. 2002; Garabrant et al. 2003; Nietert et al. 1998), including one pooled analysis of these studies (Cooper et al. 2009), and one case-control study of undifferentiated connective tissue disease (Lacey et al. 1999). Results from these studies are summarized in Table 5-5. No epidemiological studies of trichloroethylene exposure and rheumatoid arthritis or other autoimmune diseases were identified.

Table 5-5 Case-control Studies of Trichloroethylene Exposure and Autoimmune Diseases in Humans^a^

Reference | Study Population # Cases & Controls | Exposure Assessment | OR (95% CI); # of Exposed Cases | Comments
Systemic sclerosis (SSc)
Nietert et al. (1998) South Carolina (USA) | Hospital-based case-control study 178 cases of SSc 200 unmatched clinic controls free of autoimmune and connective tissue disease | Structured interview of self-reported job history (titles, industry, task) Semi-quantitative JEM with expert review to assign scores of intensity and probability of solvents for each job. Cumulative exposure intensity also factored in duration, frequency, and calendar year | Total cases Cumulative intensity 2.0 (0.7–5.3); 32 M 1.2 (0.5–2.6); 10 W Maximum intensity 3.3 (1.0–10.3); 30 M 0.9 (0.3–2.3); 6 W Anti-Scl-70^a^ SSc cases Cumulative intensity 2.6* M; 4.0* W Maximum intensity 4.8* M; 0.9 W | Covariates/consideration of confounding: Adjusted for age at disease onset; findings stratified by sex. On average, cases were younger than controls. A greater proportion of cases were women than controls, but racial distribution was similar Strengths: Relatively large study; analysis by multiple matrices of exposure and disease subtypes Limitations: Limited exposure assessment; no control for possible co-exposures to other solvents and other potential confounders
Diot et al. (2002) France | Hospital-based case-control study 80 cases of SSc 160 matched (age, gender, smoking habits) controls without known autoimmune or chronic interstitial lung disease | Structured interview of self-reported job history (appears self-reported solvent exposures) Semi-quantitative/expert assessment to assign scores for probability, intensity, frequency, and duration of exposure for each employment period; cumulative exposure sum of exposure scores for all employment periods | Ever vs. never exposure 4.7 (1.0–21.9); 7 M 2.1 (0.7–6.8); 6 W High cumulative exposure 7.6 (1.5–37.4); 7 M + W | Consideration of confounding: Socioeconomic level, professional status, age, sex, and smoking habits similar between cases and controls. No subjects reported history of silicone implants, cosmetic surgery, frequency of hair dyes or drug use (which may be associated with SSc) Strengths: Analysis of high cumulative exposure reduces potential for exposure misclassification. Consideration of potential confounding Limitations: Limited statistical power for TCE exposure, no adjustment for possible co-exposures to other solvents
Garabrant et al. (2003) Michigan & Ohio (USA) | Population-based case-control study 660 cases 2,227 matched (race, age, and geographical region) controls without SSc identified by RDD | Structured interview of self-reported job and hobby exposure to 9 solvents and PPE Self-reported exposure to solvent confirmed by expert review of job history | Women only Self-reported 2.0 (0.8–4.8); 8 Confirmed by expert review 1.9 (0.6–6.6); 4 | Covariates/consideration of confounding: Adjusted for age, race, region, and year of birth. Race/ethnicity, education, marital status, frequency of smoking, and alcohol consumption were similar among cases and controls. Current smoking more common in controls and annual income higher in controls Limitations: Potential for exposure misclassification because of limited exposure assessment; small number of exposed cases and controls no control for co-exposures to solvents
Cooper et al. (2009) | Pooled case-control analysis (Diot et al. 2002; Garabrant et al. 2003; Nietert et al. 1998) | See individual studies in this table | 2.5 (1.1–5.4) M 1.2 (0.6–2.6) W | Evidence of association with TCE exposure, mostly in men
Marie et al. (2014) France | Population-based case-control study 100 cases 300 controls matched (for age, gender, and smoking habits) without history of connective tissue disease, systemic vasculitis, other autoimmune systemic disease, cancer, or chronic interstitial lung disease | Structured interview of self-reported job history Semi-quantitative/expert assessment assignment of probability, intensity, frequency, and duration of exposure for each employment period; cumulative exposure based on sum of exposure scores for all employment periods | Ever exposure 2.8 (0.8–9.4); 8 M 1.4 (0.3–5.4); 4 W High cumulative exposure (M + W) 3.6 (1.2–12.09); 8 | Consideration of confounding: No differences between cases and controls for age, sex, geographical region, smoking habits, socioeconomic and medical history, including surgeries and drug use, which may be related to autoimmune disease, and hair dying Strengths: Analysis of high cumulative exposure reduces potential for exposure misclassification Limitations: Limited statistical power for TCE exposure, no adjustment for possible co-exposures and other confounders
Undifferentiated connective tissue disease
Lacey et al. (1999) Michigan & Ohio (USA) Same design as Garabrant et al. (2003) | Population-based case-control study Women only 205 cases 2,079 matched (race, age, and geographical region) controls without a medical history of other connective tissue diseases identified by RDD | Same as Garabrant et al. (2003) | Women only Self-reported 0.9 (0.1–7.0) 1 case Confirmed by expert review 1.7 (0.2–15.0) 1 case | Covariates/consideration of confounding: Adjusted for age, year of birth. Ethnicity, annual household income, education, marital status, and smoking frequencies and alcohol use were similar between cases and controls Limitations: Potential for exposure and disease misclassification. Only one exposed case

* p < 0.05.

JEM = job exposure matrix; PPE = personal protective equipment; RRD = random digit dialing.

^a^ Auto-antibody.

There is consistent evidence from the body of studies that trichloroethylene exposure is associated with scleroderma for men, but not consistently for women (Diot et al. 2002; Garabrant et al. 2003; Marie et al. 2014; Nietert et al. 1998); see Table 5-5. One study found a stronger association of cumulative and maximum intensity exposure to TCE and systemic sclerosis among both men and women who tested positive for anti-Scl-70 autoantibody compared with those who tested negative for the antibody (Nietert et al. 1998). The studies have somewhat limited exposure assessments and statistical power due to small numbers of exposed cases to detect an effect of exposure, however. A strength of the studies was that they considered potential demographic or lifestyle confounders. In a pooled analysis of three of the four case-control studies of scleroderma, combined ORs of 2.5 (95% CI = 1.1 to 5.4) among men and 1.2 (95% CI = 0.6 to 2.6) among women were reported (Cooper et al. 2009). The data were insufficient to evaluate the findings for undifferentiated connective tissue disease since there was only one exposed case in the only study reporting on this disease (Lacey et al. 1999).

Cases of severe generalized dermatitis (i.e., hypersensitivity skin disorders) also were reported among workers in China (Dai et al. 2004; Dai et al. 2009; Huang et al. 2006; Huang et al. 2012; Kamijima et al. 2008; Kamijima et al. 2013; Liu et al. 2009) and in Japan, the United States, Canada, and Spain (see also review by Watanabe 2011). Disease onset usually occurs within 2 to 5 weeks of exposure, resembles severe drug-induced hypersensitivity syndrome, and is associated with elevated inflammatory responses, oxidative stress, and reactivation of latent human herpesvirus 6 (Huang et al. 2006; Huang et al. 2012; Kamijima et al. 2013). The cases of hypersensitivity skin disorders are frequently accompanied by immune-mediated (toxic) hepatitis and liver dysfunction (Huang et al. 2006; Kamijima et al. 2013; see also review by Watanabe 2011). Cases of idiosyncratic toxic hepatitis have also been reported in Korean workers occupationally exposed to trichloroethylene (see review by Kim and Kim 2010). An immunologic-type reaction was thought to be responsible because disease onset was sporadic, generally not dose related, and usually occurred after 30 days of exposure. Although these reports do indicate that exposure to trichloroethylene could be related to the observed immunomodulation, no studies evaluated whether these effects could be linked to NHL.

Studies of trichloroethylene exposure and biomarkers of immunomodulation (e.g., lymphocyte subset populations, antibodies, or other biomarkers of immune function) included both occupational and population-based studies. The occupational studies consisted of a series of studies of trichloroethylene-exposed workers in metalworking and electronic factories in Guangdong province, China (Bassig et al. 2013; Dai et al. 2004; Hosgood et al. 2012; Huang et al. 2006; Huang et al. 2012; Kamijima et al. 2008; Lan et al. 2010; Liu et al. 2009; Zhang et al. 2013b) and a study in the Italian printing industry (Iavicoli et al. 2005). The population studies included two prospective studies of immune markers among a birth cohort exposed pre- and postnatally to trichloroethylene in Leipzig, Germany (Lehmann et al. 2001; Lehmann et al. 2002). Further details of these studies are provided in Table 5-6.

Table 5-6 Studies of Trichloroethylene Exposure and Lymphocytes, and Immune Markers in Humans^a^

Reference | Study Population | Exposure Assessment Exposure Levels | Findings | Comments
Series of studies of Chinese workers from 6 factories in Guangdong
Lan et al. (2010) Hosgood et al. (2012) China | Metal/electronics factory workers Cross-sectional study of healthy workers (excluded those with history of cancer, chemotherapy, and radiotherapy) 80 exposed 96 unexposed (frequency matched by age, sex, and region) | Personal air samples 3 weeks prior to blood and urine collection Mean air (SD) All: 22.5 (35.9) Low (<12 ppm): 5.2 (3.5) High (>12 ppm) 38.4 (44.6) | Exposed vs. non-exposed Lan et al. (2010) sCD27^b^: ↓, E/R sCD30^b^: ↓, E/R Lymphocytes: ↓, E/R NK cells: ↓, E/R B cells: ↓, E/R Total T cells: ↓, E/R CD4 T cells: ↓, E/R CD8 T cells: ↓, E/R No differences: WBC, granulocytes, monocytes Hosgood et al. (2012) CD4 and CD8 Subsets ↓, E/R CD4 naïve CD4 effector memory CD8 naïve T subsets: P > 0.05: CD4 central memory CD8 central and effector memory Regulatory | Covariates/consideration of confounding: Adjusted for age, sex; (B cells also adjusted for smoking status); smoking status, alcohol consumption, recent infection, and BMI considered in analysis. No differences between exposed and unexposed in smoking status, sex distribution, recent infection, and BMI Strengths: Exposure misclassification unlikely because of good exposure assessment; negligible co-exposures to e.g., benzene, styrene, formaldehyde, chlorinated solvents; ability to evaluate exposure-response relationships; healthy participants with no previous cancer, chemotherapy, radiation Limitations: Small study population, cross-sectional design
Bassig et al. (2013) China (same population base and design as Lan et al. (2010)) | Metal/electronics factory workers Cross-sectional 71 exposed 78 unexposed (frequency matched by age, sex, and region) | Personal air samples (See Lan et al. 2010) | Exposed vs. non-exposed IL-10: ↓: Controls: ~11 pg/mL <12 ppm: ~3 pg/mL >12 ppm: ~5 pg/mL IL-6: No differences TNF-α: No differences | See Lan et al. (2010) Covariates/consideration of confounding: Adjusted for age, sex, total lymphocyte count (IL-10 and TNF-α). Smoking status, BMI, and recent infection considered in analysis Strengths: Analyses adjusted for potential confounders Limitations: Small study population, cross-sectional design
Zhang et al. (2013a) China (same population base and design as Lan et al. (2010)) | Metal/electronics factory workers Cross-sectional 80 exposed 45 unexposed (frequency matched by age, sex, and region) | Personal air samples (see Lan et al. 2010) | Exposed vs. non-exposed IgG: ↓, E/R IgM: ↓, E/R IgE: No differences | See Lan et al. (2010) Covariates/consideration of confounding Adjusted for age, sex, alcohol use (IgE only). Current smoking, alcohol use, BMI, and recent infection considered in analysis. Strengths: Adequate exposure assessment and sample size for immunoglobulin analysis Limitations: Cross-sectional design
Other studies
Iavicoli et al. (2005) Italy | Printing workers/degreasing process Cross-sectional: workers in same factory 35 TCE-exposed workers 30 unexposed factory workers 40 office workers | Assigned to exposure group based on magnitude of TCE exposure (degreasing process) Personal air TCE: exposed workers 35 ± 14 mg/m^3^ Urine TCA (mg/g creatinine) Exp. workers: 13.3 ± 5.9 Unexp. workers: 0.02 ± 0.02 (detection level) | Exposed vs. non-exposed (factory and office workers) IL-2: ↑ IL-4: ↓ IFN-γ: ↑ | Consideration of confounding: No significant differences in age, smoking habits, and residence among the three groups Strengths: Quantitative exposure assessment Limitations: Small, cross-sectional study
Lehmann et al. (2002) | Infants Longitudinal birth cohort 85 randomly selected infants from study population of ~976 full-term neonates | Passive air sampling of VOCs in children’s housing over a 4-week period after birth: Median TCE: 0.6 μg/m^3^ Maternal exposure questionnaire on sources of exposure | Cytokine-producing cord blood T cells Crude data (Mann Whitney U-test) ↓IL-2 for highest TCE exp. No association for Il-4, IFN-γ, TNF-α Adj. OR for TCE exposure ↑IFN-γ: 3.6 (0.9–14.9): >75th percentile ↓IL-4: 4.4 (1.1–17.8); <25th percentile TNF-α and Il-2: No association with ↑ or ↓ | Covariates/consideration of confounding: Family atopy history, gender, maternal smoking during pregnancy Limitations: Limited assessment of TCE and other VOC exposures of infants; measured after cord blood analysis: unclear if investigators blind to cytokine status of infants; multiple VOCs were correlated with TCE
Lehmann et al. (2001) Germany | 3-year-old children (atopy risk) LARS (Leipzig Allergy Risk Children’s Study) Longitudinal birth cohort 121 3-year-olds at risk for atopy (IgE > 0.9 kU/L)) with VOC data; cytokines producing T cells on subgroup of 28 | Passive air sampling of VOCs in infant bedrooms over a 4-week period at the end of the 3rd year of life. Mean TCE: 0.42 μg/m^3^ | OR for TCE exposure and allergy sensitization (measured by >75% IgE) Milk: 0.7 (0.1–3.5) Egg: 1.3 (0.2–9.5) No significant correlation with indoor TCE exposure and IL-4 and IFN-γ producing T cells (CD+3, CD+8, CD+4) | Covariates/consideration of confounding: Family atopy history, passive smoking Limitations: Limited assessment of TCE and other VOC exposures of infants, and multiple VOCs were correlated with TCE. Results of at-risk population may not be generalizable to the general population. Small numbers of subject for cytokine analysis

ANCA = antinuclear antibodies; CD = cluster of differentiation (T cell types); E/R = exposure-response relationship; IFN = interferon; IgG, E, M = immunoglobulin G, E, M; NK = natural killer cells; IL = interleukin; TNF = tumor necrosis factor; VOC = volatile organic compounds; ↓ = statistically significant decrease; ↑ = statistically significant increase.

^a^ Case reports, studies of mixed or chlorinated solvents, or ecological studies are excluded.

^b^ TNF receptor markers.

The series of cross-sectional studies of metal and electronics workers in Guangdong province, China, and the Italian study of printing workers conducted the most extensive exposure assessments and provided clear evidence that subjects were exposed to moderate to high levels of trichloroethylene. Studies by Lan et al. (2010), Hosgood et al. (2012), Bassig et al. (2013), and Zhang et al. (2013b) were conducted on total lymphocyte and specific subsets. Lan et al. (2010) reported that workers exposed to trichloroethylene had dose-related statistically significant lower counts of total lymphocytes, B cells and specific subsets of T lymphocytes (CD4+, CD8+) and natural killer cells in peripheral blood compared with unexposed controls. A further analysis found significant decreases in CD4+ and CD8 naïve and CD4+ effector memory cells but not other types of CD4+ (central memory) and CD8 (memory) subsets or T cell regulation subsets among trichloroethylene workers compared with controls (Hosgood et al. 2012). Trichloroethylene-exposed workers had lower serum levels of IgG, IgM, and lower levels of CD27, and sCD30 cells (members of the TNF receptor family that help regulate cellular activity of T, B and natural killer cells) (Lan et al. 2010) suggesting that trichloroethylene impairs B cell stimulation. Bassig et al. (2013) also reported lower serum levels of IL-10 among exposed workers, which may indicate chemically induced alterations in Th1/Th2 balance. Iavicoli et al. (2005) also reported lower serum levels of the Th2 cytokine, IL-4, and increased levels of the Th1 cytokines, IL-2 and interferon-gamma, among trichloroethylene-exposed workers. Overall, these studies provide some evidence of immune modulation associated with trichloroethylene exposure, and possibly with measures of precursors of autoimmunity (e.g., IFN- γ).

Two studies of possible immune effects of trichloroethylene in children and infants were identified but they are of limited utility, in part due to the limited exposure assessment of maternal and child exposure and low reported overall levels of trichloroethylene. The German birth cohort studies of children with atopy (Lehmann et al. 2001) potentially exposed to trichloroethylene and other volatile organic compounds reported no association for trichloroethylene exposure and allergies and IL-4 and IFN-γ-producing T cells or cytokines. In the study of infants (Lehmann et al. 2002), increasing trichloroethylene exposure was associated with a statistically significant decrease in IL-4-producing T cells and non-statistically significant increase in IFN-γ-producing T cells but not with IL-2- (in multivariate analysis) or TNF-α-producing T cells. An immunosuppressive effect of trichloroethylene is suggested by the significant reduction reported for IL-2-producing T cells in cord blood. However, due to the limited exposure noted above and the correlation of trichloroethylene with other volatile organic compounds and the small number of subjects available for cytokine analysis (in the children’s study), no conclusions can be drawn from these studies.

#### 5.2.2.2 Studies of Immunomodulation in Experimental Animals

Overall, evidence suggests that exposure to trichloroethylene or its metabolites causes alterations in the immune system, including autoimmune disease, in experimental animals based on studies showing signs of autoimmune disease and/or changes in leukocyte numbers, proliferation, activation, and function (see Table E-4). As explained in more detail in Section 5.2.1, immunomodulation resulting from autoimmunity or immunosuppression leading to continual B cell activation are linked to NHL and could possibly be involved in the mode of action for trichloroethylene-induced lymphoma.

Many studies were identified that examined the immunological effects of trichloroethylene in experimental animals. The results for the same endpoint often varied between studies, but these differences might be explained by differences in exposure or by intra- or interspecies variation (e.g., strain of mice, use of rats or dogs). Differences in species, strain, and exposure were considered and are noted in the text below when results differ between studies. Many of the relevant studies were conducted in MRL+/+ mice, which spontaneously develop a systemic lupus erythematosus-like autoimmunity. The various study designs and immunomodulatory endpoints are presented in Table E-1 and Table E-2. Results from these studies are summarized by endpoint in Table E-3 (blood - adducts and leukocyte numbers), Table E-4 (blood – antibodies), Table E-5 (spleen), Table E-6 (liver and kidney), and Table E-7 (splenic ex vivo cytokines, lymph nodes, and anti-bacterial response).

While experimental animal models do not exist for all human autoimmune diseases (see Section 5.2.2.1), the autoimmune-prone MRL+/+ mice develop many of the features of systemic lupus erythematosus. General signs of autoimmune disease were suggested by changes in antibodies, immune cell activities, and autoimmune hepatitis in MRL+/+ mice and other species and strains of experimental animals exposed to trichloroethylene or its metabolites (see Table F-1, Table F-2, Table F-3, and Table F-4). Exposure-related effects included increased IgG and autoantibody formation (anti-nuclear, anti-DNA, anti-albumin, and anti-liver) (Blossom et al. 2004; Cai et al. 2007b; Cai et al. 2006; Gilbert et al. 2009; Griffin et al. 2000a; Griffin et al. 2000c; Keil et al. 2009; Khan et al. 1995; Wang et al. 2007a; Wang et al. 2007b; Wang et al. 2008; Wang et al. 2012b; Wang et al. 2013). The presence of autoantibodies indicated that self-antigens were recognized by the immune system as “foreign” which can provide persistent antigen stimulation and B cell activation. However, cell surface markers for B cell activation (MHC II) and B cell proliferation were not consistently altered and other markers of B cell activation were not examined. In addition to autoantibodies, lymphocyte numbers (especially CD4 T cells) were increased in the spleen as well as lymphocyte proliferation (Cai et al. 2006; Griffin et al. 2000b; Sanders et al. 1982; Wang et al. 2008). These general signs support the idea that autoimmunity is induced by trichloroethylene or its metabolites and that continual B cell activation may be occurring in target organs such as the liver.

The initiation of autoimmune disease from exposure to trichloroethylene or its metabolites may have been caused by the formation of protein adducts with metabolites (dichloroacetyl-protein) and, through increased oxidative stress, with products of lipid peroxidation (malondialdehyde-protein, hydroxynonenal-protein) (Cai et al. 2007b; Cai et al. 2006; Griffin et al. 2000a; Griffin et al. 2000b; Griffin et al. 2000c; Halmes et al. 1997; Khan et al. 1995; Khan et al. 2001; Wang et al. 2007a; Wang et al. 2008; Wang et al. 2012b; Wang et al. 2013). Protein adducts were found in the serum and liver, and antibodies against these adducts were found in the serum. A role for formation of trichloroethylene metabolites in these effects is indicated by the finding that inhibition of CYP2E1 by co-exposure with diallyl sulfide prevented the formation of dichloroacetyl-protein adducts and its specific antibodies (Griffin et al. 2000b). In addition, decreasing oxidative stress by the enhancement of the antioxidant activity of glutathione, by co-exposure to N-acetylcysteine, prevented the formation of malondialdehyde-protein and hydroxynonenal-protein adducts and their specific antibodies (Wang et al. 2013). Splenocytes from trichloroethylene-exposed mice produced Th1 cytokines (IFN-gamma, IL-2) when stimulated with preformed lipid peroxidation product-albumin adducts (malondialdehyde-albumin, hydroxynonenal-albumin) (Cai et al. 2006; Wang et al. 2008; Wang et al. 2012b). These studies show that trichloroethylene induced neoimmunogenic protein adducts in the serum and liver by both CYP2E1-mediated metabolic activation and increased oxidative stress. In addition to antibodies against the protein adducts found in the liver, antibodies against normal, non-adducted, liver proteins were formed (Gilbert et al. 2009). Similarly, exposure to preformed trichloroethylene-albumin adducts not only induced the formation of antibodies against the albumin adducts (formyl-albumin, trichloroethene oxide-albumin, and dichloroacetyl-albumin), but also to the non-adducted albumin (Cai et al. 2007b). These results indicate that trichloroethylene is inducing autoimmunity toward “self” proteins found in the blood and liver. Besides autoimmunity, other trichloroethylene-induced immune effects were reported.

Immunomodulatory findings were reported for a number of different organs and endpoints. While immunomodulatory effects can include immunosuppression, direct evidence for this effect was not generally available. Some evidence for a systemic immunomodulatory effect of trichloroethylene was reported from studies showing increased mortality in mice following a bacterial challenge; however, effects on alveolar macrophage phagocytic activity and phagocytic clearance of bacteria were not entirely consistent with the mortality data (Aranyi et al. 1986; Selgrade and Gilmour 2010). Immunomodulation was suggested by a decrease in various peripheral blood leukocytes in studies in different species by different routes of administration. These included decreased numbers of leukocytes, lymphocytes, CD4 T cells, CD8 T cells, and B cells in NOD mice exposed via drinking water (Ravel et al. 2004), but the effects were observed only at 23 weeks of exposure and no treatment-related functional effects were observed for serum cytokine levels. Decreased CD4 T cell numbers were also reported in rats exposed by intradermal injection (Chen et al. 2006), but no differences in cytokines (IL-4 and IFNγ) were found. Decreases in both leukocytes and neutrophils were reported in dogs exposed by intratracheal instillation or intravenous injection (Chen et al. 2006; Hobara et al. 1984; Ravel et al. 2004); however, the leukocyte count in the latter study reached a minimum 30 minutes after injection and gradually returned toward normal. The only endpoints that decreased in more than one study were the CD4 T-cell numbers and leukocyte numbers. No effect on peripheral blood leukocyte populations was seen in one study testing chloral hydrate in mice.

Possible signs of immunomodulation were observed in specific organs. In the liver, the cytolytic activity of NK cells was decreased (Wright et al. 1991); however, mixed results were seen in the spleen and lymph nodes. For the spleen, most studies found no differences with exposure to trichloroethylene or its metabolites, and no differences in experimental design variables of species, strain, or route of exposure were identified that could explain the mixed results in the spleen. Immune effects observed in some of these studies included decreases in the number of CD4 T cells (2/4 studies), CD8 T cells (1/7 studies), and B cells (2/7 studies) and increases in lymphocyte number (2/2 studies), lymphocyte proliferation (1/1 study), and CD4 T cell proliferation (2/3 studies) (Blossom and Doss 2007; Blossom et al. 2007; Blossom and Gilbert 2006; Blossom et al. 2004; Cai et al. 2006; Gilbert et al. 2011; Griffin et al. 2000a; Griffin et al. 2000b; Kauffmann et al. 1982; Keil et al. 2009; Peden-Adams et al. 2006; Peden-Adams et al. 2008; Wang et al. 2008). Initial B cell activation against sheep red blood cells in the spleen was increased in one study and decreased in two studies (Kauffmann et al. 1982; Peden-Adams et al. 2006; Sanders et al. 1982). The numbers of CD4 T cells, CD8 T cells, and B cells in lymph nodes and activation of those B cells were unaffected (Blossom et al. 2006; Blossom et al. 2004; Gilbert et al. 2012; Gilbert et al. 2011).

The mixed results in the spleen and lack of effect in the lymph nodes suggest that trichloroethylene does not affect the amount or activity of immune cells in those organs. Since there were decreases in leukocytes in the peripheral blood, but no consistent results in the spleen or lymph nodes, it is possible that the effects seen in the blood were the result of leukocyte extravasation into tissue. The data from studies in mice (Ravel et al. 2004) and rats (Chen et al. 2006) do not give support for either extravasation or decreases in leukocyte numbers since they did not also look at leukocyte numbers in the spleen or lymph nodes. Changes in cytokines, however, did not similarly decrease along with CD4 and CD8 T cells (Chen et al. 2006; Ravel et al. 2004). Blood leukocyte numbers in the dog studies (Hobara et al. 1984) suggest extravasation might be the explanation since the decreases were temporary and occurred for only ≤2 hours before increasing back towards pre-dose levels.

### 5.2.3 Possible Modes of Action for Trichloroethylene-induced Immune Modulation and NHL

As discussed above, trichloroethylene induces immune modulation in humans and laboratory animals with the strongest evidence for autoimmune effects (Boverhof et al. 2013; Cooper et al. 2009; Rusyn et al. 2014; Weinhold 2009). Immune modulation and autoimmunity can lead to chronic inflammation and antigenic stimulation. Only a few studies in humans examined the immunomodulatory effects of trichloroethylene. Most studies in experimental animals used mouse strains that spontaneously develop conditions resembling systemic lupus erythematosus. Since immunomodulation and autoimmune diseases are known risk factors for NHL, altered immunity and chronic inflammation may be involved in trichloroethylene-induced NHL.

The relationship between immune status and cancer risk is complex. It is well accepted that chronic inflammation plays an essential role in tumorigenesis; however, the underlying molecular mechanisms linking inflammation and cancer are not completely understood (Wu et al. 2013). The normal physiological response to infection or tissue damage is acute inflammation. Cases of unresolved inflammation, as occurs with immune suppression or autoimmune disease, evoke chronic inflammation and antigenic stimulation. Chronic inflammation predisposes the host to cancer by inducing DNA damage and chromosomal instability and promoting tumor development. Possible modes of action include the following: (1) immunosuppression of tumor surveillance activity, (2) effects from oncogenic viruses (and, for NHL, Epstein-Barr virus [EBV] reactivation in particular) due to impaired viral surveillance and clearance, and (3) chronic antigenic stimulation due to an unchecked inflammatory response to foreign triggers (infections, allograft) or autoimmunity (Ponce et al. 2014). Chronic antigenic stimulation leads to a state of sustained B cell hyperstimulation and the potential for oncogenic transformation (see Section 5.2.2).

Findings from the series of Chinese studies generally suggest that trichloroethylene exerts immunomodulatory effects; however, lower serum levels of IgG, IgM, sCD27, and sCD30 suggest that trichloroethylene impairs B cell stimulation and is counter to the proposed mechanism of B cell activation. Trichloroethylene-exposed workers generally had lower levels of B and T lymphocytes but not of granulocytes, platelets, or monocytes. These data suggest that trichloroethylene exerts a specific effect on lymphoid progenitor cell division or maturation. However, reduced CD4 T cells reflect immunosuppressive effects that could impair control over inflammation and increase B cell activation. Autoimmune effects in humans, in particular, are consistent with the hypothesized mechanisms of action linking severe immune dysregulation and NHL. It is quite possible that the observed immunologic effects of trichloroethylene are reflective of other poorly understood mechanisms that increase the risk of malignant transformation of B cells.

The data show that trichloroethylene is immunomodulatory in rodents (see Section 5.2.2.2). Several studies in MRL+/+ mice suggested that oxidative and nitrosative stress from reactive oxygen and nitrogen species may contribute to the autoimmune response (Khan et al. 2001; Wang et al. 2007a; Wang et al. 2007b; Wang et al. 2008; Wang et al. 2012b; Wang et al. 2013; Wang et al. 2009a). Reactive oxygen and nitrogen species have been implicated in the pathogenesis of several autoimmune diseases including systemic lupus erythematosus (Wang et al. 2007b). Other studies with MRL+/+ mice demonstrated that trichloroethylene metabolites also formed immunoreactive protein adducts resulting in antibody formation (Cai et al. 2007a; Cai et al. 2007b; Cai et al. 2006; Griffin et al. 2000a; Griffin et al. 2000b; Griffin et al. 2000c; Halmes et al. 1996; Halmes et al. 1997; Khan et al. 1995). Metabolic activation by CYP2E1 was at least partially responsible for the autoimmune response (Griffin et al. 2000b).

### 5.2.4 Summary

Severe immune dysregulation, whether from immunosuppression, inflammation, or autoimmune disease, is associated with an increased risk of NHL. Thus, it is biologically plausible that the mode of action of trichloroethylene-induced NHL could involve altered immunity. However, no human or animal studies directly investigated the possible relationship between trichloroethylene exposure, immunomodulation, and lymphoproliferative disorders and some of the data were not consistent with the proposed mechanisms. Use of other activation markers (e.g., CD23, CD27, CD30, CD44, and CXCL13) might have allowed for a more complete assessment of B cell response. Although few applicable studies were conducted in humans, the available data provide evidence that trichloroethylene can alter the immune system based on some studies finding an association between markers of immune modulation and other studies showing an association with autoimmune disease (e.g., systemic sclerosis). Studies in MRL+/+ mice show that trichloroethylene accelerates lupus conditions. Possible key events demonstrated in mice (mostly in strains predisposed to autoimmune disease) include lipid peroxidation, CYP2E1 metabolism to reactive metabolites, formation of immunoreactive protein adducts, formation of antibodies against the adducted proteins, autoimmune response via cross-reaction of antibodies to non-adducted (normal “self”) proteins, and chronic inflammation. Chronic inflammation is a known risk factor for tumor promotion and progression. However, the available data are insufficient to demonstrate that immunomodulation is operant as a mode of action for trichloroethylene-induced NHL.