# 4 Kidney Cancer

The previous sections of the cancer evaluation component contain relevant information—ADME (Section 1), genetic and related effects (Section 2), and overview and assessment of the quality of the human cancer studies (Section 3)—that are important for several of the three cancer endpoints of interest. This section builds on that information and evaluates the human cancer studies (Section 4.1) and mechanistic data (Section 4.2) specifically for kidney cancer.

## 4.1 Human Cancer Studies

Kidney cancer is considered to be uncommon; the age-adjusted annual kidney cancer (kidney and renal pelvis) rates (per 100,000 males or females) in the United States from 2007 to 2011 (SEER 2014a) were approximately 21.2 (male) and 10.6 (female) for incidence and 5.8 (male) and 2.6 (female) for mortality, with a five-year survival rate of approximately 70%, suggesting that incidence data may be more informative than mortality data. The incidence rate of kidney cancer has been increasing for several decades in the United States from an incidence rate of approximately 7 per 100,000 in 1975 at a rate of approximately 2% per year over the past decade, while death rates have declined slightly by approximately 0.6% per year. Incidence rates and trends in the European countries (Ferlay et al. 2014; Ferlay et al. 2013) in which the remainder of the studies were conducted are broadly similar to those in the United States. For example, age-standardized incidence rates in the United Kingdom in 2011 (Cancer Research U.K. 2014a) were approximately 16 per 100,000 (male) and 9 per 100,000 (female), with an increase in the combined U.K. male and female incidence rate from approximately 5 per 100,000 in 1975 to 12.3 per 100,00 in 2011, representing a rate of increase of approximately 3% per year over the decade from 2001 to 2011. Latencies for solid tumors such as kidney cancer are generally estimated to exceed approximately 20 years but may vary considerably. Incidence rates generally increase sharply after approximately 50 years of age. Case-control studies of trichloroethylene and kidney cancer are of renal-cell carcinoma, which makes up approximately 90% of all kidney cancers, whereas most of the cohort studies are of combined (renal, pelvis and/or ureter) kidney cancer.

For each of the reviewed studies, summary data on study design, methods, and findings, systematically extracted from relevant publications as described in the study protocol, are presented in Table D-2. The evaluation of study quality, including methods of exposure and cancer endpoint assessment, and other elements related to the ability to inform the cancer hazard assessment (such as study sensitivity) is reported in Table D-4, Table D-5, Table D-6, and Table D-7. Section 3 provided an overview of the study population characteristics and methods and a discussion of the utility of the studies. Figure 4-1 (below) provides an overview of the conclusions from that evaluation and identifies the most informative studies based on the overall utility of the study.

Figure 4-1

Study Utility Ranking: Kidney Cancer

E/R = exposure response.

Gray shading (left-hand column): Utility to inform hazard evaluation; light shading = highest utility; dark shading = lowest utility. Blue shading (right-hand column): Potential bias and study sensitivity; light shading = least biased or most sensitive; dark shading = overall potential biases towards the null or lower sensitivity.

^a^(Tan shading): Multiple limitations; overall direction of potential biases is unknown.

^b^(Peach shading): Most potential biases away from the null.

This section summarizes and interprets the findings for kidney cancer from the individual epidemiological studies brought forward for evaluation and integrates the evidence across studies. The key questions for evaluating the level of evidence across the body of studies is whether there is credible evidence of an association between trichloroethylene exposure and kidney cancer, and if so, could it be explained by chance, bias, or confounding. Several of the considerations developed by Austin Bradford Hill (Hill 1965) are relevant to the evaluation of the level of evidence for human carcinogenicity, including the magnitude (strength) and consistency of any observed associations across studies; evidence for exposure-response relationships and associations with appropriate latency; and the degree to which chance, bias, and confounding could plausibly explain observed associations. The level of evidence conclusion for the carcinogenicity of trichloroethylene from studies in humans is provided in Section 7.

### 4.1.1 Study Findings

This cancer hazard evaluation reports on the latest update of a cohort or case-control study and meta-analyses and includes any additional relevant data (e.g., analyses or exposure information) from previous publications. The available studies that reported on kidney cancer and trichloroethylene exposure and were considered to be adequate for inclusion in the evaluation include 12 cohort or nested case-control studies and 7 population-based case-control studies. (Two cohort studies of uranium processing workers (Bahr et al. 2011; Ritz 1999) did not report on kidney cancer and exposure specifically to trichloroethylene.) In addition, three recent meta-analyses were identified and are included in the evaluation. The findings of the individual studies are discussed below and presented in Table 4-1 and Table 4-2. Although the database consists of many reasonably well-conducted studies, some of which are large, in the majority of studies few workers were exposed to high levels of trichloroethylene with reasonable confidence of exposure. Thus, most studies had limited statistical power to evaluate a modest risk of kidney cancer (if it exists) from exposure to trichloroethylene and exposure-response relationships. Statistical power was limited in the cohort studies, in part, because kidney cancer is uncommon or exposure levels were low in the larger studies, and in case-control studies because trichloroethylene exposure prevalence was low and exposure levels in the general population studies were most likely lower than the cohort studies. These studies may not be sensitive to detect effects that are due to high exposures. In addition, a major limitation of the studies was non-differential exposure misclassification, which would most likely bias the findings toward the null. The case-control study by Vamvakas et al. (1998) and the cohort study by Henschler et al. (1995) had methodological concerns that may potentially bias the findings away from the null.

Table 4-1 Trichloroethylene Cohort and Nested Case-control Studies: Findings for Kidney Cancer^a^

Reference | Study Size (N) Exposure Assessment | Exposure Groups | External Analysis SMR, SIR (95% CI) # Cases/Deaths | Internal Analysis: HR, RR, SRR, or OR (95% CI) # Exposed Cases/Deaths | Interpretation
Nordic studies
Vlaanderen et al. (2013) | 5 Nordic countries Record linkage of cancer registry with census questionnaire M: 44,708 cases, 223,540 controls F: 31,422 cases, 157,110 controls Semi-quantitative JEM | Cumulative exposure (unit-years) 0 0.04 0.13 0.72 High-exposure group [underlined: Cumulative] Men Women [underlined: Intensity × prevalence] Men Women | | HR (incidence) 1.00 1.01 (0.95–1.07); 1,217 1.02 (0.97–1.08); 1,556 1.00 (0.95–1.07); 1,372 0.92 (0.77–1.09); 159 0.92 (0.77–1.09); 92 1.10 (0.97–1.25); 297 0.78 (0.62–0.97); 9 | Low prevalence of exposure (TCE) and exposure levels likely to be low Matching criteria: Age, country, sex Strengths: Long follow-up, large numbers of cases Limitations: Misclassification of exposure likely; JEM had poor sensitivity and did not account for heterogeneity within jobs and over time Null: No evidence for a positive association but limited utility due to low exposure levels and exposure misclassification
Hansen et al. (2013) (Potential overlap with Raaschou-Nielsen et al. (2003)) | Pooled and updated Nordic cohorts Axelson et al. (1994), Anttila et al. (1995), Hansen et al. (2001) 5,553 (3,776 M, 1,777 F) Biomonitoring (U-TCA) | All exposed subjects 0-yr lag 10-yr lag 20-yr lag U-TCA (mg/L) <5 5–25 25–50 >50 p_trend_ | SIR 1.01 (0.70–1.42); 32 1.04 (0.71–1.50); 30 1.11 (0.67–1.73); 19 | HRR (no lag); incidence 1.0 (Ref); 9 1.12 (0.46–2.70); 11 0.81 (0.21–2.97); 3 2.04 (0.81–5.17); 9 0.19 | Low exposure levels for most workers (only 20% exposed to ≥20 ppm) and short duration of employment Covariates: Age, sex, calendar period, country; indirect consideration of smoking and alcohol consumption Strengths: Biomonitoring data; large numbers of workers ever exposed Limitations: Only 2 or 3 U-TCA measurements per individual and unlikely to estimate lifetime or cumulative exposure; low statistical power for evaluating modest risks; limited ability to evaluate exposure-response relationship Limited evidence for a positive association: Statistically non-significant, moderately elevated effect estimate in the highest exposed group
Raaschou-Nielsen et al. (2003) (Potential overlap with Hansen et al. (2013)) | Danish blue-collar workers 40,049 M+F (approx. 70% M) Working at TCE company; size of company surrogate for TCE exposure prevalence | Subcohort: higher exposed [underlined: Lag time (yr)] 0–9 10–19 ≥20 [underlined: Duration employment (yr]) 1–4 ≥5 [underlined: Yr. of 1st employment] Before 1970 1970–1979 | SIR 1.4 (1.0–1.8); 53 0.9 (0.3–1.8); 6 1.5 (0.9–2.2); 22 1.6 (1.0–2.3); 25 1.1 (0.7–1.7); 23 1.7 (1.1–2.4); 30 1.9 (1.4–2.6); 41 0.7 (0.4–1.2); 12 | | Higher levels of TCE prior to 1970 (40–60 ppm); low levels of exposure after that time Covariates: Age, sex, calendar year Strengths: Large numbers of exposed cases; subcohort of subjects with higher exposure potential Limitations: Young cohort, possible selection bias for difference in SES, external analysis only; possible exposure misclassification Evidence for a positive association: Statistically significant, moderately elevated effect estimates; some evidence for exposure-response relationship unlikely to be explained by confounding by smoking or differences in SES
Aerospace and aircraft workers
Lipworth et al. (2011) (update of Boice et al. (1999)) | Burbank, CA (USA) aircraft manufacturing workers 5,443 (approx. 80% M) Qualitative JEM Individual work histories | TCE TCE: years exposed 0 <1 1–4 5+ p_trend_ | SMR 0.66 (0.38–1.07); 16 | RR (mortality) 1.00; 33 0.52 (0.21–1.30); 6 0.42 (0.13–1.42); 3 0.85 (0.33–2.19); 6 0.20 | Exposure levels not reported; exposure duration likely to be short Covariates: Age, date of birth, date of hire, termination date, sex, and race Strengths: Long follow up, adequate number of deaths for ever exposure Limitations: Evidence of HWE, few exposed deaths in subgroup analysis; exposure misclassification is a concern; no evaluation of exposure intensity, 70% had exposure to mixed solvents Null: No evidence for a positive association but limited utility (limitations are mainly towards the null)
Radican et al. (2008) (mortality to 2000) Blair et al. (1998) (incidence 1973–1990) | Utah (USA) aircraft maintenance workers 7,204 (6,153 M, 1,051 F) Semi-quantitative JEM; Individual work histories | Mortality Ever-exposed (M & F) 1990 follow-up 2000 follow-up Only 2 cases in females Males only 2000 follow-up [underlined: Cumulative exp. (unit-yr)] All 0–5 5–25 >25 [underlined: Exposure pattern] Low intermittent Low continuous Peak infrequent Peak frequent Incidence 1990 follow-up [underlined: Cumulative exp. (units-yr)] None 0–5 2–25 >25 | | HR (mortality) 2.3 (0.6–8.4); 15 1.18 (0.47–2.94); 18 1.24 (0.41–3.71); 16 1.87 (0.59–5.97); 10 0.31 (0.03–2.75); 1 1.16 (0.31–4.32); 5 1.58 (0.52–4.76); 15 1.79 (0.57–5.62); 11 1.04 (0.19–5.70); 2 1.11 (0.31–3.96); 6 RR (incidence) 1.6 (0.5–5.4); 9 1.4 (0.4–4.7); 9 1.3 (0.3–4.7); 5 0.4 (0.1–2.3); 2 | Estimated exposure: Most workers exposed to low levels (~10 ppm), modest number of workers exposed to higher levels (~100 ppm) Covariates: Age, calendar year, race, and sex Strengths: Adequate semi-quantitative JEM, long follow-up, adequate statistical power for ever exposure Limitations: Potential for exposure misclassification because of missing information for some workers; limited power due to low numbers of higher exposed workers; long follow-up time (45 years) may be past induction time Null: Small increase in effect estimate but limited utility due to limited statistical power
Boice et al. (2006) (Overlaps with Zhao et al. (2005)) | Los Angeles, CA (USA) Rocket engine testing workers 1,111 Men Qualitative JEM; Individual work histories | Ever exposed Exposure to TCE during engine flush (test-yr) Referent (other depts.) 0 <4 ≥4 p_trend_ | SMR 2.22 (0.89–4.57); 7 | RR (mortality) 1.00; 28 1.21 (0.33–4.35); 3 2.51 (0.27–23.5); 1 3.13 (0.74–13.2); 3 0.59 | Exposure occurs during test engine flush, which is likely to be high Covariates: Date of birth, year of hire, pay type (surrogate for SES), and exposure to hydrazine Strengths: Adequate follow-up Limitations: Qualitative exposure assessment; few exposed deaths Limited evidence for a positive association: Statistically non-significant elevated effect estimate among highest exposed group
Zhao et al. (2005) Overlap with Boice et al. (2006) | Los Angeles, CA (USA) Male aerospace workers 6,044 (mortality) 5,049 (incidence) Semi-quantitative JEM; individual work history | All analyses: 3 levels TCE cumulative exposure score Co-exp. Unadj.; 0-yr lag Low Medium High p_trend_ Co-exp. Adj.; 0-yr lag Low Medium High p_trend_ Similar RR for 20-yr lag adj. model Co-exp. Unadj. 0-yr lag Low Medium High p_trend_ Co-exp. Adj. 20-yr lag Low Medium High p_trend_ No association in co-exp adj. 0-yr lag | | RR (incidence) 1.00; 6 1.87 (0.56–6.20); 6 4.90 (1.23–19.6); 4 0.023 1.00; 6 1.26 (0.26–6.14); 6 7.71 (0.65–91.4); 4 0.103 RR (mortality) 1.0; 7 1.43 (0.49–4.16); 7 2.03 (0.50–8.32); 3 0.307 1.00; 10 1.69 (0.29–9.70); 6 1.82 (0.09–38.6); 1 0.635 | Exposure levels not reported but presumed to be high Covariates: All models—time since first employment, SES, age at event—additional analysis adjusted for co-exposure to carcinogenic chemicals Strengths: Semi-quantitative exposure assessment; multivariate analysis evaluating exposure-response relationships adjusting for co-exposures Limitations: Few cases in subgroup analyses Evidence for a positive association: Statistically significant, high effect estimates; evidence of exposure-response relationship; unlikely to be explained by confounding by co-exposures
Morgan et al. (1998) | Arizona (USA) Aircraft manufacturing workers 4,733 (2,555 M, 2,178 F) Semi-quantitative JEM; individual work history | All TCE-exposed workers Cumulative exp. score Low (2,357) High (2,376) Peak (med/high) vs. low/no | SMR (All) 1.32 (0.57–2.60); 8 0.47 (0.01–2.62); 1 1.78 (0.72–3.66); 7 | RR (mortality) 1.14 (0.51–2.58); 8^b^ 0.31 (0.04–2.36); 1 1.59 (0.68–3.71); 7 1.89 (0.85–4.23); 8 | High-exposure jobs were considered to be ≥50 ppm Covariates: Age at hire, gender (decade of hire considered but no effect) Strengths: Long follow-up and semi-quantitative exposure Limitations: Evidence of an HWE; potential exposure misclassification among low/medium exposure groups; mortality analysis and few exposed deaths Limited evidence for a positive association: Statistically non-significant elevated effect estimate among the highest exposed group
Other occupational studies
Silver et al. (2014) | New York State (USA) micro-electronics manufacturing workers cohort mortality 3,113 TCE exposed Semi-qualitative JEM | 5 modified exposure years (exposure duration modified by exposure potential); 10-yr lag | | 1.24 (0.87–1.77); NR | Exposure levels NR; only 13.9% of cohort exposed Covariates: Paycode and sex, age. Variables considered in analyses but which did not change risk estimate were birth cohort, time since last exposure (healthy worker survival), hire era, and employment duration prior to 1966 Limitations: Evidence of HWE, Exposure classification based on potential exposure and duration; only one cumulative exposure variable reported in analysis. Young cohort with only 17% deaths Limited evidence for a positive association: Non-statistically significant elevated effect estimate
Henschler et al. (1995) | German cardboard manufacturing cohort 169 exposed men 190 unexposed men Individual work history | Rates 1956–1993 Denmark 1956–1993 Germany 1956–1992 Denmark 1956–1992 Germany Cases within follow-up Cases outside of follow-up | SIR 11.15 (4.49–23.00); 7 13.53 (5.44–27.89); 7 7.97 (2.59–8.59); 5 9.66 (3.14–22.55); 5 | Mantel-Haenszel test 7.15 (NR); 7: p = 0.005 5.35 (NR); 5: p = 0.014 (no cases observed in unexposed group) | Qualitative evidence of high TCE exposure (Estimated >2,000 ppm for peak exposure and >100 ppm for sustained long-term exposure). Long exposure periods (17.8 months) Covariates: Age Strengths: Detailed information on plant conditions with evidence of high exposure, misclassification unlikely Limitations: Possible selection bias (original cluster investigation) Evidence for a positive association: Statistically significant, high, elevated effect estimates: likely an overestimate of the risk estimate, however, unlikely that biases would nullify the association.
Greenland et al. (1994) (nested case-control) | Massachusetts (USA) electrical manufacturers N = 12 cases (exposed controls NR) | Ever exposure | | OR (cases) 0.99 (0.30–3.32); NR | Only 10% of jobs had exposure to TCE, most of which were from indirect exposure Covariates: Age, date of death, covariates that changed risk estimate by 20%. Limitations: Small numbers of cases and controls and short follow-up, possible selection bias, low quality exposure assessment Null: No evidence of an association but limited utility (limitations are mainly towards the null)
Environmental exposure
Bove et al. (2014) | North Carolina (USA) (Camp Lejeune) 154,932 men and women | TCE in drinking water (μg/L-month) <1 (43%) >1–3,100 (20%) >3,100–7,700 (18%) >7,700–39,745 (20%) | | HR (Mortality); 10-yr lag 1.0; 13 1.54 (0.65–3.61); 11 1.21 (0.47–3.09); 8 1.52 (0.64–3.61); 11 | Estimated mean levels (μg/L-month) TCE from water supply = 358.7; overall cumulative exposure = 6,369 (median) and 5,289 (mean); 20% were exposed to levels between 7,700 and 39,745 Covariates: sex, race, rank, and education; other variables considered in the model (did not change risk estimates by 10%) include marital status, birth cohort, date of death, duty occupation Strengths: Large cohort and adequate modeling of exposure Limitations: Young cohort; no information on individual water consumption; potential confounding from other contaminants, e.g., tetrachloroethylene Limited evidence for a positive association: Statistically non-significant elevated effect estimates

CI = confidence interval; F = female; HR = hazard ratio; JEM = job-exposure matrix; M = male; NR = not reported; OR = odds ratio; RR = relative risk; SIR = standardized incidence ratio; SMR = standardized mortality ratio; SRR = standardized rate ratio; TCA = trichloroacetic acid; TCE = trichloroethylene; U-TCA = urine trichloroacetic acid.

^a^ Within each category, studies are generally organizing by descending publication date.

^b^ As reported by Scott and Jinot (2011).

Table 4-2 Case-control Studies of Trichloroethylene Exposure: Findings for Kidney Cancer

Reference | Study Size (N) Exposure Assessment | Exposure Groups | RR or OR (95% CI) # Exposed Cases/Controls | Interpretation
Studies in specific areas with knowledge of local industries
Moore et al. (2010) | Central/Eastern Europe Hospital based 1999–2003 1,097 cases RCC 1,476 hospital controls Expert assessment based on occupational data from interviews | High confidence assessments No TCE exposure Ever TCE exposure [underlined: Years TCE Exposure] <13.5 ≥13.5 p_trend_ [underlined: Hours TCE Exposure] <1,080 ≥1,080 p_trend_ [underlined: Cumulative (ppm-yr]) <1.58 ≥1.58 p_trend_ [underlined: Average intensity (ppm)] <0.076 ≥0.076 p_trend_ TCE exposure stratified by GSTT1 [underlined: GSTT1 null] No Yes Duration (years) Hours Cumulative exposure Average exposure | OR 1.00; 777/1,144 2.05 (1.13–3.73); 29/19 1.89 (0.84–4.28); 15/10 2.25 (0.95–5.29); 14/9 0.02 1.22 (0.48–3.12); 9/9 2.86 (1.31–6.23); 20/10 0.01 1.77 (0.64–4.80); 9/7 2.23 (1.07–4.64); 20/12 0.02 1.73 (0.75–4.02); 13/10 2.41 (1.05–5.56); 16/9 0.02 1.0; 119/149 0.93 (0.35–2.44) [underlined: p_trend_] 0.41 0.95 0.75 1.0 | Intensity and prevalence of occupational exposure have been higher in Central and Eastern Europe than other industrial areas Covariates: Age, sex, center; residence, smoking, BMI, and history of hypertension considered but did not affect risk estimate Strengths: Analysis of high confidence assessment reduces potential for exposure misclassification. Large number of exposed cases and controls in overall and subanalysis Limitations: Potential for selection bias Evidence for a positive association: Statistically significant, moderately elevated effect estimates; evidence of exposure-response relationship; unlikely to be explained by biases or confounding Increased risks of cancer among subjects with an active GSTT1 allele but not with GSTT1 null genotype is consistent with proposed mechanism of carcinogenicity
Moore et al. (2010) | Central/Eastern Europe Hospital based 1999–2003 1,097 cases RCC 1,476 hospital controls Expert assessment based on occupational data from interviews | [underlined: GSTT1 Active] No Yes Duration (years) Hours Cumulative exposure Average exposure | 1.0; 466/729 1.88 (1.06–3.33); 23 [underlined: p_trend_] 0.03 0.02 0.01 0.02
Charbotel et al. (2006); Charbotel et al. (2009) | Arve Valley, France 86 RCC cases 326 hospital controls Expert assessment, semi-quantitative JEM | 2006 analysis Non-exposed (ever) Ever exposed High confidence (Model 1) [underlined: Cumulative dose] Non-exposed Low Medium High [underlined: Cumulative exp. + peaks] Non-exposed Low/medium no peaks Low/medium + peaks High no peaks High + peaks All workers High cum. dose (Model 1) High cum. dose (Model 2) High + peaks (Model 1) High + peaks (Model 2) 2009 analysis: combined effects TCE & cutting oil (Model 2) [underlined: Cutting oil/TCE] No/No Yes/No No/Yes Yes/<50 ppm Yes/≥50 ppm | OR 1.00; 44/188 1.88 (0.89–3.98); 16/37 1.00 0.85 (0.10–7.41); 1/8 1.03 (0.29–3.70); 4/13 3.34 (1.27–8.74); 11/16 1.00; 44/188 0.90 (0.27–3.01); 4/18 1.34 (0.13–14.02); 1/3 2.74 (0.66–11.42); 4/8 3.80 (1.27–11.40); 7/8 2.16 (1.02–4.60); 16/37 1.96 (0.71–5.37) 2.73 (1.06–7.07); 8/14 2.63 (0.79–8.83) 1.00; 46/200 2.39 (0.52–11.03); 3/6 1.62 (0.76–3.44); 15/46 1.14 (0.49–2.66); 12/47 2.70 (1.02–7.17); 10/17 | High intensity of exposure and high exposure prevalence. Screw cutting industry. Estimated TCE intensities for high exposure jobs were 300–600 ppm Covariates: (Model 1) Sex, age, smoking, BMI; (Model 2) sex, age, cutting oils, petroleum oils, and/or other mineral oils. No significant difference between cases and controls in a number of medical history-related factors Strengths: Good exposure assessment and consideration of co-exposures Limitations: Small number of exposed cases and controls in subgroup analyses Evidence for a positive association Statistically significant, moderately elevated effect estimates; evidence of exposure-response relationship; unlikely to be explained by confounding
Brüning et al. (2003) (no overlap with Vamvakas et al. (1998)) | Germany regional (Arnsberg) hospital-based 134 cases (83 M, 51 F) 401 hospital controls (225 M, 176 F) Self-assessed exposure including self-reported narcotic symptoms, JEM based on CAREX database (job titles) or British JEM for grouped solvents | CAREX Database Longest held job with TCE/Perc exposure (compared with no TCE) Any metal greasing/degreasing Self-assessed TCE exposure Ever [underlined: Exposure + Narcotic symptoms] Any Non-daily occurrence Daily occurrence [underlined: Duration exposure (yr]) No exposure <10 10–19 20+ [underlined: Time since 1st exp (yr)] No exposure 5–9 10–19 20+ No increasing risks with time since last exposure | OR 1.80 (1.01–3.20); 117/316 5.57 (2.33–13.32); 15/11 2.47 (1.36–4.49); 25/38 3.71 (1.80–7.54); 19/18 4.60 (1.87–11.30); 13/10 5.91 (1.46–23.99); 5/4 1.00; 109/363 3.78 (1.54–9.28); 11/14 1.80 (0.67–4.79); 7/13 2.69 (0.84–8.66); 6/7 1.00; 109/363 3.21 (0.28–37.38); 1/2 1.50 (0.28–8.10); 2/6 2.86 (1.49–5.49); 22/27 | Very high exposure and long exposures; estimated exposure 400 to 600 ppm during peak (hot dipping) and >100 ppm overall (Cherrie et al. 2001). Approx. 50% cases >10 years’ exposure Covariates: Sex, age, smoking; cases and controls had similar BMI Strengths: Appears reasonable that workers with self-reported exposure had high levels of exposure and exposure to other chlorinated solvents was unlikely Limitations: Qualitative exposure assessment; possible selection bias Evidence for a positive association: Statistically significant, high effect estimates; unlikely to be explained by confounding
Vamvakas et al. (1998) | Germany regional hospital-based 58 RCC cases 84 hospital controls Expert assessment based on severity of pre-narcotic symptom and exposure duration using occupational history data from interviews | Ever TCE exposure TCE exposure categories No TCE exposure Low TCE exposure Medium TCE exposure High TCE exposure | OR 10.80 (3.36–34.75); 19/7 1.00; 39/77 6.61 (0.50–87.76); 2/2 11.92 (2.55–55.60); 9/3 11.42 (1.96–66.79); 8/2 | High level of exposure [see Brüning et al. (2003)] Mean duration of exposure: 16 years cases, 7 years controls Covariates: Age, sex, smoking, BMI, blood pressure, and diuretic intake Strengths: High level of confidence that workers had high level of exposure and exposure to other chlorinated solvents was unlikely Limitations: Potential selection bias (differential) away from the null Evidence for a positive association: Statistically significant, high effect estimates; unlikely to be explained by confounding or co-exposures; potential for biases would lead to an over-estimate of the risk estimate
Other occupational studies
Christensen et al. (2013) | Montreal, Québec (Canada) Population- and hospital-based 1975–1985 177 male RCC cases RCC 533 population-based controls 1999 cancer controls Expert assessment of occupational data from interviews | Ever exposure Substantial exposure | OR (95%CI) #cases/#cancer controls/#population controls 0.9 (0.4–2.4); 5/63/15 0.6 (0.1–2.8); 2/34/9 | Exposure prevalence to TCE very rare; ≤2% of cancer controls or population controls had substantial exposure and 3% had any exposure Covariates: age, census tract, median income, ethnicity, self vs. proxy respondent, smoking, alcohol consumption, coffee use, education Strengths: Adequate quality of exposure assessment Limitations: Low exposure prevalence resulting in low statistical power Null: No evidence for a positive association but limited utility
Pesch et al. (2000b) | Germany Cancer registry study 935 (570 M, 365 F) RCC cases 4,298 (2,650 M, 1,648 F) registry control JEM and JTEM | JTEM Men No exposure Medium TCE exposure High TCE exposure Substantial TCE exposure Women No exposure Medium TCE exposure High TCE exposure Substantial TCE exposure | (Controls not reported) OR 1.00 1.3 (1.0–1.8); 68 1.1 (0.8–1.5); 59 1.3 (0.8–2.1); 22 OR 1.00 1.3 (0.7–2.6); 11 0.8 (0.4–1.9); 7 1.8 (0.6–5.0); 5 | Prevalence of substantial TCE exposure was low among cases and varied by type of JEM Covariates: Age, center, and smoking. Cases and controls did not differ in BMI, education, age, region, and smoking status and analgesics use Strengths: Adequate number of exposed cases and controls Limitations: Potential for exposure misclassification Limited evidence for a positive association: Non-statistically significant elevated effect estimates
Dosemeci et al. (1999) | Minnesota (USA) Registry-based 1988–1999 438 living cases RCC (273 M, 165 F); 687 population controls Qualitative JEM based on occupational data from interviews | Men Women Total | 1.04 (0.6–1.7); 33 (controls NR) 1.96 (1.0–4.0); 22 (controls NR) 1.30 (0.9–1.9); 55 (controls NR) | Exposure prevalence to TCE among controls was 13% Covariates: Age, sex, smoking, BMI, hypertension, use of diuretics or hypertension drugs Strengths: Adequate number of exposed cases Limitations: Exposure assessment only considered current and usual jobs, no assessment of intensity or duration of exposure Limited evidence for a positive association: Moderate (borderline statistical significance) elevated effect estimate among women only

BMI = body mass index; Cum. = cumulative; Exp. = exposure; JEM = job exposure matrix; JTEM = job task exposure matrix; NR = not reported; OR = odds ratio; ppm = parts per million; RCC = renal cell carcinoma; RR = relative risk; TCE = trichloroethylene.

The findings of the individual studies are discussed below and presented in Table 4-1 and Table 4-2.

#### 4.1.1.1 Cohort and Nested Case-control Studies

The available cohort studies include three studies conducted in Nordic countries, five cohorts of aerospace and aircraft workers, a cohort study of cardboard manufacturing workers, a nested case-control study of electronic workers and a cohort of military personnel exposed to trichloroethylene in drinking water. An overview of the ability of the studies to inform the cancer hazard evaluation is shown in Figure 4-1 and details are presented in Section 3 and Appendix D.

##### Nordic Studies

These studies consist of a pooled analysis of biomonitored workers (Hansen et al. 2013), a cohort study of blue-collar workers at companies using trichloroethylene (Raaschou-Nielsen et al. 2003), and a large population-based cancer registry study (Vlaanderen et al. 2013). The studies included subjects with occupational exposure to trichloroethylene from diverse industries, and workers and exposed subjects who were identified from broad occupational or population-based databases. Both the cohort study of blue-collar workers (Raaschou-Nielsen et al. 2003) and the updated and pooled analysis of three cohort studies of biomonitored workers in Sweden, Finland, and Norway (Hansen et al. 2013) provide some evidence of an association of exposure to trichloroethylene and kidney cancer. In the former study, statistically significant (or approaching significance) increased risks of renal-cell cancer incidence were found among all workers (SIR = 1.4, 95% CI = 1.0 to 1.8, 53 exposed cases), workers with longer lag time (SIR = 1.6, 95% CI = 1.0 to 2.3, 25 exposed cases), and workers employed before 1970 (SIR = 1.9, 95% CI = 1.4 to 2.6, 41 exposed cases). Air monitoring data indicated that trichloroethylene levels were much higher (40 to 60 ppm) prior to 1970. Strengths of this study were its large size and analysis of long-term exposure using duration of exposure and calendar period as surrogates. Although the study was limited by its use of crude exposure surrogates (blue-collar workers, duration of employment), exposure misclassification was probably lower among the higher exposed subcohort than the total cohort. In the pooled analysis of biomonitored workers (Hansen et al. 2013), a statistically non-significant increase in risk of kidney cancer (hazard rate ratio [HRR] = 2.04, 95% CI = 0.81 to 5.17; 9 exposed cases) was found among the highest exposed workers with urinary trichloroacetic acid (U-TCA) levels >50 mg/L (estimated as equivalent to 20 ppm) but not among ever-exposed workers. Although this study was a large, well-conducted study, only 20% of the workers were exposed to levels >20 ppm and estimated exposures for most of the workers were between 4 and 12 ppm. There was also a lack of specificity and possible misclassification of exposure, in part because some of the population was exposed to tetrachloroethylene, which is also metabolized to trichloroacetic acid (Anttila et al. 1995). In addition, most workers only had one to three U-TCA measurements over their entire work history and no information was available on lifetime cumulative exposure (Hansen et al. 2013).

No association between trichloroethylene exposure and kidney cancer was found in the large population-based study by Vlaanderen et al. (2013). Exposure to trichloroethylene was likely low in the study, and exposure misclassification (non-differential) was considered to be substantial because of lack of detailed occupational information (tasks, working conditions), heterogeneity of exposure levels within and across jobs with the same job title, and overtime, and use of a JEM that may not be country specific. These limitations would bias the findings towards the null.

##### Aerospace or Aircraft Manufacturing Workers

These studies include two overlapping, but with different exposure assessments, cohorts of rocket engine workers (Boice et al. 2006; Zhao et al. 2005) and three studies of aircraft manufacturing workers in Burbank, California (Lipworth et al. 2011), Utah (Blair et al. 1998; Radican et al. 2008), and Arizona (Morgan et al. 1998). Taken together, the studies of the rocket engine workers provide evidence of an association between trichloroethylene exposure and renal-cell cancer, with the strongest evidence coming from the Zhao et al. study, which was considered to be a highly informative study based on a semi-quantitative exposure assessment and evaluation of exposure-response relationships for both cancer incidence and mortality in models that adjusted for co-exposure to other chemicals. In this study, the risk of kidney cancer increased with increasing cumulative exposure in both adjusted and unadjusted models (although the trend was only statistically significant in the unadjusted model (p = 0.023) with risks ranging from 5-fold (unadjusted) to 7-fold (adjusted) in the highest exposure category. Statistical power was most likely reduced in the adjusted models. Similar patterns of increasing risks were also observed for kidney cancer mortality, although the magnitudes of the risk estimates were lower as might be expected since mortality is a less informative outcome measure than incidence. The study by Boice et al. (2006) (using a qualitative JEM) found a three-fold, statistically non-significant increased risk among workers with the longest exposure to trichloroethylene during engine flush and support the findings by Zhao et al. (2005), although this may not be independent evidence. Although exposure levels were not reported, the potential for high exposure to trichloroethylene during this task was much higher than during other tasks, such as the use of trichloroethylene as a utility solvent, according to the authors.

Among the studies of aircraft manufacturing workers, the mortality study of Arizona workers (Morgan et al. 1998) found statistically non-significant increased risks for kidney cancer among workers with the highest cumulative exposure (RR = 1.59, 95% CI = 0.68 to 3.71, 7 exposed deaths) and with high peak exposure (RR = 1.89; 95% CI = 0.85 to 4.23, 8 exposed deaths) with some evidence of increasing risks with increasing exposure. Statistical power was limited due to few exposed subjects in the high-exposure categories. Exposure intensity for the highest exposed workers was estimated to be ≥50 ppm. Findings were null in the other two studies. Radican et al. (2008) found small non-statistically significant elevated risks in some subgroup analyses of the Utah workers but no evidence of an exposure-response gradient. Risks were less than unity in the internal and external analyses in the study of California workers by Lipworth et al. (2011). These studies had limited statistical power to detect a small excess in risk based on few workers with higher or longer exposure, and the study by Lipworth et al. (2011) had a higher potential for non-differential exposure misclassification. Although exposure levels were not reported, the NRC (2006) estimated that a modest number of the Utah workers (Radican et al. 2008) were exposed to higher levels (approximately 100 ppm) but that most workers were exposed to low levels of trichloroethylene. There was evidence of a healthy worker effect in two of the aircraft manufacturing studies (Lipworth et al. 2011; Radican et al. 2008) and the aerospace worker study by Boice et al. (2006), which would bias external analyses towards the null. In addition, exposure duration for some workers in the Lipworth et al. (2011) study may have been relatively short for some workers because use of trichloroethylene was discontinued in 1966.

##### Other Mortality Cohort Studies

These studies were generally considered to be less informative (i.e., lower utility to inform the cancer hazard evaluation) than most of the cohort studies of aerospace workers or the Nordic studies. A statistically significant high risk estimate (approximately 8- to 13-fold depending on reference population rates) was observed in the study of cardboard manufacturing workers (Henschler et al. 1995), which may in part reflect selection and diagnostic biases because the study was designed around a cluster and cases of kidney cancer were identified using sonography (the latter would bias the external but probably not the internal analyses). However, the NRC (2006) estimated that the SMR would be approximately 3.2 if the three cases diagnosed in 1990 that represented the original cluster were excluded from the analyses. There was also qualitative evidence that high exposures (estimated peak exposure >2,000 ppm and long-term exposure of >100 ppm) (Cherrie et al. 2001) occurred in this cohort. Silver et al. (2014) reported a hazard ratio [HR] of 1.24 (95% CI = 0.87 to 1.77, 56 exposed deaths) among U.S. microelectronics workers; the cohort was relatively young, with only 17% deaths in the total cohort, and the exposure assessment was limited. No excess risk was found in the nested case-control study of electrical workers (Greenland et al. 1994) which had several methodological limitations and low probability of exposure; only 10% of jobs had exposure to trichloroethylene, most of which was from indirect exposure. Finally, Bove et al. (2014) reported an HR of 1.52 (95% CI = 0.64 to 3.61, 11 exposed deaths) among U.S. military personnel exposed to the highest level of trichloroethylene in their drinking water. The exposure assessment was based on modeled levels and duration at residence and no information on individual water consumption was available. Although follow-up was long, the cohort was relatively young, suggesting additional follow-up might increase statistical power.

#### 4.1.1.2 Population-based Case-control Studies

The case-control studies include four studies conducted in areas with presumably higher levels and prevalence of trichloroethylene exposure using experts with knowledge of the local industry, and three studies of more widespread populations.

##### Studies in Specific Areas with Knowledge of Local Industries

As mentioned in Section 3, two non-overlapping case-control studies (Brüning et al. 2003; Vamvakas et al. 1998) were conducted in Arnsberg, Germany, which is a small geographical area with a large number of companies engaged in metal and electronics work. Trichloroethylene use was widespread and reportedly one of only two solvents (the other was carbon tetrachloride) used in the industry. This is the same geographical area as the German cardboard manufacturing cohort study of renal cancer, although cases do not overlap. A third case-control study (Charbotel et al. 2006; Charbotel et al. 2009) was conducted in the Arve Valley in France, which is an area with a widespread screw-cutting industry that used trichloroethylene as a degreaser. Although population based, the French and German studies have a higher prevalence of subjects with presumably higher levels of trichloroethylene and from more homogenous industries. The fourth study was a multi-center study of renal-cell cancer conducted in four countries in central and Eastern Europe, in regions in which occupational exposure to trichloroethylene was thought to be higher and more prevalent than other industrial areas. Exposure was assessed in each of the different countries by a team of experts with knowledge of industries in their area (Moore et al. 2010). The studies by Brüning et al., Charbotel et al., and Moore et al. are considered to have a greater ability to detect an effect because of greater confidence that most of the subjects classified as exposed were most likely exposed to substantial levels of trichloroethylene (Brüning et al. 2003; Charbotel et al. 2006; Charbotel et al. 2009) or, in the study by Moore et al. (2010), analyses focused on the highest exposed individuals with high probability of exposure. The studies by Charbotel et al. (2006) and Moore et al. (2010) were considered to have the best methodologies.

The study by Charbotel et al. (2006); (2009) is considered to be the most informative because in addition to the advantages stated above, it also evaluated exposure-response relationships and controlled for potential confounding from lifestyle factors and mineral oils, the major co-exposure in this industry, and conducted separate analyses among workers with high confidence of exposure. Kidney cancer risk increased with increasing exposure (no trend reported) with statistically significant risks (approximately 2- to 3-fold) observed among individuals with the highest cumulative exposure and high cumulative exposure together with peak exposure. Exposure levels were considered to be high in this study, ranging up to 300 to 600 ppm for high-exposure jobs.

Strengths of the multi-center study in Central/Eastern Europe (Moore et al. 2010) were its large size and good exposure assessment. In this study, statistically significant risks were found among trichloroethylene-exposed individuals with high confidence exposure assessments (OR = 2.05, 95% CI = 1.13 to 3.73, 29 cases/19 controls). Risk estimates were higher among individuals with longer or higher levels of exposure (both average intensity and cumulative exposure). The authors also evaluated exposure to trichloroethylene and kidney cancer risk stratified by GSTT1 genotypes; a significant increase in risk was observed among those with at least one active allele of the GSTT1 genotype but not among individuals with GSTT1-null genotypes (see Section 4.2). Although there was potential selection bias due to the exclusion of controls with tobacco-related diseases, it can reasonably be ruled out since initial regression analyses of exposure-response relationships examining smoking did not alter the ORs.

Statistically significant high risks were found for exposure to trichloroethylene and renal-cell cancer in the two German studies (Brüning et al. 2003; Vamvakas et al. 1998). Although the exposure assessments were rather limited in both studies and relied on self-reported exposure, there is reasonable confidence that most workers were exposed to trichloroethylene based on detailed information on the exposure settings suggesting high exposure, the presence of narcotic symptoms and use of expert assessment (integrating frequency and severity of symptoms with exposure duration) (see Section 3). The earlier study by Vamvakas et al. reported a much higher risk estimate for any exposure (OR = 10.80, 95% CI = 3.36 to 34.75, 19 cases and 7 controls) than the later study by Brüning et al. (OR = 2.47, 95% CI = 1.36 to 4.49, 25 cases and 38 controls). The higher risk estimate in the earlier study should be viewed with some caution because of the potential for selection and other biases (see Section 3), which would most likely bias towards an overestimation of the risk. However, given the high levels of exposure to trichloroethylene, it seems unlikely that the distortion of the potential biases would nullify the observed positive association. Estimated levels of exposure were high; peak exposures were estimated to be 400 to 600 ppm and long-term exposure to be >100 ppm (Cherrie et al. 2001; NRC 2006). The later study by Brüning et al. (2003) minimized some of the methodological concerns of the Vamvakas et al. study and thus is given greater weight in this evaluation. In the Vamvakas et al. study, there was little evidence of a linear exposure-response relationship, although risks were higher in both the moderate and high exposure categories compared with the lowest exposure category; exposure levels may have been somewhat homogeneous due to exposure from open systems in small spaces. In the Brüning et al. study, a higher risk (compared with any exposure) was found among individuals with daily narcotic symptoms (OR = 5.91, 95% CI = 1.46 to 23.99, 5 exposed cases and 4 controls), which may be a surrogate for exposure intensity. Brüning et al. also used a crude JEM from the United Kingdom to assess exposures in German industries, likely introducing misclassification bias, and found a two-fold increase among workers who held a job with trichloroethylene exposure compared with those who did not.

##### Other Studies

These included population-based case-control studies in Minnesota (Dosemeci et al. 1999) and Germany (five regions) (Pesch et al. 2000b) and a study using both population and hospital controls in Montreal (Christensen et al. 2013). These studies are considered to have more limited ability to inform hazard identification because of limited statistical power (inadequate numbers of exposed subjects), low overall exposure or exposure misclassification. In the Minnesota study, risk approached statistical significance (OR = 1.96, 95% CI = 1.0 to 4.4, 22 cases) among women ever exposed to trichloroethylene but risks were close to unity among men. A small, non-statistically elevated risk was reported in the multi-center German study (Pesch et al. 2000b) and no increase in risk was found among subjects with substantial exposure in the Canadian study, but there were only two exposed cases (Christensen et al. 2013).

### 4.1.2 Meta-analyses: Kidney Cancer

Meta-analyses have been recommended as an approach to analyze the body of epidemiological studies of trichloroethylene (NRC 2006) in order to provide a synthesis of data and to partly overcome the limitations of individual studies due to low statistical power. Several meta-analyses of kidney cancer and trichloroethylene exposure have been conducted (Karami et al. 2012; Kelsh et al. 2010; Scott and Jinot 2011; USEPA 2011a; Wartenberg and Reyner 2000). This evaluation is limited to the recent meta-analyses by the EPA (2011a), Scott and Jinot (2011), Karami et al. (2012) and Kelsh et al. (2010) because many studies have been published since the older evaluations. The EPA and Karami et al. meta-analyses primarily analyzed cohort and case-control studies with specific exposure to trichloroethylene reviewed in this monograph although Karami et al. (2012) also included two studies (Asal et al. 1988; Harrington et al. 1989) that were not considered to be specific for trichloroethylene and thus were excluded from this evaluation. The meta-analysis by Kelsh et al. also included a larger number of studies not specific for trichloroethylene that were excluded from this monograph (see Table 4-3). Both the EPA (Scott and Jinot 2011) and Karami et al. (2012) meta-analyses pre-dated the pooled and updated Nordic cohort study (Hansen et al. 2013), the population-based Nordic study by Vlaanderen et al. (2013), the Montreal case-control study by Christensen et al. (2013), and the drinking water study by Bove et al. (2014). The EPA meta-analysis (Scott and Jinot 2011) included an earlier update (Boice et al. 1999) of the cohort study of aircraft manufacturing workers in Burbank, CA, whereas the later update by Lipworth et al. (2011) was included in the analysis by Karami et al. (2012). An earlier update of the Montreal Canadian study or the component studies (in the case of the pooled analysis) were included in both meta-analyses, and the only new study populations are those reported by Vlaanderen et al. (2013) and Bove et al. (2014).

Table 4-3 Meta-analyses of Kidney Cancer and Trichloroethylene Exposure

Reference | Study Design (# Studies) | mRR (95% CI) All | mRR (95% CI) Highest Exposure | Comments
EPA (2011a)/Scott and Jinot (2011) | Combined cohort and case-control studies (15 for any exposure, 13 for high exposure) | 1.27 (1.13–1.43) | 1.58 (1.28–1.96) | Random effects model Low sensitivity to removal of individual studies or selection of alternative RRs Little evidence of heterogeneity or publication bias
EPA (2011a)/Scott and Jinot (2011) | Cohorts (8) | 1.16 (0.96–1.40) | NR | No sig. diff. between cohort and case-control mRRs No heterogeneity in cohorts, low to moderate heterogeneity in case-control studies
EPA (2011a)/Scott and Jinot (2011) | Case-control (7) | 1.48 (1.15–1.91) | NR | No sig. diff. between cohort and case-control mRRs No heterogeneity in cohorts, low to moderate heterogeneity in case-control studies
Karami et al. (2012) | TCE-exposed cohort + case-control studies (18) | 1.32 (1.17–1.50)^a^ | NR | Random effects model Little evidence of heterogeneity and publication bias Higher mRR among incidence vs. mortality studies
Karami et al. (2012) | TCE-exposed cohorts (9) Exp.-Response Long duration vs. short duration (3) Subset of U-TCA studies (3) | 1.26 (1.02–1.56)^a^ 1.03 (0.59–1.78) | 1.52 (1.08–2.13) 0.90 (0.56–1.45) | Little evidence of heterogeneity or publication bias
Karami et al. (2012) | TCE-exposed case-control studies (9) Exp.-Response High intensity vs. low intensity (6) | 1.35 (1.17–1.57)^a^ | 1.68 (1.23–2.30) 1.49 (1.02–2.17)^a^ | Little evidence of heterogeneity or publication bias
Kelsh et al. (2010) | TCE-exposed cohorts (8) Exp.-Response Long duration vs. short duration^b^ (7) High cum. exp. vs. low cum. exp.^b^ (3) | 1.34 (1.07–1.67)^a^ | 1.24 (0.69–2.23) 1.50 (0.89–2.26) 1.39 (0.75–2.59) 1.29 (0.68–2.47)^a^ | Little evidence of heterogeneity or publication bias
Kelsh et al. (2010) | TCE-exposed case-control (6) | 1.33 (1.02–1.73) | See above | Little evidence of heterogeneity or publication bias

See Appendix D for a list of the studies included in the meta-analyses.

mRR = meta-relative risk; NR = not reported; RR = relative risk; U-TCA = urine trichloroacetic acid.

^a^ Excluding studies by Henschler et al. (1995) and/or Vamvakas et al. (1998).

^b^ Combined cohort and case-control studies.

The EPA meta-analyses (Scott and Jinot 2011; USEPA 2011a) included systematic data extraction of eight cohort and seven case-control studies (including one nested case-control study) in which potential trichloroethylene exposure was documented and risk estimates for kidney cancer and trichloroethylene exposure were calculated (Table 4-3). Studies with evidence of a low potential for exposure to trichloroethylene were excluded. Fixed and random effects models, tests for heterogeneity and publication bias, and sensitivity analyses (to examine the impact of individual studies and selection of alternative relative risk selections on meta-relative risk estimates) were used to calculate summary meta-relative risks using, where provided, adjusted or crude risk estimates from internal analyses rather than external (SMR or SIR) estimates. In addition, separate meta-analyses were conducted for the highest exposure groups (either by duration and/or intensity) within trichloroethylene-exposed populations (reported in 13 of the 15 constituent studies). In these highest exposure subgroups, non-differential misclassification of exposure would be expected to be less than among the whole group, bearing in mind that actual levels and lengths of exposure might have differed considerably across studies.

Karami et al. (2012) used similar inclusion/exclusion criteria to the EPA and considered an overlapping body of studies, but with the inclusion of cohort studies by Boice et al. (2006) (rather than Zhao et al. (2005), with which it overlaps) and Lipworth et al. (2011) and, as noted, the case-control studies by Asal et al. (1988) and Harrington et al. (1989). Initial examination of the cohort study of German cardboard manufacturers Henschler et al. (1995) and the case-control study by Vamvakas et al. (1998) introduced the greatest heterogeneity and so were excluded from some analyses. Only the data for analyses excluding these studies, which are more closely comparable with the EPA analysis, are reported in Table 4-3 below. Since Kelsh et al. (2010) included a number of studies that were considered non-specific for trichloroethylene exposure, the results should be interpreted with caution.

The overall results of the three meta-analyses were broadly comparable, with some variation partly depending on which specific studies were included. Both cohort and case-control studies, separately and combined, yield robust and statistically significant but modest increases in meta-relative risks (mRRs) for kidney cancer in the two most recent and comparable meta-analyses, approximately 1.3 (for case-control and cohort combined), with little evidence of heterogeneity and publication bias, and with slightly higher statistically significant mRRs among the case-control studies than the cohort studies. Importantly, the mRR was robust and not sensitive to removal of individual studies or selection of alternative RRs. Investigation of the highest exposure groups in the EPA analysis of the combined cohort and case-control studies (Scott and Jinot 2011; USEPA 2011a), yielding a statistically significant mRR of 1.58, provides some evidence of higher risk among more highly exposed workers. This was similar to the mRRs for higher exposure calculated in the separate cohort and case-control analyses by Karami et al. (2012), but slightly higher than those reported by Kelsh et al. (2010) (which, as noted, included some different studies). However, the data were insufficient to distinguish which metric of exposure (among the studies categorized as “high” exposure) is more clearly associated with an increase in the risk of kidney cancer mRRs.

#### 4.1.2.1 Evaluation of Potential Confounding by Occupational Co-exposures or Other Risk Factors

Section 3 discussed the adequacy of the methods used in the cohort (Section 3.2) and case-control studies (Sections 3.3 and 3.4) for evaluating potential confounding from occupational co-exposures and non-occupational factors. However, that assessment was not specific for kidney cancer. This section builds on that assessment, integrating it with other relevant information and evaluating whether confounding can explain the increased risks of kidney cancer observed in many of the studies.

#### 4.1.2.2 Occupational Co-exposures

With respect to occupational agents, IARC (Cogliano et al. 2011) and/or the Report on Carcinogens (NTP 2011) have identified X-radiation as a known kidney carcinogen in humans and concluded that there was limited evidence of carcinogenicity for arsenic, cadmium, and printing processes. Few of the cohort and nested case-control studies provided qualitative or quantitative data on potential co-exposures or adjusted for (or considered) them in statistical analyses. The potential co-exposures include a wide range of other chemical or physical agents, principally the chlorinated solvents tetrachloroethylene and 1,1,1-trichloroethane in both the Nordic and aerospace and aircraft studies, and cutting fluids such as mineral and petroleum oils, hydrazine, benzene, chromates, and PAHs in the aerospace and aircraft industries, although the most common co-exposures among the group of studies are probably chlorinated solvents and cutting oils such as mineral and petroleum oils. The workers in the Nordic studies had diverse occupations, and thus the types, patterns, and levels of co-exposures to other agents are likely to vary across the different industries and time periods. In most studies, it is not clear if or how strongly exposures to other occupational agents were correlated with exposure to trichloroethylene. Moreover, none of these substances has been identified as a known or suspected kidney carcinogen in humans to date although some are carcinogenic in animals. IARC (2014) recently concluded that there was little overall evidence of an association of exposure to tetrachloroethylene with kidney cancer in humans. No independent epidemiological data on 1,1,1-trichoroethane and kidney cancer were identified.

The two studies of aerospace workers, which found a positive association between trichloroethylene exposure and kidney cancer, adjusted for exposure to known co-exposures. Zhao et al. (2005) directly adjusted for co-exposures (mineral or petroleum oils) in their internal analysis of trichloroethylene and kidney cancer risk, and Boice et al. (2006) adjusted for hydrazine exposure.

Case-control studies were more limited on information for potential occupational co-exposures. However, as in the Nordic studies, workers were from diverse industries, with varying types and patterns of co-exposures. Only one study (Charbotel et al. 2006; Charbotel et al. 2009) adjusted for co-exposures (to petroleum and cutting oils); risks for trichloroethylene exposure were still elevated but slightly attenuated (from 2.23 to 1.96) and an elevated risk (although not statistically significant) was observed among workers without exposure to mineral oils in combined analyses. There is no independent evidence that mineral oils are associated with kidney cancer.

#### 4.1.2.3 Lifestyle and Other Potential Confounders

Non-occupational risk factors for kidney cancer include tobacco smoking, obesity (BMI), diabetes, hypertension (diuretics), and X-radiation (see e.g., Chow et al. (2010), Cogliano et al. (2011)). It is not clear whether any of these would be associated with trichloroethylene exposure, but tobacco smoking may be the most likely risk factor.

The majority of cohort and nested case-control studies conducted age-, sex-, race- and calendar-year or period-standardized comparisons in external analyses (SMR or SIR) where appropriate and age-, sex-, race- and in some cases calendar-period-adjusted comparisons in internal analyses. In addition, all of the studies, except for the Danish blue-collar worker study, conducted internal analyses, which would mitigate potential confounding from lifestyle factors. Each of the case-control studies, in addition to matching or adjusting for demographic variables including age, sex, and residential location, examined or adjusted for BMI and/or measures of hypertension, with the exception of Christensen et al. (2013) and Vamvakas et al. (1998). There was no clear evidence of confounding by these variables in the studies that examined or adjusted for them. Some studies also considered socioeconomic factors (Christensen et al. 2013), medical history or conditions (Dosemeci et al. 1999; Moore et al. 2010; Pesch et al. 2000b; Vamvakas et al. 1998), or other lifestyle factors (Christensen et al. 2013).

Potential confounding from smoking can reasonably be ruled out. Smoking is a relatively weak risk factor for kidney cancer (approximately 1.4 for current smoking in meta-analyses data), and the NRC (2006) estimated that it most likely would only account for approximately 10% increase in risk if smoking differences were 20% higher among trichloroethylene-exposed populations. Increased risks of kidney cancer were observed in several case-control studies that adjusted for or considered smoking habits (Brüning et al. 2003; Charbotel et al. 2006; Charbotel et al. 2009; Dosemeci et al. 1999; Moore et al. 2010; Pesch et al. 2000b; Vamvakas et al. 1998). Although most of the cohort studies did not adjust for smoking, lung cancer rates among the trichloroethylene-exposed workers appear to be unremarkable, with the exception of significantly elevated risks (approximately 40%) for men and women in the Danish blue-collar cohort (Raaschou-Nielsen et al. 2003); however, this likely explains <6% of the excess risk from trichloroethylene (USEPA 2011a). The EPA (2011a) also found no association with lung cancer and trichloroethylene in a meta-analysis of studies (OR approximately 1 for all studies and also for high trichloroethylene exposure).

Overall, there was little evidence to suggest that confounding by occupational co-exposures explains the observed increases in kidney cancer, which have been reported in populations with different industries and lifestyle factors and in different regions.

### 4.1.3 Forest Plot Methods

Forest plots were constructed using risk estimates for kidney cancer and ever exposure (Figure 4-2) or the highest exposure category (Figure 4-3) and grouping the studies by ranking of the utility of the studies to inform the cancer hazard evaluation or by broad group of estimated exposure (high exposure risk estimates only) (Figure 4-4). Cohort and case-control studies were presented together because the meta-analyses did not report statistically significant differences for the meta-relative risks between the two study designs.

Figure 4-2

Forest Plot-1: Kidney Cancer and Ever Exposure to Trichloroethylene

Effect estimate and 95% CI for ever exposure to trichloroethylene and kidney cancer by study utility category (see Figure 4-1) and overall prediction of direction of any bias for low utility studies as described in Section 4.1.3. Studies by Bove et al. (2014) and Vlaanderen et al. (2013) are not graphed because they did not report relative risk for ever exposure but they are reported in Figure 4-3 and Table 4-1. Effect estimates are also reported in Table 4-1. For studies reporting multiple effect estimate, preference is given to analysis for longer lags (Hansen et al. (2013) [20 years], Raaschou-Nielsen et al. (2003) [≥20 years]) and internal analysis; RR for Morgan et al. (1998) was reported by Scott and Jinot (2011).

Figure 4-3

Forest Plot-2: Kidney Cancer and High Exposure to Trichloroethylene

Effect estimate and 95% CI for high exposure to trichloroethylene and kidney cancer by study utility category (see Figure 4-1) and overall prediction of direction of any bias for low utility studies as described in Section 4.1.3. Studies by Greenland et al. (1994), Dosemeci et al. (1999), and Silver et al. (2014) are not graphed because they did not report a risk estimate for high exposure. Findings for these studies are reported in Table 4-1 and in Figure 4-2. Effect estimates are also reported in Table 4-1; the effect estimate for men and women combined in Pesch et al. (2000b) was reported by Scott and Jinot (2011).

Figure 4-4

Forest Plot-3: Kidney Cancer and Estimated Exposure Level for Trichloroethylene

Effect estimate and 95% CI for high exposure to trichloroethylene and kidney cancer and estimated exposure level (see Table D-5 and Table D-7) as described in Section 4.1.3. Studies by Greenland et al. (1994), Dosemeci et al. (1999), and Silver et al. (2014) are not graphed because they did not report a risk estimate for high exposure. Findings for these studies are reported in Table 4-1 and Figure 4-2. The effect estimate for Pesch et al. (2000b) was reported by Scott and Jinot (2011).

Different metrics of exposure were graphed and are as follows:

^a^Exposure intensity.

^b^Cumulative exposure.

^c^Exposure duration.

^d^Categories including confidence of probability of exposure with level and/or duration.

^e^Cumulative exposure measures that included exposure prevalence.

High-exposure category: For each study, risk estimates (SMR, SIR, RR, HR, or OR) were extracted for the highest estimated exposure group (intensity or cumulative exposure), if reported. In the cohort study by Lipworth et al. (2011), duration was used because risk by exposure level was not reported. In some cases, surrogates for exposure intensity were used. Calendar year was used as a surrogate in one cohort study (Raaschou-Nielsen et al. 2003) because additional data suggested that average exposures were highest in the earliest calendar period (prior to 1970). In the case-control study of renal-cell carcinoma by Brüning et al. (2003), prevalence of narcotic symptoms was used as a surrogate by the authors to indicate the highest exposed workers.

Utility of the studies to inform the cancer hazard evaluation: Studies were ranked into categories of utility: high; moderate; low with potential bias most likely towards the null; and low with potential bias most likely towards a positive effect (overestimate of the risk estimate). Studies with low or low/moderate utility in Figure 4-2 were combined into one category. This broad ranking was based on consideration of selection bias and information bias (quality of exposure and disease characterization and likely degree of exposure or disease misclassification), and on study sensitivity (as a function of statistical power, estimated exposure levels, and length of follow-up). (See Sections 3.2.2.6, 3.3.2.6, and 3.4.2.6; Appendix D; and Figure 4-1) for detailed summaries of these elements.)

Ranked estimated exposure: For each study the effect estimate and 95% CI for the highest exposure level was plotted as described above. The studies reported different metrics of exposure, including intensity (or surrogate for intensity), cumulative exposure, and duration. Some studies used an exposure category that integrated confidence or probability with intensity or duration (Christensen et al. 2013; Pesch et al. 2000b). Although there were very few data on actual exposure levels, some authors or reviewers have estimated exposure for either jobs or cumulative exposure or intensity for individuals, and this information was used to group the studies in three broad exposure level groups. (See Table D-4, and Table D-6 for estimated exposure level and ranked exposure group.) The exposure group (high to very high, moderate to high, low) is for the estimated exposure level for the exposure metric reported in that study—e.g., studies reporting effect estimates for exposure for cumulative exposure are ranked according to the estimated cumulative exposure for that study.

### 4.1.4 Integration Across Studies

There is credible evidence of an association between exposure to trichloroethylene and kidney cancer risk based on consistent findings of increased risks of kidney cancer across studies of different designs, different geographical areas, and different occupational settings (see Figure 4-2 and Figure 4-3) and evidence of exposure-response relationships. The most convincing evidence for an association between kidney cancer incidence and exposure to trichloroethylene comes from the three most informative (high utility) studies (Charbotel et al. 2006; Charbotel et al. 2009; Moore et al. 2010; Zhao et al. 2005), and two studies with moderate or moderate to low utility, a Nordic cohort of blue-collar workers in companies using trichloroethylene (Raaschou-Nielsen et al. 2003), and a case-control study from an area in Germany with known trichloroethylene exposure (Brüning et al. 2003), all of which found statistically significant elevated risks of kidney cancer among workers with the highest exposure to trichloroethylene (see Figure 4-3). These findings are supported by weaker associations (in analyses of high or ever exposure to trichloroethylene) found in most of the other studies considered to be of moderate utility (Hansen et al. 2013; Morgan et al. 1998), and some studies considered to have low to moderate utility (Dosemeci et al. 1999; Pesch et al. 2000b) or low utility (Bove et al. 2014; Silver et al. 2014). Limitations in most of these studies would most likely bias towards the null, and the fact that the studies were considered to be of lower utility does not detract from the positive evidence. Statistically significant increased risks were also found in two German studies located in a geographical area known to have industries with exposure to high levels of trichloroethylene: a cohort study of cardboard manufacturing workers (Henschler et al. 1995), and a case-control study by Vamvakas et al. (1998). Both of these studies have potential biases that would most likely lead to an overestimate of the risk estimate although it is unlikely that the biases nullify the large excess risk found in these studies. Figure 4-3 plots the risk estimate for the high-exposure group from each study and groups the studies according to broad groups of estimated exposure. The highest risks were found among studies with very high or high to moderate exposure to trichloroethylene, and findings were more heterogeneous among studies with low estimated exposure.

Meta-analyses are useful for evaluating potential heterogeneity between studies or types of studies and also for summarizing the results of studies. The most recent meta-analyses (Karami et al. 2012; Scott and Jinot 2011) provide strong evidence for an association between trichloroethylene exposure and kidney cancer. Both analyses found statistically significant meta-relative risks of similar magnitudes, i.e., 1.27 (95% CI = 1.13 to 1.43) by Scott and Jinot (2011) and 1.32 (95% CI = 1.17 to 1.50) by Karami et al. (2012). Importantly, the mRR was robust and not sensitive to removal of individual studies or selection of alternative RRs. There was no evidence of publication bias or heterogeneity across studies (which did not include the studies by Vamvakas et al. and Henschler et al., which have the high-risk estimates) or publication bias in both meta-analyses. Although a lower mRR was found for cohort studies than case-control studies, the subgroup risk estimates for case-control and cohort studies did not significantly differ from each other.

There was evidence for positive exposure-response relationships or higher risks in more highly or longer exposed groups in both cohort and case-control studies with several exposure metrics. Risks increased with increasing exposure intensity or cumulative exposure in the cohort study of aerospace workers (Zhao et al. 2005), the French case-control study, which was primarily of workers in the screw-cutting industries (Charbotel et al. 2006; Charbotel et al. 2009), the European study (Moore et al. 2010), and the Nordic study of blue-collar workers (Raaschou-Nielsen et al. 2003), using calendar year of first exposure as a surrogate for exposure level. Other studies found higher risk among individuals with longer exposure to trichloroethylene (Moore et al. 2010) or employment duration (Raaschou-Nielsen et al. 2003). The meta-analyses also provide evidence for exposure-response relationships between trichloroethylene exposure and kidney cancer. The EPA meta-analysis found a higher mRR for higher-exposure groups (1.6) across studies compared with the risk for ever exposure across studies (1.3) (Scott and Jinot 2011). Karami et al. (2012) found higher mRRs for high (vs. low) intensity exposure and long (vs. short) duration of exposure in separate analyses of cohort and case-control studies.

The database was inadequate to evaluate the effect of latency, as few cohort or case-control studies conducted lagged vs. unlagged or time since first exposure analyses and data are generally sparse due to limited numbers of cases. SIRs for kidney cancer increased with increasing lagging time in the study of blue-collar workers (Raaschou-Nielsen et al. 2003) and were slightly higher (10%) in the 20-year lagged analysis compared with the 10-year lagged and unlagged analyses in the study of biomonitored workers (Hansen et al. 2013). However, no differences in effect estimates after lagging by varying periods of between approximately 0 and ≥20 years were reported in other studies (Brüning et al. 2003; Moore et al. 2010; Vlaanderen et al. 2013; Zhao et al. 2005). The rest of the studies did not conduct lagged analysis (Boice et al. 2006; Charbotel et al. 2006; Charbotel et al. 2009; Christensen et al. 2013; Dosemeci et al. 1999; Henschler et al. 1995; Lipworth et al. 2011; Morgan et al. 1998; Pesch et al. 2000b; Radican et al. 2008) or only reported effect estimates for one lagging period (Bove et al. 2014; Greenland et al. 1994) and Silver et al. (2014).

The findings across studies are unlikely to be explained by biases. Although selection bias cannot be ruled out in the studies by Henschler et al. (1995) and Vamvakas et al. (1998), these studies were not included in the meta-analyses, and thus do not affect the overall conclusion. Confounding from smoking and other lifestyle factors can also be reasonably ruled out across studies. Increased risks were found in case-control studies, which adjusted for these factors. Almost all the cohort studies conducted internal analyses, which can mitigate concerns about lifestyle factors, and the lack of an association with exposure to trichloroethylene and lung cancer in these studies argues against confounding by smoking, which is not strongly associated with renal cancer. Potential selection bias and confounding from smoking in the study of blue-collar workers does not explain all of the excess risk of kidney cancer associated with trichloroethylene exposure. Although information on occupational co-exposures is missing in most of the studies, the identified co-exposures were neither known nor suspected renal carcinogens. In addition, some of the positive studies found increased risks after controlling for (primarily mineral oils) or considering exposure to known occupational co-exposures; co-exposures were not likely to confound the German studies (Brüning et al. 2003; Henschler et al. 1995; Vamvakas et al. 1998). Most of the other positive studies were from diverse industries with varying levels and patterns of co-exposures. Exposure to chlorinated solvents other than trichloroethylene and mineral oils may be the most common exposures across industries, and these are not known or suspected renal carcinogens. Thus, no identified risk factors for renal cancer are likely to explain the increased risks found in these studies.

## 4.2 Mechanistic Data for Kidney Carcinogenicity

EPA (2011a; 2011b) and IARC (2014) recently reviewed the mechanistic data for trichloroethylene. The findings from these reviews and other mechanistic data are presented here. Relevant primary literature is cited if the study was not included in these reviews, or if specific data or further details of the study were needed for clarification.

### 4.2.1 Hypothesized Modes of Action

Hypothesized modes of action for trichloroethylene-induced kidney carcinogenicity include key events attributed to GSH-conjugation-derived metabolites (genotoxicity and cytotoxicity) and those attributed to oxidative metabolites (peroxisome proliferation activated receptor α (PPARα) activation, α_2u_-globulin-related nephropathy, and formic acid-related nephrotoxicity) (USEPA 2011a). The key events associated with each of these hypothesized modes of action are listed in Table 4-4. Modes of action associated with GSH-derived metabolites are discussed in Section 4.2.2 while those associated with oxidative metabolites are discussed in Section 4.2.3.

Table 4-4 Hypothesized Modes of Action and Key Events for Kidney Tumors

Mode of Action | Key Events
Genotoxicity | 1. GSH-conjugation-derived metabolites produced in situ or delivered systemically to kidney 2. Genotoxic effects induced by metabolites in kidney (e.g., mutations, DNA damage, DNA strand breaks, micronuclei) that advance acquisition of multiple critical traits contributing to carcinogenesis
Cytotoxicity and regenerative proliferation | 1. GSH-conjugation-derived metabolites produced in situ or delivered systemically to kidney 2. Cytotoxicity and compensatory cell proliferation 3. Clonal expansion of initiated cells
PPARα activation | 1. Oxidative metabolites produced in the liver activate PPARα in the kidney 2. Alterations in cell proliferation and apoptosis 3. Clonal expansion of initiated cells
α_2u_-Globulin-related nephropathy (relevant only in male rats) | 1. Oxidative metabolites cause hyaline droplet accumulation and an increase in α_2u_-globulin resulting in nephrotoxicity 2. Subsequent cytotoxicity, necrosis, and sustained regenerative tubule-cell proliferation 3. Development of intraluminal granular casts from sloughed cellular debris associated with tubule dilation and papillary mineralization 4. Foci of tubule hyperplasia in the convoluted proximal tubules 5. Renal tubule tumors
Formic acid-related nephropathy | 1. Oxidative metabolites produced in the liver lead to increased formation and urinary excretion of formic acid 2. Increased formic acid causes cytotoxicity in the kidney 3. Compensatory cell proliferation 4. Clonal expansion of initiated cells

Source: Adapted from EPA (2011a).

### 4.2.2 The Proposed Role of GSH-conjugation-derived Metabolites in Kidney Carcinogenicity

The toxicology of trichloroethylene has been extensively studied, and the data indicate that metabolites are responsible for most of the toxic effects. As discussed in Section 1.2, trichloroethylene is metabolized in the liver by two separate pathways, cytochrome P450-dependent oxidation (Figure 1-1) and GSH conjugation (Figure 1-2). These metabolic pathways act in parallel and may compete for trichloroethylene as a substrate, thus, factors that affect the relative flux of trichloroethylene through each pathway (e.g., metabolic saturation, polymorphisms, enzyme induction/inhibition) can alter the toxic response. Both oxidative (trichloroethanol and trichloroacetic acid) and GSH-conjugation-derived metabolites (DCVG, DCVC, and related metabolites) have been associated with various nephrotoxic effects; however, the experimental data indicate that metabolites derived from the GSH-conjugation pathway are more important for nephrotoxicity. The role of oxidative metabolites, if any, is comparatively small.

The proposed key events for kidney carcinogenicity include (1) GSH-conjugation-derived metabolites produced in situ or delivered systemically to the kidneys, and (2) mutagenic, genotoxic (see Section 4.2.2.1) and cytotoxic effects (see Section 4.2.2.2) induced by these metabolites in the kidneys advance the acquisition of multiple critical traits contributing to carcinogenesis (USEPA 2011a).

Disposition and toxicokinetic data (reviewed in Section 1) show that metabolites from the GSH-conjugation pathway are formed in the liver and kidneys and that flux through the GSH pathway is more substantial than previous estimates based on urinary metabolites indicated. Metabolites formed in the liver are delivered to the kidneys through the systemic circulation. In vitro studies using liver and kidney cells from humans and rodents and subcellular fractions incubated with trichloroethylene also have shown formation of GSH-derived metabolites. These metabolites include DCVG, DCVC, NAcDCVC, and other metabolites derived from subsequent β-lyase, flavin-containing monooxygenase 3 (FMO3), or CYP3A metabolism within the liver or kidneys (see Section 1.2.2, Figure 1-2). The data also show that levels of some of the metabolites (e.g., NAcDCVC) may accumulate in the kidney due to both in situ production and systemic delivery from the liver.

Studies in humans provide support for the importance of the GSH-conjugation pathway in renal cancer development. Three studies, using different types of analyses (or statistical analyses), specifically investigated GST polymorphisms and renal-cell cancer among humans exposed to trichloroethylene (Brüning et al. 1997a; Moore et al. 2010; Wiesenhutter et al. 2007). The Central and Eastern European case-control study by Moore et al. (2010) (see Sections 3 and 4.1) was considered to be the most informative study to evaluate potential effect modification of GST genotypes and trichloroethylene exposure because of a large number of exposed kidney cancer cases (1,097) and controls (1,476), study design (calculated ORs for trichloroethylene exposure stratified by GSTT1 genotype), and evaluation of exposure-response relationships. Positive associations (p_trend_ < 0.05) with kidney cancer were found for all trichloroethylene exposure metrics (any, duration, average, and cumulative exposure) among subjects with GSTT1 active genotypes but not among subjects with two deleted alleles (null genotype) (see Table 4-2). Moore et al. also found statistically significant interaction between trichloroethylene exposure (ever versus never) and minor alleles in single nucleotide polymorphisms (SNPs) spanning the renal cysteine β-lyase (CCBL1) gene region. Thus, the findings of Moore et al. (2010) are consistent with the hypothesis that genes involved in the GSH-conjugation pathway are involved in trichloroethylene-induced renal cancer.

The other two studies had limited methods for evaluating potential effect modification. Brüning et al. (1997a) reported that having a GSTT1 or GSTM1 active genotype increased the risk of renal cancer in a small study of cases and controls, all of whom had been exposed to high concentrations of trichloroethylene, from a highly industrial region in Germany (see Section 3 for a description of occupational exposure in the Arnsberg area of Germany). EPA (2011a) noted that the frequency of GSTM1 in the controls was lower than that of background European populations. In a later study, using cases and controls from the hospital-based case-control study by Brüning et al. (2003) (see Sections 3 and 4.1), and an additional control group, Wiesenhutter et al. (2007) reported that frequency of GSTT1, GSTM1, and NAT1 polymorphisms was similar among cases and controls, and among trichloroethylene-exposed cases and non-exposed cases. Genotype distribution in exposed controls versus non-exposed controls was not reported and there appear to be some errors in the reporting of the frequency of the GSTT1 genotypes of exposed and non-exposed cases.

#### 4.2.2.1 Genotoxicity

Genotoxicity is a well-established cause of carcinogenicity. Although trichloroethylene was not mutagenic without metabolic activation in most standard bacterial assays, GSH-conjugation pathway-derived metabolites are genotoxic (see Section 2). Although there are some data limitations, the available evidence indicates that DCVC is a more potent mutagen than any of the oxidative metabolites (Moore and Harrington-Brock 2000). Positive genotoxicity data for GSH-derived metabolites were reported (primarily from in vitro assays). DCVG, DCVC, and NAcDCVC were mutagenic in the Ames test, and kidney-specific genotoxic effects also were reported (IARC 2014; USEPA 2011a). DCVC and DCVG were direct-acting mutagens in some strains of S. typhimurium. Furthermore, the use of β-lyase inhibitors or kidney subcellular fractions for metabolic activation supported the importance of in situ metabolism in the genotoxicity of these metabolites in the kidney. DCVC induced dose-dependent increases in unscheduled DNA synthesis in porcine kidney tubular epithelial cells and Syrian hamster embryo fibroblasts. Other genotoxic effects of DCVC included DNA strand breaks in the kidneys of rats and rabbits (oral exposure), and micronuclei in primary kidney cells from humans and rats. A single study in Eker rats, which are prone to the development of renal tumors, showed no increase in tumor incidence or in VHL mutations in trichloroethylene-exposed animals compared with controls (Mally et al. 2006).

Doses used in the in vitro assays were generally in the sub-nmol to nmol range for the Ames assay and in the μM to mM range with mammalian cells. Thus, many of the in vitro assays used concentrations higher than those observed in vivo. Lash et al. (1999b) reported maximum DCVG levels of approximately 110 nmol/mL (0.11 μM) in the blood of human volunteers exposed to trichloroethylene vapors (100 ppm) for 4 hours. DCVG concentrations were not measured in tissues but would likely have been higher in the kidney due to in situ metabolism and a trichloroethylene tissue:blood partition coefficient >1 (see Section 1.1.1). The available in vivo data do show some genotoxic effects in target tissues (likely resulting from GSH-conjugation-derived metabolites and including micronuclei and DNA single-strand breaks in the kidney) in rodents exposed to trichloroethylene. Other studies in rodents show that sufficient DCVC is formed in vivo from trichloroethylene metabolism to account for histological changes in the renal tubules (USEPA 2011a).

Only one study was identified that investigated the genotoxic effects of trichloroethylene in the mouse kidney (Douglas et al. 1999). Mutations were not increased in the kidney of lacZ transgenic mice exposed to trichloroethylene vapors for 12 days (USEPA 2011a). However, these results are not highly informative as to the role of mutagenicity in trichloroethylene-induced kidney tumors given the uncertainties of the mouse model in the production of genotoxic GSH-conjugation-derived metabolites and the low carcinogenic potency of trichloroethylene in the mouse kidney. Although renal tumors were not increased in mice, this is not an unusual finding compared with results for other genotoxic kidney carcinogens. Five of seven direct-acting genotoxic carcinogens also induced kidney tumors in rats but not in mice. Since kidney tumors are rare in rodents and given that the incidence of kidney tumors was low in rats, it is not unreasonable that a small difference in potency in mice compared with rats would not be detected in chronic bioassays. Toxicokinetic data (see Section 1.3.2 and Appendix B) did not indicate that GSH conjugation and subsequent renal metabolism were lower in mice compared with rats; however, there is substantial uncertainty in the total flux through this pathway. Therefore, the lack of a detectable response in mice does not rule out a genotoxic mode of action.

Inactivation of the VHL tumor suppressor gene from base-change mutations, silencing, or small deletions is thought to be an early and causative event in human renal clear-cell carcinomas (USEPA 2011a). Mutations in the VHL gene from exposure to trichloroethylene were evaluated in four case-control studies (Brauch et al. 1999; Brauch et al. 2004; Brüning et al. 1997b; Charbotel et al. 2007) and one case-series study (Moore et al. 2011) of renal-cell carcinomas (Table 4-5). Moore et al. (2011) reported that VHL inactivation, either through genetic alterations or promoter methylation in tumor DNA, occurred in more than 86% of the 470 sporadic clear-cell renal cancer cases examined. In addition, some researchers have reported differences between trichloroethylene-exposed and nonexposed renal-cell carcinoma patients in the frequency of somatic mutations in the VHL gene (Brauch et al. 1999; Brauch et al. 2004; Brüning et al. 1997b). The two studies by Brauch et al. reported multiple mutations in the VHL gene and increased frequencies with trichloroethylene exposure. Additionally, Brauch et al. (2004) reported that trichloroethylene-exposed patients were diagnosed with renal-cell carcinoma at a younger age than non-exposed patients. Brauch et al. (1999) reported that 39% of clear-cell renal carcinomas from trichloroethylene-exposed individuals contained a hot-spot mutation (C to T transition) in the VHL gene at nucleotide 463 that caused a substitution of serine for proline at amino acid 81 (P81S). Overall, VHL mutations were found in about 75% of the exposed patients and there was an association between the number of mutations and the severity of trichloroethylene exposure.

Table 4-5 Studies of VHL Mutation in Trichloroethylene-exposed Human Subjects with Renal-cell Carcinoma

Reference Country | Study Type Population | Exposure Estimate Method | Findings Incidences | Comments
Brüning et al. (1997a) Germany | Case-control 23 exposed | Semi-quantitative Work history and acute exposure symptoms | Unable to assess mutation differences 23/23 mutated in exposed 30% in exon 1 44% in exon 2 26% in exon 3 | No unexposed controls or increase in mutations with higher exposure
Brauch et al. (1999) Germany | Case-control 44 exposed 107 controls | Low/medium/high Occupational hygienist | Increased mutations 33/44 mutated in exposed 54% in exon 1 39% at nucleotide 454 32% of mutations were multiple mutations 42/73 mutated in controls 0% of mutations were multiple mutations | Number of mutations increased with higher levels of estimated exposure
Brauch et al. (2004) Germany | Case-control 17 (exposed) 21 (unexposed) | Low/medium/high Occupational hygienist | Increased mutations 14/17 mutated in exposed 39% at nucleotide 454 50% of mutations were multiple mutations 2/21 mutated in controls | RCC cases exposed or unexposed to trichloroethylene Exposure decreased the age of diagnosis
Charbotel et al. (2007) France | Case-control 69 cases of RCC | Low/medium/high Expert-evaluated questionnaire | No mutation differences 2/23 mutated in exposed 2/25 mutated in controls | Low rate of mutation and no difference in mutations with exposure Potential for exposure misclassification
Moore et al. (2011) Europe | Case-series 470 sporadic clear cell RCC cases | Levels of exposure not reported Expert interview | No mutation differences 415/470 mutated in clear-cell renal carcinoma 37% in exon 1 30% in exon 2 26% in exon 3 | Level of exposure not reported. Only 1 unexposed case had mutation at nucleotide 454 Non-clear-cell renal carcinoma were <10% of RCC

Source: IARC (2014).

RCC = renal-cell carcinoma.

VHL mutations also were frequently accompanied by loss of heterozygosity. However, other researchers have not found a higher incidence of VHL mutations in trichloroethylene-exposed patients with renal clear-cell carcinomas compared with nonexposed patients (Charbotel et al. 2007). The Moore et al. (2011) study reported that most of the renal-cell carcinomas were clear-cell renal carcinoma, while <10% of the cancers were non-clear-cell renal carcinoma. One study was unable to assess a change in mutations from trichloroethylene exposure, because no unexposed control was included (Brüning et al. 1997b). Of those cases with mutations in the VHL gene, mutations occurred more frequently in exon 1 (Brauch et al. 1999; Moore et al. 2011), exon 2 (Brüning et al. 1997b), and nucleotide 454, which is considered a hotspot (Brauch et al. 1999; Brauch et al. 2004). DeSimone et al. (2013) compared the activity of the trichloroethylene-associated P81S VHL mutation with cells expressing normal VHL and another VHL mutant (R167Q). Their data indicated that the P81S VHL mutation initiated pleiotropic effects that selectively influenced tumor behavior in a mutation-specific manner. These effects provided a selective growth advantage through metabolic pathway diversification, suppression of apoptosis, and alteration of DNA damage response.

Further data are needed to determine the validity of VHL mutations as a legitimate biomarker for trichloroethylene-induced renal tumors (USEPA 2011a). If valid, these data suggest that a specific mutational spectrum might be associated with trichloroethylene-induced kidney tumors and adds biological plausibility for a mutagenic mode of action. There are currently no data to determine if there is a possible link between trichloroethylene metabolites and these events. Recent studies do suggest that multiple genes are involved in renal clear-cell carcinoma; therefore, the inconsistent results with respect to VHL mutations do not constitute negative evidence for a mutagenic mode of action. Overall, the data clearly show that human and rodent kidneys are exposed to GSH-conjugation-derived metabolites following exposure to trichloroethylene and that these metabolites are capable of causing genetic damage. Thus, the data are sufficient to conclude that a mutagenic mode of action is likely operative in trichloroethylene-induced kidney tumors.

#### 4.2.2.2 Cytotoxicity and Regenerative Proliferation

The key events for cytotoxicity and regenerative proliferation are: (1) formation of cytotoxic GSH-conjugated metabolites of trichloroethylene, which are either formed within the kidney or delivered systemically to the kidney, (2) nephrotoxicity leading to compensatory cellular proliferation and an increased mutation rate, and (3) tumor formation through clonal expansion of initiated cells. Although the available data currently are insufficient to establish a causal link between trichloroethylene-induced nephrotoxicity and sustained regenerative cellular proliferation and carcinogenicity, there is substantial evidence that trichloroethylene and/or its metabolites are nephrotoxic (USEPA 2011a). The experimental evidence includes the following: (1) increased urinary excretion of nephrotoxicity markers in humans (especially evident from chronic occupational exposure to high concentrations), (2) high incidences of proximal tubule cytomegaly and toxic nephropathy only in dosed male and female rats from five strains in chronic bioassays, (3) high incidences of proximal tubule cytomegaly only in dosed male and female mice in a chronic bioassay, (4) kidney toxicity in rodents exposed to DCVC and other GSH-conjugation-derived metabolites, (5) toxicokinetic data showing that DCVC is formed in the kidney following exposure to trichloroethylene, and (6) data that demonstrate that nephrotoxic metabolites formed in the liver are delivered through the systemic circulation to the kidney.

Nephrotoxic trichloroethylene metabolites derived from the GSH-conjugation pathway are formed in the kidney and also are delivered from the liver to the kidney via the systemic circulation (Irving and Elfarra 2012). Some nephrotoxic effects also have been reported for trichloroethanol and trichloroacetic acid (oxidative metabolites of trichloroethylene) in rats. Chronic exposure to trichloroethanol caused tubular degeneration in rats but there was no evidence of karyomegaly or cytomegaly (Green et al. 2003; USEPA 2011a). Overall, trichloroethanol did not induce the same pathology as trichloroethylene or DCVC. Trichloroacetic acid administered to rats caused an increase in the kidney-weight to body-weight ratio but did not cause histopathologic changes in the kidney. However, trichloroacetic acid has been associated with peroxisomal proliferation in the kidney (discussed below). Both trichloroethanol and trichloroacetic acid may contribute to trichloroethylene-induced nephrotoxicity through formic acid formation (discussed below), but the overall contribution is likely very small compared with the GSH-conjugation-derived metabolites (USEPA 2011a).

Urinary biomarkers of early renal dysfunction include glutathione-S-transferase α, glutathione-S-transferase π, β_2_-microglobulin, α_1_-microglobulin, retinol binding protein, N-acetylglucosaminidase (NAG), kidney injury molecule-1, albumin, and total protein (Green et al. 2004; Vermeulen et al. 2012). Several studies have reported an increase in urinary markers of proximal tubule injury in workers repeatedly exposed to high concentrations of trichloroethylene over an extended period (Bolt et al. 2004; Brüning et al. 1999a; Brüning et al. 1999b) or following acute intoxication (Brüning et al. 1998). Peak exposures were estimated to have frequently exceeded 500 ppm based on reported narcotic symptoms (drunkenness, dizziness, headache, and drowsiness). The workers also reported that they frequently had to leave the work area to recover in fresh air. Two of these studies also reported that there were significantly more cases of tubular damage (measured by increased α_1_-microglobulin in the urine) among renal-cell carcinoma patients exposed to high levels of trichloroethylene over many years compared with nonexposed patients with renal-cell carcinoma or exposed controls (Bolt et al. 2004; Brüning et al. 1999a). Vermeulen et al. (2012) investigated nephrotoxicity among 80 Chinese factory workers (mean duration of employment 2 years) exposed to trichloroethylene concentrations (22.2 ppm ± 35.9) below the Occupational Safety and Health Administration permissible exposure limit of 100 ppm (8-h TWA). Urinary levels of kidney injury molecule-1 were significantly elevated in exposed workers compared with controls and an increase in glutathione-S-transferase π was borderline statistically significant. Other markers of kidney toxicity (NAG and glutathione-S-transferase α) were not significantly different. This was the first study to show that relatively low occupational exposures to trichloroethylene could induce kidney toxicity.

An earlier study by Green et al. (2004) did not find evidence of exposure-related kidney damage in 70 workers exposed to relatively low trichloroethylene concentrations (mean = 32 ppm, range = 0.5 to 252 ppm). There was a significant dose-dependent increase in urinary glutathione-S-transferase α activity; however, the levels were not significantly increased compared with controls. Although NAG and albumin levels were significantly higher in the exposed workers compared with controls, the levels of these markers were not correlated with either the magnitude or duration of exposure and could be explained by chance or by exposure to some unidentified agent. In vitro studies with primary cultures of human proximal tubular cells show that DCVC caused necrosis at high concentrations (>100μM) and increased cell proliferation and apoptosis at lower concentrations (Lash et al. 2005). These effects were associated with changes in expression of proteins that regulate apoptosis, cellular growth, differentiation, and stress response. A study by Xu et al. (2008) indicated that mitochondrial dysfunction was an early, obligatory step in DCVC-induced cytotoxicity in cultured human proximal tubular cells. Overall, the data support the hypothesis that chronic tubular damage is a precondition for the nephrocarcinogenic effects of trichloroethylene in humans.

DCVC was nephrotoxic in rats, mice, guinea pigs, rabbits, cats, and dogs (USEPA 2011a). DCVC may be metabolized to other nephrotoxic metabolites by FMO3, β-lyase, or NAT (see Figure 1-2). Mice appear to be more sensitive to the acute nephrotoxic effects than rats but are less susceptible to renal carcinogenesis. Studies reviewed by EPA (2011a) reported that mice administered a single dose of 1 mg/kg DCVC developed proximal tubule cell damage, and karyomegaly was noted following repeat doses of 1 mg/kg/day for 10 days. Higher doses in mice resulted in more severe damage including desquamation and necrosis of the tubular epithelium. In rats, no histological changes were observed following single doses up to 10 mg/kg or 10 daily doses of 0.5 to 5 mg/kg. Single doses in rats of 25 mg/kg or 50 mg/kg resulted in cellular debris in the tubular lumen and slight degeneration and necrosis, respectively. Irving et al. (2013) investigated the nephrotoxicity of NAcDCVCS, NAcDCVC, and DCVCS in male Sprague-Dawley rats following a single i.p. injection (230 μmol/kg b.w.). Nephrotoxic effects occurred at 24 hours post treatment for all three compounds. NAcDCVCS and NAcDCVC had similar effects causing necrosis in the proximal tubules in the outer medulla and adjacent inner cortex but were less nephrotoxic than DCVCS on an equimolar basis. DCVCS caused acute proximal tubular necrosis in the cortex but not in the medulla. Based on a comparison of kidney lesions of rats dosed with trichloroethylene or DCVC, the data suggest that these compounds also may play a role in trichloroethylene-induced nephrotoxicity.

Subchronic and chronic studies in rats and mice exposed to DCVC via drinking water consistently report pathological and histological effects in the kidney and show a progression from tubular necrosis and shedding of pyknotic cells into the lumen during the first few days to increased prominence of karyomegaly and cytomegaly in tubular cells after several weeks of exposure (USEPA 2011a). Effects were noted at doses as low as 1 to 2 mg/kg/day and did not show a difference in sensitivity between rats and mice. In a recent study, Shirai et al. (2012) administered DCVC to male BALB/c mice orally or by i.p. injection for 13 weeks at 1, 10, and 30 mg/kg/day. Dose-related effects in the kidney were reported that progressed from weak tubular dilation, but no necrosis or fibrosis, at the low dose to renal tubular degeneration characterized by moderate tubular necrosis and marked interstitial fibrosis at the high dose.

The histological and morphological changes in the tubular cells observed in studies with DCVC were similar to those reported in chronic studies with trichloroethylene (NTP 1988; 1990). The NTP studies were conducted with five rat strains and one mouse strain and reported high incidences of cytomegaly of the proximal tubules (82% to 100%) in dosed groups of males and females of all strains and species. Cytomegaly was more severe in male rats than female rats and more severe in rats than in mice, but it was not observed in the unexposed control or vehicle control groups. In addition, NTP (1988) reported high incidences of toxic nephropathy (17% to 80%) only in dosed rats from four strains that was not related to the common spontaneous nephropathy of aging rats. Lash et al. (1998) reported that the greater sensitivity of trichloroethylene-induced kidney toxicity in male rats compared with females was correlated with the rate of DCVG formation. However, species-dependent differences in nephrotoxicity and carcinogenicity between rats and mice were not correlated with rates of DCVG formation and suggested that other enzymes (e.g., β-lyase, NAT, GGT, or deacetylase) may be responsible for the lower susceptibility in mice.

Cytotoxicity alone is insufficient for tumor formation because all cytotoxins clearly are not carcinogenic. Further, nephrotoxicity occurred at much lower doses and was observed at near 100% incidences in all dose groups while renal tumors occurred only in rats in the high-dose group (NTP 1988; 1990). Multiple factors may contribute to cytotoxicity including oxidative stress, alterations in calcium ion homeostasis, mitochondrial dysfunction, protein alkylation, cellular repair processes, and alterations in gene expression (Lash et al. 2000b). Each of these factors may have ancillary consequences related to tumor induction that are independent of cytotoxicity per se (USEPA 2011a). El Arem et al. (2014a); El Arem et al. (2014b) reported that dichloroacetic acid and trichloroacetic acid were nephrotoxic in rats and that the kidney damage could be prevented by antioxidants. However, it is not known whether cytotoxicity is causally related to carcinogenesis or is merely a marker for a different, key causal event. Although experimental data currently do not demonstrate a causal link between nephrotoxicity/sustained cellular proliferation and renal tumors, the data are consistent with the hypothesis that cytotoxicity and regenerative proliferation contribute to trichloroethylene-induced kidney tumors, either independently or in combination with a mutagenic mode of action. The more biologically plausible mode of action likely involves a combination of mutagenicity and cytotoxicity. That is, DNA adducts in combination with toxic doses of trichloroethylene could lead to sustained regenerative cellular proliferation that promotes the selection, survival, and clonal expansion of mutated cells in the tubular epithelium.

### 4.2.3 Proposed Modes of Action Associated with Oxidative Metabolites

As mentioned above, several modes of action associated with oxidative metabolites have been proposed (PPARα activation, α_2u_-globulin-related nephropathy, and formic acid-related nephrotoxicity). These modes of action have little to no experimental support and are briefly reviewed below.

#### 4.2.3.1 PPARα Activation

Tubular epithelial cells are relatively rich in peroxisomes and trichloroacetic acid and dichloroacetic acid, oxidative metabolites of trichloroethylene, are PPARα agonists (USEPA Lash et al. 2000b; Rusyn et al. 2014; 2011a). However, renal peroxisomes are generally less responsive than hepatic peroxisomes to peroxisome proliferators and humans are markedly less responsive to peroxisome proliferation than rodents. Only one study was identified that investigated peroxisome proliferation in kidneys of rats and mice exposed to trichloroethylene (Goldsworthy and Popp 1987). Trichloroethylene induced peroxisome proliferation in the liver and kidneys of rats and mice; however, similar levels were observed in both species. Thus, there was no correlation between induction of peroxisome proliferation in the kidneys and species-specific renal carcinogenicity. Another study investigated the role of trichloroacetic acid in carcinogenesis and peroxisome proliferation in liver and kidneys of rats and mice exposed to tetrachloroethylene, which can be metabolized to trichloroacetic acid (Odum et al. 1988). Due to differences in toxicokinetics, male mice were exposed to higher levels of trichloroacetic acid than male rats, and peroxisome proliferation was observed only in male mouse liver. The data did not support a role of trichloroacetic acid and peroxisome proliferation in the carcinogenicity of tetrachloroethylene in the male rat kidney. Although some metabolites of trichloroethylene are peroxisome proliferators, the available data are insufficient to support peroxisome proliferation as a mode of action for trichloroethylene-induced kidney tumors (USEPA 2011a).

#### 4.2.3.2 α_2u_-Globulin-related Nephropathy

α_2u_-Globulin-related nephropathy is characterized by the rapid accumulation of protein droplets containing α_2u_-globulin (hyaline droplets) in lysosomes in the P2 segment of the proximal tubule and is specific to male rats (IARC 1999; Lash et al. 2000b; Swenberg and Lehman-McKeeman 1999). A number of chemicals, including several halogenated organic solvents, are known to cause hyaline droplet nephropathy. Goldsworthy et al. (1988) investigated α_2u_-globulin nephropathy in both male and female F344 rats exposed to trichloroethylene, tetrachloroethylene, or pentachloroethane to determine if the effects were male rat specific. There was no increase in renal α_2u_-globulin concentrations or cell replication in male or female rats exposed to trichloroethylene but some effects were consistent with α_2u_-globulin nephropathy in male rats for the other compounds tested. Trichloroethylene nephrotoxicity has been observed in rats and mice of both sexes and in humans, and kidney tumor incidences were elevated (although not always statistically significant) in both male and female rats. Thus, the data do not support the hypothesis that α_2u_-globulin nephropathy is a factor in trichloroethylene-induced kidney carcinogenesis in rats.

#### 4.2.3.3 Formic Acid-related Nephrotoxicity

Some investigators have suggested that since the nephrotoxic metabolite DCVC is formed in very small amounts it fails to explain the male rat specific renal carcinogenicity of trichloroethylene and have proposed that trichloroethylene nephrotoxicity may be caused by formic acid (Green et al. 2003; Green et al. 1998). The sequence of events for formic acid-related nephropathy is the same as for cytotoxicity induced by GSH-conjugation-derived metabolites discussed above but is related to oxidative metabolites (trichloroacetic acid and trichloroethanol). Formic acid is not a metabolite of trichloroethylene but may accumulate as an indirect consequence of vitamin B_12_ and folate depletion caused by trichloroethylene exposure (Dow and Green 2000). Male Fischer rats exposed to trichloroethylene, trichloroacetic acid, or trichloroethanol via gavage, drinking water, or inhalation for 1 day to 1 year excreted large amounts of formic acid in urine (Dow and Green 2000; Green et al. 2003; Green et al. 1998). No kidney damage was reported in rats following acute exposures (1 to 5 daily doses) or subacute exposures of 15 to 28 days (oral and inhalation). In contrast, male rats exposed to trichloroethanol at 500 to 1,000 mg/L for 52 weeks developed kidney damage characterized by increased urinary NAG, protein excretion, basophilic tubules, tubular damage, increased cell replication, and focal proliferation of abnormal tubules (Green et al. 2003). However, the characteristics of trichloroethanol-induced nephrotoxicity did not account for the full range of effects observed after exposure to trichloroethylene or DCVC (USEPA 2011a). Studies with trichloroacetic acid did not report histopathologic changes in the rat kidney. Yaqoob et al. (2013) also reported that male and female rats exposed to low doses of trichloroethylene for 3 days excreted formic acid in the urine but did not develop nephropathy. The induced formic aciduria was less pronounced in female rats and was less in male Wistar rats compared with male F344 rats. Yaqoob et al. (2014) compared the renal toxicity of trichloroethylene and trichloroethanol administered to male F-344 rats for 12 weeks to determine whether the GSH pathway or formic aciduria were responsible for nephrotoxicity. Although their findings did not clearly identify the pathway responsible for renal toxicity, the data provided some support for the GSH conjugation pathway.

Although rats chronically exposed to trichloroethanol excreted significantly larger amounts of formic acid and developed tubular degeneration, there were important dissimilarities in the characteristics of the nephrotoxicity compared with rats exposed to trichloroethylene or DCVC (USEPA 2011a). Histological changes associated with trichloroethylene and DCVC included karyomegaly, cytomegaly, and flattening and dilation of the tubular epithelium. These effects did not occur in rats exposed to trichloroethanol. Furthermore, no specific evidence links the particular nephrotoxic effects caused by trichloroethanol/formic acid to carcinogenesis. Thus, the data do not support the hypothesis that cytotoxicity mediated by oxidative metabolites via increased formic acid production is a major contributor to trichloroethylene-induced kidney carcinogenesis.

### 4.2.4 Summary

The mode of action for trichloroethylene-induced kidney cancer is not completely understood but the available data provide support for a mutagenic and cytotoxic mode of action mediated by GSH-conjugation-derived metabolites. There is experimental evidence that GSH metabolites (particularly DCVC) are genotoxic and nephrotoxic and are both formed in and delivered to the kidney following exposure to trichloroethylene. Factors that increase the proportion of trichloroethylene undergoing GSH conjugation (e.g., CYP enzyme inhibition or saturation, polymorphic expression of metabolizing enzymes) would be expected to increase kidney toxicity. Although there is some evidence that chronic tubular damage might be a precondition for the nephrocarcinogenic effects of trichloroethylene in humans, tubular toxicity has not been established as a necessary precursor or causal event for carcinogenesis. However, the data are consistent with the hypothesis that cytotoxicity and regenerative proliferation contribute to trichloroethylene-induced kidney tumors, most likely in combination with a mutagenic mode of action. Mutagenic and cytotoxic modes of action are relevant to humans. Other hypothesized modes of action for kidney carcinogenicity have inadequate or limited experimental support.