# 3 Human Cancer Studies

## Introduction

As discussed in the “Introduction” and “Methods” sections, the cancer hazard evaluation of trichloroethylene focuses on three specific cancers: kidney (see Section 4.1), NHL and its histological subtypes and related cancers (see Section 5.1), and liver (see Section 6.1). Because many studies (primarily the cohort studies) are common for all these cancer sites, this section provides information on the studies that are relevant for cancer hazard evaluation, including an overview of the studies’ methods and characteristics and an assessment of the studies’ ability to inform the cancer evaluation. The steps in the cancer hazard evaluation, including the location of the discussion of these steps, are listed below.

1. Selection of the relevant literature included in the cancer evaluation (Section 3.1 and Trichloroethylene Protocol, https://ntp.niehs.nih.gov/NTP/roc/thirteenth/Protocols/TCE_Protocol12-31-13_508.pdf).
2. Description of the study methods and characteristics and evaluation of study quality and other elements related to the utility of the studies to inform the cancer hazard evaluation: Cohort studies (Section 3.2, Table D-1, Table D-4, and Table D-5), kidney and liver case-control studies (Section 3.3, Table D-2, Table D-6 and Table D-7), and NHL case-control studies (Section 3.4, Table D-3, Table D-8, and Table D-9).
3. Cancer assessment: Kidney (Section 4.1), NHL and its subtypes (Section 5.1), and liver (Section 6.1).
4. NTP recommendation for the level of evidence of carcinogenicity (sufficient, limited, or inadequate) of trichloroethylene from human studies (Section 7).

## 3.1 Literature Search Strategy and Selection of the Relevant Literature

The literature search strategy (including the databases and search terms, and other sources for identifying literature) and procedures for selecting the literature (systematic screening procedures and inclusion/exclusion criteria) are described in detail in the Protocol (https://ntp.niehs.nih.gov/NTP/roc/thirteenth/Protocols/TCE_Protocol12-31-13_508.pdf). Primary epidemiological studies were considered for the cancer evaluation if the study was peer reviewed, provided risk estimates (or information to calculate risk estimates) for trichloroethylene and human cancer (kidney, liver, or NHL), and provided information specific for trichloroethylene exposure at the individual level or an estimate of the proportion of exposed subjects in defined exposure groups. Studies of dry cleaners and laundry workers were excluded, as the extent of exposure to trichloroethylene is often unclear and indistinguishable from tetrachloroethylene, or other petroleum-derived solvents such as carbon tetrachloride (NRC 2006). In general, cohort or case-control studies of populations with jobs, workplaces or environmental exposures in which trichloroethylene exposure may have occurred (e.g., studies of grouped chlorinated or organic solvents, degreasing agents, metal cleaners, or jobs and occupations such as degreasing, metalworking, painting, electronics manufacturing, aircraft manufacturing) were excluded if a specific risk estimate for trichloroethylene exposure was not reported as noted above, although several were included in one or more reviews or meta-analyses of trichloroethylene (Asal et al. 1988; Chang et al. 2003; Costa et al. 1989; Garabrant et al. 1988; Harrington et al. 1989; Seldén and Ahlborg 1991; Sinks et al. 1992). In addition, descriptive studies (with no risk estimate) and geographic studies were also excluded, again because these studies were unlikely to be specific for trichloroethylene exposure, with the exception of one drinking water study (Bove et al. 2014). This study was included because it identified an exposed cohort and assigned individual exposure based on the household drinking water level of trichloroethylene (rather than the township level), which increased the likelihood for ever exposure to trichloroethylene.

## 3.2 Cohort Studies

### 3.2.1 Overview of the Methodologies and Study Characteristics

Table 3-1 lists the 16 occupational cohort studies, nested case-control studies, or pooled analyses that satisfied the inclusion criteria. In general, the list includes only the latest update of the study or the most comprehensive report on a population; however, additional relevant analyses or information from previous publications are considered in the evaluation. Studies of overlapping publications are included if the overlap is not known and there are differences in methodologies (such as exposure assessment). For each of the reviewed studies, detailed data on study design, methods, and findings were systematically extracted from relevant publications, as described in the study protocol, into Table D-1 and Table D-2. The cohort and nested case-control studies can be divided into several broad occupational groups related to the exposure scenarios or occupations. Within each of these groups, studies are organized by descending publication date.

Table 3-1 Cohort and Nested Case-control Studies of Trichloroethylene Exposure

Reference | Population | Exposure Assessment Exposure Metric | Cancer Assessment Endpoints^a^
Nordic studies
Vlaanderen et al. (2013) | NOCCA study Population-based cancer registry and occupational database linkage Kidney (N = 76,130), liver (N = 896), NHL (N = 69,254), MM (N = 35,534) | Linkage of historical job information from census with national JEMs constructed from occupation data Cumulative exposure (incorporates exposure prevalence) | Incidence Internal analysis Kidney, liver, NHL, MM
Hansen et al. (2013) | Pooled Nordic biomonitored cohort: diverse occupations N = 5,553 workers | Urine TCA surveillance U-TCA (mg/L) | Incidence External and internal analyses Kidney, liver, NHL, MM
Raaschou-Nielsen et al. (2003) | Danish TCE-exposed blue-collar workers cohort: diverse occupations N = 40,049 | Blue-collar workers in TCE-using companies with potential exposure to TCE Employment duration Year of first employment (crude surrogate for exposure level) | Incidence External analysis Kidney, liver, NHL, MM
Aerospace and aircraft manufacturing workers
Lipworth et al. (2011) | Burbank, CA (USA) aircraft manufacturing workers cohort N = 5,443 | Qualitative JEM Employment duration | Mortality External and internal analyses Kidney, liver, NHL, MM
Radican et al. (2008)/Blair et al. (1998) | Utah (USA) aircraft maintenance workers cohort N = 7,204 | Semi-quantitative JEM Cumulative exposure (units/yr) Exposure pattern (continuous, intermittent, peaks) | Mortality (Radican)/ incidence (Blair) External and internal analyses Kidney, liver, NHL, MM
Boice et al. (2006) (overlaps with Zhao et al. (2005)) | Los Angeles (USA) rocket engine testing workers cohort N = 1,111 | Qualitative JEM Ever exposure Exposure duration (kidney only) | Mortality External and internal analyses Kidney, liver, NHL, MM, CLL
Zhao et al. (2005) (overlaps with Boice et al. (2006)) | Los Angeles (USA) aerospace workers cohort N = 6,044 | Semi-quantitative JEM Cumulative exposure score | Mortality/incidence External and internal analyses Kidney, liver, NHL + leukemia combined
Morgan et al. (1998) | Arizona (USA) aircraft manufacturing workers cohort N = 4,733 | Semi-quantitative JEM Cumulative exposure score | Mortality External and internal analyses NHL, kidney, liver
Other studies of specific industries
Silver et al. (2014) | New York (USA) micro-electronics manufacturing cohort N = 34,494 | Department-year exposure matrix Cumulative exposure ranking | Mortality Internal analyses Kidney, NHL, multiple myeloma, liver, biliary and gallbladder combined
Bahr et al. (2011) | Kentucky (USA) uranium enrichment workers cohort N = 4,792 | JEM Exposure level (ranked order) | Mortality External and internal analyses NHL, liver
Yiin et al. (2009) | Tennessee (USA) nested case-control study of uranium enrichment workers N = 47,941 cohort 98 MM cases, 483 controls | Modified semi-quantitative JEM TCE evaluated as a potential confounder; major focus: uranium exposure Average cumulative exposure score | Mortality Internal analysis MM
Ritz (1999) | Ohio (USA) uranium processing workers cohort N = 3,184 | Semi-quantitative JEM Exposure level (low, moderate) Exposure duration | Mortality Internal analysis Liver
Henschler et al. (1995) | German cardboard manufacturers cohort N = 169 | Job location from individual work histories and knowledge of plant conditions. Ever exposed | Incidence External and internal analyses Kidney
Greenland et al. (1994) | Massachusetts (USA) nested case-control study of electrical manufacturers cohort N = 1,821 cohort; 512 cancer deaths; 1,202 non-cancer deaths (controls) | Qualitative JEM Ever exposed | Mortality Kidney (N = 12), liver (N = 9), lymphoma (N = 15)
Wilcosky et al. (1984) | Ohio (USA) nested case-control study of rubber manufacturing workers cohort N = 6,678 cohort (controls 20% sampling) | Working in area of authorized use of specific solvents Ever exposed (potential) | Mortality NHL (N = 9)
Environmental exposure
Bove et al. (2014) | North Carolina (USA) military cohort Drinking water study N = 154,932 | Duration of residence and modeled TCE concentration in drinking water and cumulative exposure TCE (μg/L-month) | Mortality External and internal analyses NHL, kidney, liver

CLL = chronic lymphocytic leukemia; JEM = job-exposure matrix; MM = multiple myeloma; NHL = non-Hodgkin lymphoma.

^a^ Cancer endpoints of a priori interest only (kidney cancer, liver cancer, and NHL and its subtypes).

#### 3.2.1.1 Nordic Studies: Three Incidence Studies

Several cohort studies reporting on cancer incidence were published among workers in Nordic countries. These studies include subjects with occupational exposure to trichloroethylene from diverse industries, and workers and exposed subjects were identified from broad occupational or population-based databases. The largest study (Vlaanderen et al. 2013) includes trichloroethylene-exposed workers in the Nordic Occupational Cancer (NOCCA) study, which links occupational data reported in censuses (Sweden, Finland, Denmark, Iceland, and Norway) with their national cancer registries. The census occupational history data were linked to the NOCCA job exposure matrix (JEM) to develop semi-quantitative estimates of exposure to trichloroethylene. This large study may have included some of the same subjects as the other studies, but these were likely a very small percentage. Three cohort studies reported on cancer findings among workers who had urinary trichloroacetic acid (U-TCA) measurements as part of trichloroethylene monitoring programs in Sweden (Axelson et al. 1978; Axelson et al. 1994), Finland (Anttila et al. 1995), and Denmark (Hansen et al. 2001). These workers were included in a pooled analysis reported by Hansen et al. (2013), which is reviewed rather than the individual studies because it includes all the workers from the constituent studies and uses a similar exposure assessment (although any additional information from the individual studies will be brought forward). The third cohort study is of blue-collar Danish workers at companies using trichloroethylene (Raaschou-Nielsen et al. 2003). Although this study may include a small proportion of workers from the Danish component of the pooled analysis, it is included in the review because the extent of the overlap is unknown, and the exposure assessment is different.

#### 3.2.1.2 Aerospace (Rocket Engine) and Aircraft Manufacturing Workers: Five Incidence or Mortality Studies

Two cohort studies evaluated risk among rocket engine workers with potential exposure to trichloroethylene at the Santa Susana Field Laboratory (SSFL) in California; these studies are part of the Rocketdyne Aerospace workers cohort (Boice et al. 2006; Zhao et al. 2005). Although there is likely to be considerable overlap between the two studies, both studies are reviewed (noting potential overlap) because of differences in exposure and disease assessments and numbers of exposed workers. Boice et al. (2006) reported mortality findings based on a qualitative exposure assessment and Zhao et al. (2005) reported both mortality and incidence findings for trichloroethylene-exposed workers (intensity score >3) based on a semi-quantitative JEM. Among the three cohort studies of U.S. aircraft manufacturing workers with potential exposure to trichloroethylene, two cohort studies reported mortality findings (Lipworth et al. 2011; Morgan et al. 1998) and the third (Blair et al. 1998; Radican et al. 2008) reported both incidence and mortality. Morgan et al. (1998) and Radican et al. (2008) used a semi-quantitative exposure assessment and Lipworth et al. (2011) used a qualitative exposure assessment, all of which assigned exposure using individual work history information and expert-assigned JEMs. All studies conducted both internal and external analyses.

#### 3.2.1.3 Other Studies of Specific Industries: Seven Incidence or Mortality Studies

Two cohort studies (Bahr et al. 2011; Ritz et al. 1999) and one nested case-control study (Yiin et al. 2009) of uranium processing or enrichment workers, which used a JEM and/or individual work histories to classify workers according to ranked exposure levels or probability of exposure, were identified that met the inclusion criteria. Bahr et al. (2011) evaluated cancer incidence and mortality among Kentucky uranium enrichment workers, and Ritz (1999) and Yiin et al. (2009) evaluated mortality among Ohio and Tennessee uranium processing workers, respectively. The nested case-control study by Yiin et al. (2009) of multiple myeloma evaluated trichloroethylene as a potential confounder for uranium exposure, which was the major focus of the study. The remaining studies consisted of one study in each of several different manufacturing industries using trichloroethylene as a degreaser or solvent. Silver et al. (2014) conducted a cohort mortality analysis of New York electronics workers, based on ranked exposure scores. A small cohort study of German cardboard manufacturing workers focusing on renal-cell carcinoma (Henschler et al. 1995) assessed exposure using job location at the plant and surveys of plant conditions. Greenland et al. (1994) conducted a nested case-control study of lymphoma, and kidney and liver cancer among a cohort of workers at a Massachusetts electrical transformer manufacturing plant, using a qualitative JEM to assess exposure. Finally, Wilcosky et al. (1984) reported on a small nested case-control study of NHL and other cancers among a cohort of rubber manufacturing workers in which potential exposure to trichloroethylene was assessed by work in an area where trichloroethylene was authorized for use.

#### 3.2.1.4 Environmental Exposure: One Mortality Study

In the drinking water study, exposure to trichloroethylene was based on duration at a residence and modeled trichloroethylene concentration levels from the water supply system (Bove et al. 2014).

### 3.2.2 Evaluation of Study Quality and Other Elements Related to the Utility of the Studies to Inform the Cancer Hazard Evaluation

This section discusses the assessment of study quality and other elements related to the utility of the individual studies to inform the cancer hazard evaluation. Each study was assessed (prior to evaluating the findings) for the potential for biases and other factors related to informing the cancer hazard evaluation according to the approach described in the protocol. (See Table D-4 and Table D-5 for a study-by-study assessment of potential for biases, study quality, and study sensitivity.) The impact of these factors, for example the analysis of cancer incidence vs. mortality, the length of follow-up, the potential for disease misclassification, and the statistical power of the study, may differ according to the specific cancer endpoint being evaluated (kidney cancer, liver cancer, and NHL and its subtypes), and will be discussed separately where relevant.

#### 3.2.2.1 Selection Bias

The potential for selection bias was considered unlikely in the majority of cohort or nested case-control studies (Blair et al. 1998; Bove et al. 2014; Hansen et al. 2013; Lipworth et al. 2011; Morgan et al. 1998; Radican et al. 2008; Vlaanderen et al. 2013; Wilcosky et al. 1984; Zhao et al. 2005). There was the potential for bias in the following studies. The German cardboard manufacturing cohort (Henschler et al. 1995) was initiated because of a cluster of renal cancers and included the index cases in their cohort analysis (Bloemen and Tomenson 1995; IARC 2014), which would result in an over-estimate of the risk estimate. In two of the uranium workers cohorts (Ritz 1999; Yiin et al. 2009), workers were selected based on having radiation monitoring data, which may result in selection bias (if trichloroethylene-exposed workers without monitoring data were excluded) and potential confounding. In the nested case-control study of electrical workers by Greenland et al. (1994), the cohort was selected from workers participating in the pension scheme, introducing potential selection bias. In addition, the blue-collar workers included in the Nordic study by Raaschou-Nielsen et al. (2003) differed with respect to socioeconomic status from the referent (general) population, which may result in an over- or underestimate of expected cases, depending on the endpoint. Little information was provided to evaluate how workers were selected or excluded in the study of Kentucky uranium enrichment workers (Bahr et al. 2011).

There was evidence of a possible healthy worker effect in five studies, based on statistically significant decreases in all-cause mortality rates: the aerospace worker study reported by Boice et al. (2006), two aircraft manufacturing studies (Lipworth et al. 2011; Morgan et al. 1998), and two studies of uranium workers (Bahr et al. 2011; Ritz 1999); and the micro-electronic study (Silver et al. 2014) and the study of cardboard manufacturing workers (Henschler et al. 1995). A healthy worker effect would bias the findings of an external analysis towards the null. The study by Silver et al. (2014) only conducted internal analyses. There was also evidence for a healthy worker survival effect in the study by Bahr et al. (2011), which would also bias internal analyses. In addition, three of the cohorts are relatively young (Bove et al. 2014; Raaschou-Nielsen et al. 2003; Silver et al. 2014), suggesting that further follow-up would be informative.

There was generally insufficient information to evaluate the possibility of systematic selection out of the cohorts once established with the possible exception of Bahr et al. (2011) as noted above. The loss to follow-up was minimal in the studies that reported it, but it is not reported in several studies. Internal analyses, conducted in addition to external (SMR, SIR) analyses in the majority of cohort studies (Boice et al. 2006; Bove et al. 2014; Hansen et al. 2013; Henschler et al. 1995; Lipworth et al. 2011; Morgan et al. 1998; Radican et al. 2008; Ritz 1999; Vlaanderen et al. 2013; Zhao et al. 2005), also indirectly address the potential for selection bias.

#### 3.2.2.2 Information Bias: Exposure Assessment

The quality of the exposure assessment and the potential for exposure misclassification were systematically evaluated for each study. In general, the evaluation of the exposure assessment refers to the quality of the expert assessment and/or JEM used to evaluate the frequency, confidence, and probability of exposure to trichloroethylene from specific jobs or tasks. The evaluation of the potential for exposure misclassification integrates the quality of the exposure assessment with other exposure information such as the exposure setting. The majority of studies used qualitative exposure assessments or semi-quantitative categories of exposure based on job-exposure or job-task exposure matrices and/or estimates of exposure ranks or levels; quantitative historical exposure monitoring data, if available, were limited. The quality of job-exposure matrices and similar methods of estimating exposure varies considerably; for example, generic JEMs based on broad occupational or industry classifications (e.g., occupational titles or standardized industrial classification codes) may be insufficiently detailed for specific workplaces, jobs or tasks compared with those developed specifically for the study and validated or reviewed using, for example, expert assessment or veteran workers.

In the most recent population-based Nordic study (Vlaanderen et al. 2013), exposure was assessed by linking generic country-specific JEMs to job titles reported on census data. Individuals were assumed to have the same job between censuses. Cumulative exposure was characterized as the product of the average exposure intensity and prevalence of exposure. For jobs with low exposure prevalence, this approach would underestimate exposure intensity and classify unexposed workers with these jobs as exposed. Misclassification of exposure for individual participants was likely to be considerable because of the lack of detailed occupational information (tasks and working conditions), heterogeneity of exposure levels within and across jobs with the same job title, and overtime.

The pooled and updated Nordic study of Hansen et al. (2013) was based on biomonitoring data (urinary U-TCA measurements), together with some ambient air monitoring data. This study most likely had high sensitivity for identifying exposed workers; however, specificity may be a concern because some workers were exposed to other chlorinated solvents that are metabolized to TCA (Anttila et al. 1995). In addition, because large numbers of workers may have only had one to three U-TCA measurements, and the half-life of U-TCA is approximately 100 hours, the available U-TCA measurements may not represent a worker’s past or future exposure to trichloroethylene. Individuals classified as unexposed workers could in fact be exposed and misclassification of intensity of exposure is possible. Furthermore, this study did not provide information on lifetime or cumulative exposure, thus limiting the analysis of exposure-response relationships.

Non-differential misclassification of exposure was a concern in the Danish blue-collar workers study (Raaschou-Nielsen et al. 2003), in which an estimate of the proportion of blue-collar workers in companies using trichloroethylene was used as a surrogate for trichloroethylene exposure; only an estimated 41% of workers included in the analysis were probably exposed to trichloroethylene. Air and urine monitoring data were available for only a small proportion of workers. Although these measurements were not used in the exposure assessment, they provided information on the estimated level of exposure for different calendar periods, which was used in the analysis as a surrogate for exposure intensity. There was greater confidence in exposure classification for the analyses of a subcohort considered to have higher exposure than for the entire cohort.

Among the five U.S. aerospace or aircraft manufacturing cohorts, the studies that used semi-quantitative job-exposure matrices based on detailed job tasks and work histories to classify exposure among individual workers by ever vs. never, and/or by categories of exposure level or duration of employment (Blair et al. 1998; Morgan et al. 1998; Radican et al. 2008; Zhao et al. 2005) were the most informative with respect to the overall quality of the exposure assessment; Zhao et al. (2005) classified aerospace workers as exposed if they had a trichloroethylene exposure score >3, which reduced the potential for exposure misclassification. Although the quality of the exposure assessment of the Utah aircraft-manufacturing workers by Radican et al. (2008) was considered to be adequate, exposure assessment for some subjects with missing exposure records was based on position description, which increases the potential for exposure misclassification. A limitation of the study of Arizona aircraft manufacturing workers (Morgan et al. 1998) was that the exposure assessment does not appear to be calendar specific; however, there was greater confidence of actual exposure among the highest exposed workers in this study. The exposure assessments of the other two studies (Boice et al. 2006; Lipworth et al. 2011), especially the study of California aircraft manufacturing workers, were considered to be more limited because they provided little information on exposure intensity. In the study of aerospace workers by Boice et al. (2006), non-differential exposure misclassification was a concern in the analysis of any exposure to trichloroethylene, (which included test stand mechanics using trichloroethylene as a general utility cleaning agent) although there was greater confidence in actual exposure in the analysis restricted to exposure duration of workers engaged in test engine flushing, a task in which exposure intensity is suspected to be high. No information or analysis of exposure intensity was available for the California trichloroethylene-exposed aerospace workers studied by Lipworth et al. (2011); evaluation of exposure-response relationships was based only on duration, i.e., length of time in jobs with potential exposure to trichloroethylene; no data were reported for exposure intensity or cumulative exposure.

In general, exposure misclassification was a concern in the studies of other specific industries because of low-quality exposure assessments with the possible exception of the German study of cardboard manufacturing workers (Henschler et al. 1995). Although the exposure assessment in this study was based on job location in the plant as well as a detailed description of the work environment and considered to be of limited quality, exposure misclassification is unlikely because high levels of exposure in an open system in small work environments were likely to have occurred in the past, based on job task descriptions of and reports of illness and the odor or taste of trichloroethylene by workers. Wilcosky et al. (1984) classified workers based on ever working in an area of authorized use of trichloroethylene in the nested case-control study of rubber workers; however, actual use of trichloroethylene was not reported, and thus the exposure assessment was considered to be inadequate to inform the hazard evaluation.

The remaining studies used JEMs of varying quality to estimate ranked exposure level (Bove et al. 2014; Ritz 1999), duration (Ritz 1999), probability of exposure (Bahr et al. 2011), a cumulative exposure score (Silver et al. 2014; Yiin et al. 2009) or ever exposure (Greenland et al. 1994). The quality of the exposure assessment in two studies of uranium enrichment or processing workers using semi-quantitative assessments (Ritz 1999; Yiin et al. 2009) were considered to be somewhat better than the other studies. Ritz (1999) used a semi-quantitative exposure assessment, although not calendar-year specific, to assign uranium-processing workers to two exposure categories. A modified job-exposure matrix was employed in the Tennessee uranium workers nested case-control study (Yiin et al. 2009). Exposure assessment in the electronics worker cohort (Silver et al. 2014) used a relative cumulative exposure score, based on department-year level use of trichloroethylene and employment duration. Non-differential exposure misclassification was a concern in this study due to lack of information on job tasks, exposure conditions, levels of use and incomplete records. Electronic workers in the nested case-control study by Greenland et al. (1994) were classified as ever exposed to trichloroethylene based on a generic JEM. It is difficult to evaluate the quality of the exposure assessment including the basis for the exposure probabilities categories in the study of Kentucky uranium processing workers (Bahr et al. 2011) because of inadequate information provided in the publication. Finally, in the cohort study of drinking water contamination (Bove et al. 2014), exposure misclassification for both ever exposure and exposure category (based on modeled trichloroethylene concentration by residence) was a concern, although less so for participants estimated to have higher cumulative exposure.

In all the studies, the potential for exposure misclassification was generally considered to be non-differential and would most likely bias towards the null. In subgroup analyses, exposure misclassification between exposure groups would most likely attenuate any exposure-response relationships.

#### 3.2.2.3 Information Bias: Cancer Ascertainment and Disease Misclassification

Studies evaluating cancer incidence (or incidence and mortality) (Bove et al. 2014; Hansen et al. 2013; Henschler et al. 1995; Raaschou-Nielsen et al. 2003; Radican et al. 2008; Vlaanderen et al. 2013; Zhao et al. 2005) Mortality-only analyses (Bahr et al. 2011; Boice et al. 2006; Greenland et al. 1994; Lipworth et al. 2011; Morgan et al. 1998; Ritz 1999) Disease misclassification was unlikely for kidney cancers (and for liver cancers, either in the mortality-only studies or the incidence analyses. Mortality analyses are less informative for kidney cancer due to high 5-year survival rates. Disease assessment was considered to be limited in the German study of cardboard manufacturing workers because different methods for disease diagnosis may have been used for the exposed cohort (physicians’ records, abdominal sonogram) than for the general population, which could potentially bias external analyses towards an over-estimate of the risk estimate. This bias should not affect internal analyses. The quality of disease ascertainment of the Kentucky uranium enrichment workers (Bahr et al. 2011) could not be evaluated because of inadequate information on the source and completeness of vital status and cause of death data.

In the case of NHL and its subtypes, however, changes in classification systems, together with differences between studies with respect to groupings of lymphohematopoietic cancer endpoints used in analyses, were of greater concern. Considerable changes in the classification systems used for these lymphomas have been made. Starting with the Revised European American Classification of Lymphoid Neoplasms (REAL) in 1994 (Harris et al. 1994), which was partly incorporated into the ICD Oncology Second Revision (ICD-O-2), recent substantial revisions in the classification of NHL and its subtypes were made by the WHO in 2001 (Morton et al. 2007) (and again in 2008) and used in the ICD Oncology Third Revision (ICD-O-3). The 2001 and 2008 revisions are the most informative for the classification of NHL and its subtypes. The ICD-7 NHL classifications used in the Nordic studies (Hansen et al. 2013; Raaschou-Nielsen et al. 2003; Vlaanderen et al. 2013) and to a lesser extent the older classifications used by Greenland et al. (1994), Morgan et al. (1998), Blair et al. (1998), Ritz (1999) , Boice et al. (2006), Lipworth et al. (2011), Bahr et al. (2011), Silver et al. (2014) and Yiin et al. (2009) were somewhat broader and less informative than more recent systems, which were applied in only two studies (Radican et al. 2008; Zhao et al. 2005).

Finally, death certificate data used in mortality studies (which also use underlying cause of death only, with the exception of Zhao et al. (2005)), may be more likely to result in both missing cases and NHL misclassification than cancer registry data used in incidence studies.

#### 3.2.2.4 Study Sensitivity and Exposure-response Relationships

In addition to the analyses of biases and confounding, study sensitivity and analyses of exposure-response relationships also impacts the ability of a study to inform the cancer evaluation. Study sensitivity (or the ability to detect an effect), is dependent on the numbers of exposed subjects or cases and controls (which is related to the sample size and exposure prevalence), exposure level (intensity and/or duration), and the length of follow-up, which is of particular concern for longer latency cancers such as liver and kidney cancer. True relative risks will usually be lower among study populations with lower exposure (NRC 2006) and are also dependent on the biological properties of the agent. The evaluation of exposure-response relationships depends on an adequate range of exposure (in intensity or duration) among the study participants, adequate numbers of subjects in each exposure category and the confidence with which exposure groups are correctly classified.

A strength of the database is that all the studies had relatively long overall follow-up periods, although the average length of follow-up is not always clear. Three cohorts (Bove et al. 2014; Raaschou-Nielsen et al. 2003; Silver et al. 2014) were relatively young, however, suggesting additional follow-up may be informative, particularly for kidney and liver cancer.

Without considering exposure levels or exposure misclassification, only the largest cohort studies (Bove et al. 2014; Hansen et al. 2013; Lipworth et al. 2011; Raaschou-Nielsen et al. 2003; Radican et al. 2008; Vlaanderen et al. 2013) probably had adequate statistical power to observe a two-fold relative risk (see calculations by EPA (2011a) and NRC (2006) for some of these studies) for ever vs. never exposed analyses, and only the two largest Nordic cohorts (Raaschou-Nielsen et al. 2003; Vlaanderen et al. 2013) had adequate numbers of cases in subgroup analyses, specifically for the highest trichloroethylene-exposed workers in the cohort. Most studies may not have had sufficient power to detect lower risk estimates (e.g., 1.3) for ever vs. never exposure. Some studies did not report the number of trichloroethylene-exposed cases for the cancer sites of interest (Silver et al. 2014; Yiin et al. 2009).

Although overall there are limited quantitative ambient or personal air monitoring data in the body of studies, there were reported levels of exposure for some of the Nordic studies and estimated levels of exposure for other populations. Moreover, different studies used different exposure metrics (see Table 3-1), which complicates comparisons of exposure levels across studies. Biomonitoring data from individual studies in the pooled Nordic cohort (Hansen et al. 2013) indicated that exposure levels were relatively low in this study (median equivalent ambient trichloroethylene levels probably ranged between 4 and 12 ppm based on the individual studies) and only 20% of the subjects had U-TCA levels >50 mg/L, which is equivalent to approximately 20 ppm ambient air trichloroethylene, in the pooled analyses. Ambient air monitoring data relevant to Raaschou-Nielsen et al. (2003) (see Raaschou-Nielsen et al. (2002)) indicate that exposures were higher prior to 1970 (40 to 60 ppm), 10 to 20 ppm between 1970 and 1979 and 4 ppm after 1980. Thus, analyses of the subcohort of presumably higher exposed workers with employment before 1980 are considered to be more informative than analyses for the total cohort. Exposure levels, although not measured, were estimated by the JEM to be low in the large study reported by Vlaanderen et al. (2013). Estimated median exposure (units-yr [approximately equivalent to ppm]) for the cumulative exposure categories were 0.01 to 0.04 for the first tertile (depending on the endpoint), 0.12 to 0.13 for the second tertile, and 0.72 to 0.77 for the third tertile of cumulative exposure. However, the use of prevalence to calculate cumulative exposure complicates the interpretation of these levels. High exposure in this study was assigned to laundry workers, shoe and leather workers, or mechanics.

There were few data on exposure levels among the aerospace and aircraft cohorts. Most of the available data were estimated levels for Radican et al. (2008). Exposure intensity from degreasing was most likely high (ranging from 200 to 600 ppm depending on time period) and estimated cumulative exposure was likely to range from 8 to 38 ppm-yr for use as a degreasing agent and 5 to 15 ppm-yr for benchwork (personal communication from Dr. Patricia Stewart to Dr. Ruth Lunn [June 23, 2014]). The National Academy of Sciences (NRC 2006) concluded that the cohort had modest numbers of highly exposed workers but most workers were exposed to approximately 10 ppm. There were few exposed cases (<5) for kidney or liver cancer and 12 cases of NHL in the highest exposed group, and thus the study had limited statistical power to evaluate effects from high exposure to trichloroethylene. Little information is available on the other cohorts, although exposures among the highest exposure group in the study by Morgan et al. (1998) were estimated to be >50 ppm. Exposure intensity was likely high among test mechanics in the aerospace worker cohort especially in the earlier time periods (Boice et al. 2006; Zhao et al. 2005). The study by Lipworth et al. (2006) was considered to have limited ability to detect an effect because exposure duration can be an insensitive metric for cumulative exposure and was likely to be low. The cohort enrolled workers employed at three facilities on or after 1960; however, trichloroethylene use ceased in 1966, and an unknown proportion of the cohort was exposed for shorter periods, although they were followed for long periods of time. Years exposed would include individuals with low and high cumulative and intensity of exposure.

In the German study of cardboard manufacturing workers, estimated peak exposure was >2,000 ppm and long-term exposure exceeded 100 ppm (Cherrie et al. 2001); in addition, the workers were exposed for long periods (average 17.8 months). Thus, despite the low numbers of exposed cases, statistical power was probably adequate to detect the effect of high exposure. Exposure levels were not measured or estimated in the other studies (Fleming et al. 2014; Silver et al. 2014; Yiin et al. 2009). In other studies, exposure level (Ritz 1999), probability (Wilcosky et al. 1984), or few workers appear to be exposed to trichloroethylene by indirect means (Greenland et al. 1994). With respect to the drinking water study (Bove et al. 2014), the authors estimated that maximum consumption could be 3.6 mg/day from water, based on measured trichloroethylene levels (combining ingestion, dermal, and inhalation exposure from showering), which would be the equivalent of approximately 0.07 ppm as an 8-hour TWA (assuming 100% intestinal absorption) and potentially as high as 25 ppm-year. It is more difficult to assess levels of exposure due to unknown actual individual consumption patterns and compare with studies in which ambient exposure occurred, due to uncertainty as to whether biological effects would differ by route of exposure. In addition, the number of exposed cases in subgroup analyses was not reported.

The ability of a study to evaluate exposure-response relationships depends on the adequacy of the exposure assessment, statistical power, and range of exposure levels included in the exposure-response analysis. Of the 16 identified studies, 10 reported risk estimates for 2 or more categories of exposure (Bahr et al. 2011; Boice et al. 2006; Bove et al. 2014; Hansen et al. 2013; Lipworth et al. 2011; Morgan et al. 1998; Raaschou-Nielsen et al. 2003; Radican et al. 2008; Ritz 1999; Vlaanderen et al. 2013; Zhao et al. 2005). However, most studies had limited ability to evaluate exposure-response relationships because of (1) lack of information on lifetime exposure (Hansen et al. 2013), (2) substantial concerns for exposure misclassification (Bove et al. 2014; Vlaanderen et al. 2013), (3) limited range of exposure levels because of overall low exposure levels or only two exposure categories (Boice et al. 2006; Morgan et al. 1998; Ritz 1999; Vlaanderen et al. 2013), (4) adequacy of the exposure surrogate for evaluating exposure, i.e., time since first exposure (Raaschou-Nielsen et al. 2003), exposure probability (Bahr et al. 2011), and exposure duration (Boice et al. 2006; Lipworth et al. 2011), or (5) limited statistical power because of few subjects in each exposure subgroup (most studies except for Vlaanderen et al. (2013)). The remaining studies only reported risk estimates for one category of exposure (Greenland et al. 1994; Henschler et al. 1995; Silver et al. 2014; Wilcosky et al. 1984; Yiin et al. 2009).

#### 3.2.2.5 Methods for Evaluating Confounding

The majority of cohort and nested case-control studies conducted age-, sex-, race- and calendar year- or period-standardized comparisons in external analyses (SMR or SIR) where appropriate and age-, sex-, race- and in some cases calendar-period-adjusted comparisons in internal analyses. Most studies did not collect information on lifestyle factors, although internal analyses were conducted in a number of studies, which can reduce the potential for confounding as well as selection bias. However, confounding is generally unlikely to strongly influence risk estimates unless there is a strong association between the potential confounder to both exposure and cancer endpoint, which has not been demonstrated for most lifestyle or demographic factors or many of the identified co-exposures. The most informative study for considering confounding was the study of aircraft workers by Zhao et al. (2005), which conducted analyses controlling for co-exposures. Some studies conducted separate analyses of major co-exposures (Boice et al. 2006; Bove et al. 2014; Zhao et al. 2005). Yiin et al. (2009) conducted multivariate analyses including trichloroethylene, nickel, mercury, and radiation dose, although the latter was the primary focus of the study and thus detailed exposure data on trichloroethylene exposure was lacking. A discussion of confounding is presented in the cancer evaluation of each cancer endpoint, as their potential impact differs depending on the specific cancer endpoint.

#### 3.2.2.6 Summary

The database of cohort studies consisted of a large number of studies, many of which were considered to have adequate methodologies for evaluating potential cancer hazards. Although many of the cohorts were relatively large, most studies were still underpowered because of few exposed cases or deaths, especially in subgroups with higher exposure to trichloroethylene, to evaluate risks from the cancer sites of a priori interest, i.e., kidney cancer, liver cancer, and NHL, which are relatively uncommon. In addition, for some studies with adequate numbers of observed cases or deaths for kidney cancer, NHL, or liver cancer, exposure levels for trichloroethylene were low and/or exposure misclassification was a concern. Figure 3-1 depicts the overall assessment of the ability to inform the cancer evaluation based on the overall utility of the studies, including potential for biases and study sensitivity. The most informative studies (moderate- or high-utility studies) include the Nordic study of biomonitored workers (Hansen et al. 2013), and the aerospace and aircraft worker cohorts by Zhao et al. (2005), Morgan et al. (1998), and Radican et al. (2008)/Blair et al. (1998). Overall, these studies had adequate methods to assess exposure, little evidence of differential biases, and evaluated risks among subjects exposed to moderate to high levels of trichloroethylene. The study of aerospace workers (Zhao et al. 2005) was considered to be the most informative study because it evaluated cancer incidence, conducted detailed analysis of exposure-response relationships, and adjusted for potential confounding from co-exposures. Although the biomonitoring study was relatively good for identifying individuals who were ever exposed to trichloroethylene, U-TCA may not be a good marker for lifetime exposure or exposure intensity. The study by Morgan et al. (1998) was ranked lower for evaluating NHL compared with kidney and liver cancer because of fewer NHL cases compared with cases for the other endpoints.

Figure 3-1

Study Utility Ranking: Cohort Studies

E/R = exposure response.

Gray shading (left-hand column): Utility to inform hazard evaluation; light shading = highest utility; dark shading = lowest utility. Blue shading (right-hand column): Potential bias and study sensitivity; light shading = least biased or most sensitive; dark shading = overall potential biases towards the null or lower sensitivity.

^a^(Tan shading): Multiple limitations; overall direction of potential biases is unknown.

^b^(Peach shading): Most potential biases away from the null.

Studies considered to have low/moderate ability to inform the cancer hazard evaluation, primarily because of more limited (mainly qualitative) exposure assessments and/or lower sensitivity, include the Nordic blue-collar worker study by Raaschou-Nielsen et al. (2003), aerospace workers by Boice et al. (2006), California aircraft manufacturing workers (Lipworth et al. 2011), and the nested case-control study of multiple myeloma among Tennessee uranium enrichment workers (Yiin et al. 2009). In the blue-collar worker study, the analysis of the subcohort of workers employed before 1980, when exposure levels were high, was considered to be more informative than analysis of the entire cohort. Exposure levels were presumably moderate to high in these studies; however, the study by Lipworth et al. (2011) only evaluated exposure duration, which most likely included workers with low levels of exposure. In addition, exposure duration was likely short in this study, which limited its sensitivity to detect an effect. In the Nordic study of blue-collar workers, there was the potential for confounding by, e.g., smoking, due to the differences in socioeconomic status between the cohort and the referent population; potential residual confounding from radiation exposure was also considered possible in the study by Yiin et al. (2009). Overall, however, the other limitations in all the studies (e.g., study sensitivity) were primarily toward the null.

The population-based Nordic study (Vlaanderen et al. 2013), the study of micro-electronic workers (Silver et al. 2014), the drinking water study (Bove et al. 2014), and the nested case-control study of electrical workers (Greenland et al. 1994) were considered to be of limited ability to inform the cancer hazard evaluation primarily because of low study sensitivity (e.g., lower levels of exposure) or potential for exposure misclassification. Studies having potential differential biases (away from the null) or potential confounding from occupational co-exposures include the German cardboard manufacturers cohort study (Henschler et al. 1995) and the uranium enrichment workers study (Ritz 1999). The study by Bahr et al. (2011) had limited documentation on the selection of the cohort and exposure and disease assessments, which complicate the evaluation of its quality. Finally, there was low confidence as to whether exposure to trichloroethylene occurred in the nested case-control study by Wilcosky et al. (1984) in addition to other methodological concerns and it was considered to have inadequate utility and was not brought forward in the hazard evaluations for specific cancers (Sections 4, 5, and 6).

## 3.3 Kidney or Liver Cancer Case-control Studies

### 3.3.1 Overview of the Methodologies and Study Characteristics

Table 3-2 lists seven kidney case-control studies that satisfied the inclusion criteria; one of these studies also reported on liver cancer (Christensen et al. 2013) (see Section 6). These include four studies conducted in areas with presumably higher levels and prevalence of trichloroethylene exposure using experts with knowledge of the local industry, and three studies of more widespread populations with more varying exposure potential for trichloroethylene, resulting in an overall lower average exposure levels in these populations. A multi-center study of renal-cell cancer was conducted in four countries of Central and Eastern Europe, in which occupational exposure to trichloroethylene was thought to be higher and more prevalent than in other industrial areas. Exposure was assessed in each of the different countries by a team of experts with knowledge of industries in their area (Moore et al. 2010). Charbotel et al. (2006); (2009) conducted a case-control study of kidney cases in the Arve Valley, France, which is an area with a widespread screw-cutting industry that used trichloroethylene as a degreaser. Although population based, the French and German studies had a higher prevalence of subjects with presumably higher levels of trichloroethylene and from more homogenous industries. Two studies (Brüning et al. 2003; Vamvakas et al. 1998) were conducted on a non-overlapping consecutive series of cases and controls among the same general population in the town and immediate surrounds of Arnsberg, Germany (Vamvakas et al. 1998) or the town and a somewhat wider surrounding area (Brüning et al. 2003), which has a large number of companies doing metal and electronics work. Trichloroethylene use was widespread and one of only two principal solvents (the other was carbon tetrachloride) used in the industry. Neither study included renal-cell carcinoma (RCC) cases from the cohort study of workers at a cardboard factory from the same region (Henschler et al. 1995). Although population based, the French and German studies had a higher prevalence of subjects with presumably higher levels of trichloroethylene and from more homogenous industries. The remaining studies included population-based case-control studies in Minnesota (Dosemeci et al. 1999) and Germany (Pesch et al. 2000b) and a population-based study using both population and hospital controls in Montreal, Quebec (Christensen et al. 2013). The population-based study by Pesch et al. (2000b) included five German regions, one of which (Leverkusen) was, like Arnsberg, in North Rhine-Westphalia.

Table 3-2 Case-control Studies of Trichloroethylene Exposure: Kidney or Liver Cancer

Primary Reference | Study Population Total # Cases/Controls | Exposure Assessment Exposure Metric | Cancer Assessment
Studies in specific areas with knowledge of local industries
Moore et al. (2010) | Multi-center, Central and Eastern Europe, hospital-based 1,097/1,476 | In-person interviews using structured questionnaire, expert assessment Exposure duration (years, hours) Cumulative exposure (ppm-yr) Average exposure (ppm) | Incident RCC cases
Charbotel et al. (2006); Charbotel et al. (2009) | Arve Valley, France, hospital-based 86/326 | Telephone interviews using structured questionnaire, expert assessment, semi-quantitative JEM Cumulative exposure (ranked) | Incident and deceased RCC cases
Brüning et al. (2003) | Arnsberg, Germany, hospital-based 134/401 | In-person or proxy interviews using structured questionnaire, self- and expert assessment (JEM) Exposure + narcotic symptoms Exposure duration (yr) Longest job using TCE, metal degreasing | Incident and deceased RCC cases
Vamvakas et al. (1998) | Arnsberg, Germany, hospital-based 58/84 | In-person (case or proxy) interviews using structured questionnaire, expert assessment Ever exposed Exposure category (ranked) | Incident and deceased RCC cases
Other studies
Christensen et al. (2013) | Montreal, Quebec (Canada), hospital- and population-based 177/533 | In-person interviews using structured questionnaire, expert assessment Ever and substantial exposure (includes probability) | Incident RCC and liver cancer cases
Pesch et al. (2000b) | Multi-center, Germany, population-based 935/4,298 | In-person interviews using structured questionnaire, expert assessment, JTEM Median, high & substantial exposure (includes probability) | Incident RCC cases
Dosemeci et al. (1999) | Minnesota, (USA) population-based 438/687 | In-person interviews using structured questionnaire (occupation, exposures), JEM Ever exposed | Incident RCC cases

JEM = job-exposure matrix; JTEM = job-task exposure matrix; RCC = renal-cell carcinoma.

For each of the reviewed studies, detailed data on study design, methods, and findings were systematically extracted from relevant publications, as described in the study protocol, into Table D-1 and Table D-2.

### 3.3.2 Evaluation of Study Quality and Other Elements Related to the Utility of the Studies to Inform the Cancer Hazard Evaluation

The methods for evaluation of study quality and other relevant study elements of the kidney and liver cancer case-control studies were similar to those described for cohort studies (see Section 3.2.2). Details of the systematic assessment of potential bias, study quality, and factors related to study sensitivity and assessment of exposure-response relationships for each study are available in Table D-6 and Table D-7.

#### 3.3.2.1 Selection and Participation Bias

Selection bias was not a concern in the population-based case-control studies conducted in Montreal (which also used cancer controls) (Christensen et al. 2013), Minnesota (Dosemeci et al. 1999), and Germany (multi-center) (Pesch et al. 2000b) and the hospital-based case-control study in France (Charbotel et al. 2006; Charbotel et al. 2009). These studies selected cases and controls from the same population using similar inclusion criteria; controls were randomly selected and matched to the cases on age, sex, or location, if relevant. Although hospital controls may introduce selection bias if the diseases observed among controls are related to trichloroethylene exposure, several hospital-based case-control studies minimized this impact by excluding diseases related to kidney cancer (Charbotel et al. 2006; Charbotel et al. 2009; Moore et al. 2010), or restricted the inclusion of any specific disease (Moore et al. 2010) or cancer (Christensen et al. 2013) to <20% of the total number of diseases/tumor sites. Persons with tobacco-related diseases were excluded for controls in the multicenter European study (Moore et al. 2010), because the potential for selection bias could be increased if smoking or other (lifestyle or co-exposure) risk factors related to smoking are related to kidney cancer risk and to exposure to trichloroethylene.

In the later German case-control study (Brüning et al. 2003), there was the potential for selection bias (possible) because of the use of prevalent cases (selected from1992 to 2000) and residual non-cases as controls (1999 to 2000). Controls were matched to cases on sex and age and were selected from surgery and geriatric departments from the same region as cases (selected from the urology department).

The study with the most concern for potential selection bias (probable) was the earlier Arnsberg study (Vamvakas et al. 1998). Cases (prevalent) were not interviewed until after the selection period, and cases who died in the interim were excluded from that analysis. In contrast, unmatched controls were recruited from hospitals adjacent to Arnsberg and selected at the end of the study. Controls were also younger than cases, but age was adjusted for in the analysis. This could potentially bias the findings away from the null and towards an overestimate of the risk estimate if exposure prevalence varies by geographical location and within the time period of the study. In addition, the study was conducted during a time period of legal proceedings.

Similar to many case-control studies, participation rates were somewhat higher among cases (>80%) than controls (Charbotel et al. 2006; Charbotel et al. 2009; Christensen et al. 2013; Pesch et al. 2000b; Vamvakas et al. 1998). Participation rates were lower among controls in the Minnesota case-control study (Dosemeci et al. 1999), which could reduce precision. Rates were not reported for controls and/or cases in two of the hospital-based studies (Brüning et al. 2003; Moore et al. 2010).

#### 3.3.2.2 Information Bias: Exposure Assessment and Misclassification

The adequacy of the exposure assessment and the potential for exposure misclassification were considered, both with respect to whether cases or controls were ever exposed, and, if exposure ranks, categories, or levels were assigned, the degree to which misclassification among exposed subjects may have occurred within those categories. Misclassification of exposure category, low levels of exposure, or similar exposure levels across exposure groups can attenuate exposure-response relationships.

Case-control studies typically rely on questionnaire data and recall of past occupational histories to assign exposure in the absence of quantitative exposure data. The assignment of exposure to trichloroethylene thus depends on detailed job or job-task description data or recall of actual exposures, which depending also on the availability of industrial hygiene data and the type and quality of the expert review or job exposure or job-task exposure matrix used, might limit exposure characterization and introduce the probability of exposure misclassification for ever/never exposure or within categories of exposure. Exposure misclassification was likely to be non-differential and to bias towards the null.

These studies used self- and/or proxy-report of work histories, jobs, or tasks using structured questionnaires and interviews, combined with expert assessment and/or JEM/job-task exposure assessment (JTEM) to estimate exposure probability, frequency, or level of potential exposure to trichloroethylene. However, the quality of the assessment varied depending on the available information. The studies in France (Charbotel et al. 2006; Charbotel et al. 2009), the Montreal study (Christensen et al. 2013), and the multi-center European study (Moore et al. 2010) were considered to have high-quality assessments because they collected detailed information on job tasks, considered calendar year and personal protective equipment, and provided semi-quantitative estimates of trichloroethylene exposure. In the French (Charbotel et al. 2006; Charbotel et al. 2009) study, these estimates were based on ambient trichloroethylene levels for different jobs and tasks reported or estimated by other investigators in other studies. The likelihood of exposure, especially among individuals with higher exposure levels, is probably greater in the French (Charbotel et al. 2006; Charbotel et al. 2009) and European (Moore et al. 2010) studies than in the Montreal study (Christensen et al. 2013). In contrast to Christensen et al. (2013), in which the subjects were employed in diverse industries and jobs, the French study was conducted in an area with more homogeneous industries and with a high prevalence of exposure to high levels of trichloroethylene. In addition, the study had a good exposure assessment so that misclassification of workers was not a concern. Although the Central and East European study was conducted in several different areas, researchers chose the study subjects from industrial areas thought to have higher exposure to trichloroethylene, used experts from the region for the exposure assessment, and validated the assessment at a later time period (with 83% agreement in one country and 100% agreement in two countries). Additionally, investigators presented separate analyses among individuals with high confidence of exposure as an attempt to reduce the potential for exposure misclassification bias. Although the quality of the exposure assessment was considered to be adequate in the Montreal study, misclassification of exposure is still possible because of the lower likelihood of exposure in a population-based study.

The analysis by Vamvakas et al. (1998), and to a lesser extent by Brüning et al. (2003), relied more heavily on self-reported “pre-narcotic symptoms” (dizziness, nausea, headaches, and drowsiness) to indirectly characterize exposure to trichloroethylene (and tetrachloroethylene). In Vamvakas et al. (1998), experts integrated this information with exposure duration to assign workers to different exposure categories, whereas in Brüning et al. (2003), there was no expert assessment of the self-reported symptoms or exposure information. However, although self-reported exposure is usually considered to be less reliable than semi-quantitative or quantitative assessments and is subject to recall bias, exposure misclassification was not a serious concern in these studies, because of the frequency and severity of symptoms among the majority of cases in both studies as well as detailed descriptions of working conditions in the local industries, all of which suggest that most subjects were exposed to substantial levels of trichloroethylene. Interviewers were not blinded in the Vamvakas et al. (1998) study, and it is not clear whether the exposure assessment experts were blinded to disease status, which would have greater impact on misclassification than lack of blinding among the interviewers. In both cases, potential for differential misclassification is a concern and could lead to an overestimation of risk. Brüning et al. (2003) also assessed exposure to trichloroethylene using a JEM (see below).

Three studies used less detailed work information with respect to job task or a more generic JEM to assess exposure to trichloroethylene: the larger multi-center German study (Pesch et al. 2000b), the later Arnsberg study (Brüning et al. 2003) and the Minnesota study (Dosemeci et al. 1999). In the Pesch et al. study, the JTEM was considered to be more informative than the JEM exposure assessment, although detailed information on job tasks was limited. The JEM used in the other two studies was based on broad occupation groups, was not calendar specific or area specific; a U.S.-wide JEM was used in the Minnesota study (Dosemeci et al. 1999) and a British JEM was used in the German study by (Brüning et al. 2003). These JEMs were considered to be more limited in quality than the JTEM used by Pesch et al. (2000b), which was developed by the study investigators although little information was provided on job tasks. Misclassification of exposure (or the use of the JEM analysis to classify exposure in the Brüning et al. (2003) study) is a concern in these three studies.

#### 3.3.2.3 Information Bias: Disease Assessment

Renal-cell carcinomas were identified from hospital files or cancer registries and appear to have been histologically or sonographically confirmed in each study, and thus there is little concern about misclassification of disease. Three studies (Brüning et al. 2003; Charbotel et al. 2006; Charbotel et al. 2009; Vamvakas et al. 1998) also included a small number of deceased cases, but as the sources for both the living and deceased cases were the same, it is unlikely that any misclassification would have occurred among the latter cases. In the single study that reported on liver cancer (Christensen et al. 2013), incident cases (identified via hospitals) were also histologically confirmed.

#### 3.3.2.4 Study Sensitivity and Exposure-response Relationships

In addition to the analysis of biases and confounding, study sensitivity and the ability to analyze exposure-response relationships also impact the ability of a study to inform the cancer evaluation. As noted in the discussion of the cohort studies, study sensitivity (i.e., the ability to detect an effect) is a function of exposure prevalence and levels, sample size, and length of follow-up. Subgroup analyses that examine risks among individuals with higher exposure or higher probability of exposure were considered to be more informative for cancer hazard evaluation.

Few quantitative exposure data were available for the reviewed studies although estimated exposure levels are available for several studies. Moreover, different metrics were used in the different studies, which complicates comparisons of exposure levels across studies (see Table 3-2). In the studies conducted in the industrial regions of the Arve Valley in France (Charbotel et al. 2006; Charbotel et al. 2009) and the Arnsberg region of Germany (Brüning et al. 2003; Vamvakas et al. 1998), the study authors or other reviewers (Cherrie et al. 2001; NRC 2006) have provided estimates of exposure intensity that indicate that the study participants were exposed to high levels of trichloroethylene in both regions. In the German study, peak exposure was estimated to range from 400 to 600 ppm and overall exposure was >100 ppm (Cherrie et al. 2001). In the French study, exposures of 300 to 600 ppm were estimated for some tasks. In contrast, the NRC (2006) estimated that most subjects in the multicenter study in Germany (Pesch et al. 2000a) had minimal contact with trichloroethylene, with concentrations up to 10 ppm.

The French (Charbotel et al. 2006; Charbotel et al. 2009) and German (Brüning et al. 2003; Vamvakas et al. 1998) studies conducted in small industrial areas had adequate sensitivity to detect an effect (if one exists) because of the higher levels of exposure and/or prevalence in these regions. These studies appear to have had adequate overall numbers of workers and had higher estimated levels of exposure than the population-based studies. The statistical power for subgroup analyses conducted by Charbotel et al. (2006); Charbotel et al. (2009) and Vamvakas et al. (1998) was more limited, however. A further strength of the French study was analyses of exposure-response relationships with cumulative exposure that included an adequate range of exposure levels for trend analyses and greater confidence in the exposure assessment. The Eastern and Central European study (Moore et al. 2010) had adequate study sensitivity due to its large size and estimated moderate exposure (among the highest exposed subjects), although there were fewer subjects with both high exposure and high-confidence exposure assessments. Another strength of the study was that it conducted analyses of several metrics of exposures (duration, cumulative, and intensity). The two studies of the Arnsberg area workers probably had limited ability to look at exposure-response relationships because of a presumed narrow range due to widespread high exposure; Vamvakas et al. (1998) reported risk estimates for ranked exposure category and Brüning et al. (2003) evaluated categories of severity of symptoms (surrogates for exposure intensity and exposure duration).

Study sensitivity in the Montreal study (Christensen et al. 2013), reporting on kidney and liver cancer, was limited by few cases (two for kidney and one for liver) with substantial exposure to trichloroethylene (levels unknown), and that in the German multicenter study (Pesch et al. 2000b) was limited by lower levels of exposure. The studies by Pesch et al. (2000b) and Christensen et al. (2013) combined confidence or probability as part of their exposure categories, which complicated the evaluation of exposure-response relationships. The study by Dosemeci et al. (1999) appeared to have sufficient statistical power (based on numbers of exposed subjects) to evaluate ever-exposed cases, but it did not report data on levels or duration of exposure.

#### 3.3.2.5 Confounding

All of the studies adjusted for (or considered) age, sex, and smoking, and all except Vamvakas et al. (1998) and Christensen et al. (2013) adjusted for body mass index for renal-cell carcinoma. Some studies considered socioeconomic factors and, for risk estimates for liver cancer, alcohol consumption (Christensen et al. 2013), medical history or conditions (Dosemeci et al. 1999; Moore et al. 2010; Pesch et al. 2000b; Vamvakas et al. 1998), or other lifestyle factors (Christensen et al. 2013). Only the French study (Charbotel et al. 2006; Charbotel et al. 2009) presented additional analyses adjusting for co-exposures to other occupational carcinogens.

#### 3.3.2.6 Summary

The major strength of the database of case-control studies was the inclusion of studies that selected populations with higher likelihood of exposure to trichloroethylene, more homogeneous industries, and use of experts with knowledge of the local industries. In addition, most of the studies were able to adjust or consider potential confounding from lifestyle habits or medical history. Most studies had limited statistical power due to small numbers of subjects exposed to high levels of trichloroethylene. The studies by Charbotel et al. (2006); Charbotel et al. (2009) and Moore et al. (2010) were considered to be the most informative for the cancer evaluation because of greater confidence that most of the subjects classified as exposed were most likely exposed to substantial levels of trichloroethylene (Charbotel et al. 2006; Charbotel et al. 2009); in the study by Moore et al. (2010), analyses focused on the highest exposed individuals with high probability of exposure. Other strengths of the Charbotel et al. study were controlling for potential confounding from co-exposures in the analysis and evaluating exposure-response relationships for cumulative and peak exposure. The study by Brüning et al. (2003) was considered to be of moderate ability to inform the cancer hazard evaluation. Although the exposure assessment relied primarily on self-assessed exposure to identify workers exposed to trichloroethylene, study sensitivity was high because the presence of symptoms and qualitative job description data strongly suggest that these workers experienced high levels of exposure. The remaining studies were considered to have low to low/moderate utility. Although the study by Christensen et al. (2013) also evaluated risks among individuals with substantial exposure (integration of intensity, duration, and frequency), there were few exposed cases (two cases for kidney, and one for liver cancer), which limited its ability to inform the cancer hazard evaluation. No other case-control study reported on liver cancer. The study by Pesch et al. (2000b), and, to a greater degree, the study by Dosemeci et al. (1999), were considered to be more limited because of concerns of exposure misclassification, which would most likely bias towards the null, and limit the ability to detect an effect (if present). Finally, the study by Vamvakas et al. (1998) should be viewed with some caution because of the potential for selection bias, which would most likely lead to an overestimate of the risk estimate. However, the likelihood of exposure to substantial levels of trichloroethylene in this study should also be considered in evaluating the degree of distortion due to selection bias on the findings in this study.

The findings from these studies and the cohort studies reporting risk estimates for kidney cancer are discussed in the cancer hazard evaluation for kidney cancer, which will integrate the study quality assessment and other elements related to its utility to inform the cancer evaluation, discuss whether chance, bias, or confounding can be ruled out for studies with positive findings, discuss other studies and integrate the findings from meta-analyses of these studies (see Section 4.1).

## 3.4 Case-control Studies of NHL and Related Subtypes

### 3.4.1 Overview of the Methodologies and Study Characteristics

Table 3-3 lists six case-control studies of NHL (some of which also evaluated several subtypes, and one study specific for hairy-cell leukemia [HCL], a type of NHL), and two studies specific for multiple myeloma (which is considered a type of B-cell lymphoma) that met the inclusion criteria. The studies include the International Lymphoma Epidemiology Consortium study (InterLymph) pooled case-control study (Cocco et al. 2013), and population-based studies in Montreal, Quebec, Canada (Christensen et al. 2013), Connecticut, USA (Deng et al. 2013; Wang et al. 2009b), and Sweden (Hardell et al. 1994); a pooled analysis of two studies from Sweden (Persson and Fredrikson 1999); and a study of HCL in Sweden (Nordström et al. 1998). The InterLymph study (Cocco et al. 2013) includes pooled cases and controls from four large multi-center studies: the EPILYMPH study in Europe (Cocco et al. 2010), the ENGELA study in France (Orsi et al. 2010), the Multicentre Italian Study (MIS) (Miligi et al. 2006), and the NCI-SEER study in the United States (Purdue et al. 2011a). Because the InterLymph pooled analysis included all the subjects of the four constituent studies and harmonized the exposure and disease assessment, this evaluation primarily reviews the pooled analysis. Information (e.g., analyses of different exposure metrics) from the individual studies that was not incorporated in the pooled analysis was considered in the cancer hazard evaluation. An additional study in Germany by Seidler et al. (2007) was also identified, but was not reviewed because its population was included in the EPILYMPH multi-center study (Cocco et al. 2010), which was then included in the InterLymph pooled analysis.

Table 3-3 Case-control Studies of Trichloroethylene Exposure and NHL and Its Subtypes

Primary Reference Years | Study Population Cases/Controls | Exposure Classification Exposure Metric | Cancer Assessment
Christensen et al. (2013) 1979–1985 | Montreal, Quebec (Canada) 215/533 | In-person interview using structured questionnaire, expert assessment Ever and substantial exposure (includes probability) | NHL, MM ICD-9: 200+202 (NHL) Hospital; histologically confirmed
Cocco et al. (2013) 1991–2004 | 4 pooled studies Cocco et al. (2010); Miligi et al. (2006); Orsi et al. (2010); Purdue et al. (2011a) 3,788/4,279 | Questionnaire, expert assessment Exposure probability Exposure duration (yr) Exposure frequency (% work time) Exposure intensity (ppm) | NHL and subtypes WHO InterLymph consortium classification Histologically confirmed
Deng et al. (2013)/Wang et al. (2009b) 1996–2000 | Connecticut (USA) 601/7,171 | Questionnaire, JEM Exposure probability Exposure intensity (ranked) | NHL and subtypes ICD-O-2, codes M-9590–9642, 9690–9701, 9740–9750 Histologically confirmed
Gold et al. (2011) 2000–2002 | SEER registries, Seattle Detroit 9,731/9,732 | In-person interviews using structured questionnaire, expert assessment Exposure duration (yr) Cumulative exposure (ppm-hr) | MM ICD-O-2/3 SEER cancer registry; histologically confirmed
Costantini et al. (2008) 1991–1993 | Regional Italy 263/1,100 MM 586/1,278 (all leukemia; subtype totals NR) | In-person interviews using structured questionnaire, expert assessment Exposure intensity (ranked) Exposure duration (yr) | MM, CL ICD-9: 203 (MM), 204.1 (CLL) Hospitals; histological confirmation NR
Persson and Fredrikson (1999) 1964–1986 | Sweden Pooled analysis of 2 studies (1983 and 1989) 199/479 | Self-reported ranked exposure Ever exposed | NHL 2nd (1989) study: ICD-8: 200+202 NR in 1989 study Hospital; histologically confirmed
Nordström et al. (1998) 1987–1992 | Sweden 121/484 | Self-reported occupational history Ever exposed | HCL Cancer registry; classification and histological confirmation NR
Hardell et al. (1994) 1974–1978 | Umeå Region Sweden | Self-reported occupational history Ever exposed | NHL Hospital histologically verified; Rappaport classification; stages and anatomical sites

Other lymphohematopoietic endpoints, including all leukemia combined (ICD-9 204–208), are not included in the table.

CLL = chronic lymphocytic leukemia; ICD = International Classification of Diseases; HCL = hairy-cell leukemia; JEM = job-exposure matrix; NHL = non-Hodgkin lymphoma; MM = multiple myeloma; NR = not reported; SEER = Surveillance, Epidemiology and End Results program (U.S. National Cancer Institute); WHO = World Health Organization.

For multiple myeloma, two additional studies were identified, one in Italy (Costantini et al. 2008), using the same population as the MIS study) and one in the United States (two of the SEER registries) (Gold et al. 2011), as well as the InterLymph study pooled analysis (Cocco et al. 2013) and the Montreal study (Christensen et al. 2013). The InterLymph pooled analysis and the Italian study (Costantini et al. 2008) also reported findings for chronic lymphocytic leukemia (CLL).

For each of the reviewed studies, detailed data on study design, methods, and findings were systematically extracted from relevant publications, as described in the study protocol, into Table D-3. Studies are organized by lymphoma type and then by chronological order.

### 3.4.2 Evaluation of Study Quality and Other Elements Related to the Utility of the Studies to Inform the Cancer Hazard Evaluation

The methods for evaluation of study quality of the NHL case-control studies were similar to that described for cohort studies (see Section 3.2.2). Details of the systematic review of bias and factors and study sensitivity for each study are available in Table D-8 and Table D-9.

#### 3.4.2.1 Selection and Participation Bias

Selection bias was considered unlikely in these studies. In general, cases and controls were selected from the same underlying population using similar inclusion criteria; controls were randomly selected and age matched (and sex matched where both sexes were included) to the controls. Most studies had participation rates >80% for cases and >70% for controls. The Swedish studies had high participation rates (83% to approximately 96%) Studies having lower participation rates among cases and controls were the Connecticut population-based case-control study of NHL (Deng et al. 2013; Wang et al. 2009b), the SEER study (Seattle, Washington and Detroit Michigan) of multiple myeloma, and one of the component studies (Purdue et al. (2011a), Cocco et al. (2010) for population controls) of the pooled InterLymph case-control study (Cocco et al. 2013).

#### 3.4.2.2 Information Bias: Exposure Assessment and Misclassification

The exposure assessments in the InterLymph pooled case-control study (Cocco et al. 2013), the Montreal study (Christensen et al. 2013), the SEER study of multiple myeloma (Gold et al. 2011), and the Italian study of multiple myeloma and chronic lymphocytic leukemia (Costantini et al. 2008) used experts to rate frequency, confidence, intensity, and duration of exposure to trichloroethylene for each job (or task) reported in the questionnaire data, taking into consideration changes in trichloroethylene exposure over calendar periods. The InterLymph (Cocco et al. 2013) and Seattle and Detroit-SEER (Gold et al. 2011) studies provided quantitative ratings, and the exposure assessment approaches were considered as high quality. The Detroit-SEER study used the same methods to assess exposure as the NCI-SEER study by Purdue et al. (2011a), one of the studies in the pooled analysis in the InterLymph analysis. An advantage of these two studies was that they conducted separate analyses of individuals with high probability of exposure, which helped to mitigate concerns of exposure misclassification, especially among subjects with higher levels of exposure. The Montreal study (Christensen et al. 2013) and the Italian study (Costantini et al. 2008) provided semi-quantitative ratings of exposure.

The Connecticut study (Deng et al. 2013; Wang et al. 2009b) used a JEM to provide semi-quantitative ratings, and exposure ranks were based on broad occupational groups rather than job tasks. The quality of the exposure assessment is considered to be more limited than in studies using job and task rankings and exposure misclassification was a concern, although to a lesser degree among individuals in the categories of higher probability or higher intensity of exposure. The exposure assessments of the three Swedish studies were primarily based on self-reported job titles and exposures to a specific set of chemicals with either a minimum (1 day) criterion for the exposed group (Hardell et al. 1994; Nordström et al. 1998) or five categories of ranked exposure with a minimum of 1 year of exposure (Persson and Fredrikson 1999) and thus were considered to be of lower quality. Misclassification of exposure is likely to be substantial and is a concern. The direction of the bias is not known since self-reported data may differ by disease status; however, there is also the potential for non-differential misclassification.

As noted in the discussion for kidney cancer, misclassification of exposure in these studies was most likely non-differential and would bias results towards the null. This type of misclassification would most likely attenuate the ability to observe an exposure-response relationship. There was generally greater confidence that individuals in the highest exposure categories were actually exposed to trichloroethylene than in the lower categories, although there may be misclassification with respect to the intensity of exposure.

#### 3.4.2.3 Information Bias: Disease Endpoints

Histological confirmation of cases was conducted on all studies with the possible exception of the study of HCL (Nordström et al. 1998) and the Italian study of multiple myeloma (Costantini et al. 2008), neither of which reported whether the cases were confirmed. As noted in the discussion of cohort studies, changes have been made in the classification systems used for these lymphomas. The WHO REAL classification (used from 2001 on; see e.g., Morton et al. (2007)) used in the ICD Oncology Second and Third Revisions is the most recent and most informative for the revised classification of B- and T-cell lymphomas (including NHL and its subtypes). This classification system was used in the InterLymph pooled analysis (Cocco et al. 2013), the Connecticut study (Deng et al. 2013; Wang et al. 2009b), and the SEER study of multiple myeloma (Gold et al. 2011) (see table in Section 4.1.2. Meta-analyses: Kidney Cancer). Older classifications (ICD-9 and earlier) were used in the Swedish studies (Hardell et al. 1994; Nordström et al. 1998; Persson and Fredrikson 1999) and the Montreal study (Christensen et al. 2013). Costantini et al. (2008) use a broader grouped classification for NHL, together with MM and CLL, from ICD-9. Overall, changes in the classification systems used would be expected to introduce heterogeneity in study comparisons because of differences in lymphoma groupings between the systems.

#### 3.4.2.4 Study Sensitivity and Exposure-response Relationships

In addition to the analysis of biases and confounding, study sensitivity (the ability to detect an effect from exposure) and the ability to analyze exposure-response relationships also impact the ability of a study to inform cancer evaluation. Population- or hospital-based case-control studies often lack adequate power to detect an effect for NHL, as reflected by the low numbers of exposed cases (Table D-9). Actual exposure levels were not reported for any studies. Some studies (Cocco et al. 2013; Gold et al. 2011; Purdue et al. 2011a) reported estimates in their exposure-response analysis. Estimated exposure levels in the highest exposure categories were >75 or 150 ppm (Cocco et al. 2013) for average exposure intensity, >200,000 ppm-hr (Purdue et al. 2011a) or up to 50,000 ppm-hr (Gold et al. 2011) for cumulative exposure. Purdue et al. (2011a) was a component study of the InterLymph pooled analysis.) These estimates suggest that exposure level among the highest exposed may be in the range of estimated levels reported in the cohort studies, although these should be interpreted with caution because actual ambient trichloroethylene levels were generally not available.

Although the available database included one very large study, and several medium to large studies, exposure prevalence was low to relatively low in most of the studies, ranging from <1% to 11% for most studies with the exception of the multiple myeloma study by Gold et al. (2011), which had an exposure prevalence of close to 30%. The prevalence of subjects with higher probability of exposure was even lower. In the InterLymph pooled case-control study of over 35,000 cases (Cocco et al. 2013), 7% of the workers were exposed to trichloroethylene, but only 1% were classified as definitely exposed. Two studies (Cocco et al. 2013; Deng et al. 2013; Wang et al. 2009b) had relatively large numbers of exposed cases and controls and most likely had adequate statistical power, although average exposure levels were not reported. A strength of both studies was that they stratified by both probability of exposure and exposure intensity level; however, in the study by Deng et al. (2013)/Wang et al. (2009b), no subjects had high probability and medium or high intensity of exposure. In the InterLymph study, statistical power for NHL subtypes appeared to be good in evaluating risks for high exposure among all subjects although there were fewer subjects in the analyses of subjects with high probability of exposure. Finally, in the smaller studies conducted in Sweden (Hardell et al. 1994; Nordström et al. 1998; Persson and Fredrikson 1999) the observed prevalence of trichloroethylene exposure was <5% among referents, and these studies did not present analyses by exposure categories. In addition, these studies had low minimal criteria to be considered as ever exposed, based on either 1-week or 1-day duration of exposure, and thus some exposed individuals would typically be considered as unexposed by other investigators.

Studies evaluating exposure-response relationships (or looking at different levels of exposure) using multiple metrics of exposure (Cocco et al. 2013; Deng et al. 2013; Gold et al. 2011; Wang et al. 2009b) were considered to be more informative for the cancer hazard evaluation. Although the exposure range was adequate in these studies and exposure levels were high in some of the studies, they had limited statistical power because of small numbers of cases and controls in each level of exposure.

#### 3.4.2.5 Confounding

Each of the studies matched or adjusted for age, sex, birth year, or race, using conditional or unconditional logistic regression, as appropriate. Some studies (Christensen et al. 2013; Costantini et al. 2008; Deng et al. 2013; Wang et al. 2009b), and some of the component studies of the pooled analysis (Cocco et al. 2010; Miligi et al. 2006; Purdue et al. 2011a) also considered or adjusted for smoking, other lifestyle factors, and surrogates of socioeconomic status. Little information was available on potential occupational co-exposures, with the partial exception of Gold et al. (2011) who reported modest correlations (16% or less) between trichloroethylene, carbon tetrachloride, methylene chloride, and 1,1,1-trichloroethane among controls. In the study by Hardell et al. (1994), subjects may have been exposed to phenoxyacetic acids, chlorophenols or other organic solvents. None of the other studies adjusted for co-exposures in their analysis, although the InterLymph study (Cocco et al. 2013) conducted a sensitivity analysis excluding subjects exposed to benzene. Study participants in these population-based studies of NHL most likely came from diverse industries and thus it was not clear whether any specific co-exposures (other than perhaps other chlorinated or other organic solvents) would likely be correlated with trichloroethylene exposure.

#### 3.4.2.6 Summary

Overall, the strengths of the NHL case-control study database are two studies of large populations, high-quality exposure assessment, evaluation of NHL subtypes and consideration or adjustment for potential confounding from life-style habits. The pooled analysis (Cocco et al. 2013) and the SEER study on multiple myeloma (Gold et al. 2011) were considered to be the most informative studies because of the quality of the exposure and disease assessments, evaluation of multiple metrics of exposure, and larger numbers of exposed cases and controls, especially among individuals with higher probability or intensity of exposure. Studies by Christensen et al. (2013), Costantini et al. (2008) and Deng et al. (2013)/Wang et al. (2009b) were considered to be of low to moderate utility for the cancer hazard evaluation and were limited by one or more factors: limited statistical power, lower quality exposure assessment, or use of older disease classifications. The three Swedish case-control studies (Hardell et al. 1994; Nordström et al. 1998; Persson and Fredrikson 1999) were considered to be of low utility because of concerns for substantial misclassification of exposure (self-reported), use of older disease classification systems, and relatively small numbers of exposed subjects.