# 2 Genotoxicity and Related Effects

This section addresses genotoxicity and related biological adverse effects that are possibly involved in the mode of action of trichloroethylene-induced carcinogenicity. Genotoxicity is well recognized as a characteristic of many carcinogenic chemicals and a key event for many malignant diseases. The mechanistic implications of these genotoxic effects are discussed in subsequent sections. Related effects, such as cell transformation and DNA and protein binding, are included in the review when data were available.

Trichloroethylene has been tested in short-term assays to evaluate mutagenicity and other potential genotoxic effects. The data presented in Section 2 are a compilation of evidence in studies available from authoritative reviews (IARC 1995; NRC 2006; USEPA 2011a) as well as a few recently published primary peer-reviewed articles. Trichloroethylene is often stabilized using a number of different chemicals, such as epichlorohydrin or 1,2-epoxybutane (both of which are potent mutagens); the presence of these stabilizers and/or the purity of trichloroethylene test substance are noted if that information is available.

While many variables in experimental design can affect the results of studies and create apparent discrepancies in responses for the same endpoint, two in particular are pertinent to trichloroethylene exposures, chemical volatility and the choice of solvent used for test agents. Another potential cause for differences in results between studies includes cytotoxicity or other physiological changes to the test organism, which can affect results but is not always measured and/or reported. Finally, consideration of the positive or negative result should be informed by the study design and reporting (e.g., it is possible that an impure test sample could result in a ‘positive’ result that is actually due to a contaminant). For example, when epichlorohydrin or 1,2-epoxybutane is present as a stabilizer in the test sample of trichloroethylene, an observed mutagenic response could actually be due to those chemicals rather than to the trichloroethylene. Conversely, false ‘negative’ results could occur if the study design is not optimal; the use of inappropriate treatment methods or assay type could compromise the results. For example, a volatile chemical may test “negative” in a standard mutagenicity assay but “positive” when the assay is modified for testing vapor phase samples. In addition, solvents such as DMSO can react chemically with some test chemicals, including raising the pH, which could result in effects that would not otherwise be observed; thus, careful consideration should be made of assays in which reactive solvents are used.

Results from studies on the genotoxic effects of trichloroethylene are summarized in tables in Appendix C and an overall summary call is provided by endpoint in Table 2-1, based on the integration of the evidence from authoritative reviews (IARC 2014) and any additional studies identified.

Table 2-1 Summary Assessment of Genotoxicity and Related Effects for Trichloroethylene and Its Metabolites

TCE or Metabolite Endpoint | Summary of Findings across Studies
TCE or Metabolite Endpoint | In Vitro | | In Vivo (Animal)
TCE or Metabolite Endpoint | (−S9) | (+S9) | In Vivo (Animal)
TCE
Gene mutation (bacteria and yeast) | − | (+) | NT
Gene mutation (mammalian) | − | ±^a^ | −
Gene conversion | − | (+) | NT
Aneuploidy | + | (+) | NT
Recombination/gene crossover | − | (+) | NT
DNA strand break | + | NT | (+)
UDS (DNA repair) | (−) | NT | −
Chromosomal aberrations | − | − | −
Sister chromatid exchange | + | (+) | −
Micronucleus induction | + | NT | (+)
DNA binding | ± | + | (+)
Protein binding | + | NT | +
TCA
Gene mutation | − | (−) | NT
DNA damage/strand breaks | ± | NT | (−)
Chromosomal aberrations | (?)b | NT | +
Micronucleus induction | (+)c | NT | ±
TCOH
Gene mutation | − | + | NT
Micronucleus induction | + | NT | NT
DCA
Gene mutation | (+) | (+) | +
Aneuploidy | − | NT | NT
DNA strand break | − | − | (+)
Chromosomal aberrations | ± | NT | NT
Micronucleus induction | ± | NT | ±
CH
Gene mutation | + | + | NT
Non-disjunction | + | NT | NT
Aneuploidy/polyploidy | + | NT | ±
Gene crossover | − | NT | NT
DNA strand break (liver) | − | NT | ±
DNA damage (human lymphoblast) | + | NT | NT
Chromosomal aberrations | + | + | (−)
Sister chromatid exchange | + | + | NT
Micronucleus induction | (+) | − | (+)
DNA binding | (+) | NT | −
DNA-protein crosslinks | − | NT | NT
DCVC/DCVG
Gene mutation | + | + | NT
Mutation (loss of heterozygosity) | − | NT | NT
DNA strand break | + | + | +
UDS (DNA repair) | + | NT | NT
Micronucleus induction | − | NT | NT
Cell transformation | + | NT | NT
Gene expression | + | NT | NT
DNA binding | + | NT | NT
Protein binding | + | NT | +
NAcDCVC
Gene mutation | + | + | NT

Sources: IARC (2014) and EPA (2011a), also Tabrez and Ahmad (2012), Varshney et al. (2013a; 2013b)), and Zhang et al. (2012), as described in the text.

Summary calls for all of the endpoints in this table were determined by integrating the findings across all available studies, with consideration of methodological and/or purity issues.

+ = positive; (+) = mostly positive evidence; ± = mixed results; (−) = mostly negative evidence; − = negative; NT = not tested.

^a^ Bacteria results are based on positive findings in TA 100 studies not using stabilizers.

^b^ Methodological concerns limit interpretation of the evidence across studies and positive findings may be due to a pH effect.

^c^ Based on one study using 0.3% DMSO (see text).

## 2.1 In Vitro Mutagenicity Studies of Trichloroethylene in Bacteria

Trichloroethylene exposure induced mutants in Salmonella typhimurium tester strain TA100 in several, but not all, studies that tested pure (no stabilizer) samples of trichlorethylene. Although results in other strains (TA97, TA98, and TA1537) were negative, the positive results in stain TA100 are attributed to base-pair substitution and thus provide some evidence for mutagenicity of trichloroethylene in the presence of metabolic activation (IARC 2014). Results from these studies are discussed below and summarized in Table C-1.

Trichloroethylene without stabilizers (high purity) induced a slight, but reproducible, response in most, but not all, studies using Salmonella strain TA100, with the addition of exogenous metabolic activation (S9). Of the five positive studies in TA100 that tested samples without stabilizers, only one used DMSO as a solvent (see Section 2.7.1 for a discussion of the potential interaction between DMSO and TCA), suggesting that the solvent used did not affect the results. Trichloroethylene was weakly positive in one study with strain TA1535, tested without S9. A negative response was noted for all other strains, either with or without S9. Different tester strains of Salmonella are designed to detect the type of mutation that is induced. Negative results in TA97, TA98, and TA1537 suggest that trichloroethylene does not induce frameshift mutations while the positive results observed for strains TA1535 and TA100 are attributed to base-pair substitution. In addition, strain TA100 was derived from TA1535 with the addition of plasmid pKM101, which makes it more sensitive and could explain the results observed with these two strains. Some mutagenic activity was reported in multiple Salmonella strains when impure trichloroethylene or trichloroethylene with stabilizers was used as the test agent. One study reported a mutagenic response but only at high levels of toxicity (McGregor et al. 1989). A study utilizing a Salmonella strain competent in CYP2E1 metabolism (Emmert et al. 2006) reported mutagenic effects and there was a low-level (two-fold) response at a single locus (arg_56_) observed in a reversion assay using E. coli K12, but only with the addition of metabolic activation; however, DMSO was used in this study. Furthermore, the use of certain solvents (e.g., DMSO, ethanol) can be a concern if they chemically interact with the test compound (see discussion in Section 2.7.1) or affect key metabolizing enzymes such as CYP2E1, which can lead to false negative results.

Mutagenicity studies of trichloroethylene in wastewater suggest that the parent compound or its metabolites interact with other chemicals present in the water to enhance the genotoxicity of complex mixtures, based on the results from tests with trichloroethylene alone or in the wastewater. In a study by Tabrez and Ahmad (2012), wastewater samples contaminated with trichloroethylene (determined by gas chromatography analysis to be 28.4 and 8.97 mg/L were mutagenic in the Ames fluctuation assay using S. typhimurium strains TA98 and TA100. The authors reported that exposure to trichloroethylene alone at concentrations up to 1,000 mg/L did not induce mutations in the assay. However, there was a significant increase in mutant induction when the wastewater samples plus 100 mg/L trichloroethylene (purity not reported) were tested, both with and without S9 activation. No determination of cytotoxicity was reported in this study.

## 2.2 In Vitro Genotoxicity Studies of Trichloroethylene in Non-mammalian Eukaryotes

Results of in vitro genotoxicity studies of trichloroethylene in non-mammalian eukaryotes are summarized in Table C-2. Positive effects were observed in several studies, for both pure (no stabilizers) test samples and those of unknown purity; none of these studies used DMSO as a solvent. Overall, there is limited evidence for genotoxic activity of trichloroethylene in fungi, and possibly plants, and this activity is most likely mediated by its metabolites.

In fungi, trichloroethylene has been evaluated for gene mutation, conversion, and recombination, as well as mitotic segregation and aneuploidy. There is some evidence that trichloroethylene causes gene conversion and gene mutation in Saccharomyces cerevisiae D7 in the presence of metabolic activation. Evidence for gene conversion comes from positive findings in two of three studies (Bronzetti et al. 1978; Callen et al. 1980), one of which used trichloroethylene that did not contain stabilizers (Bronzetti et al. 1978); findings were negative in strain D4, which has a lower activity of CYP than strain D7. Trichloroethylene exposure caused gene mutations in all three studies in S. cerevisiae D7 including one study using a preparation that did not use stabilizers, and in actively growing (not quiescent) cultures of the mold Aspergillus nidulans (Crebelli et al. 1985). However, trichloroethylene was not mutagenic in the yeast Schizosaccharomyces pombe, either with or without S9 activation (Rossi et al. 1983). Trichloroethylene also caused aneuploidy in S. cerevisiae D7 (with and without activation) and recombination and mitotic crossover in S. cerevisiae D7 (with metabolic activation) but not in quiescent or growing A. nidulans cells. Interpretation of these endpoints is limited because purity of trichloroethylene is not known in any of the studies.

In the study of wastewater genotoxicity described above, wastewater samples alone (which were contaminated with trichloroethylene) also induced a significant rise in chromosomal aberrations in the Allium cepa (onion) bulb genotoxicity test. Wastewater samples spiked with 100 mg/L trichloroethylene (purity not reported) increased the frequency of chromosomal aberrations. Since there was no effect of trichloroethylene exposure alone at up to 1,000 mg/L, this suggests that trichloroethylene and/or its metabolites might have interacted with chemicals present in the wastewater to enhance the genotoxicity. No determination of cytotoxicity was reported in this study (Tabrez and Ahmad 2012).

## 2.3 In Vitro Studies of Genotoxicity and Related Effects of Trichloroethylene in Mammalian Cells

Several studies have examined the potential for trichloroethylene-induced genotoxicity in mammalian systems in vitro; findings are discussed below and summarized in Table C-3[underlined: . These studies suggest that trichloroethylene causes genotoxicity in vitro, specifically DNA strand breaks, micronucleus formation, and sister chromatid exchanges in vitro. Importantly, some of these effects (DNA strand breaks and micronuclei) were observed in the kidney. A limitation of these studies is that, for many of them, the purity of trichloroethylene is unknown. Regarding the use of DMSO as a solvent in these studies, it does not appear to be a confounding issue. Very few studies included exogenous metabolic activation and the only two studies that reported positive results apparently used DMSO as a solvent. However, several assays reporting positive results were conducted using primary cells, which presumably have retained endogenous metabolic capability, and most of these studies did not use DMSO as a solvent. In addition, trichloroethylene also caused cell transformation, which can arise from genotoxic and non-genotoxic mechanisms.]

Trichloroethylene exposure induced dose-dependent increases in micronucleus formation and DNA strand breaks in primary cultures of rat and human kidney cells and in the human hepatoma HepG2 cell line (Hu et al. 2008; Robbiano et al. 2004; Wang et al. 2001); these results may be due to trichloroethylene metabolites since cultured primary cells generally retain endogenous metabolic activation capabilities. However, there was also a significant increase in micronuclei in CHO-K_1_ cells treated with trichloroethylene (>99.5% pure) without the addition of exogenous S9, suggesting metabolism was not needed for the observed effect (Wang et al. 2001) but not in human lymphocytes (Kumar et al. 2009). In vitro trichloroethylene exposure increased the frequency of sister chromatid exchange (SCE) in mammalian cells in two studies using pure samples (Galloway et al. 1987; Gu et al. 1981; White et al. 1979); a short exposure time, limited dose levels, and lack of a positive control limit the interpretation of the results of the third study (White et al. 1979). Trichloroethylene exposure did not induce chromosomal aberrations in Chinese hamster ovary or lung cells or in human lymphocytes (Galloway et al. 1987; Kumar et al. 2009; Sofuni et al. 1985).

Findings were inclusive for gene mutation; increased mutations were observed in mouse lymphoma cells treated with trichloroethylene (in the presence, but not absence, of exogenous metabolic activation S9); however, mutation was not reported in treated human TK6 cells, with or without S9 (Caspary et al. 1988). Results for trichloroethylene induction of unscheduled DNA synthesis (UDS) were negative in rat and mouse hepatocytes when pure samples were tested (Shimada et al. 1985; Williams et al. 1989), but results were mixed when test samples of trichloroethylene contained stabilizers or were of unknown purity (Costa and Ivanetich 1984; Milman et al. 1988; Shimada et al. 1985; Williams et al. 1989). A study in human lymphocytes showed a weak response for UDS induction after exposure to trichloroethylene; although the test sample presumably did not contain stabilizers and the DMSO concentration was only 1% (IARC 2014).

Cell transformation was induced by trichloroethylene in BALB/c-3T3, rat embryo cells, and Syrian hamster embryo cells (Amacher and Zelljadt 1983; Price et al. 1978; Tu et al. 1985). Cell transformation assays may not indicate a genotoxic mechanism.

## 2.4 Studies of Nucleic Acid and Protein Binding of Trichloroethylene

Binding of trichloroethylene to nucleic acids and proteins has been studied in cell-free systems and in vivo in rodents and are discussed below and summarized in Table C-4. The available evidence shows that trichloroethylene can bind both DNA and protein. None of the reviewed studies reported using DMSO as a solvent.

In vitro trichloroethylene exposure results in binding to nucleic acids and protein and is likely dependent on metabolite formation, with mouse microsomes inducing a higher level of binding than rat microsomes. Incubation with ^14^C-labeled trichloroethylene resulted in covalent binding to salmon sperm DNA (Banerjee and Van Duuren 1978), calf thymus DNA (DiRenzo et al. 1982), and rat and mouse hepatocyte DNA (Miller and Guengerich 1983). Binding was observed in microsomal proteins from mouse and rat liver, lung, stomach, and kidney (Banerjee and Van Duuren 1978; Miller and Guengerich 1983) and human liver (Miller and Guengerich 1983). All but one of these in vitro studies used test samples that did not contain stabilizers; Mazzullo et al. (1992) used 98.9% pure trichloroethylene, which may have contained stabilizers or impurities (IARC 2014). Studies showing significant binding of trichloroethylene metabolites to DNA and protein postulated that trichloroethylene oxide, which is formed as an oxidative intermediate in trichloroethylene metabolism in rodent microsomes, is the form that binds most readily to protein (Cai and Guengerich 2001) and, to a lesser extent, DNA (Miller and Guengerich 1983). Phenobarbital pretreatment increased the formation of the trichloroethylene metabolites chloral hydrate (CH) and trichloroethylene oxide and increased the formation of DNA and protein adducts (Miller and Guengerich 1983).

Studies in vivo provide evidence of binding to protein and DNA in both mice and rats following trichloroethylene administration. Protein binding was observed in both liver and kidney from B6C3F_1_ mice but not Osborne-Mendel rats exposed to trichloroethylene by inhalation (Stott et al. 1982). In the same study, results for DNA binding in the liver for mice treated orally were inconclusive. However, a second study reported weak DNA binding in the liver, kidney, lung, and stomach of both the BALB/c mouse and the Wistar rat exposed to trichloroethylene by i.p. injection; test sample purity was 98.9% (Mazzullo et al. 1992). NMRI mice treated i.p. with trichloroethylene (≥99% pure) showed increased radioactivity in nucleic acids for several tissues (spleen, lung, kidney, pancreas, testis, and brain), this effect was due to the metabolic incorporation of ^14^C-labeled nucleotides directly into DNA and RNA, especially guanine and adenine, rather than adduct formation (Bergman 1983).

## 2.5 In Vivo Genotoxicity Studies in Rodents

Trichloroethylene has been tested for genotoxicity in vivo and study results are discussed below and summarized in Table C-5. Overall, there is some evidence that trichloroethylene can induce DNA strand breaks and micronucleus formation, depending on the tissue, in rodents. These two endpoints are consistent with in vitro studies, and similar to in vitro studies, positive findings were observed in the kidney. Studies on the effects of trichloroethylene exposure at other endpoints, including gene mutation, chromosomal aberrations, SCE, and UDS, were all negative (see Table C-5 and IARC (2014)). DMSO was probably not used in any of the studies (there were only two studies where its use was unknown).

Trichloroethylene caused DNA strand breaks in liver in a study in rats (Nelson and Bull 1988) and in two of three studies in mice (Nelson and Bull 1988; Parchman and Magee 1982; Robbiano et al. 2004). Findings in kidney were positive in the mouse (Walles 1986) but inconsistent in the rat. Robbiano et al. (2004) reported positive findings in the rat kidney after a single exposure to 3,591 mg/kg trichloroethylene (reagent grade purity) by oral administration, while a 5-day 2,000-ppm inhalation study (99.5% pure test sample, no information on stabilizers) yielded negative results (Clay 2008). Differences do not seem to be explained by dose because the dose from the inhalation exposure may have been higher than the oral dose. Estimated inhalation exposure is 10,800 mg/kg/day assuming 100% absorption, which is most likely lower at high exposures, such as 2,000 ppm, and thus would result in a lower estimated mg/kg/day dose.

Trichloroethylene exposure in vivo induced micronucleus formation in kidney cells of rats treated orally (Robbiano et al. 2004). For rats treated by inhalation, one study reported dose-related micronucleus induction in bone marrow erythrocytes after a single inhalation exposure; the authors replicated the findings in a subsequent one-dose experiment (Kligerman et al. 1994). No increase in micronucleus formation was observed in a 4-day inhalation exposure by the same authors; however, the authors noted that the micronucleus formation in the concurrent controls was unusually high. A negative finding was reported in a single inhalation exposure study by a different author (Wilmer et al. 2014). All of the studies used trichloroethylene exposure without stabilizers. No increase in micronucleus formation was observed in peripheral blood lymphocytes after inhalation exposure (Kligerman et al. 1994). In studies in the mouse, there was micronucleus induction in the bone-marrow erythrocytes of exposed animals in two of four studies (Duprat and Gradiski 1980; Hrelia et al. 1994; Kligerman et al. 1994; Shelby et al. 1993), which used different routes of exposure (inhalation, i.p. and p.o.) and strains of mice. One study reported a correlation with urinary TCOH, which strengthens the findings (Hrelia et al. 1994). No increase in micronuclei was observed in either splenocytes or spermatocytes from mice exposed to trichloroethylene by inhalation (Allen et al. 1994; Kligerman et al. 1994).

## 2.6 Studies of Genotoxicity in Humans Exposed to Trichloroethylene

A few studies have examined cytogenetic endpoints in peripheral blood lymphocytes of trichloroethylene-exposed workers, including one that evaluated chromosomal aberrations and three that measured SCEs. Findings from these studies are discussed below and summarized in Table C-6[underlined: .]

In addition, several case-control studies of renal-cell cancer evaluated mutations in the von Hippel-Lindau (VHL) gene of trichloroethylene-exposed workers (see Section 4.2.2.1 and the associated table in that section).

The available database on cytogenetic studies is inadequate to evaluate conclusively because it is limited by small numbers of exposed workers in a few studies. In a group of Danish workers, Rasmussen et al. (1988) found statistically significant increases in chromosomal aberrations among 15 metal degreasers exposed to trichloroethylene for >20 hours per week. Conflicting findings were described for SCE induction. Although Gu et al. (1981) measured a statistically significant increase in SCE in 6 exposed workers, no increase was reported in a somewhat larger study of trichloroethylene-exposed workers (22) from Japan (Nagaya et al. 1989). Another study in Japan found statistically significant increases in SCE among male smokers but not among male or female non-smokers; smoking was not independently related to SCE in the study (Seiji et al. 1990).

## 2.7 Genotoxic and Related Effects of the Metabolites of Trichloroethylene

The metabolites of trichloroethylene have been tested in short-term assays to evaluate mutagenicity and other potential genotoxic effects. This section provides a summary of the available information from authoritative reviews (IARC 2014; USEPA 2011a) on several metabolites, including trichloroacetic acid (TCA), trichloroethanol (TCOH), dichloroacetic acid (DCA), chloral hydrate (CH), S-(1,2-dichlorovinyl)-L-cysteine (DCVC), S-(1,2-dichlorovinyl)glutathione (DCVG) and N-acetyl DCVC (NAcDCVC). Information is available for all of these metabolites, but is limited to a few studies for TCOH, DCVG, and NAcDCVC. Results on the genotoxic effects of trichloroethylene metabolites are summarized in Table 2-1 and are based on the integration of the evidence provided from the authoritative reviews (IARC 2014), as well as any additional studies identified. A 2000 review of genotoxicity information for trichloroethylene and its metabolites discussed the mutagenic potency of trichloroethylene metabolites and reported that the oxidative metabolites required very high doses to induce an effect (Moore and Harrington-Brock 2000). In their evaluation, DCVC was the most potent mutagen while TCA was the least potent mutagen.

### 2.7.1 Trichloroacetic Acid (TCA)

Overall, there is weak evidence for the genotoxicity of TCA based on a recent study reporting it caused chromosomal aberrations in vivo; however, there is limited or no evidence for other genotoxicity endpoints. TCA was reported as non-mutagenic in almost all bacterial assays, both with and without exogenous metabolic activation (S9). Considering both in vitro and in vivo studies, findings for DNA strand breaks were mostly negative, and were mixed for micronucleus formation. Methodological concerns in the in vitro studies limited the interpretation of the evidence for other endpoints. Table 2-1 summarizes the conclusions for each genotoxic endpoint across studies) and details of the study findings are discussed below (as cited in IARC (2014) TCA Monograph, pp. 413–437).

TCA was tested for mutation in bacterial systems by numerous investigators (see IARC (2014)), with only two studies reporting a positive response. TCA induced mutation in assays using S. typhimurium TA1535 with metabolic activation in an SOS DNA repair assay and in strain TA100, both with and without metabolic activation, using a fluctuation assay (Giller et al. 1997; Ono et al. 1991). However, TCA did not induce mutations (with or without S9) in several S. typhimurium reverse mutation assays, using standard or special tester strains or protocols, nor in a lambda prophage assay in E. coli (IARC 2014). One of two studies of gene mutation in cultured mammalian cells reported a weak mutagenic effect (with the addition of S9) but both studies reported high cytotoxicity (Harrington-Brock et al. 1998; Zhang et al. 2010).

The acidity of TCA is an important consideration in evaluating in vitro test results. An earlier study by Nestmann et al. (1980) showed that TCA was mutagenic in S. typhimurium bacteria only when dissolved in DMSO; results were negative when water was used as the solvent. Their observations suggested that a short-lived mutagen was formed when the test compound TCA was dissolved in DMSO. In another experiment in the same study, the findings for mutagenicity were negative when water was used as the solvent. Decarboxylation of TCA in DMSO was described in a study by Laque and Ronneberg (1970) and showed a first order reaction that was rate-dependent on the concentration of DMSO and availability of trichloroacetate ion. A report of increased chromosomal aberrations in cultured human peripheral lymphocytes exposed to TCA was considered by the authors (Mackay et al. 1995) to be related to a treatment-induced reduction in pH, rather than due to direct genotoxic action of the TCA. Recent studies in cultured human peripheral blood lymphocytes exposed to TCA in vitro by Varshney et al. reported that TCA (0.3% DMSO in culture) increased micronucleus frequency (2013b) and chromosomal aberrations (2013a).

TCA also reportedly induced dose-related increases in DNA strand breaks as measured by the comet assay in human HepG2 liver carcinoma cells (Zhang et al. 2012) but not in CHO cells (Plewa et al. 2002; Plewa et al. 2010); no studies used DMSO as a solvent.

In vivo studies of TCA reported chromosomal aberrations in bone marrow cells of Swiss mice (Bhunya and Behera 1987) and chickens (Bhunya and Jena 1996). TCA induced micronucleus formation in the peripheral erythrocytes of newt larvae (Giller et al. 1997) and bone marrow erythrocytes of Swiss mice (Bhunya and Behera 1987) but not in C57BL/6JfBL10/Alpk mice (Bhunya and Behera 1987; Bhunya and Jena 1996; Mackay et al. 1995). Dose-dependent increases in DNA single-strand breaks were induced by TCA in studies in B6C3F_1_ mouse liver (Hassoun et al. 2010a; Nelson and Bull 1988; Nelson et al. 1989) However, some subsequent studies by the same authors failed to confirm the original finding (Nelson et al. 1989) even in the presence of liver growth induction (Styles et al. 1991). In addition, oral treatment by TCA did not induce DNA single-strand breaks in liver or epithelial cells from the stomach or duodenum of B6C3F_1_ mice, nor in F344 rats following a single treatment by oral gavage (Chang et al. 1992).

### 2.7.2 Trichloroethanol (TCOH)

TCOH was negative in all bacterial mutagenicity tests without exogenous metabolic activation S9 (IARC 2014), but it did increase mutant frequency in the presence of S9 at a dose >2,500 μg/plate (NTP 1999). It also induced formation of micronuclei in vitro in cultured human peripheral lymphocytes (Varshney et al. 2013b) (see Table 2-1 for conclusions of the evidence across studies).

### 2.7.3 Dichloroacetic Acid (DCA)

There is some evidence for genotoxicity of DCA. Overall results for DCA in vitro show some evidence for mutagenicity both in vivo and in vitro and for DNA strand breaks in vivo but not in vitro. Mixed results were observed for chromosomal aberrations (in vitro only) and micronucleus induction (in vitro and in vivo). Table 2-1 summarizes the conclusions for each genotoxic endpoint across studies and details of the findings are discussed below (as cited in IARC (2014) Monograph of DCA, pp. 368–375).]

DCA was mutagenic in the bacteria S. typhimurium tester strains TA98 and TA100 in some studies, both with and without the addition of metabolic activation, but was not mutagenic in all other strains or in E. coli WP2 uvrA (DeMarini et al. 1994; Giller et al. 1997; Kargalioglu et al. 2002). Analysis of mutation spectra in TA100 indicates that DCA induces primarily GC-AT transitions in this strain. DCA also induced prophage (DeMarini et al. 1994) and weakly induced SOS repair (Giller et al. 1997) in E. coli. Exposure to DCA in vitro resulted in statistically significant increases in HGPRT mutant frequency in CHOK_1_ cells at a single concentration (1,000 μM); it was cytotoxic at higher doses (Zhang et al. 2010). Harrington-Brock et al. (1998) reported dose-related increases in TK locus mutations and chromosomal aberrations in mouse lymphoma L5178Y/TK^±^-3.7.2C cells treated with DCA. In contrast, Fox et al. (1996) found no evidence for elevated mutation levels in mouse lymphoma cells nor increased chromosomal aberrations in CHO cells after exposure to DCA.

Results were conflicting for DCA-induced micronucleus formation in vitro; a significant increase in micronuclei was reported in human peripheral blood lymphocytes (Varshney et al. 2013b) but not in L5178Y/Tk+/- mouse lymphoma cells (Harrington-Brock et al. 1998). Zhang et al. (2012) reported that DCA induced a dose-related increase in DNA damage by the comet assay after 4 hours of exposure in human HepG2 cells. However, treatment with DCA did not induce DNA strand breaks in several other cell types, including cultured primary rat or mouse hepatocytes, or in human CCRF-CEM lymphoblastoid cells in the DNA unwinding assay (Chang et al. 1992) nor in CHO or CHO-AS52 cells in the comet assay (Plewa et al. 2002; Plewa et al. 2010).

In vivo, DCA administered in drinking water induced lacI mutations in B6C3F_1_ transgenic mice in a dose-related manner at 60 weeks; the induced mutations were 33% GC-AT transitions and 21% GC-TA transversions (Leavitt et al. 1997). Fuscoe et al. (1996) reported increased micronucleus frequency in peripheral PCEs of male B6C3F_1_ mice following subchronic (9 days) or chronic (>10 weeks) exposure to DCA, but not after a 28-day exposure; studies were negative in rat and newt larvae peripheral erythrocytes. However, two other studies reported negative results for micronuclei in bone-marrow erythrocytes of male and female Sprague-Dawley rats (Fox et al. 1996) and newt larvae peripheral erythrocytes (Giller et al. 1997). There is evidence that DCA induces single-strand breaks. Nelson and Bull (1988) and Nelson et al. (1989) reported increased DNA strand breaks in livers of B6C3F_1_ mice and Sprague-Dawley rats exposed to DCA orally. DNA strand breaks, alkali-labile sites, and crosslinking were also induced in blood leukocytes of male B6C3F_1_ mice treated in drinking water (Fuscoe et al. 1996). However, there was no evidence of DNA strand breaks in the liver of male F344 rats, nor in the liver, spleen, or intestinal epithelium of male B6C3F_1_ mouse after oral or drinking-water treatment with DCA (Chang et al. 1992). Study results on DCA induction of micronuclei were also somewhat conflicting.

### 2.7.4 Chloral Hydrate (CH)

In vitro tests showed CH to be a direct mutagen and genotoxic for most of the endpoints tested, including the induction of DNA damage, chromosomal aberrations, and micronuclei. In other assays, CH caused non-disjunction and aneuploidy/polyploidy as well as transformed cells. A limited number of studies were conducted in vivo, and test results for many of these were inconsistent although there was some evidence suggesting that CH causes micronuclei (similar to the in vitro studies) in mouse bone marrow erythrocytes and spermatids, and mixed findings for DNA strand breaks, aneuploidy, and hyperploidy. Table 2-1 summaries the conclusions for each genotoxic endpoint across studies, and details of the findings are described below (as cited in IARC (2014) CH Monograph, pp. 452-462).

In several experiments in bacteria, CH exposure induced mutants in Salmonella tester strains TA100 and TA104, both with and without S9 metabolic activation; results in other strains were negative. Different tester strains of Salmonella are designed to detect different types of mutagenicity; positive results in TA100 are attributed to base-pair substitution so the overall response is considered positive for mutation. In the fungi Aspergillus nidulans, CH exposure caused aneuploidy and nondisjunction but not mitotic crossover (Crebelli et al. 1991; Kafer 1986; Kappas 1989). CH induced disomy and mitotic malsegregation in the yeast S. cerevisiae and was positive for wing-spot mutations, but negative for sex-linked lethal mutations, in Drosophila melanogaster (Albertini 1990; NTP 1999; Sora and Agostini Carbone 1987; Zordan et al. 1994). There were no increases in mutations in L5178Y/TK^±^-3.7.2C cells (Liviac et al. 2011).

In vitro exposure to CH in mammalian cells, both with and without S9, resulted in increased SCEs and chromosomal aberrations. It also induced micronuclei and aneuploidy, as well as cell transformation in Syrian hamster cells (IARC 2014). Several studies reported positive results for micronucleus formation; the micronuclei were consistently kinetochore positive, indicating that they formed from whole chromosomes or larger chromosome segments rather than from chromosome fragments (Degrassi and Tanzarella 1988; Lynch and Parry 1993; Parry et al. 1990). Only one study evaluated micronucleus formation with the addition of exogenous metabolic activation S9; in that study, micronuclei were induced in lymphocytes in the absence, but not presence, of S9. An increase in cytotoxicity, but not micronucleus induction, was noted in human peripheral lymphocytes after a 48-hour exposure to 25, 50, or 100 μg/mL of CH (Varshney et al. 2013b). There were no increases in micronucleus formation in peripheral human lymphocytes or TK6 cells (Liviac et al. 2010) or mutations in L5178Y/TK^±^-3.7.2C cells (Liviac et al. 2011).

Three studies reported that CH caused aneuploidy induction without exogenous metabolic activation in Chinese hamster cells; one study in mouse lymphoma cells reported it negative. CH exposure did not cause the formation of DNA-protein crosslinks in rat liver nuclei nor induce DNA single-strand breaks in rat primary hepatocytes (Chang et al. 1992; Keller and Heck 1988). A few studies have examined DNA binding of CH and adduct formation in CH-exposed tissues and DNA. Keller and Heck (1988) demonstrated that protein from [^14^C] chloral-treated rat liver nuclei had a concentration-related binding of [^14^C] but did not observe DNA adducts. Other studies demonstrated an increase in malondialdehyde-derived DNA adducts and an increase in the levels of 8-oxoguanine adducts in livers of CH-exposed mice, as well as increased CH adducts in calf thymus DNA (Ni et al. 1995; Von Tungeln et al. 2002).

There are a few in vitro studies of CH exposure in human cells. DNA single-strand breaks were induced after CH exposure in vitro in human lymphoblast TK6 cells (Liviac et al. 2010), but not HepG2 cells (Zhang et al. 2012), as measured by the comet assay.

Results of in vivo studies of genotoxicity following exposure to CH were limited by few studies for some endpoints and somewhat inconsistent results for others. CH induced DNA single-strand breaks in both mouse and rat liver in one study (Nelson and Bull 1988), but not in another (Chang et al. 1992). CH exposure (i.p.) in mouse strains C57B1, B6C3F_1_, and BALB/c (early spermatids only) resulted in increased frequency of micronucleus formation in spermatids (Allen et al. 1994; Nutley et al. 1996; Russo and Levis 1992). Studies of micronucleus induction in bone-marrow erythrocytes reported positive effects in several strains of male mice, but not others. Positive results were reported for BALB/c, Swiss CD-1 and B6C3F_1_ mice (Marrazzini et al. 1994; NTP 1999; Russo and Levis 1992; Russo et al. 1992) but not NMRI (Leuschner and Leuschner 1991) or (C57BL/Cne x C3H/Cne)F_1_ mice (Leopardi et al. 1993). Results were negative for micronucleus induction in BALB/c mouse peripheral blood lymphocytes (Grawe et al. 1997).

Significant increases in both micronuclei and SCE frequencies in peripheral blood lymphocytes from human infants were found following administration of CH as a sedative prior to a hearing test (Ikbal et al. 2004). CH induced chromosomal aberrations in sperm cells in one study (Russo et al. 1984), but was negative for other studies (IARC 2014). Aneuploidy was observed after exposure by i.p. injection in one of two studies in mouse secondary spermatocytes (Leopardi et al. 1993; Miller and Adler 1992) and hyperploidy, but not polyploidy, was reported for mouse bone-marrow erythrocytes (Marrazzini et al. 1994; Xu and Adler 1990).

### 2.7.5 S-(1,2-dichlorovinyl)-L-cysteine (DCVC), S-(1,2-dichlorovinyl)glutathione (DCVG), and NAcDCVC

The available studies on GSH-conjugation pathway metabolites of trichloroethylene suggested that they are genotoxic, however, there are few in vivo studies. More genotoxicity studies were available for DCVC than for DCVG or NAcDCVC. Almost all of the genotoxic endpoints evaluated in vitro were positive for DCVC, including mutation, DNA strand breaks, UDS (DNA repair), cell transformation, gene expression, and DNA and protein binding. Tests for micronucleus induction were negative. In vivo studies were limited to two endpoints, DNA strand breaks and protein binding, but both were positive. Table 2-1 summarizes the conclusions of the evidence for each genotoxic endpoint and details of the findings are discussed below (as cited in IARC (2014) TCE Monograph, pp. 145-149).

DCVC and DCVG are cysteine intermediates of trichloroethylene formed during metabolic conjugation by glutathione-S-transferase; NAcDCVC has also been identified as another metabolite of trichloroethylene. DCVC has consistently shown genotoxic effects but there are very few studies on the genotoxicity of DCVG or NAcDCVC (IARC 2014).

Both DCVC and DCVG were positive for mutation induction in bacterial assays; both metabolites were direct acting, i.e., induced mutations without the addition of metabolic activation, but the response was increased with the addition of kidney-derived activation systems (S9) (Dekant et al. 1986; Vamvakas et al. 1988a). Additionally, this response was diminished by addition of a beta-lyase inhibitor, suggesting that beta-lyase bioactivation plays a role in the genotoxicity (Irving and Elfarra 2013). DCVC induced DNA strand breaks in male rabbits in vivo and in perfused kidneys and proximal tubules in vitro (Jaffe et al. 1985). Clay (2008) observed a significant increase in DNA strand breaks 2 hours after a single oral dose of trichloroethylene (purity 99.5%) but reported no effect 16 hours after treatment.

In vitro exposure to DCVC resulted in increased UDS in Syrian hamster embryo fibroblasts and in a porcine kidney epithelial cell line (Vamvakas et al. 1989; Vamvakas et al. 1988b) and cell transformation in rat kidney epithelial cells (Mally et al. 2006; Vamvakas et al. 1996). Gene expression was also increased in a kidney tubular epithelial cell line after treatment with DCVC (Vamvakas et al. 1996). Studies have shown that DCVC forms covalent adducts in vitro with DNA (Muller et al. 1998) and protein adducts in vitro and in vivo, (Eyre et al. 1995; Hayden et al. 1992). NAcDCVC was a direct-acting mutagen in a study in S. typhimurium strain TA2638; the effects were enhanced when kidney metabolic activation was included (Vamvakas et al. 1987).

## 2.8 Summary of Genotoxicity and Related Effects of Trichloroethylene and Its Metabolites

A table of summary assessments of the genotoxicity studies for trichloroethylene and its metabolites (primarily from authoritative reviews by IARC (2014) and EPA (2011a) and as discussed in this document) is provided in Table 2-1. The assessment for each endpoint in the table takes into account all of the information currently available, including consideration of any methodological and/or purity issues, to provide an overall evaluation. For example, positive findings for trichloroethylene might have been due to impurities or chemical stabilizers present in the test sample. Other issues considered that might have caused mixed findings are the use of DMSO as a solvent; whether trichloroethylene, which is a volatile liquid, was tested in liquid solution or in the vapor phase; and the metabolic activation system used in the assay.

### 2.8.1 Trichloroethylene

Overall, there is some evidence that trichloroethylene is genotoxic, which is likely caused by its metabolites. Some of these metabolites have been shown to be direct mutagens (see Section 2.8.2). In most in vitro studies of rodent and human cells and in in vivo studies, exposure to trichloroethylene caused DNA strand breaks and micronucleus formation. Importantly, trichloroethylene was shown to cause some types of genotoxicity in kidney cells or tissue from exposed animals. It also increased SCE in studies in vitro but not in vivo. There is little evidence that trichloroethylene is a direct mutagen; however, there is some evidence that trichloroethylene is mutagenic in bacteria (strain TA100, which detects base-pairing changes) and in yeast in the presence of metabolic activation. Evidence in other bacteria strains was weak and most positive findings in other bacteria strains were only observed in the presence of mutagenic stabilizers. Findings for mutagenicity in mammalian cells were mixed (based on only two studies) and negative in in vivo rodent studies. In vivo studies in rodents evaluating chromosomal aberrations, increased sister chromatid exchange, and UDS were negative.

Although not necessarily a genotoxic effect, trichloroethylene was reported to covalently bind mammalian DNA and protein from several tissues in rodents and humans in most in vitro and in vivo studies. Binding to DNA and protein was enhanced by metabolic activation. Trichloroethylene also was shown to transform cells. DNA and protein binding and cell transformation were included in this section as relevant effects; however, positive results do not necessarily imply that the test agent is genotoxic. Cell transformation assays measure the phenotypic conversion from normal to malignant characteristics in mammalian cells and are capable of detecting both genotoxic and non-genotoxic carcinogens.

Trichloroethylene is highly metabolized, and trichloroethylene metabolites, as previously noted, appear to be responsible for many of the biological effects reported. A wide variety of activation systems were used in the reviewed studies, including exogenous liver microsome preparations, metabolically competent cell lines, and induced and uninduced primary cells from liver, kidney, blood, and embryos. Mixed results may be a consequence of incomplete metabolic activation in some of the systems used. Moreover, in a few cases, a requirement for metabolic activation was not observed, as trichloroethylene induced micronuclei and sister chromatid exchange in cultured Chinese hamster ovary (CHO) cells without the addition of exogenous activation.

Another possible cause to consider for confounding results is the use of solvents such as DMSO to solubilize the test chemical for treatment. Since trichloroethylene is not very water soluble, some in vitro assays (discussed above) utilized DMSO as the test chemical solvent; however, none of the in vivo assays identified reported using DMSO as a vehicle control. As discussed for the trichloroethylene metabolite TCA, there is a concern for pH effects when using solvents such as DMSO to prepare the test chemical. However, the reaction rate was dependent on the concentration of DMSO; the reaction-rate constants increased by a factor of 6 to 7 with a change in DMSO concentration from 50% to 86%. When trichloroethylene is tested in vitro with metabolic activation, either endogenous (e.g., primary cells) or exogenous (addition of S9), it can be metabolized to TCA. However, DMSO can be ruled out as an alternative explanation for explaining the positive findings of trichloroethylene. DMSO was not used as a solvent in the majority of the genotoxicity studies reporting positive finding. In the few studies where it was used (e.g., two in vitro studies in mammalian cells and in some studies in bacteria), positive findings for the specific endpoint (e.g., mutagenicity) were also found in studies not using DMSO as a solvent. Moreover, the DMSO used was usually at 0.3% to 1% final volume; only one study exceeded that at 2%, and thus it is unlikely that the few positive findings were due to DMSO interacting with the trichloroethylene metabolite, TCA, and some studies using DMSO as a solvent were negative. Finally, the other trichloroethylene metabolites are more likely to contribute to trichloroethylene genotoxicity, and no evidence was identified to suggest that they would interact with DMSO to cause a false positive.

### 2.8.2 Trichloroethylene Metabolites

Metabolites of trichloroethylene resulting from both the GSH conjugation and oxidative pathways have been shown to induce genotoxic effects. The strongest evidence for genotoxicity is for DCVC and DCVG, followed by CH. There is some evidence for the genotoxicity of DCA and weak evidence for TCA. The GSH conjugation pathway metabolite DCVG may be formed in the kidney as well as the liver; DCVC is formed in the kidney. Both are mutagenic in bacterial assays (with and without metabolic activation); notably there was an increased mutagenic response with the addition of kidney-derived microsomal metabolic activation. In vitro, DCVC induced UDS, and increased cell transformation in a variety of cell types, including rodent kidney cells; DCVC induced DNA strand breaks both in vitro and in vivo and showed protein binding. The evidence is not strong for genotoxicity for the oxidative metabolites (CH, DCA, TCA, TCOH) and there are only a few available studies for some. The most active metabolite of these is CH, which induced sister chromatid exchange, chromosomal aberrations, and cell transformation in vitro. Test results showed that CH is direct acting, i.e., similar effects were observed in the in vitro assays with or without the addition of metabolic activation. DCA was mutagenic and there was limited evidence that it induced DNA strand breaks and micronuclei, and possibly chromosomal aberrations. TCA is the least genotoxic metabolite; it was not mutagenic, and the results in vitro may have been a pH-effect and/or due to the use of DMSO as a solvent. Results in vivo were mixed except for increases in chromosomal aberrations.