# 1 Disposition and Toxicokinetics

Disposition and toxicokinetics refer to how a chemical can enter and leave the body, what happens to it once it is in the body, and the rates of these processes. Disposition includes absorption, distribution, metabolism, and excretion while toxicokinetics refers to the mathematical description of the time course of disposition of a chemical in the body. Section 1.1 discusses the absorption, distribution, and excretion of trichloroethylene; metabolism is discussed in Section 1.2; and toxicokinetic data derived primarily from in vitro studies are presented in Section 1.3. These data show that there are qualitative similarities between rodents and humans. Disposition and toxicokinetic data are important because they describe various factors that affect the toxicity of a chemical. These factors include routes and rates of absorption, tissue concentrations and their temporal changes, reactive metabolites, intoxication and detoxication reactions, routes of elimination, and gender and/or species differences in these factors. The mechanistic implications of these data are discussed in subsequent sections.

## 1.1 Absorption, Distribution, and Excretion

Trichloroethylene is a small, volatile, lipophilic compound that readily crosses cell membranes. The absorption, distribution, and excretion of trichloroethylene in humans and experimental animals has been extensively investigated and reported in several recent high quality reviews published by EPA (2011a), ATSDR (1997; 2013), and IARC (2014). Therefore, this section focuses on the principal findings from those reviews. Overall, the data indicate that trichloroethylene is well absorbed by all routes of exposure, widely distributed, and excreted either unchanged in expired air or as metabolites in the urine.

### 1.1.1 Human Studies

Humans are exposed to trichloroethylene from a variety of sources and by different routes (ATSDR 1997; USEPA 2011a). Occupational exposure occurs primarily by inhalation of vapors and dermal contact with vapors or liquid. Trichloroethylene is a common environmental contaminant; thus, the general population may be exposed from contact with contaminated air, food, and water. Oral absorption in humans is rapid and extensive based on clinical symptoms and measurements of trichloroethylene and its metabolites in urine and blood following accidental or intentional ingestion. However, quantitative estimates of absorption were not possible because the ingested amounts were unknown. Several controlled inhalation and dermal exposure studies have been conducted in humans. Uptake from the lungs is rapid and the absorbed dose is proportional to exposure concentration, duration, and pulmonary ventilation rate. Absorption from the lungs in subjects exposed to trichloroethylene concentrations of 9 to 200 ppm for 30 minutes to 5 hours ranged from about 40% to 70% at rest and 25% to 46% during exercise. Steady-state concentrations in blood were reached within a few hours after the start of exposure. The resulting concentration in the blood after establishment of equilibrium with alveolar air is determined by the blood-to-air partition coefficient. Measured blood-to-air partition coefficients for trichloroethylene in humans ranged from 8.1 to 11.7. Dermal absorption of trichloroethylene vapors or liquid is rapid (within minutes of application) with peak concentrations in exhaled breath occurring within 15 to 30 minutes. However, a dermal flux rate of 430 ± 295 nmol/cm^2^/minute measured in a study of volunteers exposed to neat liquid for 3 minutes indicated high interindividual variability. Poet et al. (2000) conducted skin absorption studies of trichloroethylene in water and soil using human volunteers (N = 3) exposed by hand immersion or forearm patch tests. Mean permeability constants were 0.015 cm/hour (hand immersion) and 0.019 cm/hour (patch) in water, and 0.0074 cm/hour (hand immersion) and 0.0043 cm/hour (patch) in soil. For the patch tests, 4% and 0.6% of the applied trichloroethylene dose was absorbed through the skin from water and soil, respectively. An in vitro study using surgically removed skin samples exposed to trichloroethylene in aqueous solution reported a permeability constant of 0.12 cm/hour (USEPA 2011a).

Once absorbed, trichloroethylene is rapidly distributed throughout the body (USEPA 2011a). Tissue samples collected at autopsy following accidental poisonings or from surgical patients exposed environmentally show that trichloroethylene is distributed to all tested tissues including the brain, muscle, heart, kidney, lung, and liver. Trichloroethylene also crosses the human placenta with ratios of concentrations in fetal:maternal blood ranging from approximately 0.5 to 2. Body distribution is largely determined by solubility in each organ and can be measured by tissue:blood partition coefficient. Partition coefficients reported for human tissues are as follows: fat (63.8 to 70.2), liver (3.6 to 5.9), brain (2.6), muscle (1.7 to 2.4), kidney (1.3 to 1.8), and lung (0.5 to 1.7). Thus, post-exposure distribution of trichloroethylene is affected by the relative amount of fat tissue in the body, and accumulation of trichloroethylene in fat may prolong internal exposure.

Trichloroethylene is primarily excreted as urinary metabolites (see Section 1.1) or in expired air as the unchanged compound or carbon dioxide (USEPA 2011a). Controlled inhalation studies in humans indicated that 10% to 20% is exhaled unchanged while urinary metabolites accounted for about 50% to 75% of the retained dose (Bartoníček 1962; IARC 2014; Souček and Vlachová 1960; USEPA 2011a). No quantitative estimates of CO_2_ elimination in humans were identified. One study reported that 8.4% of the two primary metabolites (trichloroethanol and trichloroacetic acid) were eliminated in the feces (Bartoníček 1962). Elimination of unchanged trichloroethylene in the urine is minimal. Small amounts of metabolites may be excreted in sweat, milk, and saliva.

### 1.1.2 Laboratory Animal Studies

Trichloroethylene is well absorbed in laboratory animals by all exposure routes (ATSDR 1997; USEPA 2011a). Studies in mice and rats show that absorption of orally administered trichloroethylene may approach 100%; however, other factors such as stomach contents, vehicle, and dose may affect the degree of absorption. Bioavailability from the gastrointestinal tract is higher in fasted animals, and uptake is faster and more extensive when administered in an aqueous vehicle compared with an oil vehicle. Peak blood levels occurred within minutes of dosing, indicating rapid absorption. Both closed-chamber gas uptake studies and blood concentration measurements following open-chamber experiments demonstrated rapid absorption of trichloroethylene from the respiratory tract of rodents. One study reported that the fractional absorption of trichloroethylene vapors was >90% during the initial 5 minutes in rats exposed to 50 or 500 ppm but declined to about 70% during the second hour of exposure. Studies with guinea pigs and rats indicate that trichloroethylene readily penetrates the skin. Estimated permeability constants in hairless guinea pigs were 0.16 to 0.47 mL/cm^2^/hour (Bogen et al. 1992). (The authors noted that this unit is equivalent to the more commonly used unit of cm/hour, but they considered it more meaningful for the permeability constant in this context.) Rat skin was shown to be significantly more permeable to trichloroethylene in water or soil than human skin with permeability coefficients of 0.31 cm/hour in water and about 0.09 cm/hour in soil (Poet et al. 2000).

Detailed tissue distribution studies have been conducted in rodents using different routes of administration (USEPA 2011a). These studies show that trichloroethylene is rapidly distributed throughout the body following inhalation or oral exposure. Tissue:blood partition coefficient values in rats and mice are shown in Table 1-1. The highest tissue concentrations were measured in fat; however, the fat:blood partition coefficients in rats and mice were lower than those reported for humans (63.8 to 70.2, see Section 1.1.1).

Table 1-1 Tissue:Blood Partition Coefficients of Trichloroethylene in Rats and Mice

Species | Fat | Brain | Liver | Kidney | Lung | Heart | Muscle
Rat | 22.7–36.1 | 0.71–1.29 | 1.03–2.43 | 1.0–1.55 | 1.03 | 1.1 | 0.46–0.84
Mouse | 36.4 | – | 1.62 | 2.1 | 2.6 | – | 2.36

Source: Adapted from EPA (2011a).

As in humans, laboratory animals primarily excrete trichloroethylene metabolites in the urine (USEPA 2011a). Unchanged trichloroethylene and CO_2_ are exhaled, and moderate amounts of metabolites are excreted in the feces. The amount of unchanged trichloroethylene exhaled increases with dose in mice and rats, which suggests saturation of metabolic pathways at high doses. In mice, 1% to 6% is exhaled unchanged at low doses but increases to 10% to 18% at high doses. Rats excrete about 1% to 3% unchanged at low doses but show a much higher increase at high doses (43% to 78%). At exposures below metabolic saturation, most of the administered trichloroethylene is eliminated as urinary metabolites.

## 1.2 Metabolism

Trichloroethylene metabolism is extensive and complex and most of the toxic effects of this compound have been linked to its metabolites (ATSDR 1997; IARC 2014; USEPA 2011a). Controlled acute and subacute inhalation studies in humans at trichloroethylene concentrations up to 320 ppm show that 81% to 92% of the retained dose is metabolized (Bogen 1988). Saturation of trichloroethylene metabolism occurs at lower doses in rats than in mice, and mathematical simulation models have predicted metabolic saturation in humans at high exposure concentrations (ATSDR 1997). Although there are sex, species, and interindividual differences in metabolism, humans and laboratory animals have in common two distinct pathways: cytochrome P450-dependent oxidation (CYP) and glutathione (GSH) conjugation (USEPA 2011a). Quantitatively, the oxidative pathway predominates in all species studied. Oxidative metabolites have been linked to liver toxicity, while reactive metabolites generated by the GSH pathway have been linked to kidney toxicity. Hepatic first-pass oxidative metabolism is important. In addition to the liver, other important sites of metabolism include the kidney, lung, blood, and male reproductive system (Chiu et al. 2006; Cummings et al. 2001; Lash et al. 2014; Lipscomb et al. 1996). The following sections describe the primary metabolic pathways and metabolites.

### 1.2.1 CYP-dependent Oxidation

CYP-dependent oxidation occurs in humans and rodents and is illustrated in Figure 1-1. The primary urinary metabolites detected in humans and rodents include trichloroethanol, trichloroethanol-glucuronide, and trichloroacetic acid (Lash et al. 2014; USEPA 2011a). Chloral also is a major oxidative metabolite but has low systemic levels due to rapid transformation to other metabolites (USEPA 2011a). Bradford et al. (2011) reported more than a fourfold difference in peak serum concentrations of trichloroacetic acid in male mice from 15 different strains administered a single oral dose of trichloroethylene. Serum concentrations of dichloroacetic acid varied more than 100-fold between strains but were about 1,000 times lower than trichloroacetic acid concentrations. In vitro data indicate that rodents have a higher capacity to metabolize trichloroethylene than humans, but this has not been verified in vivo (USEPA 2011a). Knadle et al. (1990) reported that rat hepatocytes produced 5 to 20 times more oxidative metabolites of trichloroethylene than human hepatocytes under the same experimental conditions.

Figure 1-1

Oxidative Metabolism of Trichloroethylene (TCE)

Compounds that are recovered in urine are shown in boxes while chemically unstable or reactive compounds are enclosed in brackets. Heavy arrows indicate primary pathways. ADH = alcohol dehydrogenase; ALDH = aldehyde dehydrogenase; DCA = dichloroacetic acid; DCAC = dichloroacetylchloride; EHR = enterohepatic recirculation; GST = glutathione-S-transferase; MCA = monochloroacetic acid; OA = oxalic acid; TCA = trichloroacetic acid; TCE-O = trichloroethylene oxide; TCOG = trichloroethanol-glucuronide conjugate; TCOH = trichloroethanol; UGT = UDP-glucuronosyltransferase.

Adapted from: Chiu et al. (2013), Cummings et al. (2001), EPA (2011a), Kim et al. (2009b).

Briefly, oxidation in the liver (primarily via CYP2E1) yields a chemically unstable oxygenated trichloroethylene-P450 intermediate that rapidly forms chloral, trichloroethylene oxide, and N-(hydroxyacetyl)-aminoethanol. The majority of the flux is towards chloral via chlorine migration (Lash et al. 2014). In body water, chloral is in equilibrium with chloral hydrate. Chloral/chloral hydrate is rapidly reduced by alcohol dehydrogenase or P450 to form trichloroethanol or oxidized by aldehyde dehydrogenase to form trichloroacetic acid. Trichloroethanol production was favored in humans and experimental animals following oral chloral exposure (USEPA 2011a). Trichloroethanol may be oxidized to trichloroacetic acid or form a glucuronide conjugate. Glucuronide conjugates excreted in the bile may be hydrolyzed back to trichloroethanol in the intestine and reabsorbed. In vivo studies in rats showed that enterohepatic circulation of trichloroethanol and subsequent oxidation was responsible for 76% of the trichloroethanol measured in blood. Although trichloroacetic acid is poorly metabolized it may undergo dechlorination to form dichloroacetic acid. Dichloroacetic acid also may form from trichloroethylene oxide, a short-lived intermediate metabolite. A few in vivo studies in mice have reported that dichloroacetic acid was produced to a very limited extent compared with trichloroacetic acid (Bradford et al. 2011; Kim et al. 2009a; Kim et al. 2009b). Trichloroethylene-oxide was the most likely source (Kim et al. 2009b). However, there is some uncertainty about the sources and amounts of dichloroacetic acid production in vivo, and direct evidence for its formation from trichloroethylene exposure remains equivocal, especially in humans (Lash et al. 2000a; USEPA 2011a). Dichloroacetic acid is difficult to detect in blood because it is rapidly metabolized to monochloroacetic acid by dechlorination or to glyoxylic acid by GST-zeta in hepatic cytosol (Lash et al. 2014; USEPA 2011a). Glyoxylic acid is subsequently converted to oxalic acid, glycine, and carbon dioxide.

Lipscomb et al. (1997) determined that CYP2E1 was responsible for more than 60% of oxidative trichloroethylene metabolism in microsomes from human lymphoblastoid cell lines selectively expressing CYP1A1, CYP1A2, CYP2E1, and CYP3A4. CYP2E1 is highly expressed in human liver and testes but is expressed at very low levels in human kidney (Lash et al. 2014). However, CYP2E1 expression is relatively high in rat kidney (Cummings et al. 2001). Although CYP2E1 is the predominant high-affinity isoform for trichloroethylene oxidation in humans and experimental animals, studies with CYP2E1 knockout mice show that considerable trichloroethylene oxidation occurs in its absence (Ghanayem and Hoffler 2007). Other P450 isozymes involved in the oxidative metabolism of trichloroethylene include CYP1A1/2, CYP2B1/2, and CYP2C11/6 in rat liver and/or kidney and CYP2F4 and CYP2F2 in rat and mouse lung, respectively (Cummings et al. 2001; Nakahama et al. 2001; Tabrez and Ahmad 2013; USEPA 2011a). Other human CYP enzymes that have some activity with trichloroethylene include CYP1A1/1A2, CYP2A6, and CYP3A4 (Lash et al. 2014; Lash et al. 2000a). CYP2E1 activity towards trichloroethylene is approximately 2-fold and 200-fold higher than that of CYP1A2 and CYP3A4, respectively (Lash et al. 2000a). Although liver P450 content is similar across species, mice and rats have higher levels of CYP2E1 than humans (USEPA 2011a). The maximal rate of CYP-dependent oxidative trichloroethylene metabolism is 2- to 4-fold higher in mice than in rats while the maximal rate in humans is 5- to more than 10-fold slower than in rats (Lash et al. 2014). Differences in content or expression of the various P450 isoforms could contribute to interspecies differences in susceptibility.

### 1.2.2 GSH Conjugation

Trichloroethylene flux through the GSH conjugation pathway (Figure 1-2) is much less than through the oxidative pathway in humans and experimental animals; however, factors that affect the oxidative pathway indirectly affect the GSH pathway (USEPA 2011a). In vitro studies show that inhibition of P450-mediated oxidation increases GSH conjugation. Reactive metabolites produced several steps downstream from the initial conjugation are thought to cause cytotoxicity and carcinogenicity, particularly in the kidney. Glutathione S-transferase (GST) activity is highest in the liver but appreciable activity also occurs in other tissues including the kidneys (primarily the proximal tubules) (Lash et al. 2014). There is some uncertainty regarding the specific GST isoforms that mediate trichloroethylene conjugation; however, Lash et al. (1999b) reported evidence of high- and low-activity populations among male and female volunteers exposed to trichloroethylene vapors for 4 hours. These data suggest that polymorphisms affect GSH conjugation of trichloroethylene in humans. Several studies have reported that GST polymorphisms modify the risk of renal-cell carcinoma and that specific chemical exposures (including trichloroethylene) can affect the risk (Brüning et al. 1997a; Buzio et al. 2003; Cheng et al. 2012; Moore et al. 2010; Sweeney et al. 2000); however, two recent studies reported no association (Liu et al. 2012; Yang et al. 2013).

Figure 1-2

Glutathione-dependent Metabolic Pathways of Trichloroethylene

Only 1,2-dichlorovinyl isomers shown but 2,2-dichlorovinyl isomers also produced.

Compounds that are recovered in urine are shown in boxes while chemically unstable or reactive compounds are enclosed in brackets. CGDP = cysteinylglycine dipeptidases; CTAC = chlorothionoacetyl chloride; CTK = chlorothioketene; DCVC = S-dichlorovinyl-L-cysteine; DCVG = S-dichlorovinyl-glutathione; DCVCS = DCVC sulfoxide; DCVT = S-dichlorovinyl thiol; FMO = flavin monooxygenase; GGT = γ-glutamyl transpeptidase; GST = glutathione-S-transferase; NAcDCVC = N-acetyl DCVC; NAcDCVCS = N-acetyl DCVCS; NAT = N-acetyltransferase.

Adapted from: Chiu et al. (2006), Dekant et al. (1988), EPA (2011a), Irving and Elfarra (2012).

The initial GSH-conjugation step occurs primarily in the liver and involves GSH displacement of a chloride ion from trichloroethylene via a nucleophilic substitution reaction. Products of this reaction include S-(1,2-dichlorovinyl)glutathione and its isomer S-(2,2-dichlorovinyl)glutathione (DCVG) (Lash et al. 2014; USEPA 2011a). Subsequent metabolism through the GSH conjugation pathway occurs primarily in the kidneys (Lash et al. 2014; USEPA 2011a). DCVG, whether it is formed in the liver or within the kidneys, is converted to its corresponding cysteine conjugate, S-dichlorovinyl-L-cysteine (DCVC), by hydrolytic reactions with γ-glutamyltransferase (GGT) and cysteinylglycine dipeptidases (CGDP) in the proximal tubular brush-border membrane. GGT and CGDP activity is much higher in the kidney than the liver in rodents and humans. These reactions also may take place in the bile or gut during enterohepatic circulation where DCVG and DCVC may be reabsorbed and further metabolized in the liver. DCVG and DCVC have been detected in blood, serum, and tissues of rodents, and DCVG has been detected in the blood of humans exposed to trichloroethylene (Lash et al. 2014). In vitro studies using rodent and human liver and kidney cellular and subcellular fractions of DCVG formation from trichloroethylene show considerable differences (USEPA 2011a). DCVC is a major branch point in the metabolism of trichloroethylene leading to three possible metabolites via reactions with N-acetyltransferase, cysteine conjugate β-lyase, or flavin-containing monooxygenase 3 (FMO3) and are briefly described below.

N-Acetylation of DCVC to N-acetyl-S-dichlorovinyl-L-cysteine (NAcDCVC) can occur in the liver or kidney, thus, concentrations of the acetylated metabolite can exceed that which the kidney is capable of producing on its own (USEPA 2011a). NAcDCVC can be deacetylated to reform DCVC, oxidized by CYP3A to form the corresponding sulfoxide, or excreted in the urine. CYP3A expression is highly polymorphic in humans. NAcDCVC has been detected in urine samples from mice, rats, and humans, which indicates that N-acetylation of DCVC is a common metabolic pathway among these species. In vitro studies of DCVC metabolism indicate that N-acetylation to NAcDCVC is greater in rats than in mice or humans. Only NAcDCVC has been detected in the urine of experimental animals or humans, which might be due to the reactive nature of other metabolites generated from the GSH pathway.

Renal cysteine conjugate β-lyase catalyzes the formation of an unstable thiolate metabolite, S-dichlorovinyl-thiol (DCVT) from DCVC. This reaction has been demonstrated in vitro in rodents and humans with greater activity reported in rats compared with mice or humans (Green 1997). DCVT spontaneously rearranges to form two chemically reactive and unstable compounds, chlorothioketene and chlorothionoacetyl chloride (Dekant et al. 1988; Goeptar et al. 1995; Irving and Elfarra 2012).

Finally, DCVC also is a substrate for FMO3-catalyzed sulfoxidation (USEPA 2011a). Although the human kidney expresses relatively low levels of FMO3 (see Section 1.3.2), the available data suggest that FMO may play a more prominent role relative to β-lyase in human kidney while the reverse occurs in rat kidney (Lash et al. 2014). However, none of the possible sulfoxidation products of trichloroethylene metabolism have been reported in tissues or urine in vivo in rodents or humans.

Strain, species, and sex differences in GSH-conjugation have been reported (Lash et al. 2014; USEPA 2011a). Lash et al. (1999b) reported markedly higher amounts of DCVG formation in healthy male volunteers exposed to trichloroethylene vapors compared with females (see Section 1.3.4). In general, in vitro DCVG formation rates by liver and kidney subcellular fractions were higher in male rats and mice compared with females of the same species. Lash et al. (2006) reported that male rats formed more DCVC (considered the nephrotoxic precursor metabolite) than females. Hepatic concentrations of GSH also were reduced in male but not female rats exposed to higher doses of trichloroethylene. In mice exposed to trichloroethylene, Bradford et al. (2011) showed that the levels of DCVG and DCVC were much lower than oxidative metabolites and varied considerably with strain.

### 1.2.3 Trichloroethylene Metabolites

A summary of trichloroethylene metabolite formation and their systemic availability is shown in Table 1-2. Systemic availability depends on the chemical stability or reactivity of the metabolite. Metabolites that are chemically unstable or reactive are likely to spontaneously generate other molecules through non-enzymatic rearrangement or bind with cellular proteins, lipids, and DNA near their site of formation rather than distributing via the systemic circulation.

Table 1-2 Trichloroethylene Metabolite Formation and Systemic Availability

Pathway/Metabolite | Tissues Where Formed | Human | Rodent | Systemic Availability (Rodents and Humans)
P450 oxidation
TCE-O, DCAC | liver lung testes | yes yes yes | yes yes yes | no
CH/CHL | liver lung testes | yes yes yes | yes yes yes | yes
TCOH | liver lung GI testes | yes – yes yes | yes yes yes yes | yes
TCA | liver lung testes | yes yes yes | yes yes – | yes
TCOG | liver | yes | yes | yes
DCA | liver lung testes | – – yes | yes yes – | yes (low amount)
GSH-conjugation
DCVG, DCVC | liver kidney | yes yes | yes yes | yes
DCVT, DCVCS, CTK/CTAC | kidney hematopoietic | yes – | yes yes | no
NAcDCVC, NAcDCVS | liver kidney | yes yes | yes yes | yes

Source: Lash et al. (2014).

– = no data; CH/CHL = chloral/chloral hydrate; CTK/CTAC = chlorothioketene/chlorothionoacetyl chloride; DCA = dichloroacetic acid; DCAC = dichloroacetylchloride; DCVC = S-dichlorovinyl-L-cysteine; DCVG = S-dichlorovinyl-glutathione; DCVCS = DCVC sulfoxide; DCVT = S-dichlorovinyl thiol; NAcDCVC = N-acetyl DCVC; NAcDCVCS = N-acetyl DCVCS; TCA = trichloroacetic acid; TCE-O = trichloroethylene oxide; TCOG = trichloroethanol-glucuronide conjugate; TCOH = trichloroethanol.

## 1.3 Toxicokinetic Data

The kinetics of trichloroethylene metabolism for the oxidative and GSH conjugation pathways and elimination of metabolites are described below. Since reactive metabolites are responsible for trichloroethylene toxicity, especially for the liver and kidney (USEPA 2011a), it is important to understand the factors that affect the flux through each metabolic pathway.

### 1.3.1 Oxidative Metabolism

The oxidative metabolites of trichloroethylene proposed to contribute to liver carcinogenicity are chloral hydrate, TCA, TCOH, and DCA (see Figure 1-1 and Section 6.2). The initial oxidative step that produces chloral hydrate is critical because this is the rate-limiting step in formation of TCA and DCA, which are the putative toxic metabolites (USEPA 2011a). Mice have a greater oxidative metabolic capacity for trichloroethylene (i.e., higher Vmax) than either rats or humans (see Table B-1). However, human liver microsomes generally showed a higher affinity (i.e., lower K_m_) than rat or mouse microsomes. Thus, the lower apparent K_m_ in humans may partially offset the lower Vmax resulting in similar clearance efficiencies (Vmax/K_m_) compared with rodents. Rat kidney microsomes also had a much lower affinity for trichloroethylene than rat liver microsomes. K_m_ values for TCOH formation were much lower than for TCA formation and are consistent with TCOH formation predominating over TCA formation in all three species (see Table B-2). Since the metabolism of chloral hydrate to TCA and TCOH involves several enzymes and cofactors, changes in the cellular cofactor ratio or redox status in the liver could impact the relative amounts of TCOH and TCA produced. In humans, the total amount of TCA excreted may be similar to the amount of TCOH because TCA has a much longer urinary half-life.

Lipscomb et al. (1997) reported that K_m_ values were not normally distributed and could be separated into three statistically distinct populations among 23 human hepatic microsomal samples (see Table B-1). K_m_ values were significantly higher (33.1, N = 13) in males than in females (21.9, N = 10) but Vmax values were not significantly different. Vmax values were normally distributed and generally correlated with increasing K_m_ values. Lipscomb et al. (1998b) compared the metabolism of trichloroethylene in pooled human, mouse, and rat liver microsomes at different concentration ranges. K_m_ values in rats showed marked differences at different concentration ranges while those for mice and humans were constant. These data indicate that several CYP isoforms with different K_m_ values (high-, medium-, and low-affinity forms) metabolize trichloroethylene in the rat. High concentrations of trichloroethylene (1,000 ppm) inhibited CYP2E1 activity but increased CYP1A1/1A2 activity in all three species. Elfarra et al. (1998) reported species- and sex-related differences in kinetics of trichloroethylene metabolism. Vmax and Vmax/K_m_ values from female mouse liver microsomes were consistently higher than values from the corresponding male mouse liver microsomes or rat and human liver microsomes. There were no sex-related differences in the rates of metabolism with rat or human microsomes. Rat and human microsomes exhibited biphasic kinetics consistent with the involvement of both low-affinity and high-affinity enzymes while mouse liver microsome kinetics were described by single values for K_m_ and Vmax.

### 1.3.2 GSH Conjugation

The GSH-conjugation pathway results in formation of reactive species several steps downstream from the initial conjugation, and some of these metabolites (particularly DCVC) are nephrotoxic (see Figure 1-2 and Section 4.2) (USEPA 2011a). In vitro studies of trichloroethylene conjugation show considerable intra- and interspecies differences and, in some cases, contradictory results. For example, conjugation rates reported by Green et al. (1997) and Dekant et al. (1990) were orders of magnitude lower than those reported by Lash et al. (1999a) and Lash et al. (1998). Green et al. (1997) also reported some DCVG formation in rat liver cytosol while Dekant et al. (1990) did not. The reasons for the discrepancies are not completely understood but may be explained in part by different analytical methods (Lash et al. 2000a; Lash et al. 1999a; USEPA 2011a). However, serum concentrations of DCVG and DCVC collected from rats exposed to an oral dose of 1,970 mg/kg (Lash et al. 2006) were comparable (i.e., within an order of magnitude) to those obtained in mice exposed to an oral dose of 2,140 mg/kg in a more recent study (Kim et al. 2009a; Kim et al. 2009b).

DCVG formation was significantly higher in liver cells from male rats compared with female rats while the rates in kidney cells and subcellular fractions were comparable for both sexes. Rates of DCVG formation were significantly higher in male mouse liver microsomes and kidney cytosol compared with females, but female mice had higher rates in kidney microsomes. Overall, DCVG formation was unexpectedly higher in mice than in rats. There were no significant sex-related differences in DCVG formation in humans; however, the rate of GSH conjugation in human liver spanned a range of 2.4-fold in cytosol and 6.5-fold in microsomes (Lash et al. 1999a). Although the data show that rates of trichloroethylene conjugation are higher in human liver and kidney subcellular fractions [with the exception of Green et al. (1997)] than in rats or mice (Table B-3), there is significant uncertainty in the quantitative estimation of DCVG formation from trichloroethylene.

Reported K_m_ constants and Vmax values of GSH conjugation from pooled human kidney and liver cells and subcellular fractions and rat kidney proximal tubular cells (Table B-4) show that the liver is the primary site of GSH conjugation; however, the kidney also has significant capacity to catalyze DCVG formation. Further, conjugation of trichloroethylene in all systems, with the exception of human hepatocytes and kidney subcellular fractions, included two kinetically distinct processes (high affinity and low affinity). In human hepatocytes, DCVG formation exhibited time-, trichloroethylene concentration-, and cell concentration-dependent formation (Lash et al. 1999a). Maximum formation occurred with 500-ppm trichloroethylene but decreased at concentrations of 1,000 ppm and above. DCVG formation in liver and kidney subcellular fractions exhibited time-, protein concentration-, and both trichloroethylene and GSH concentration-dependent formation.

Most DCVG is converted to DCVC in a two-step process involving GGT and CGDP (see Figure 1-2). GGT activity is concentrated in the microsomal fraction of the cell and is much higher in the kidney than the liver in rodents and humans (USEPA 2011a). GGT activity in rat kidney microsomes were about two-fold greater than in humans and about 20-fold greater than in mice (Lash et al. 1999a; Lash et al. 1998). Whole organ CGDP activity also was higher in the kidney than liver in all mammalian species tested (Hinchman and Ballatori 1990).

As mentioned above, three potential bioactivating pathways for DCVC are cysteine conjugate β-lyase, FMO3, and CYP3A. Limited data were available describing species differences in the activities of these metabolic enzymes. Lash et al. (2000a) compiled β-lyase activity and kinetic parameters (K_m_ and Vmax) in kidney cytosol from rats, mice, and humans for several cysteine conjugates (Table B-5). These data show that β-lyase activity varies with substrate and laboratory but is higher in rats compared with humans or mice.

FMO3 is the predominant FMO isoform in the adult human liver and orthologues from various species were catalytically similar (Ripp et al. 1999). Sulfoxide formation (nmol sulfoxide/min/mg protein) was sex-dependent in mice and dogs (higher in females), but not in humans, rats, or rabbits. Sulfoxide formation was highest in rabbit liver microsomes followed by humans and rats. Data for kidney microsomes were highest for rats and were similar to values derived from rat liver microsomes. S-Oxidase activity in mouse kidney microsomes was lower than observed in mouse liver microsomes and did not show sex-dependence. No data were available for human kidney microsomes in this study. K_m_ and Vmax values obtained from incubating DCVC with membrane fractions of bacteria expressing human or rabbit FMO3 cDNA in the presence of NADPH were similar. In another study, DCVC sulfoxidation was detected with FMO3 but not with other isoforms (Krause et al. 2003). Incubations of DCVC with human liver microsomes resulted in detection of the corresponding sulfoxide but not when incubated with kidney microsomes. Expression levels of FMO1 (3.2 to 11.5 pmol/mg protein) and FMO5 (trace to 5.8 pmol/mg protein) were higher than FMO3 levels (trace to 1.3 pmol/mg protein) in human kidney samples. There were no data on species differences in CYP3A-mediated sulfoxidation of NAcDCVC (USEPA 2011a).

### 1.3.3 Comparative Elimination Half-lives

Reported plasma half-lives of trichloroethylene metabolites were much shorter in rodents than in humans (Lash et al. 2000a). Plasma half-lives of trichloroacetic acid in humans ranged from 51 to 99 hours compared with 3 to 16 hours in rodents. The plasma half-lives of trichloroethanol were about 12 hours in humans and 3 hours in mice. Reported half-lives for chloral hydrate and trichloroethanol glucuronide were 3 and 5 hours, respectively, in mice but these metabolites were not detected in humans exposed to 100 ppm for 4 hours. Lash et al. (1999b) reported that the elimination half-life of DCVG in blood of human volunteers was 0.74 hours in males and 0.94 hours in females. Several studies have investigated urinary elimination half-lives of trichloroacetic acid and trichloroethanol in workers exposed to trichloroethylene (reviewed by U.S. EPA (2011a)). Urinary trichloroacetic acid levels exhibited marked saturation at exposure >50 ppm while trichloroethanol did not. Reported half-lives for trichloroethanol ranged from about 15 to 43 hours compared with 40 to 58 hours for trichloroacetic acid. The elimination half-lives for both metabolites were higher in females than in males. Urinary elimination kinetics also were faster in rodents than in humans with some studies reporting complete elimination within 1 to 2 days.

### 1.3.4 Relative Roles of the CYP and GSH Pathways

Comprehensive mass-balance studies are unavailable in humans, but studies in rodents given 2 to 2,000 mg/kg [^14^C]-trichloroethylene reported that 95% to 99% of radioactivity excreted in urine was attributed to oxidative metabolites (USEPA 2011a). Genetic polymorphisms or exposure to CYP inducers or inhibitors can alter the balance between oxidation and GSH conjugation of trichloroethylene (Lash et al. 2014). Impacts may be more substantial at higher substrate concentrations where the Vmax may become more limiting than hepatic blood flow. Reported ratios of primary oxidative metabolites to NAcDCVC in urine ranged from 986 to 2,562:1 in rats and 3,292 to 7,163:1 in humans. Although NAcDCVC is a useful indicator of GSH conjugation, it likely represents only a small fraction of trichloroethylene flux through this pathway. The range of kinetic data for oxidation and conjugation of trichloroethylene derived from in vitro studies show substantial overlap (Table B-6) and suggest that the total flux through the GSH pathway is much more substantial than estimates derived from urinary mercapturates (<0.1%) alone would suggest. Lash et al. (1999b) also reported that maximum blood concentrations of DCVG in human volunteers exposed to trichloroethylene vapors (50 or 100 ppm) were similar to those of TCA and TCOH in the same subjects; however, the area under the curve (AUC) values for the oxidative metabolites were much higher than those for DCVG. DCVG blood concentrations were higher in males (46.1 ± 14.2 nmol/mL) than in females (13.4 ± 6.6 nmol/mL) in this study but elimination half-lives were similar. Based on an analysis of the distribution of individual values for DCVG in blood the results could indicate the existence of two subpopulations of individuals with a genetic polymorphism rather than a true gender difference. Lash et al. (1999a) also noted that GSH conjugation of trichloroethylene in vitro was inhibited by about 50% in the presence of the oxidative pathway while the addition of GSH had no effect on CYP-catalyzed formation of chloral hydrate.

EPA (2011a) developed an updated physiologically based pharmacokinetic model (PBPK) for trichloroethylene and its metabolites. A hierarchical Bayesian population analysis using Markov chain Monte Carlo sampling was performed to evaluate uncertainty in population parameters and variability within a population. Simulations for a number of representative dose-metrics across species were conducted to predict the fraction of trichloroethylene metabolized by oxidative or GSH-conjugation pathways (liver and kidney) under conditions of continuous inhalation or oral exposure. Results from these simulations for humans show that the fraction metabolized by oxidation decreases at higher doses while the fraction metabolized by GSH-conjugation increases with dose (Figure 1-3 and Figure 1-4).

Figure 1-3

PBPK Model Predictions for the Fraction of Trichloroethylene Intake That Is Metabolized under Continuous Inhalation Exposure in Humans

Source: EPA (2011a).

Figure 1-4

PBPK Model Predictions for the Fraction of Trichloroethylene Intake That Is Metabolized under Continuous Oral Exposure in Humans

Source: EPA (2011a).

## 1.4 Synthesis and Summary

Trichloroethylene is a small, lipophilic compound that readily crosses biological membranes. Studies in humans and experimental animals confirm that trichloroethylene is rapidly and efficiently absorbed following oral, inhalation, or dermal exposure. Distribution from blood to tissues is determined by the blood:tissue partition coefficients, which are largely related to tissue lipid content. High concentrations, relative to blood, occur in the kidney, liver, brain, and fat. Adipose tissue may serve as a reservoir for trichloroethylene, thus prolonging internal exposure. Metabolism is complex; however, two distinct metabolic pathways have been identified that are common to all mammalian species studied: CYP oxidation and GSH conjugation. These pathways operate in parallel. Important sites of metabolism include the liver, kidneys, lungs, blood, and male reproductive system. Oxidation is the predominant pathway and CYP2E1 is the primary isoform involved. Trichloroethanol, trichloroethanol-glucuronide, and trichloroacetic acid are the primary oxidative metabolites detected in blood and urine of humans and laboratory animals. Chloral and chloral hydrate also are formed but are rapidly metabolized. The GSH conjugation pathway produces several metabolites (DCVG, DCVC, DCVCS, DCVT, NAcDCVC, NAcDCVCS, chlorothioketene, and chlorothionoacetyl chloride); however, only NAcDCVC is stable enough to be detected in urine. Trichloroethylene is eliminated unchanged or as carbon dioxide in expired breath. Metabolites are primarily eliminated in the urine with generally smaller amounts eliminated in feces. Conjugated metabolites may be excreted in the bile and reabsorbed from the gastrointestinal tract via enterohepatic recirculation. Although metabolic pathways and metabolites detected in humans and laboratory animals are qualitatively similar, the data show substantial quantitative intra- and interspecies variability that may explain differences in susceptibility to toxic effects. Much of the variability is due to gender-, species-, and individual-dependent differences in content and activity of key metabolic enzymes (CYP2E1 and GSTs).

In vitro data indicate that mice have a higher oxidative metabolic capacity for trichloroethylene than rats or humans, but the variability within species can be 2- to 10-fold. However, K_m_ values derived from liver microsomal metabolism of trichloroethylene indicate that affinity is higher in humans than rodents. Thus, the clearance efficiency of oxidative metabolites (Vmax/K_m_) is similar among these species when exposed to low concentrations. There is evidence that humans can be divided into statistically distinct populations based on K_m_ values. Overall, females have a significantly higher affinity (lower K_m_) than males. Rat and human liver microsomes exhibited biphasic kinetics (consistent with the involvement of low-affinity and high-affinity enzymes) while incubations with mouse liver microsomes were monophasic. Reported plasma and urinary elimination half-lives of oxidative metabolites were shorter in rodents than in humans.

As with oxidative metabolism, in vitro studies of GSH conjugation of trichloroethylene in mice, rats, and humans show considerable intra- and interspecies variability. Conjugation rates also differed by several orders of magnitude between laboratories. The reasons for the discrepancies have not been fully resolved, thus, there is considerable uncertainty in quantitative estimates associated with this pathway. Most in vitro studies with subcellular fractions from the liver and kidney showed that two kinetically distinct processes (high affinity and low affinity) were involved in GSH conjugation of trichloroethylene. One study reported that the rate of GSH conjugation spanned a range of 2.4-fold in human liver cytosol and 6.5-fold in microsomes. The activities of two important enzymes in this pathway (GGT and β-lyase) were higher in rat kidney cytosol than in mice or humans; however, the rate of DCVG formation was higher in mouse liver and kidney subcellular fractions than in rats. Although oxidation clearly is the predominant metabolic pathway, the range of in vitro kinetic estimates for the two pathways showed substantial overlap and indicated that the total flux through the GSH pathway was higher than estimates derived solely from urinary metabolites.