# Peer Review

Peer review of the Draft RoC Monograph on Trichloroethylene was conducted by an ad hoc expert panel at a public meeting held August 12, 2014, in the Rodbell Auditorium at the National Institute of Environmental Health Sciences, David P. Rall Building, Research Triangle Park, NC (see https://ntp.niehs.nih.gov/go/38854 for materials, minutes, and panel recommendations from the peer-review meeting). The selection of panel members and conduct of the peer review were performed in accordance with the Federal Advisory Committee Act and Federal policies and regulations. The panel members served as independent scientists, not as representatives of any institution, company, or governmental agency.

The charge to the Peer-Review Panel was as follows:

1. Comment on the draft cancer evaluation c for trichloroethylene, specifically, whether it was technically correct and clearly stated, whether NTP has objectively presented and assessed the scientific evidence, and whether the scientific evidence is adequate for applying the RoC listing criteria,
2. Comment on the draft substance profile for trichloroethylene, specifically, whether the scientific justification presented in the substance profile supports NTP’s preliminary policy decision on the RoC listing status of the substance (available in the 14th edition of the Report on Carcinogens).

The Panel was asked to vote on the following questions:

1. Whether the scientific evidence supports NTP’s preliminary conclusion on the level of evidence for carcinogenicity from human cancer studies for each of the three cancer sites: kidney cancer, non-Hodgkin lymphoma (NHL), and liver cancer.
2. Whether the scientific evidence supports NTP’s preliminary listing decision for trichloroethylene in the RoC.

This RoC monograph on trichloroethylene has been revised based on NTP’s review of the Panel’s peer-review comments. The Peer-Review Panel Report, which captures the Panel recommendations for listing status of trichloroethylene in the RoC and their scientific comments, and the NTP Response to the Peer-Review Report are available on the Peer-Review Meeting webpage for trichloroethylene (https://ntp.niehs.nih.gov/go/38854).

## Peer Reviewers

- David A. Eastmond, Ph.D. (Chair)
  Professor and Department Chair
  Environmental Toxicology Graduate Program and Department of Cell Biology & Neuroscience
  University of California
  Riverside, California, USA
- Sarah J. Blossom, Ph.D.
  Assistant Professor of Pediatrics and Microbiology and Immunology
  UAMS College of Medicine
  Arkansas Children’s Hospital Research Institute
  Little Rock, Arkansas, USA
- Kenneth P. Cantor, Ph.D.
  Private Consultant
  KP Cantor Environmental, LLC
  Silver Spring, Maryland, USA
- John M. Cullen, V.M.D., Ph.D., DACVP, FIATP
  Alumni Distinguished Undergraduate Professor
  Department of Population Health and Pathobiology
  Research Building
  College of Veterinary Medicine
  North Carolina State University
  Raleigh, North Carolina, USA
- George R. Douglas, Ph.D.
  George R. Douglas Consulting
  Kanata, Ontario, Canada
- S. Katharine Hammond, Ph.D.
  Professor of Environmental Health Sciences
  School of Public Health
  University of California, Berkeley
  Berkeley, California, USA
- Lawrence H. Lash, Ph.D.
  Professor and Associate Chair
  Department of Pharmacology
  Wayne State University School of Medicine
  Detroit, Michigan, USA
- Marie-Elise Parent, Ph.D.
  Epidemiology and Biostatistics Unit
  INRS-Institut Armand-Frappier
  Université du Québec
  Laval, Québec, Canada
- David B. Richardson, Ph.D.
  Associate Professor
  Department of Epidemiology
  School of Public Health
  University of North Carolina
  Chapel Hill, North Carolina, USA
- Paolo Vineis, M.D., M.P.H.
  Chair in Environmental Epidemiology
  MRC/PHE Centre for Environment and Health
  School of Public Health
  Imperial College London
  London, England, United Kingdom