# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Led the preparation of the cancer hazard evaluation, including the design, conduct, assessment of studies, technical review, and proposed cancer hazard conclusions
  Ruth Lunn, Dr.P.H. (Project Co-lead)
- Contributed to the conduct, technical review, assessment of studies and proposed cancer hazard conclusions
  Gloria D. Jahnke, D.V.M., DABT
  Diane L. Spencer, M.S.
- Integrated Laboratory Systems, Inc., Research Triangle Park, North Carolina, USA
  Contributed to the conduct and technical review of the cancer hazard evaluation
  Sanford Garner, Ph.D. (Project Co-lead)
  Stanley Atwood, M.S., DABT
  Andrew Ewens, Ph.D., DABT
  Alton Peters, M.S.
  Jennifer Ratcliffe, Ph.D.
- External Advisor
  Contributed to the design, conduct, and provided expert input on report preparation and review
  Neela Guha, Ph.D., International Agency for Research on Cancer (IARC), Lyon, France