# Methods

This Report on Carcinogens (RoC) monograph on trichloroethylene reviews the relevant scientific information and assesses its quality, applies the RoC listing criteria to the scientific information, and recommends an RoC listing status for trichloroethylene. Exposure information from the substance profile in the 12th RoC was updated in the substance profile in the 14th RoC (https://ntp.niehs.nih.gov/ntp/roc/content/profiles/trichloroethylene.pdf). The exposure information in the 12th RoC meets the criteria for exposure to a significant number of persons residing in the United States in the RoC.

## Monograph Contents and Development

The methods for preparing the draft RoC monograph on trichloroethylene are described in the “Trichloroethylene Protocol” (https://ntp.niehs.nih.gov/ntp/roc/thirteenth/protocols/tce_protocol12-31-13_508.pdf). As discussed in the protocol, RoC monograph focuses on the relationship between exposure to trichloroethylene and non-Hodgkin lymphoma (NHL) and its histological subtypes and related cancers, and cancers of the kidney and liver. It provides information on the following topics that are relevant to understanding the relationship between exposure to trichloroethylene and the cancers listed above: chemical and physical properties (Introduction), disposition and toxicokinetics (Section 1), genotoxicity and related effects (Section 2), quality assessment of cancer studies in humans (Section 3), kidney cancer (Section 4), NHL (and related cancers) (Section 5), and liver cancer (Section 6). The information in Section 7 is a synthesis of Sections 1 through 6.

The information reviewed in Sections 1 through 7 (except for information on exposure and properties) must come from publicly available, peer-reviewed sources.

The process for preparing the monograph included approaches for obtaining public and scientific input and using systematic methods (e.g., standardized methods for identifying the literature [see Appendix A], inclusion/exclusion criteria, extraction of data and evaluation of study quality using specific guidelines, and assessment of the level of evidence for carcinogenicity using established criteria).

The Office of the Report on Carcinogens (ORoC) followed the approaches outlined in the concept document, which discusses the scientific issues and questions relevant to the evaluation of trichloroethylene carcinogenicity, the scope and focus of the monograph, and the approaches to obtain scientific and public input to address the key scientific questions and issues for preparing the cancer evaluation component of the draft monograph. The ORoC presented the draft concept document for trichloroethylene to the NTP Board of Scientific Counselors (BSC) at the June 21–22, 2012 meeting that provided opportunity for written and oral public comments and is available on the RoC website (https://ntp.niehs.nih.gov/go/711176[underlined: ),] after which the concept was finalized and trichloroethylene was approved by the NTP Director as a candidate substance for review.

Additional scientific input was obtained for exposure, human cancer studies, and immune effects of trichloroethylene. External advisors are identified in the “About This Report” section.

Key issues identified in the concept document include (1) the need for expert input on the quality of the methods used in the epidemiological studies to assess exposure to trichloroethylene and cancer outcome, and information on trichloroethylene exposure in the studies and (2) the potential role of immune effects of trichloroethylene in human cancer. In order to receive public and scientific input on the epidemiological studies and exposure to trichloroethylene, the ORoC held a webinar titled, “Human Cancer Studies on Exposure to Trichloroethylene (TCE): Methods Used to Assess Exposure and Cancer Outcomes,” on March 17, 2014. The ORoC also convened an information group of scientists, with expertise in immunology, cancer, epidemiology, or toxicology, who were asked to provide comments on the body of studies of trichloroethylene exposure and immune effects, and whether these studies are informative for evaluating potential mechanisms for trichloroethylene-related cancers in experimental animals and humans.

Public comments on scientific issues were requested at several times prior to the development of the draft RoC monograph, including the request for information on the nomination, and the request for comment on the draft concept document, which outlined the rationale and approach for conducting the scientific review. In addition, NTP posted its protocol for reviewing the human cancer studies and studies in experimental animals for public input on the ORoC webpage for trichloroethylene (available at (https://ntp.niehs.nih.gov/ntp/roc/thirteenth/protocols/tce_protocol12-31-13_508.pdf) prior to the release of the draft monograph. Two written public comments on trichloroethylene were received from the public as of the date on this document (https://ntp.niehs.nih.gov/go/38854).

### Key Scientific Questions and Issues Relevant for the Cancer Evaluation

The key scientific issues concern the evaluation of cancer studies in humans and experimental animals, and mechanistic data. They are as follows:

#### Questions Related to the Evaluation of Human Cancer Studies

- What is the level of evidence (sufficient, limited) for the carcinogenicity of trichloroethylene from studies in humans?
- What are the major strengths and limitations in the individual studies and how do they affect the findings?
- Are the associations between exposure to trichloroethylene and NHL and cancers of the kidney and liver observed in some studies, and in the meta-analyses, credible? Can bias, chance, or confounding be ruled out with reasonable confidence?

#### Questions Related to the Evaluation of Mechanistic Data

- What are the potential mechanisms by which trichloroethylene may cause NHL and cancers of the kidney and liver?
- Is there evidence that the mechanisms by which trichloroethylene causes cancer in experimental animals may not occur in humans? If so, what is the level of evidence?
- Is there mechanistic evidence in humans that would support the associations observed in some human cancer studies? If so, what is the level of evidence? Of special interest is the level of evidence for mutagenic and cytogenetic modes of action for kidney cancer.
- Is there any evidence that trichloroethylene-induced immunologic effects are related to cancer (such as lymphoma or liver cancer) development?

### Methods for Preparing the Monograph

The procedures by which relevant literature was identified, data were systematically extracted and summarized, and the draft monograph was written, together with the processes for scientific review, quality assurance, and assessment and synthesis of data, are described below.

The preparation of the RoC monograph for trichloroethylene began with development of a literature search strategy to obtain information relevant to the topics listed above for Sections 1 through 6 using search terms developed in collaboration with a reference librarian (see Protocol). The citations (N = 3,543) identified from these searches were uploaded to a web-based systematic review software for evaluation by two separate reviewers using inclusion/exclusion criteria, and 473 references were selected for final inclusion in the draft monograph using these criteria. Studies identified from the literature searches but excluded from the review include publications on chemicals other than trichloroethylene (or relevant structurally related compounds such as trichloroethylene metabolites and analogues or byproducts of production of trichloroethylene), and studies involving exposure to trichloroethylene that reported results for topics not covered in this monograph (see Section Monograph Contents).

Information for the relevant cancer and mechanistic sections was systematically extracted in tabular format and/or summarized in the text, following specific procedures developed by ORoC, from studies selected for inclusion in the monograph. All sections of the monograph underwent scientific review and quality assurance (QA) (i.e., assuring that all the relevant data and factual information extracted from the publications have been reported accurately) by a separate reviewer. Any discrepancies between the writer and the reviewer were resolved by mutual discussion in reference to the original data source.

Strengths, weaknesses, and study quality of the cancer studies for trichloroethylene in humans (see Appendix D) were assessed based on a series of a priori considerations (questions and guidelines for answering the questions), which are available in the protocol (available at https://ntp.niehs.nih.gov/ntp/roc/thirteenth/protocols/tce_protocol12-31-13_508.pdf). Two reviewers evaluated the quality of each study. Any discrepancies between the two reviewers were resolved by mutual discussion in reference to the original data source. Relevant genotoxicity and mechanistic studies were also assessed for their strengths and weaknesses.

RoC listing criteria (see text box) were applied to the available database of carcinogenicity data to assess the level of evidence (sufficient, limited, or inadequate) for the carcinogenicity of trichloroethylene from studies in humans and the level of evidence (sufficient, not sufficient) from studies in experimental animals. The approach for synthesizing the evidence across studies and reaching a level of evidence conclusion was outlined in the protocol. The evaluation of the mechanistic data included a complete discussion and assessment of the strength of evidence for potential modes of action for trichloroethylene-induced neoplasia, including metabolic activation, cytotoxicity, genetic-related effects, and epigenetic effects. The RoC listing criteria were then applied to the body of knowledge (cancer studies in humans and experimental animals and mechanistic data) for trichloroethylene to reach a listing recommendation.

RoC Listing Criteria

##### Known to Be Human Carcinogen

There is sufficient evidence of carcinogenicity from studies in humans*, which indicates a causal relationship between exposure to the agent, substance, or mixture, and human cancer.

##### Reasonably Anticipated to Be Human Carcinogen

There is limited evidence of carcinogenicity from studies in humans*, which indicates that causal interpretation is credible, but that alternative explanations, such as chance, bias, or confounding factors, could not adequately be excluded, OR

there is sufficient evidence of carcinogenicity from studies in experimental animals, which indicates there is an increased incidence of malignant and/or a combination of malignant and benign tumors (1) in multiple species or at multiple tissue sites, or (2) by multiple routes of exposure, or (3) to an unusual degree with regard to incidence, site, or type of tumor, or age at onset, OR

there is less than sufficient evidence of carcinogenicity in humans or laboratory animals; however, the agent, substance, or mixture belongs to a well-defined, structurally related class of substances whose members are listed in a previous Report on Carcinogens as either known to be a human carcinogen or reasonably anticipated to be a human carcinogen, or there is convincing relevant information that the agent acts through mechanisms indicating it would likely cause cancer in humans.

Conclusions regarding carcinogenicity in humans or experimental animals are based on scientific judgment, with consideration given to all relevant information. Relevant information includes, but is not limited to, dose response, route of exposure, chemical structure, metabolism, pharmacokinetics, sensitive sub-populations, genetic effects, or other data relating to mechanism of action or factors that may be unique to a given substance. For example, there may be substances for which there is evidence of carcinogenicity in laboratory animals, but there are compelling data indicating that the agent acts through mechanisms which do not operate in humans and would therefore not reasonably be anticipated to cause cancer in humans.

*This evidence can include traditional cancer epidemiology studies, data from clinical studies, and/or data derived from the study of tissues or cells from humans exposed to the substance in question that can be useful for evaluating whether a relevant cancer mechanism is operating in people.