# Glossary

Alpha_2u_-globulin: α_2u_-Globulin is a low molecular weight protein that is synthesized in the liver of male rats and is regulated by complex hormonal interactions. Androgens stimulate synthesis, whereas estrogens repress synthesis.
Ames assay: The Ames Salmonella/microsome mutagenicity assay is a short-term bacterial reverse mutation assay specifically designed to detect a wide range of chemical substances that can produce genetic damage that leads to gene mutations.
Aneuploidy: An abnormality involving a chromosome number that is not an exact multiple of the haploid number (one chromosome set is incomplete).
Apoptosis: Cell deletion by fragmentation into membrane-bound particles, which are phagocytosed by other cells.
Arabinose resistance: The L-arabinose resistance test with Salmonella typhimurium (Ara test) is a forward mutation assay that selects a single phenotypic change (from L-arabinose sensitivity to L-arabinose resistance) in a unique tester strain (an araD mutant).
Aroclor 1254-induced liver: Liver tissue treated with the polychlorinated biphenyl mixture Aroclor 1254 used as a source of S9 fraction for mutagenic and genotoxic effects testing.
Ascertainment bias: Systematic failure to represent equally all classes of cases or persons supposed to be represented in a sample.
Attrition bias: Systematic differences between comparison groups in withdrawals or exclusions of participants from the results of a study.
Biexponential process: A process of drug (or xenobiotic) clearance with two phases with different rates. The first phase often involves rapid distribution of a drug to peripheral tissues, while the second phase represents clearance mechanisms that eliminate the drug from the body. (See “Two-compartment pharmacokinetic model.”)
Biodegradation: Biotransformation; the conversion within an organism of molecules from one form to another. A change often associated with change in pharmacologic activity.
Boiling point: The boiling point of the anhydrous substance at atmospheric pressure (101.3 kPa) unless a different pressure is stated. If the substance decomposes below or at the boiling point, this is noted (dec). The temperature is rounded off to the nearest °C.
CD8+ T-cell blast: An immature, undifferentiated lymphocyte that expresses the CD8 transmembrane glycoprotein.
Chemical Data Reporting Rule: Chemical Data Reporting (CDR) is the new name for Inventory Update Reporting (IUR). The purpose of Chemical Data Reporting is to collect quality screening-level, exposure-related information on chemical substances and to make that information available for use by the U.S. Environmental Protection Agency (EPA) and, to the extent possible, to the public. The IUR/CDR data are used to support risk screening, assessment, priority setting and management activities and constitute the most comprehensive source of basic screening-level, exposure-related information on chemicals available to EPA. The required frequency of reporting currently is once every 4 years.
Cochran-Armitage trend test: A statistical test used in categorical data analysis when the aim is to assess for the presence of an association between a variable with two categories and a variable with k categories. It modifies the chi-square test to incorporate a suspected ordering in the effects of the k categories of the second variable.
Comet assay: Single cell gel electrophoresis for assessment of DNA damage in presumptive target tissues.
Connexin proteins: A group of transmembrane proteins that form the intermembrane channels of gap junctions. They are used by inorganic ions and most small organic molecules to pass through cell interiors.
Conversion factor: A numerical factor used to multiply or divide a quantity when converting from one system of units to another.
Critical temperature: The temperature at and above which a gas cannot be liquefied, no matter how much pressure is applied.
Dehydrodehalogenation: An elimination reaction in which a halogen is removed from one carbon and a hydrogen is removed from an adjacent carbon.
Differential selection: Selective pressure for self-renewal. Gene mutations that confer a growth or survival advantage on the cells that express them will be selectively enriched in the genome of tumors.
Disposition: The description of absorption, distribution, metabolism, and excretion of a chemical in the body.
Dominant lethal mutation assay: The dominant lethal assay identifies germ cell mutagens by measuring the ability of a chemical to penetrate gonadal tissue and produce embryonic death due to chromosomal breakage in parent germ cells.
Double acid conjugate: A compound formed by the joining of two acids.
Ecological study: A study in which the units of analysis are populations or groups of people rather than individuals.
ELISA assay: Enzyme-linked immunosorbent assay; a sensitive immunoassay that uses an enzyme linked to an antibody or antigen as a marker for the detection of a specific protein, especially an antigen or antibody.
Epigenetic mechanisms: Changes in gene function that do not involve a change in DNA sequence but are nevertheless mitotically and/or meiotically heritable. Examples include DNA methylation, alternative splicing of gene transcripts, and assembly of immunoglobulin genes in cells of the immune system.
F_0_ generation: The initial parent generation in a multi-generation reproduction study.
F_1_ and F_2_ offspring: F_1_ offspring is the first filial generation, which comprises offspring resulting from a cross between strains of distinct genotypes. The F_1_ generation is the generation resulting immediately from a cross of the first set of parents (parental generation, i.e., F_0_ generation). F_2_ offspring is the second filial generation, which comprises offspring resulting from a cross of the members of F_1_ generation. The F_2_ generation is the result of a cross between two F_1_ individuals (from F_1_ generation).
FDA Good Laboratory Practice Regulations: A quality system codified by the U.S. Food and Drug Administration that prescribes operating procedures for conducting nonclinical laboratory studies that support or are intended to support applications for research or marketing permits for products regulated by the Food and Drug Administration.
Fisher’s exact test: The test for association in a two-by-two table that is based on the exact hypergeometric distribution of the frequencies within the table.
Follow-up: Observation over a period of time of a person, group, or initially defined population whose appropriate characteristics have been assessed to observe changes in health status or health-related variables.
Freund’s adjuvant: A water-in-oil emulsion injected with immunogen (Freund's incomplete adjuvant) or with immunogen and killed mycobacteria (Freund's complete adjuvant) to enhance the immune response to the immunogen.
Genomic instability: An increased propensity for genomic alterations that often occurs in cancer cells. During the process of cell division (mitosis) the inaccurate duplication of the genome in parent cells or the improper distribution of genomic material between daughter cells can result from genomic instability.
Glioma: A cancer of the brain that begins in glial cells (cells that surround and support nerve cells).
Hairy-cell leukemia: A rare type of leukemia in which abnormal B-lymphocytes (a type of white blood cell) are present in the bone marrow, spleen, and peripheral blood. When viewed under a microscope, these cells appear to be covered with tiny hair-like projections.
Healthy worker hire effect: Initial selection of healthy individuals at time of hire so that their disease risks differ from the disease risks in the source (general) population.
Healthy worker survival effect: A continuing selection process such that those who remain employed tend to be healthier than those who leave employment.
Hemangiosarcoma: A type of cancer that begins in the cells that line blood vessels.
Henry’s Law constant: The ratio of the aqueous-phase concentration of a chemical to its equilibrium partial pressure in the gas phase. The larger the Henry’s law constant the less soluble it is (i.e., greater tendency for vapor phase). The relationship is defined for a constant temperature, e.g., 25°C.
Hepatoma: A liver tumor.
Host-mediated assay: This assay evaluates the genotoxicity of a substance to microbial cells introduced (e.g., by intravenous injection) into a host animal. The host animal receives the test compound orally, and therefore acts as a source of chemical metabolism, distribution, and excretion of the test compound.
Immersion cleaning: A process in which a tank containing cleaning solvent at a temperature below its boiling point is used for metal parts cleaning. To use the vapor degreaser, the operator places the parts to be cleaned in a metal wire basket, removes the cover, and lowers the basket of parts by hand into the cleaning solvent. After a brief period of time, the operator raises the basket and allows the parts to drip-dry inside the degreaser.
Keratosis: A localized horny overgrowth of the skin, such as a wart or callus.
Loss of heterozygosity: If there is one normal and one abnormal allele at a particular locus, as might be seen in an inherited autosomal dominant cancer susceptibility disorder, loss of the normal allele produces a locus with no normal function. When the loss of heterozygosity involves the normal allele, it creates a cell that is more likely to show malignant growth if the altered gene is a tumor suppressor gene.
Lymphokine-activated killer cell: Killer cell lymphocytes activated in the presence of interleukin-2 (IL-2). Lymphokine-activated killer cells (LAKs) are cytotoxic effector cells with an exceptionally wide target cell spectrum including normal and malignant cells of different origins. LAKs exhibit a profound heterogeneity with regard to phenotype surface marker expression; it remains to be determined if they represent a unique cell lineage.
Melting point: The melting point of the substance at atmospheric pressure (101.3 kPa). When there is a significant difference between the melting point and the freezing point, a range is given. In case of hydrated substances (i.e., those with crystal water), the apparent melting point is given. If the substance decomposes at or below its melting point, this is noted (dec). The temperature is rounded off to the nearest °C.
Metabolic activation: The chemical alteration of an exogenous substance by or in a biological system. The alteration may inactivate the compound, or it may result in the production of an active metabolite of an inactive parent compound.
Metaplasia: A change of cells to a form that does not normally occur in the tissue in which it is found.
Methemoglobin: A form of hemoglobin found in the blood in small amounts. Unlike normal hemoglobin, methemoglobin cannot carry oxygen. Injury or certain drugs, chemicals, or foods may cause a higher-than-normal amount of methemoglobin to be made. This causes a condition called methemoglobinemia.
Micronuclei: Small nuclei separate from, and additional to, the main nucleus of a cell, produced during the telophase of mitosis or meiosis by lagging chromosomes or chromosome fragments derived from spontaneous or experimentally induced chromosomal structural changes.
Miscible: A physical characteristic of a liquid that forms one liquid phase with another liquid (e.g., water) when they are mixed in any proportion.
Molecular chaperone: Any of a diverse group of proteins that oversee the correct intracellular folding and assembly of polypeptides without being components of the final structure.
Molecular weight: The molecular weight of a substance is the weight in atomic mass units of all the atoms in a given formula. The value is rounded to the nearest tenth.
Multiple myeloma: A type of cancer that begins in plasma cells (white blood cells that produce antibodies). Also called Kahler disease, myelomatosis, and plasma cell myeloma.
Mutations: A change in the structure of a gene, resulting from the alteration of single base units in DNA, or the deletion, insertion, or rearrangement of larger sections of genes or chromosomes. The genetic variant can be transmitted to subsequent generations.
National Health and Nutrition Examination Survey: A program of studies designed to assess the health and nutritional status of adults and children in the United States. The survey is unique in that it combines interviews and physical examinations.
Natural killer cells: A type of white blood cell that contains granules with enzymes that can kill tumor cells or microbial cells. Also called large granular lymphocytes.
Non-differential misclassification: The probability of erroneous classification of an individual, a value, or an attribute into a category other than that to which it should be assigned is the same in all study groups.
Non-Hodgkin lymphoma: A heterogeneous group of malignant lymphomas; the only common feature being an absence of the giant Reed-Sternberg cells characteristic of Hodgkin disease.
Normochromatic erythrocyte: A mature erythrocyte that lacks ribosomes and can be distinguished from immature, polychromatic erythrocytes by stains selective for RNA.
Octanol/water partition coefficient (log Kow): A measure of the equilibrium concentration of a compound between octanol and water.
One-compartment model: A pharmacokinetic modeling approach that models the entire body as a single compartment into which a drug is added by a rapid single dose, or bolus. It is assumed that the drug concentration is uniform in the body compartment at all times and is eliminated by a first order process that is described by a first order rate constant.
Ozone-depleting substance: A family of man-made compounds that includes, but are not limited to, chlorofluorocarbons (CFCs), bromofluorocarbons (halons), methyl chloroform, carbon tetrachloride, methyl bromide, and hydrochlorofluorocarbons (HCFCs). These compounds have been shown to deplete stratospheric ozone.
Papilloma: A small solid benign tumor with a clear-cut border that projects above the surrounding tissue.
Personal breathing zone: A sampling area as close as practical to an employee’s nose and mouth, (i.e., in a hemisphere forward of the shoulders within a radius of approximately nine inches) so that it does not interfere with work performance or safety of the employee.
Personal protective equipment: Specialized clothing or equipment, worn by an employee to minimize exposure to a variety of hazards. Examples of PPE include such items as gloves, foot and eye protection, protective hearing devices (earplugs, muffs), hard hats, respirators, and full body suits.
Phase I metabolism: Metabolism of drugs or other xenobiotic molecules, usually by oxidation or hydrolysis and involving a cytochrome P450 monooxygenase.
Phase II metabolism: A conjugation reaction that forms a covalent linkage between a functional group on a xenobiotic molecule and glucuronic acid, sulfate, glutathione, amino acid, or acetate.
Plaque assay: An assay for antibody production by single lymphocytes using cells isolated from the spleen or lymph nodes of animals injected with sheep red blood cells as an antigen. Incubation of the antibody-forming cells together with sheep red cells in an agar layer with exposure to guinea pig serum as complement results in formation of microscopic plaques (i.e., circular areas of hemolytic clearance around a lymphoid cell) due to release of hemolysin.
Plate incorporation: A commonly used procedure for performing a bacterial reverse mutation test. Suspensions of bacterial cells are exposed to the test substance in the presence and in the absence of an exogenous metabolic activation system. In the plate-incorporation method, these suspensions are mixed with an overlay agar and plated immediately onto minimal medium. After 2 or 3 days of incubation, revertant colonies are counted and compared with the number of spontaneous revertant colonies on solvent control plates.
Point emission: A release that can be identified with a single discharge source or attributed to a specific physical location.
Polychromatic erythrocyte: A newly formed erythrocyte (reticulocyte) containing RNA.
Prophage lambda (λ): A virus in Escherichia coli (E. coli) bacteria that has integrated itself into the host E. coli DNA.
Proto-oncogene: A gene involved in normal cell growth. Mutations (changes) in a proto-oncogene may cause it to become an oncogene, which can cause the growth of cancer cells.
p_trend_: Level of statistical significance of a change over time in a group selected to represent a larger population.
Pyknotic shrinkage: A thickening, especially the degeneration of a cell in which the nucleus shrinks in size and the chromatin condenses to a solid, structureless mass or masses.
Pyrolysis: The chemical and physical decomposition of organic material that occurs at high temperatures in the absence of oxygen.
QUOSA: A collection of scientific literature management software and services for researchers and information professionals in the life sciences and related scientific and medical areas designed to retrieve, organize, and analyze full-text articles and documents.
Selection bias: An error in choosing the individuals or groups to take part in a study. Ideally, the subjects in a study should be very similar to one another and to the larger population from which they are drawn (for example, all individuals with the same disease or condition). If there are important differences, the results of the study may not be valid.
Sister-chromatid exchange: The exchange during mitosis of homologous genetic material between sister chromatids; increased as a result of inordinate chromosomal fragility due to genetic or environmental factors.
SKF-525A: An inhibitor of drug metabolism and cytochrome P-450 activity.
Soft tissue sarcoma: A cancer that begins in the muscle, fat, fibrous tissue, blood vessels, or other supporting tissue of the body.
Solubility: The ability of a substance to dissolve in another substance and form a solution. The Report on Carcinogens uses the following definitions (and concentration ranges) for degrees of solubility: (1) miscible (see definition), (2) freely soluble-capable of being dissolved in a specified solvent to a high degree (>1,000 g/L), (3) soluble- capable of being dissolved in a specified solvent (10–1,000 g/L), (4) slightly soluble- capable of being dissolved in a specified solvent to a limited degree (1–10 g/L), and (5) practically insoluble- incapable of dissolving to any significant extent in a specified solvent (<1 g/L).
Specific gravity: The ratio of the density of a material to the density of a standard material, such as water at a specific temperature; when two temperatures are specified, the first is the temperature of the material and the second is the temperature of water.
Spot test: Qualitative assay in which a small amount of test chemical is added directly to a selective agar medium plate seeded with the test organism, e.g., Salmonella. As the chemical diffuses into the agar, a concentration gradient is formed. A mutagenic chemical will give rise to a ring of revertant colonies surrounding the area where the chemical was applied; if the chemical is toxic, a zone of growth inhibition will also be observed.
Steric bulk: An indicator of the stability of the spatial arrangement of atoms in a molecule.
T-helper cell: A type of immune cell that stimulates killer T cells, macrophages, and B cells to make immune responses. A helper T cell is a type of white blood cell and a type of lymphocyte. Also called CD4-positive T lymphocyte.
Tg.AC: A transgenic mouse model with the ability to mount a tumorigenic response within 6 months in skin paint assays when dosed topically with nonmutagenic carcinogens.
Time-weighted average: The average exposure concentration of a chemical measured over a period of time (not an instantaneous concentration).
Toxicokinetics: The mathematical description (toxicokinetic models) of the time course of disposition of a chemical in the body.
Transitions: DNA nucleotide substitution mutation in which a purine base is substituted for another purine base (adenine → guanine or guanine → adenine) or a pyrimidine base for another pyrimidine base (cytosine → thymine or thymine → cytosine).
Transversions: DNA nucleotide substitution mutation in which a purine base (adenine or guanine) is substituted for a pyrimidine base (cytosine or thymine) or vice versa.
Two-compartment pharmacokinetic model: A two-compartment pharmacokinetic model resolves the body into a central compartment and a peripheral compartment. The central compartment generally comprises tissues that are highly perfused, such as heart, lungs, kidneys, liver, and brain. The peripheral compartment comprises less well-perfused tissues, such as muscle, fat, and skin. A two-compartment model assumes that, following drug administration into the central compartment, the drug distributes between that compartment and the peripheral compartment. However, the drug does not achieve instantaneous distribution (i.e., equilibrium), between the two compartments. After a time interval (t), distribution equilibrium is achieved between the central and peripheral compartments, and elimination of the drug is assumed to occur from the central compartment.
Type-I error: The error of rejecting a true null hypothesis, i.e., declaring that a difference exists when it does not.
Type-II error: The error of failing to reject a false null hypothesis, i.e., declaring that a difference does not exist when in fact it does.
Vapor degreasing: A type of cleaning procedure using a refrigerated cooling coil around the top of the interior of a vapor chamber to condense solvent vapor into liquid droplets on the surface of parts to remove surface impurities. Excess solvent drips back into the solvent sump and is recycled as the parts ascend from the vapor to condensing zones.
Vapor density, relative: A value that indicates how many times a gas (or vapor) is heavier than air at the same temperature. If the substance is a liquid or solid, the value applies only to the vapor formed from the boiling liquid.
Vapor pressure: The pressure of the vapor over a liquid (and some solids) at equilibrium, usually expressed as mm Hg at a specific temperature (°C).