# Abbreviations

  8-OHdG: 8-hydroxy-2'-deoxyguanosine
  ACGIH: American Conference of Governmental Industrial Hygienists
  ADH: alcohol dehydrogenase
  ADME: absorption, distribution, metabolism, and excretion
  AF: fraction of inhaled substance absorbed
  ALDH: aldehyde dehydrogenase
  ANCA: antinuclear antibodies
  ATSDR: Agency for Toxic Substances and Disease Registry
  BMI: body mass index
  BTC: S-(2-benzothiazolyl)-L-cysteine
  BW: body weight
  CA: chromosomal aberration
  CAREX: CARcinogen EXposure (Canada)
  CASRN: Chemical Abstracts Service registry number
  CAT: catalase
  CD: cluster of differentiation
  CDC: Centers for Disease Control and Prevention
  CDR: Chemical Data Reporting Rule
  CERHR: Center for the Evaluation of Risks to Human Reproduction
  CH: chloral hydrate
  CI: confidence interval
  CIN: chromosomal instability
  CLL: chronic lymphocytic lymphoma
  cm^2^: square centimeter
  cum.: cumulative
  CGDP: cysteinylglycine dipeptidases
  CO_2_: carbon dioxide
  CTAC: chlorothionoacetyl chloride
  CTFC: S-(2-chloro-1,1,2-trifluoroethyl)-L-cysteine
  CTK: chlorothioketene
  CYP: cytochrome P450
  D: day or days
  DlBCL: diffuse large B-cell lymphoma
  DCA: dichloroacetic acid
  DCAA: dichloroacetyl chloride
  DCAC: dichloroacetyl anhydride
  DCVC: S-(1,2-dichlorovinyl)-L-cysteine
  DCVG: S-(1,2-dichlorovinyl)glutathione
  DCVT: S-dichlorovinyl-thiol
  DLBCL: diffuse large B-cell lymphoma
  DMSO: dimethyl sulfoxide
  DMV: Department of Motor Vehicles
  DNA: deoxyribonucleic acid
  E/R: exposure response
  EAC: equivalent airborne concentrations
  EBV: Epstein-Barr virus
  eEF1A1: eukaryotic translation elongation factor 1 alpha 1
  eEF1A2: eukaryotic translation elongation factor 1 alpha 2
  EHR: enterohepatic recirculation
  EL: exposure length (min)
  ENGELA: Environment and Adult Lymphoma Genetics
  EPA: Environmental Protection Agency
  EPILYMPH: Environmental exposures and lymphoid neoplasms
  Exp.: exposed
  F: female
  FDA: Food and Drug Administration
  FL: follicular lymphoma
  FMO: flavin monooxygenase
  FR: Federal Register
  ft: foot/feet
  G: guanine
  GGT: γ-glutamyltransferase
  GI: gastrointestinal
  GPO: glutathione peroxidase
  GSH: glutathione
  GST: glutathione-S-transferase
  HCL: hairy-cell leukemia
  Hg: mercury
  HGPRT: hypoxanthine-guanine phosphoribosyltransferase
  HHS: Department of Health and Human Services
  HIC: highest ineffective concentration
  HID: highest ineffective dose
  HIV: human immunodeficiency virus
  HL: Hodgkin lymphoma
  HP: Hadnot Point (Camp Lejeune)
  hr: hour or hours
  HR: hazard ratio
  HRR: hazard rate ratio
  HWE: healthy worker (hire or survival) effect
  I: inconclusive
  I2PP2A: protein phosphatase 2A inhibitor
  i.p.: intraperitoneal
  IARC: International Agency for Research on Cancer
  ICAM: intercellular adhesion molecule
  ICD: International Classification of Diseases
  ICD-O: International Classification of Diseases for Oncology
  ICDA: International Classification of Diseases-Adjusted
  ID: identity
  IDLH: immediately dangerous to life and health
  IFN: interferon
  IgE: immunoglobulin E
  IgG: immunoglobulin G
  IgM: immunoglobulin M
  IL: interleukin
  in: inch or inches
  inh: inhalation
  INS: insignificant change compared to controls
  IQR: interquartile ratio
  IRIS: Integrated Risk Information System
  IUR: Inventory Update Rule
  JEM: job-exposure matrix
  JP4: jet propellant-4
  JTEM: job-task exposure matrix
  kg: kilogram
  Km: Michaelis-Menten constant
  K_ow_: Octanol-water partition coefficient
  L: liter
  LARS: Leipzig Allergy Risk Children’s Study
  LDH: lactate dehydrogenase
  LEC: lowest effective concentration
  LED: lowest effective dose
  LH: lymphohematopoietic
  LHC: lymphohematopoietic cancer
  Log K_ow_: logarithm of octanol/water partition coefficient
  LP: lipid peroxidation
  M: male
  m^3^: cubic meter
  MCA: monochloroacetic acid
  MCL: maximum contaminant level
  MG: methylguanine
  mg: milligram
  MHC II: major histocompatibility complex II
  MIS: Multicentre Italian Study
  mL: milliliter
  mm: millimeter
  MM: multiple myeloma
  MMAI: maleylacetoacetate isomerase
  MN: micronuclei
  mol: mole
  mRR: meta-relative risk
  MV: minute volume
  N: number
  NA: not available; not applicable
  NAcDCVC: N-acetyl-S-dichlorovinyl-L-cysteine
  NAcDCVCS: N-acetyl DCVCS
  NAS: National Academy of Science
  NAT: N-acetyltransferase
  NCI: National Cancer Institute
  NCTR: National Center for Toxicological Research
  ND: not detected; not determined; not done
  NDI: National Death Index
  ng: nanogram
  NHANES: National Health and Nutrition Examination Survey
  NHL: non-Hodgkin lymphoma
  NIEHS: National Institute of Environmental Health Sciences
  NIH: National Institutes of Health
  NIOSH: National Institute for Occupational Safety and Health
  NK: natural killer cells
  NLM: National Library of Medicine
  nmol: nanomole
  NOCCA: Nordic Occupational Cancer
  NOES: National Occupational Exposure Survey
  NOS: not otherwise specified
  NR: not reported; none reported
  ns: not specified
  NS: not significant
  nt: nucleotides
  NT: not tested
  NTP: National Toxicology Program
  OA: oxalic acid
  OD: oral dose (mg/kg)
  OR: odds ratio
  OSHA: Occupational Safety and Health Administration
  p.o.: per os (oral administration)
  PAH: polycyclic aromatic hydrocarbon
  PBPK: physiologically based pharmacokinetic model
  PCBs: polychlorinated biphenyls
  PCE: polychromatic erythrocyte
  PCNA: proliferating cell nuclear antigen
  PEL: permissible exposure limit
  Perc: perchloroethylene (tetrachloroethylene)
  PGDP: Paduca Gaseous Diffusion Plant
  PLC: peritoneal lavage cell
  PPARα: peroxisome proliferation activated receptor α
  PPE: Personal Protective Equipment
  ppm: parts per million
  ppt: parts per trillion
  p_trend_: p value for trend
  R: estimated daily production of adducts
  r: correlation coefficient
  RBC: red blood cell
  RCC: renal-cell cancer
  RDD: random-digit dialing
  REAL: Revised European-American Lymphoma classification
  REL: recommended exposure limit
  RfC: reference dose
  RLV: Rauscher-leukemia virus
  R-N: Raaschou-Nielsen
  RNA: ribonucleic acid
  RoC: Report on Carcinogens
  ROS: reactive oxygen species
  RQ: reportable quantity
  RR: relative risk
  RRD: random digit dialing
  SCE: sister-chromatid exchange
  SD: standard deviation
  SEER: Surveillance, Epidemiology and End Results Program (US National Cancer Institute)
  SES: socioeconomic status
  SIR: standardized incidence ratio
  SLL: small cell lymphocytic lymphoma
  SMR: standardized mortality ratio
  SOD: superoxide dismutase
  SRR: standardized rate ratio, standardized relative risk
  SSA: Social Security Administration
  SSB: single strand break
  SSc: systemic sclerosis
  SSFL: Santa Susanna Field Laboratory
  SSN: Social Security number
  TBARS: thiobarbituric acid-reactive substances
  TCA: trichloroacetic acid
  TCAH: trichloroacetyl hydrate
  TCDD: 2,3,7,8-tetrachlorodibenzo-p-dioxin
  TCE: trichloroethylene
  TCE-O: Trichloroethylene oxide
  TCOG: trichloroethanol-glucuronide conjugate
  TCOH: trichloroethanol
  TCVC: S-(1,2,2-trichlorovinyl)-L-cysteine
  TLV-TWA: threshold limit value time-weighted average
  TLV-STEL: Threshold limit value – short-term exposure limit
  t_max_: time to maximum concentration in plasma
  TNF: tumor necrosis factor
  TRI: Toxics Release Inventory
  TSCA: Toxic Substances Control Act
  TT: Tarawa Terrace (Camp Lejeune)
  TWA: time-weighted average
  UDP: uridine diphosphate
  UDS: unscheduled DNA synthesis
  UGT: UDP-glucuronosyltransferase
  UK: United Kingdom
  U-TCA: urine trichloroacetic acid
  VHL: von Hippel-Lindau
  V_max_: maximum reaction velocity
  VOC: volatile organic compound
  W: women
  WBC: white blood cell
  WHO: World Health Organization
  wk: week or weeks
  wt%: weight percent
  yr: year or years
  μg: microgram
  μg/L: micrograms/liter
  μg/L-mo: micrograms/liter-months
  μM: micromolar