# References

Adamson P, Bray F, Costantini AS, Tao MH, Weiderpass E, Roman E. 2007. Time trends in the registration of Hodgkin and non-Hodgkin lymphomas in Europe. Eur J Cancer. 43(2):391–401. 10.1016/j.ejca.2006.10.008 17134891
Agency for Toxic Substances Disease Registry (ATSDR). 1997. Toxicological profile for trichloroethylene. Atlanta, GA: Agency for Toxic Substances and Disease Registry.
Agency for Toxic Substances Disease Registry (ATSDR).2013. Addendum to the toxicological profile for trichloroethylene. Atlanta, GA: Agency for Toxic Substances and Disease Registry.https://www.atsdr.cdc.gov/toxprofiles/tce_addendum.pdf.
Albertini S. 1990. Analysis of nine known or suspected spindle poisons for mitotic chromosome malsegregation using Saccharomyces cerevisiae D61.M. Mutagenesis. 5(5):453–459. 10.1093/mutage/5.5.453 2263203
Alexander DD, Kelsh MA, Mink PJ, Mandel JH, Basu R, Weingart M. 2007. A meta-analysis of occupational trichloroethylene exposure and liver cancer. Int Arch Occup Environ Health. 81(2):127–143. 10.1007/s00420-007-0201-4 17492303
Aligo J, Walker M, Bugelski P, Weinstock D. 2014. Is murine gammaherpesvirus-68 (MHV-68) a suitable immunotoxicological model for examining immunomodulatory drug-associated viral recrudescence? J Immunotoxicol.
Allen JW, Collins BW, Evansky PA. 1994. Spermatid micronucleus analyses of trichloroethylene and chloral hydrate effects in mice. Mutat Res. 323(1-2):81–88. 10.1016/0165-7992(94)90049-3 7508572
Amacher DE, Zelljadt I. 1983. The morphological transformation of Syrian hamster embryo cells by chemicals reportedly nonmutagenic to Salmonella typhimurium. Carcinogenesis. 4(3):291–295. 10.1093/carcin/4.3.291 6339095
Anttila A, Pukkala E, Sallmén M, Hernberg S, Hemminki K. 1995. Cancer incidence among Finnish workers exposed to halogenated hydrocarbons. J Occup Environ Med. 37(7):797–806. 10.1097/00043764-199507000-00008 7552463
Aranyi C, O’Shea WJ, Graham JA, Miller FJ. 1986. The effects of inhalation of organic chemical air contaminants on murine lung host defenses. Fundam Appl Toxicol. 6(4):713–720. 10.1016/0272-0590(86)90184-3 3519345
Arp EW Jr, Wolf PH, Checkoway H. 1983. Lymphocytic leukemia and exposures to benzene and other solvents in the rubber industry. J Occup Med. 25(8):598–602. 6886869
Arslan C, Kiliçkap S, Yalçin S. 2011. Gastric cancer after cadaveric liver transplantation in a patient with autoimmune hepatitis: A case report and review of the literature. Turk J Gastroenterol. 22(1):73–76. 10.4318/tjg.2011.0160 21480115
Asal NR, Geyer JR, Risser DR, Lee ET, Kadamani S, Cherng N. 1988. Risk factors in renal cell carcinoma. II. Medical history, occupation, multivariate analysis, and conclusions. Cancer Detect Prev. 13(3-4):263–279. 3266567
Austin EW, Parrish JM, Kinder DH, Bull RJ. 1996. Lipid peroxidation and formation of 8-hydroxydeoxyguanosine from acute doses of halogenated acetic acids. Fundam Appl Toxicol. 31(1):77–82. 10.1006/faat.1996.0078 8998956
Axelson O, Andersson K, Hogstedt C, Holmberg B, Molina G, de Verdier A. 1978. A cohort study on trichloroethylene exposure and cancer mortality. J Occup Med. 20(3):194–196. 10.1097/00043764-197803000-00008 627938
Axelson O, Selden A, Andersson K, Hogstedt C. 1994. Updated and expanded Swedish cohort study on trichloroethylene and cancer risk. J Occup Med. 36(5):556–562. 8027881
Baden JM, Kelley M, Mazze RI, Simmon VF. 1979. Mutagenicity of inhalation anaesthetics: Trichloroethylene, divinyl ether, nitrous oxide and cyclopropane. Br J Anaesth. 51(5):417–421. 10.1093/bja/51.5.417 375954
Baecklund E, Smedby KE, Sutton LA, Askling J, Rosenquist R. 2014. Lymphoma development in patients with autoimmune and inflammatory disorders—what are the driving forces? Semin Cancer Biol. 24:61–70. 10.1016/j.semcancer.2013.12.001 24333759
Bahr DE, Aldrich TE, Seidu D, Brion GM, Tollerud DJ, Muldoon S, Reinhart N, Youseefagha A, McKinney P, Hughes T, et al. 2011. Occupational exposure to trichloroethylene and cancer risk for workers at the Paducah Gaseous Diffusion Plant. Int J Occup Med Environ Health. 24(1):67–77. 10.2478/s13382-011-0007-1 21468904
Bakke B, Stewart PA, Waters MA. 2007. Uses of and exposure to trichloroethylene in US industry: A systematic literature review. J Occup Environ Hyg. 4(5):375–390. 10.1080/15459620701301763 17454505
Balkwill F, Charles KA, Mantovani A. 2005. Smoldering and polarized inflammation in the initiation and promotion of malignant disease. Cancer Cell. 7(3):211–217. 10.1016/j.ccr.2005.02.013 15766659
Banerjee S, Van Duuren BL. 1978. Covalent binding of the carcinogen trichloroethylene to hepatic microsomal proteins and to exogenous DNA in vitro. Cancer Res. 38(3):776–780. 626981
Bartoníček V. 1962. Metabolism and excretion of trichloroethylene after inhalation by human subjects. Br J Ind Med. 19:134–141. 10.1136/oem.19.2.134 13865497
Bartsch H, Malaveille C, Barbin A, Planche G. 1979. Mutagenic and alkylating metabolites of halo-ethylenes, chlorobutadienes and dichlorobutenes produced by rodent or human liver tissues. Arch Toxicol. 41(4):249–277. 10.1007/BF00296896 373707
Bassig BA, Zhang L, Tang X, Vermeulen R, Shen M, Smith MT, Qiu C, Ge Y, Ji Z, Reiss B, et al. 2013. Occupational exposure to trichloroethylene and serum concentrations of IL-6, IL-10, and TNF-alpha. Environ Mol Mutagen. 54(6):450–454. 10.1002/em.21789 23798002
Bel Hadj Jrad B, Chatti A, Laatiri A, Ahmed SB, Romdhane A, Ajimi S, Chouchane L. 2006. Tumor necrosis factor promoter gene polymorphism associated with increased susceptibility to non-Hodgkin’s lymphomas. Eur J Haematol. 78(2):117–122. 10.1111/j.1600-0609.2006.00784.x 17087739
Bergman K. 1983. Interactions of trichloroethylene with DNA in vitro and with RNA and DNA of various mouse tissues in vivo. Arch Toxicol. 54(3):181–193. 10.1007/BF01239202 6197950
Bernatsky S, Ramsey-Goldman R, Clarke A. 2006. Malignancy and autoimmunity. Curr Opin Rheumatol. 18(2):129–134. 10.1097/01.bor.0000209423.39033.94 16462517
Besson H, Brennan P, Becker N, Nieters A, De Sanjosé S, Font R, Maynadie M, Foretova L, Cocco PL, Staines A, et al. 2006. Tobacco smoking, alcohol drinking and non-Hodgkin’s lymphoma: A European multicenter case-control study (Epilymph). Int J Cancer. 119(4):901–908. 10.1002/ijc.21913 16557575
Bhunya SP, Behera BC. 1987. Relative genotoxicity of trichloroacetic acid (TCA) as revealed by different cytogenetic assays: Bone marrow chromosome aberration, micronucleus and sperm-head abnormality in the mouse. Mutat Res. 188(3):215–221. 10.1016/0165-1218(87)90092-9 3600687
Bhunya SP, Jena GB. 1996. The evaluation of clastogenic potential of trichloroacetic acid (TCA) in chick in vivo test system. Mutat Res. 367(4):254–259. 10.1016/S0165-1218(96)90085-3 8628333
Blackburn AC, Matthaei KI, Lim C, Taylor MC, Cappello JY, Hayes JD, Anders MW, Board PG. 2006. Deficiency of glutathione transferase zeta causes oxidative stress and activation of antioxidant response pathways. Mol Pharmacol. 69(2):650–657. 10.1124/mol.105.018911 16278372
Blair A, Hartge P, Stewart PA, McAdams M, Lubin J. 1998. Mortality and cancer incidence of aircraft maintenance workers exposed to trichloroethylene and other organic solvents and chemicals: Extended follow up. Occup Environ Med. 55(3):161–171. 10.1136/oem.55.3.161 9624267
Bloemen LJ, Tomenson J. 1995. Increased incidence of renal cell tumours in a cohort of cardboard workers exposed to trichloroethylene. Arch Toxicol. 70(2):129–133. 10.1007/BF02733675 8773187
Blossom SJ, Doss JC. 2007. Trichloroethylene alters central and peripheral immune function in autoimmune-prone MRL(+/+) mice following continuous developmental and early life exposure. J Immunotoxicol. 4(2):129–141. 10.1080/15476910701337035 18958721
Blossom SJ, Doss JC, Gilbert KM. 2006. Ability of trichloroethylene metabolite to promote immune pathology is strain-specific. J Immunotoxicol. 3(4):179–187. 10.1080/15476910600978046 18958699
Blossom SJ, Doss JC, Gilbert KM. 2007. Chronic exposure to a trichloroethylene metabolite in autoimmune-prone MRL+/+ mice promotes immune modulation and alopecia. Toxicol Sci. 95(2):401–411. 10.1093/toxsci/kfl149 17077186
Blossom SJ, Gilbert KM. 2006. Exposure to a metabolite of the environmental toxicant, trichloroethylene, attenuates CD4+ T cell activation-induced cell death by metalloproteinase-dependent FasL shedding. Toxicol Sci. 92(1):103–114. 10.1093/toxsci/kfj212 16641322
Blossom SJ, Pumford NR, Gilbert KM. 2004. Activation and attenuation of apoptosis of CD4+ T cells following in vivo exposure to two common environmental toxicants, trichloroacetaldehyde hydrate and trichloroacetic acid. J Autoimmun. 23(3):211–220. 10.1016/j.jaut.2004.06.007 15501392
Board PG, Anders MW. 2005. Human glutathione transferase zeta. Methods Enzymol. 401:61–77. 10.1016/S0076-6879(05)01004-9 16399379
Board PG, Anders MW. 2011. Glutathione transferase zeta: Discovery, polymorphic variants, catalysis, inactivation, and properties of Gstz1 -/- mice. Drug Metab Rev. 43(2):215–225. 10.3109/03602532.2010.549132 21303221
Bogen KT. 1988. Pharmacokinetics for regulatory risk analysis: The case of trichloroethylene. Regul Toxicol Pharmacol. 8(4):447–466. 10.1016/0273-2300(88)90045-1 3222486
Bogen KT, Colston BW Jr, Machicao LK. 1992. Dermal absorption of dilute aqueous chloroform, trichloroethylene, and tetrachloroethylene in hairless guinea pigs. Fundam Appl Toxicol. 18(1):30–39. 10.1016/0272-0590(92)90192-K 1601207
Boice JD Jr, Marano DE, Cohen SS, Mumma MT, Blot WJ, Brill AB, Fryzek JP, Henderson BE, McLaughlin JK. 2006. Mortality among Rocketdyne workers who tested rocket engines, 1948-1999. J Occup Environ Med. 48(10):1070–1092. 10.1097/01.jom.0000240661.33413.b5 17033507
Boice JD Jr, Marano DE, Fryzek JP, Sadler CJ, McLaughlin JK. 1999. Mortality among aircraft manufacturing workers. Occup Environ Med. 56(9):581–597. 10.1136/oem.56.9.581 10615290
Boice JD Jr, McLaughlin JK. 2001. Errors in TCE analysis. Environ Health Perspect. 109(3):A108. 10.1289/ehp.109-a108a 11333195
Bolt HM, Lammert M, Selinski S, Brüning T. 2004. Urinary alpha(1)-microglobulin excretion as biomarker of renal toxicity in trichloroethylene-exposed persons. Int Arch Occup Environ Health. 77(3):186–190. 10.1007/s00420-003-0500-3 14986001
Bove FJ, Ruckart PZ, Maslia M, Larson TC. 2014. Evaluation of mortality among marines and navy personnel exposed to contaminated drinking water at USMC base Camp Lejeune: A retrospective cohort study. Environ Health. 13(1):10. 10.1186/1476-069X-13-10 24552493
Boverhof DR, Krieger SM, Hotchkiss JA, Stebbins KE, Thomas J, Woolhiser MR. 2013. Assessment of the immunotoxic potential of trichloroethylene and perchloroethylene in rats following inhalation exposure. J Immunotoxicol. 10(3):311–320. 10.3109/1547691X.2012.735275 23167264
Bradford BU, Lock EC, Kosyk O, Kim S, Uehara T, Harbourt D, DeSimone M, Threadgill DW, Tryndyak V, Pogribny IP, et al. 2011. Interstrain differences in the liver effects of trichloroethylene in a multistrain panel of inbred mice. Toxicol Sci. 120(1):206–217. 10.1093/toxsci/kfq362 21135412
Brauch H, Weirich G, Hornauer MA, Storkel S, Wohl T, Bruning T. 1999. Trichloroethylene exposure and specific somatic mutations in patients with renal cell carcinoma. J Natl Cancer Inst. 91(10):854–861. 10.1093/jnci/91.10.854 10340905
Brauch H, Weirich G, Klein B, Rabstein S, Bolt HM, Bruning T. 2004. VHL mutations in renal cell cancer: Does occupational exposure to trichloroethylene make a difference? Toxicol Lett. 151(1):301–310. 10.1016/j.toxlet.2003.12.074 15177666
Brennan P, van der Hel O, Moore LE, Zaridze D, Matveev V, Holcatova I, Janout V, Kollarova H, Foretova L, Szeszenia-Dabrowska N, et al. 2008. Tobacco smoking, body mass index, hypertension, and kidney cancer risk in central and eastern Europe. Br J Cancer. 99(11):1912–1915. 10.1038/sj.bjc.6604761 19034282
Bronzetti G, Zeiger E, Frezza D. 1978. Genetic activity of trichloroethylene in yeast. J Environ Pathol Toxicol. 1(4):411–418. 363965
Brüning T, Lammert M, Kempkes M, Thier R, Golka K, Bolt HM. 1997 a. Influence of polymorphisms of GSTM1 and GSTT1 for risk of renal cell cancer in workers with long-term high occupational exposure to trichloroethene. Arch Toxicol. 71(9):596–599. 10.1007/s002040050432 9285043
Brüning T, Mann H, Melzer H, Sundberg AG, Bolt HM. 1999 a. Pathological excretion patterns of urinary proteins in renal cell cancer patients exposed to trichloroethylene. Occup Med (Lond). 49(5):299–305. 10.1093/occmed/49.5.299 10628055
Brüning T, Pesch B, Wiesenhütter B, Rabstein S, Lammert M, Baumüller A, Bolt HM. 2003. Renal cell cancer risk and occupational exposure to trichloroethylene: Results of a consecutive case-control study in Arnsberg, Germany. Am J Ind Med. 43(3):274–285. 10.1002/ajim.10185 12594774
Brüning T, Sundberg AG, Birner G, Lammert M, Bolt HM, Appelkvist EL, Nilsson R, Dallner G. 1999 b. Glutathione transferase alpha as a marker for tubular damage after trichloroethylene exposure. Arch Toxicol. 73(4-5):246–254. 10.1007/s002040050613 10463390
Brüning T, Vamvakas S, Makropoulos V, Birner G. 1998. Acute intoxication with trichloroethene: Clinical symptoms, toxicokinetics, metabolism, and development of biochemical parameters for renal damage. Toxicol Sci. 41(2):157–165. 10.1093/toxsci/41.2.157 9520351
Brüning T, Weirich G, Hornauer MA, Höfler H, Brauch H. 1997 b. Renal cell carcinomas in trichloroethene (TRI) exposed persons are associated with somatic mutations in the von Hippel-Lindau (VHL) tumour suppressor gene. Arch Toxicol. 71(5):332–335. 10.1007/s002040050394 9137812
Bull RJ. 2000. Mode of action of liver tumor induction by trichloroethylene and its metabolites, trichloroacetate and dichloroacetate. Environ Health Perspect. 108 Suppl 2:241–259. 10.1289/ehp.00108s2241 10807555
Bull RJ, Orner GA, Cheng RS, Stillwell L, Stauber AJ, Sasser LB, Lingohr MK, Thrall BD. 2002. Contribution of dichloroacetate and trichloroacetate to liver tumor induction in mice by trichloroethylene. Toxicol Appl Pharmacol. 182(1):55–65. 10.1006/taap.2002.9427 12127263
Bull RJ, Sasser LB, Lei XC. 2004. Interactions in the tumor-promoting activity of carbon tetrachloride, trichloroacetate, and dichloroacetate in the liver of male B6C3F1 mice. Toxicology. 199(2-3):169–183. 10.1016/j.tox.2004.02.018 15147791
Buzio L.De, Palma G, Mozzoni P, Tondel M, Buzio C, Franchini I, Axelson O, Mutti A. 2003. Glutathione S-transferases M1-1 and T1-1 as risk modifiers for renal cell cancer associated with occupational exposure to chemicals. Occup Environ Med. 60(10):789-793. 10.1136/oem.60.10.789
Cai H, Guengerich FP. 2001. Reaction of trichloroethylene oxide with proteins and DNA: Instability of adducts and modulation of functions. Chem Res Toxicol. 14(1):54–61. 10.1021/tx000185n 11170508
Cai P, Boor PJ, Khan MF, Kaphalia BS, Ansari GAS, Konig R. 2007 a. Immuno- and hepato-toxicity of dichloroacetic acid in MRL+/+ and B6C3F1 mice. J Immunotoxicol. 4(2):107–115. 10.1080/15476910701337225 18958719
Cai P, König R, Boor PJ, Kondraganti S, Kaphalia BS, Khan MF, Ansari GA. 2008. Chronic exposure to trichloroethene causes early onset of SLE-like disease in female MRL +/+ mice. Toxicol Appl Pharmacol. 228(1):68–75. 10.1016/j.taap.2007.11.031 18234256
Cai P, König R, Khan MF, Kaphalia BS, Ansari GA. 2007 b. Differential immune responses to albumin adducts of reactive intermediates of trichloroethene in MRL+/+ mice. Toxicol Appl Pharmacol. 220(3):278–283. 10.1016/j.taap.2007.01.020 17376499
Cai P, Konig R, Khan MF, Qiu S, Kaphalia BS, Ansari GA. 2006. Autoimmune response in MRL+/+ mice following treatment with dichloroacetyl chloride or dichloroacetic anhydride. Toxicol Appl Pharmacol. 216(2):248–255. 10.1016/j.taap.2006.05.010 16806339
Caldwell JC, Keshava N. 2006. Key issues in the modes of action and effects of trichloroethylene metabolites for liver and kidney tumorigenesis. Environ Health Perspect. 114(9):1457–1463. 10.1289/ehp.8692 16966105
Callen DF, Wolf CR, Philpot RM. 1980. Cytochrome P-450 mediated genetic activity and cytotoxicity of seven halogenated aliphatic hydrocarbons in Saccharomyces cerevisiae. Mutat Res. 77(1):55–63. 10.1016/0165-1218(80)90120-2 6767185
Cantor KP, Blair A, Everett G, Gibson R, Burmeister LF, Brown LM, Schuman L, Dick FR. 1992. Pesticides and other agricultural risk factors for non-Hodgkin’s lymphoma among men in Iowa and Minnesota. Cancer Res. 52(9):2447–2455. 1568215
Carter JH, Carter HW, DeAngelo AB. 1995. Biochemical, pathologic and morphometric alterations induced in male B6C3F1 mouse liver by short-term exposure to dichloroacetic acid. Toxicol Lett. 81(1):55–71. 10.1016/0378-4274(95)03409-9 8525500
Caspary WJ, Langenbach R, Penman BW, Crespi C, Myhr BC, Mitchell AD. 1988. The mutagenic activity of selected compounds at the TK locus: Rodent vs. human cells. Mutat Res. 196(1):61–81. 10.1016/0165-1110(88)90028-0 3292900
Cearfoss J, Hassoun E. 2012. The effects of a low vitamin E diet on dichloroacetate- and trichloroacetate-induced oxidative stress in the livers of mice. J Biochem Mol Toxicol. 26(4):147–154. 10.1002/jbt.20421 22447681
Chang LW, Daniel FB, DeAngelo AB. 1992. Analysis of DNA strand breaks induced in rodent liver in vivo, hepatocytes in primary culture, and a human cell line by chlorinated acetic acids and chlorinated acetaldehydes. Environ Mol Mutagen. 20(4):277–288. 10.1002/em.2850200406 1330547
Chang YM, Tai CF, Yang SC, Chen CJ, Shih TS, Lin RS, Liou SH. 2003. A cohort mortality study of workers exposed to chlorinated organic solvents in Taiwan. Ann Epidemiol. 13(9):652–660. 10.1016/S1047-2797(03)00038-3 14732305
Channel SR, Latendresse JR, Kidney JK, Grabau JH, Lane JW, Steel-Goodwin L, Gothaus MC. 1998. A subchronic exposure to trichloroethylene causes lipid peroxidation and hepatocellular proliferation in male B6C3F1 mouse liver. Toxicol Sci. 43:145–154. 10.1093/toxsci/43.2.145 9710956
Charbotel B, Fevotte J, Hours M, Martin JL, Bergeret A. 2006. Case-control study on renal cell cancer and occupational exposure to trichloroethylene. Part II: Epidemiological aspects. Ann Occup Hyg. 50(8):777–787. 16840435
Charbotel B, Fevotte J, Martin JL, Bergeret A. 2009. Renal cell carcinoma and exposure to trichloroethylene: Are French occupational exposure limits relevant? Rev Epidemiol Sante Publique. 57(1):41–47. 10.1016/j.respe.2008.09.008 19155150
Charbotel B, Gad S, Caïola D, Béroud C, Fevotte J, Bergeret A, Ferlicot S, Richard S. 2007. Trichloroethylene exposure and somatic mutations of the VHL gene in patients with Renal Cell Carcinoma. J Occup Med Toxicol. 2:13. 10.1186/1745-6673-2-13 17997830
Charbotel B, Massardier-Pilonchery A, Fort E, Dananche B, Fevotte J, Confavreux-Romestaing C, Bergeret A. 2013. Occupational trichloroethylene exposure and cervical pathology: A case-control study. Ann Occup Hyg. 57(3):407–416. 23091111
Chatterjee N, Hartge P, Cerhan JR, Cozen W, Davis S, Ishibe N, Colt J, Goldin L, Severson RK. 2004. Risk of non-Hodgkin’s lymphoma and family history of lymphatic, hematologic, and other cancers. Cancer Epidemiol Biomarkers Prev. 13(9):1415–1421. 15342441
Chen XY, Zhuang ZX, Wang XH, Zhang JZ. 2006. Immune responses to trichloroethylene and skin gene expression profiles in Sprague Dawley rats. Biomed Environ Sci. 19(5):346–352. 17190186
Cheng HY, You HY, Zhou TB. 2012. Relationship between GSTM1/GSTT1 null genotypes and renal cell carcinoma risk: A meta-analysis. Ren Fail. 34(8):1052–1057. 10.3109/0886022X.2012.708380 22880812
Cherrie JW, Kromhout H, Semple S. 2001. The importance of reliable exposure estimates in deciding whether trichloroethylene can cause kidney cancer. J Cancer Res Clin Oncol. 127(6):400–402. 10.1007/s004320000206 11414201
Chiu WA, Jinot J, Scott CS, Makris SL, Cooper GS, Dzubow RC, Bale AS, Evans MV, Guyton KZ, Keshava N, et al. 2013. Human health effects of trichloroethylene: Key findings and scientific issues. Environ Health Perspect. 121(3):303–311. 10.1289/ehp.1205879 23249866
Chiu WA, Okino MS, Lipscomb JC, Evans MV. 2006. Issues in the pharmacokinetics of trichloroethylene and its metabolites. Environ Health Perspect. 114(9):1450–1456. 10.1289/ehp.8691 16966104
Chow WH, Dong LM, Devesa SS. 2010. Epidemiology and risk factors for kidney cancer. Nat Rev Urol. 7(5):245–257. 10.1038/nrurol.2010.46 20448658
Chow WH, Gridley G, McLaughlin JK, Mandel JS, Wacholder S, Blot WJ, Niwa S, Fraumeni JF Jr. 1994. Protein intake and risk of renal cell cancer. J Natl Cancer Inst. 86(15):1131–1139. 10.1093/jnci/86.15.1131 8028035
Christensen KY, Vizcaya D, Richardson H, Lavoué J, Aronson K, Siemiatycki J. 2013. Risk of selected cancers due to occupational exposure to chlorinated solvents in a case-control study in Montreal. J Occup Environ Med. 55(2):198–208. 10.1097/JOM.0b013e3182728eab 23147555
Clapp RW, Hoffman K. 2008. Cancer mortality in IBM Endicott plant workers, 1969-2001: An update on a NY production plant. Environ Health. 7:13. 10.1186/1476-069X-7-13 18442394
Clarke CA, Glaser SL. 2002. Changing incidence of non-Hodgkin lymphomas in the United States. Cancer. 94(7):2015–2023. 10.1002/cncr.10403 11932904
Clay P. 2008. Assessment of the genotoxicity of trichloroethylene and its metabolite, S-(1,2-dichlorovinyl)-L-cysteine (DCVC), in the comet assay in rat kidney. Mutagenesis. 23(1):27–33. 10.1093/mutage/gem034 18003627
Cocco P.t'Mannetje A, Fadda D, Melis M, Becker N, de, Sanjose S, Foretova L, Mareckova J, Staines A et al. 2010. Occupational exposure to solvents and risk of lymphoma subtypes: Results from the Epilymph case-control study. Occup Environ Med. 67(5):341-347. 10.1136/oem.2009.046839
Cocco P, Vermeulen R, Flore V, Nonne T, Campagna M, Purdue M, Blair A, Monnereau A, Orsi L, Clavel J, et al. 2013. Occupational exposure to trichloroethylene and risk of non-Hodgkin lymphoma and its major subtypes: A pooled IinterLlymph analysis. Occup Environ Med. 70:795–802. 10.1136/oemed-2013-101551 23881218
Cogliano VJ, Baan R, Straif K, Grosse Y, Lauby-Secretan B, El Ghissassi F, Bouvard V, Benbrahim-Tallaa L, Guha N, Freeman C, et al. 2011. Preventable exposures associated with human cancers. J Natl Cancer Inst. 103(24):1827–1839. 10.1093/jnci/djr483 22158127
Conroy SM, Maskarinec G, Morimoto Y, Franke AA, Cooney RV, Wilkens LR, Goodman MT, Hernadez BY, Le Marchand L, Henderson BE, et al. 2013. Non-hodgkin lymphoma and circulating markers of inflammation and adiposity in a nested case-control study: The multiethnic cohort. Cancer Epidemiol Biomarkers Prev. 22(3):337–347. 10.1158/1055-9965.EPI-12-0947 23300021
Cooper GS, Makris SL, Nietert PJ, Jinot J. 2009. Evidence of autoimmune-related effects of trichloroethylene exposure from studies in mice and humans. Environ Health Perspect. 117(5):696–702. 10.1289/ehp.11782 19479009
Corton JC. 2008. Evaluation of the role of peroxisome proliferator-activated receptor alpha (PPARalpha) in mouse liver tumor induction by trichloroethylene and metabolites. Crit Rev Toxicol. 38(10):857–875. 10.1080/10408440802209796 18821149
Costa AK, Ivanetich KM. 1984. Chlorinated ethylenes: Their metabolism and effect on DNA repair in rat hepatocytes. Carcinogenesis. 5(12):1629–1636. 10.1093/carcin/5.12.1629 6499114
Costa G, Merletti F, Segnan N. 1989. A mortality cohort study in a north Italian aircraft factory. Br J Ind Med. 46(10):738–743. 10.1136/oem.46.10.738 2818961
Costantini AS, Benvenuti A, Vineis P, Kriebel D, Tumino R, Ramazzotti V, Rodella S, Stagnaro E, Crosignani P, Amadori D, et al. 2008. Risk of leukemia and multiple myeloma associated with exposure to benzene and other organic solvents: Evidence from the Italian multicenter case-control study. Am J Ind Med. 51(11):803–811. 10.1002/ajim.20592 18651579
Costantini AS, Miligi L, Kriebel D, Ramazzotti V, Rodella S, Scarpi E, Stagnaro E, Tumino R, Fontana A, Masala G, et al. 2001. A multicenter case-control study in Italy on hematolymphopoietic neoplasms and occupation. Epidemiology. 12(1):78–87. 10.1097/00001648-200101000-00014 11138825
Coussens LM, Werb Z. 2002. Inflammation and cancer. Nature. 420(6917):860–867. 10.1038/nature01322 12490959
Crebelli R, Bignami M, Conti L, Carere A. 1982. Mutagenicity of trichloroethylene in Salmonella typhimurium TA100. Ann Ist Super Sanita. 18(1):117–121. 6763484
Crebelli R, Conti G, Conti L, Carere A. 1985. Mutagenicity of trichloroethylene, trichloroethanol and chloral hydrate in Aspergillus nidulans. Mutat Res. 155(3):105–111. 10.1016/0165-1218(85)90126-0 3883153
Crebelli R, Conti G, Conti L, Carere A. 1991. In vitro studies with nine known or suspected spindle poisons: Results in tests for chromosome malsegregation in Aspergillus nidulans. Mutagenesis. 6(2):131–136. 10.1093/mutage/6.2.131 2056914
Cummings BS, Lash LH. 2000. Metabolism and toxicity of trichloroethylene and S-(1,2-dichlorovinyl)-L-cysteine in freshly isolated human proximal tubular cells. Toxicol Sci. 53(2):458–466. 10.1093/toxsci/53.2.458 10696794
Cummings BS, Parker JC, Lash LH. 2000. Role of cytochrome P450 and glutathione S-transferase alpha in the metabolism and cytotoxicity of trichloroethylene in rat kidney. Biochem Pharmacol. 59(5):531–543. 10.1016/S0006-2952(99)00374-3 10660119
Cummings BS, Parker JC, Lash LH. 2001. Cytochrome p450-dependent metabolism of trichloroethylene in rat kidney. Toxicol Sci. 60(1):11–19. 10.1093/toxsci/60.1.11 11222868
Czaja AJ. 2013. Hepatocellular carcinoma and other malignancies in autoimmune hepatitis. Dig Dis Sci. 58(6):1459–1476. 10.1007/s10620-012-2525-5 23306849
Dai Y, Leng S, Li L, Niu Y, Huang H, Cheng J, Zheng Y. 2004. Genetic polymorphisms of cytokine genes and risk for trichloroethylene-induced severe generalized dermatitis: A case-control study. Biomarkers. 9(6):470–478. 10.1080/13547500400026920 15849067
Dai Y, Leng S, Li L, Niu Y, Huang H, Liu Q, Duan H, Cheng J, Liu Q, Zheng Y. 2009. Effects of genetic polymorphisms of N-Acetyltransferase on trichloroethylene-induced hypersensitivity dermatitis among exposed workers. Ind Health. 47(5):479–486. 10.2486/indhealth.47.479 19834256
Dalgleish AG, O’Byrne KJ. 2002. Chronic immune activation and inflammation in the pathogenesis of AIDS and cancer. Adv Cancer Res. 84:231–276. 10.1016/S0065-230X(02)84008-8 11883529
De Roos AJ, Mirick DK, Edlefsen KL, LaCroix AZ, Kopecky KJ, Madeleine MM, Magpantay L, Martínez-Maza O. 2012. Markers of B-cell activation in relation to risk of non-Hodgkin lymphoma. Cancer Res. 72(18):4733–4743. 10.1158/0008-5472.CAN-12-1639 22846913
de Visser KE, Eichten A, Coussens LM. 2006. Paradoxical roles of the immune system during cancer development. Nat Rev Cancer. 6(1):24–37. 10.1038/nrc1782 16397525
Degrassi F, Tanzarella C. 1988. Immunofluorescent staining of kinetochores in micronuclei: A new assay for the detection of aneuploidy. Mutat Res. 203(5):339–345. 10.1016/0165-1161(88)90030-1 3050494
Dekant W, Berthold K, Vamvakas S, Henschler D, Anders MW. 1988. Thioacylating intermediates as metabolites of S-(1,2-dichlorovinyl)-L-cysteine and S-(1,2,2-trichlorovinyl)-L-cysteine formed by cysteine conjugate beta-lyase. Chem Res Toxicol. 1(3):175–178. 10.1021/tx00003a008 2979728
Dekant W, Koob M, Henschler D. 1990. Metabolism of trichloroethene—in vivo and in vitro evidence for activation by glutathione conjugation. Chem Biol Interact. 73(1):89–101. 10.1016/0009-2797(90)90110-9 2302745
Dekant W, Schulz A, Metzler M, Henschler D. 1986. Absorption, elimination and metabolism of trichloroethylene: A quantitative comparison between rats and mice? Xenobiotica. 16(2):143–152. 10.3109/00498258609043517 3962335
DeMarini DM, Perry E, Shelton ML. 1994. Dichloroacetic acid and related compounds: Induction of prophage in E. coli and mutagenicity and mutation spectra in Salmonella TA100. Mutagenesis. 9(5):429–437. 10.1093/mutage/9.5.429 7837977
Deng Q, Zheng T, Lan Q, Lan Y, Holford T, Chen Y, Dai M, Leaderer B, Boyle P, Chanock SJ, et al. 2013. Occupational solvent exposure, genetic variation in immune genes, and the risk for non-Hodgkin lymphoma. Eur J Cancer Prev. 22(1):77–82. 10.1097/CEJ.0b013e328354d2c1 22609637
DeSimone MC, Rathmell WK, Threadgill DW. 2013. Pleiotropic effects of the trichloroethylene-associated P81S VHL mutation on metabolism, apoptosis, and ATM-mediated DNA damage response. J Natl Cancer Inst. 105(18):1355–1364. 10.1093/jnci/djt226 23990666
Diot E, Lesire V, Guilmot JL, Metzger MD, Pilore R, Rogier S, Stadler M, Diot P, Lemarie E, Lasfargues G. 2002. Systemic sclerosis and occupational risk factors: A case-control study. Occup Environ Med. 59(8):545–549. 10.1136/oem.59.8.545 12151611
DiRenzo AB, Gandolfi AJ, Sipes IG. 1982. Microsomal bioactivation and covalent binding of aliphatic halides to DNA. Toxicol Lett. 11(3-4):243–252. 10.1016/0378-4274(82)90157-6 7101318
Doolittle DJ, Muller G, Scribner HE. 1987. The in vivo-in vitro hepatocyte assay for assessing DNA repair and DNA replication: Studies in the CD-1 mouse. Food Chem Toxicol. 25(5):399–405. 10.1016/0278-6915(87)90176-1 3609980
Dosemeci M, Cocco P, Chow WH.1999. Gender differences in risk of renal cell carcinoma and occupational exposures to chlorinated aliphatic hydrocarbons. Am J Ind Med. 36(1):54-59. 10.1002/(SICI)1097-0274(199907)36:1<54:AID-AJIM8>3.0.CO;2-0
Douglas GR, Gingerich JD, Soper LM, Potvin M, Bjarnason S.1999. Evidence for the lack of base-change and small-deletion mutation induction by trichloroethylene in lacZ transgenic mice. Environ Mol Mutagen. 34(2-3):190-194. 10.1002/(SICI)1098-2280(1999)34:2/3<190:AID-EM18>3.0.CO;2-#
Dow JL, Green T. 2000. Trichloroethylene induced vitamin B(12) and folate deficiency leads to increased formic acid excretion in the rat. Toxicology. 146(2-3):123–136. 10.1016/S0300-483X(00)00156-6 10814845
Dow. 2008. Product safety assessment: Trichloroethylene. Dow Chemical Company.
Duprat P, Gradiski D. 1980. Cytogenetic effect of trichloroethylene in the mouse as evaluated by the micronucleus test. IRCS Med Sci. 8:182.
Eastmond DA. 2012. Factors influencing mutagenic mode of action determinations of regulatory and advisory agencies. Mutat Res. 751:49–63. 10.1016/j.mrrev.2012.04.001 22561946
El Arem A, Saafi EB, Ghrairi F, Thouri A, Zekri M, Ayed A, Zakhama A, Achour L. 2014 a. Aqueous date fruit extract protects against lipid peroxidation and improves antioxidant status in the liver of rats subchronically exposed to trichloroacetic acid. J Physiol Biochem. 70(2):451–464. 10.1007/s13105-014-0323-6 24573459
El Arem A, Thouri A, Zekri M, Saafi EB, Ghrairi F, Zakhama A, Achour L. 2014 b. Nephroprotective effect of date fruit extract against dichloroacetic acid exposure in adult rats. Food Chem Toxicol. 65:177–184. 10.1016/j.fct.2013.12.023 24394489
Elfarra AA, Krause RJ, Last AR, Lash LH, Parker JC. 1998. Species- and sex-related differences in metabolism of trichloroethylene to yield chloral and trichloroethanol in mouse, rat, and human liver microsomes. Drug Metab Dispos. 26(8):779–785. 9698293
Emmert B, Bünger J, Keuch K, Müller M, Emmert S, Hallier E, Westphal GA. 2006. Mutagenicity of cytochrome P450 2E1 substrates in the Ames test with the metabolic competent S. typhimurium strain YG7108pin3ERb5. Toxicology. 228(1):66–76. 10.1016/j.tox.2006.08.013 16978761
Eyre RJ, Stevens DK, Parker JC, Bull RJ. 1995. Renal activation of trichloroethene and S-(1,2-dichlorovinyl)-L-cysteine and cell proliferative responses in the kidneys of F344 rats and B6C3F1 mice. J Toxicol Environ Health. 46(4):465–481. 10.1080/15287399509532049 8523472
Fahrig R. 1977. The mammalian spot test (Fellfleckentest) with mice. Arch Toxicol. 38(1-2):87–98. 10.1007/BF00293666 199140
Fang YY, Kashkarov U, Anders MW, Board PG. 2006. Polymorphisms in the human glutathione transferase zeta promoter. Pharmacogenet Genomics. 16(5):307–313. 10.1097/01.fpc.0000205000.07054.b3 16609361
Ferlay J, Soerjomataram I, Dikshit R, Eser S, Mathers C, Rebelo M, Parkin DM, Forman D, Bray F. 2014. Cancer incidence and mortality worldwide: Sources, methods and major patterns in GLOBOCAN 2012. Int J Cancer.
Ferlay J, Steliarova-Foucher E, Lortet-Tieulent J, Rosso S, Coebergh JWW, Comber H, Forman D, Bray F. 2013. Cancer incidence and mortality patterns in Europe: Estimates for 40 countries in 2012. Eur J Cancer. 49:1374–1403. 10.1016/j.ejca.2012.12.027 23485231
Ferreira-Gonzalez A, DeAngelo AB, Nasim S, Garrett CT. 1995. Ras oncogene activation during hepatocarcinogenesis in B6C3F1 male mice by dichloroacetic and trichloroacetic acids. Carcinogenesis. 16(3):495–500. 10.1093/carcin/16.3.495 7697804
Fevotte J, Charbotel B, Muller-Beauté P, Martin JL, Hours M, Bergeret A. 2006. Case-control study on renal cell cancer and occupational exposure to trichloroethylene. Part I: Exposure assessment. Ann Occup Hyg. 50(8):765–775. 16840434
Fleming DA, Woskie SR, Jones JH, Silver SR, Luo L, Bertke SJ. 2014. Retrospective assessment of exposure to chemicals for a microelectronics and business machine manufacturing facility. J Occup Environ Hyg. 11(5):292–305. 10.1080/15459624.2013.862591 24224613
Fox AW, Yang X, Murli H, Lawlor TE, Cifone MA, Reno FE. 1996. Absence of mutagenic effects of sodium dichloroacetate. Fundam Appl Toxicol. 32(1):87–95. 10.1006/faat.1996.0110 8812237
Fuscoe JC, Afshari AJ, George MH, DeAngelo AB, Tice RR, Salman T, Allen JW.1996. In vivo genotoxicity of dichloroacetic acid: evaluation with the mouse peripheral blood micronucleus assay and the single cell gel assay. Environ Mol Mutagen. 27(1):1-9. 10.1002/(SICI)1098-2280(1996)27:1<1:AID-EM1>3.0.CO;2-L
Galloway SM, Armstrong MJ, Reuben C, Colman S, Brown B, Cannon C, Bloom AD, Nakamura F, Ahmed M, Duk S, et al. 1987. Chromosome aberrations and sister chromatid exchanges in Chinese hamster ovary cells: Evaluations of 108 chemicals. Environ Mol Mutagen. 10 Suppl 10:1–175. 10.1002/em.2850100502 3319609
Ganem NJ, Storchova Z, Pellman D. 2007. Tetraploidy, aneuploidy and cancer. Curr Opin Genet Dev. 17(2):157–162. 10.1016/j.gde.2007.02.011 17324569
Garabrant DH, Held J, Langholz B, Bernstein L. 1988. Mortality of aircraft manufacturing workers in southern California. Am J Ind Med. 13(6):683–693. 10.1002/ajim.4700130607 3389363
Garabrant DH, Lacey JV Jr, Laing TJ, Gillespie BW, Mayes MD, Cooper BC, Schottenfeld D. 2003. Scleroderma and solvent exposure among women. Am J Epidemiol. 157(6):493–500. 10.1093/aje/kwf223 12631538
Ghanayem BI, Hoffler U. 2007. Investigation of xenobiotics metabolism, genotoxicity, and carcinogenicity using Cyp2e1(-/-) mice. Curr Drug Metab. 8(7):728–749. 10.2174/138920007782109760 17979661
Gilbert KM, Nelson AR, Cooney CA, Reisfeld B, Blossom SJ. 2012. Epigenetic alterations may regulate temporary reversal of cd4 + T cell activation caused by trichloroethylene exposure. Toxicol Sci. 127(1):169–178. 10.1093/toxsci/kfs093 22407948
Gilbert KM, Przybyla B, Pumford NR, Han T, Fuscoe J, Schnackenberg LK, Holland RD, Doss JC, Macmillan-Crow LA, Blossom SJ. 2009. Delineating liver events in trichloroethylene-induced autoimmune hepatitis. Chem Res Toxicol. 22(4):626–632. 10.1021/tx800409r 19254012
Gilbert KM, Pumford NR, Blossom SJ. 2006. Environmental contaminant trichloroethylene promotes autoimmune disease and inhibits T-cell apoptosis in MRL(+/+) mice. J Immunotoxicol. 3(4):263–267. 10.1080/15476910601023578 18958707
Gilbert KM, Rowley B, Gomez-Acevedo H, Blossom SJ. 2011. Coexposure to mercury increases immunotoxicity of trichloroethylene. Toxicol Sci. 119(2):281–292. 10.1093/toxsci/kfq345 21084432
Giller S, Le Curieux F, Erb F, Marzin D. 1997. Comparative genotoxicity of halogenated acetic acids found in drinking water. Mutagenesis. 12(5):321–328. 10.1093/mutage/12.5.321 9379909
Goeptar AR, Commandeur JN, van Ommen B, van Bladeren PJ, Vermeulen NP. 1995. Metabolism and kinetics of trichloroethylene in relation to toxicity and carcinogenicity. Relevance of the mercapturic acid pathway. Chem Res Toxicol. 8(1):3–21. 10.1021/tx00043a001 7703363
Gold LS, Stewart PA, Milliken K, Purdue M, Severson R, Seixas N, Blair A, Hartge P, Davis S, De Roos AJ. 2011. The relationship between multiple myeloma and occupational exposure to six chlorinated solvents. Occup Environ Med. 68(6):391–399. 10.1136/oem.2009.054809 20833760
Goldsworthy TL, Lyght O, Burnett VL, Popp JA. 1988. Potential role of alpha-2 mu-globulin, protein droplet accumulation, and cell replication in the renal carcinogenicity of rats exposed to trichloroethylene, perchloroethylene, and pentachloroethane. Toxicol Appl Pharmacol. 96(2):367–379. 10.1016/0041-008X(88)90095-6 2461605
Goldsworthy TL, Popp JA. 1987. Chlorinated hydrocarbon-induced peroxisomal enzyme activity in relation to species and organ carcinogenicity. Toxicol Appl Pharmacol. 88(2):225–233. 10.1016/0041-008X(87)90008-1 3564041
Grawe J, Nusse M, Adler ID. 1997. Quantitative and qualitative studies of micronucleus induction in mouse erythrocytes using flow cytometry. I. Measurement of micronucleus induction in peripheral blood polychromatic erythrocytes by chemicals with known and suspected genotoxicity. Mutagenesis. 12(1):1–8. 10.1093/mutage/12.1.1 9025090
Green T. 1997. Trichloroethylene induced cancer in animals and its relevance to humans. J Occup Health. 39(4):261–273. 10.1539/joh.39.261
Green T, Dow J, Ellis MK, Foster JR, Odum J. 1997. The role of glutathione conjugation in the development of kidney tumours in rats exposed to trichloroethylene. Chem Biol Interact. 105(2):99–117. 10.1016/S0009-2797(97)00040-9 9251723
Green T, Dow J, Foster J. 2003. Increased formic acid excretion and the development of kidney toxicity in rats following chronic dosing with trichloroethanol, a major metabolite of trichloroethylene. Toxicology. 191(2-3):109–119. 10.1016/S0300-483X(03)00206-3 12965114
Green T, Dow J, Foster JR, Hext PM. 1998. Formic acid excretion in rats exposed to trichloroethylene: A possible explanation for renal toxicity in long-term studies. Toxicology. 127(1-3):39–47. 10.1016/S0300-483X(98)00020-1 9699792
Green T, Dow J, Ong CN, Ng V, Ong HY, Zhuang ZX, Yang XF, Bloemen L. 2004. Biological monitoring of kidney function among workers occupationally exposed to trichloroethylene. Occup Environ Med. 61(4):312–317. 10.1136/oem.2003.007153 15031388
Green T, Odum J, Nash JA, Foster JR. 1990. Perchloroethylene-induced rat kidney tumors: An investigation of the mechanisms involved and their relevance to humans. Toxicol Appl Pharmacol. 103(1):77–89. 10.1016/0041-008X(90)90264-U 1969182
Greenland S, Salvan A, Wegman DH, Hallock MF, Smith TJ. 1994. A case-control study of cancer mortality at a transformer-assembly facility. Int Arch Occup Environ Health. 66(1):49–54. 10.1007/BF00386579 7927843
Greim H, Bonse G, Radwan Z, Reichert D, Henschler D. 1975. Mutagenicity in vitro and potential carcinogenicity of chlorinated ethylenes as a function of metabolic oxiran formation. Biochem Pharmacol. 24(21):2013–2017. 10.1016/0006-2952(75)90396-2 1108881
Griffin JM, Blossom SJ, Jackson SK, Gilbert KM, Pumford NR. 2000 a. Trichloroethylene accelerates an autoimmune response by Th1 T cell activation in MRL +/+ mice. Immunopharmacology. 46(2):123–137. 10.1016/S0162-3109(99)00164-2 10647871
Griffin JM, Gilbert KM, Lamps LW, Pumford NR. 2000 b. CD4(+) T-cell activation and induction of autoimmune hepatitis following trichloroethylene treatment in MRL+/+ mice. Toxicol Sci. 57(2):345–352. 10.1093/toxsci/57.2.345 11006364
Griffin JM, Gilbert KM, Pumford NR. 2000 c. Inhibition of CYP2E1 reverses CD4+ T-cell alterations in trichloroethylene-treated MRL+/+ mice. Toxicol Sci. 54(2):384–389. 10.1093/toxsci/54.2.384 10774820
Grulich AE, Vajdic CM, Cozen W. 2007. Altered immunity as a risk factor for non-Hodgkin lymphoma. Cancer Epidemiol Biomarkers Prev. 16(3):405–408. 10.1158/1055-9965.EPI-06-1070 17337643
Gu ZW, Sele B, Jalbert P, Vincent M, Vincent F, Marka C, Chmara D, Faure J. 1981. [Induction of sister chromatid exchange by trichloroethylene and its metabolites]. Toxicol Eur Res. 3(2):63–67. 7245187
Guyton KZ, Chiu WA, Bateson TF, Jinot J, Scott CS, Brown RC, Caldwell JC. 2009. A reexamination of the PPAR-alpha activation mode of action as a basis for assessing human cancer risks of environmental contaminants. Environ Health Perspect. 117(11):1664–1672. 10.1289/ehp.0900758 20049115
Halmes NC, McMillan DC, Oatis JE, Pumford NR. 1996. Immunochemical detection of protein adducts in mice treated with trichloroethylene. Chem Res Toxicol. 9(2):451–456. 10.1021/tx950171v 8839049
Halmes NC, Perkins EJ, McMillan DC, Pumford NR. 1997. Detection of trichloroethylene-protein adducts in rat liver and plasma. Toxicol Lett. 92(3):187–194. 10.1016/S0378-4274(97)00053-2 9334829
Hansen J, Raaschou-Nielsen O, Christensen JM, Johansen I, McLaughlin JK, Lipworth L, Blot WJ, Olsen JH. 2001. Cancer incidence among Danish workers exposed to trichloroethylene. J Occup Environ Med. 43(2):133–139. 10.1097/00043764-200102000-00012 11227631
Hansen J, Sallmén M, Seldén AI, Anttila A, Pukkala E, Andersson K, Bryngelsson IL, Raaschou-Nielsen O, Olsen JH, McLaughlin JK. 2013. Risk of cancer among workers exposed to trichloroethylene: Analysis of three Nordic cohort studies. J Natl Cancer Inst. 105(12):869–877. 10.1093/jnci/djt107 23723420
Hardell L, Axelson O. 1998. Environmental and occupational aspects on the etiology of non-Hodgkin’s lymphoma. Oncol Res. 10(1):1–5. 9613451
Hardell L, Eriksson M, Degerman A. 1994. Exposure to phenoxyacetic acids, chlorophenols, or organic solvents in relation to histopathology, stage, and anatomical localization of non-Hodgkin’s lymphoma. Cancer Res. 54(9):2386–2389. 8162585
Hardell L, Eriksson M, Lenner P, Lundgren E. 1981. Malignant lymphoma and exposure to chemicals, especially organic solvents, chlorophenols and phenoxy acids: A case-control study. Br J Cancer. 43(2):169–176. 10.1038/bjc.1981.25 7470379
Hardell L, Lindström G, van Bavel B, Fredrikson M, Liljegren G. 1998. Some aspects of the etiology of non-Hodgkin’s lymphoma. Environ Health Perspect. 106 Suppl 2:679–681. 9599716
Harrington JM, Whitby H, Gray CN, Reid FJ, Aw TC, Waterhouse JA. 1989. Renal disease and occupational exposure to organic solvents: A case referent approach. Br J Ind Med. 46(9):643–650. 10.1136/oem.46.9.643 2789968
Harrington-Brock K, Doerr CL, Moore MM. 1998. Mutagenicity of three disinfection by-products: Di- and trichloroacetic acid and chloral hydrate in L5178Y/TK +/- (-)3.7.2C mouse lymphoma cells. Mutat Res. 413(3):265–276. 10.1016/S1383-5718(98)00026-6 9651541
Harris NL, Jaffe ES, Stein H, Banks PM, Chan JK, Cleary ML, Delsol G, De Wolf-Peeters C, Falini B, Gatter KC, et al. 1994. A revised European-American classification of lymphoid neoplasms: A proposal from the International Lymphoma Study Group. Blood. 84(5):1361–1392. 10.1182/blood.V84.5.1361.1361 8068936
Hassoun E, Cearfoss J, Mamada S, Al-Hassan N, Brown M, Heimberger K, Liu MC. 2014. The effects of mixtures of dichloroacetate and trichloroacetate on induction of oxidative stress in livers of mice after subchronic exposure. J Toxicol Environ Health A. 77(6):313–323. 10.1080/15287394.2013.864576 24593144
Hassoun EA, Cearfoss J. 2011. Dichloroacetate- and trichloroacetate-induced modulation of superoxide dismutase, catalase, and glutathione peroxidase activities and glutathione level in the livers of mice after subacute and subchronic exposure. Toxicol Environ Chem. 93(2):332–344. 10.1080/02772248.2010.509602 21170174
Hassoun EA, Cearfoss J, Musser B, Krispinsky S, Al-Hassan N, Liu MC. 2013. The induction of phagocytic activation by mixtures of the water chlorination by-products, dichloroacetate- and trichloroacetate, in mice after subchronic exposure. J Biochem Mol Toxicol. 27(4):237–242. 10.1002/jbt.21476 23436740
Hassoun EA, Cearfoss J, Spildener J. 2010 a. Dichloroacetate- and trichloroacetate-induced oxidative stress in the hepatic tissues of mice after long-term exposure. J Appl Toxicol. 30(5):450–456. 10.1002/jat.1516 20222146
Hassoun EA, Dey S. 2008. Dichloroacetate- and trichloroacetate-induced phagocytic activation and production of oxidative stress in the hepatic tissues of mice after acute exposure. J Biochem Mol Toxicol. 22(1):27–34. 10.1002/jbt.20210 18273911
Hassoun EA, Ray S. 2003. The induction of oxidative stress and cellular death by the drinking water disinfection by-products, dichloroacetate and trichloroacetate in J774.A1 cells. Comp Biochem Physiol C Toxicol Pharmacol. 135(2):119–128. 10.1016/S1532-0456(03)00082-6 12860050
Hassoun EA, Spildener J, Cearfoss J. 2010 b. The induction of tumor necrosis factor-alpha, superoxide anion, myeloperoxidase, and superoxide dismutase in the peritoneal lavage cells of mice after prolonged exposure to dichloroacetate and trichloroacetate. J Biochem Mol Toxicol. 24(2):136–144. 10.1002/jbt.20322 20391627
Hayden PJ, Welsh CJ, Yang Y, Schaefer WH, Ward AJ, Stevens JL. 1992. Formation of mitochondrial phospholipid adducts by nephrotoxic cysteine conjugate metabolites. Chem Res Toxicol. 5(2):232–237. 10.1021/tx00026a013 1643252
Hazardous Substances Database.Trichloroethylene. 2012. National Library of Medicine; [accessed Accessed on 5/14/14]. http://toxnet.nlm.nih.gov/cgi-bin/sis/htmlgen?HSDB and search on CAS number or compound name
Henschler D, Eder E, Neudecker T, Metzler M. 1977. Carcinogenicity of trichloroethylene: Fact or artifact? Arch Toxicol. 37(3):233–236. 10.1007/BF00355492 332116
Henschler D, Vamvakas S, Lammert M, Dekant W, Kraus B, Thomas B, Ulm K. 1995. Increased incidence of renal cell tumors in a cohort of cardboard workers exposed to trichloroethene. Arch Toxicol. 69(5):291–299. 10.1007/s002040050173 7654132
Hill AB. 1965. The environment and disease: Association or causation? Proc R Soc Med. 58:295–300. 10.1177/003591576505800503 14283879
Hinchman CA, Ballatori N. 1990. Glutathione-degrading capacities of liver and kidney in different species. Biochem Pharmacol. 40(5):1131–1135. 10.1016/0006-2952(90)90503-D 1975172
Hobara T, Kobayashi H, Higashihara E, Kawamoto T, Sakai T. 1984. Acute effects of 1,1,1-trichloroethane, trichloroethylene, and toluene on the hematologic parameters in dogs. Arch Environ Contam Toxicol. 13(5):589–593. 10.1007/BF01056337 6486885
Hong WX, Yang L, Chen M, Yang X, Ren X, Fang S, Ye J, Huang H, Peng C, Zhou L, et al. 2012. Proteomic analysis of trichloroethylene-induced alterations in expression, distribution, and interactions of SET/TAF-Ialpha and two SET/TAF-Ialpha-binding proteins, eEF1A1 and eEF1A2, in hepatic L-02 cells. Toxicol Appl Pharmacol. 263(2):259–272. 10.1016/j.taap.2012.06.018 22771849
Hong WX, Ye JB, Chen MT, Yan Y, Zhou GF, Yang XF, Yang L, Ren XH, Huang HY, Zhou L, et al. 2013. Trichloroethylene induces biphasic concentration-dependent changes in cell proliferation and the expression of SET-associated proteins in human hepatic L-02 Cells. Biomed Environ Sci. 26(7):618–621. 23895710
Hosgood HD 3rd, Zhang L, Tang X, Vermeulen R, Qiu C, Shen M, Smith MT, Ge Y, Ji Z, Xiong J, et al. 2012. Decreased numbers of CD4(+) naive and effector memory T cells, and CD8(+) naive T cells, are associated with trichloroethylene exposure. Front Oncol. 1:53. 10.3389/fonc.2011.00053 22649769
Hosnijeh FS, Krop EJ, Scoccianti C, Krogh V, Palli D, Panico S, Tumino R, Sacredote C, Nawroly N, Portengen L, et al. 2010. Plasma cytokines and future risk of non-Hodgkin lymphoma (NHL): A case-control study nested in the Italian European Prospective Investigation into Cancer and Nutrition. Cancer Epidemiol Biomarkers Prev. 19(6):1577–1584. 10.1158/1055-9965.EPI-09-1237 20501772
Howard J. 2013. Minimum Latency & Types or Categories of Cancer. World Trade Center Health Program.
Hrelia P, Maffei F, Vigagni F, Fimognari C, Flori P, Stanzani R, Cantelli Forti G. 1994. Interactive effects between trichloroethylene and pesticides at metabolic and genetic level in mice. Environ Health Perspect. 102 Suppl 9:31–34. 10.1289/ehp.94102s931 7698080
Hu C, Jiang L, Geng C, Zhang X, Cao J, Zhong L. 2008. Possible involvement of oxidative stress in trichloroethylene-induced genotoxicity in human HepG2 cells. Mutat Res. 652(1):88–94. 10.1016/j.mrgentox.2008.01.002 18289923
Huang H, Kamijima M, Wang H, Li S, Yoshikawa T, Lai G, Huang Z, Liu H, Chen J, Takeuchi Y, et al. 2006. Human herpesvirus 6 reactivation in trichloroethylene-exposed workers suffering from generalized skin disorders accompanied by hepatic dysfunction. J Occup Health. 48(6):417–423. 10.1539/joh.48.417 17179634
Huang Z, Yue F, Yang X, Xia L, Chen C, Qiu X, Huang J, Li L, Kamijima M, Nakajima T, et al. 2012. Upregulation of calprotectin and downregulation of retinol binding protein in the serum of workers with trichloroethylene-induced hypersensitivity dermatitis. J Occup Health. 54(4):299–309. 10.1539/joh.12-0012-OA 22672899
Hung RJ, Moore L, Boffetta P, Feng BJ, Toro JR, Rothman N, Zaridze D, Navratilova M, Bencko V, Janout V, et al. 2007. Family history and the risk of kidney cancer: A multicenter case-control study in Central Europe. Cancer Epidemiol Biomarkers Prev. 16(6):1287–1290. 10.1158/1055-9965.EPI-06-0963 17548699
Iavicoli I, Marinaccio A, Carelli G. 2005. Effects of occupational trichloroethylene exposure on cytokine levels in workers. J Occup Environ Med. 47(5):453–457. 10.1097/01.jom.0000161728.23285.66 15891523
Ikbal M, Tastekin A, Dogan H, Pirim I, Ors R. 2004. The assessment of genotoxic effects in lymphocyte cultures of infants treated with chloral hydrate. Mutat Res. 564(2):159–164. 10.1016/j.mrgentox.2004.08.007 15507380
International Agency for Research on Cancer (IARC). 1976. Trichloroethylene. Cadmium, Nickel, Some Epoxides, Miscellaneous Industrial Chemicals and General Considerations on Volatile Anaesthetics. Lyon, France: International Agency for Research on Cancer. p; p. 263–276.
International Agency for Research on Cancer (IARC). 1995. Trichloroethylene. Dry Cleaning, Some Chlorinated Solvents and Other Industrial Chemicals. Lyon, France: International Agency for Research on Cancer; p. 75–158.
International Agency for Research on Cancer (IARC). 1999. 1,1,1-Trichloroethane. Re-evaluation of Some Organic Chemicals,Hydrazine and Hydrogen Peroxide. Lyon, France: International Agency for Research on Cancer; p. 881–903.
International Agency for Research on Cancer (IARC). 2014. Trichloroethylene, Tetrachloroethylene and Some Other Chlorinated Agents. Lyon, France: International Agency for Research on Cancer.
Irving RM, Elfarra AA. 2012. Role of reactive metabolites in the circulation in extrahepatic toxicity. Expert Opin Drug Metab Toxicol. 8(9):1157–1172. 10.1517/17425255.2012.695347 22681489
Irving RM, Elfarra AA. 2013. Mutagenicity of the cysteine S-conjugate sulfoxides of trichloroethylene and tetrachloroethylene in the Ames test. Toxicology. 306:157–161. 10.1016/j.tox.2013.02.003 23416178
Irving RM, Pinkerton ME, Elfarra AA.2013. Characterization of the chemical reactivity and nephrotoxicity of N-acetyl-S-(1,2-dichlorovinyl)-L-cysteine sulfoxide, a potential reactive metabolite of trichloroethylene. Toxicol App Pharmacol. 267(1):1-10. 10.1016/j.taap.2012.12.002
Jaffe DR, Hassall CD, Gandolfi AJ, Brendel K. 1985. Production of DNA single strand breaks in rabbit renal tissue after exposure to 1,2-dichlorovinylcysteine. Toxicology. 35(1):25–33. 10.1016/0300-483X(85)90129-5 4002236
Kafer E. 1986. Tests which distinguish induced crossing-over and aneuploidy from secondary segregation in Aspergillus treated with chloral hydrate or gamma-rays. Mutat Res. 164(3):145–166. 10.1016/0165-1161(86)90006-3 3520302
Kamijima M, Hisanaga N, Wang H, Nakajima T. 2007. Occupational trichloroethylene exposure as a cause of idiosyncratic generalized skin disorders and accompanying hepatitis similar to drug hypersensitivities. Int Arch Occup Environ Health. 80(5):357–370. 10.1007/s00420-006-0147-y 17106739
Kamijima M, Wang H, Huang H, Li L, Shibata E, Lin B, Sakai K, Liu H, Tsuchiyama F, Chen J, et al. 2008. Trichloroethylene causes generalized hypersensitivity skin disorders complicated by hepatitis. J Occup Health. 50(4):328–338. 10.1539/joh.L8013 18540116
Kamijima M, Wang H, Yamanoshita O, Ito Y, Xia L, Yanagiba Y, Chen C, Okamura A, Huang Z, Qiu X, et al. 2013. Occupational trichloroethylene hypersensitivity syndrome: Human herpesvirus 6 reactivation and rash phenotypes. J Dermatol Sci. 72:218–224. 10.1016/j.jdermsci.2013.07.003 23928230
Kaneko T, Saegusa M, Tasaka K, Sato A.2000. Immunotoxicity of trichloroethylene: A study with MRL-lpr/lpr mice. J Appl Toxicol. 20(6):471-475. 10.1002/1099-1263(200011/12)20:6<471:AID-JAT716>3.0.CO;2-E
Kappas A. 1989. On the mechanisms of induced aneuploidy in Aspergillus nidulans and validation of tests for genomic mutations. In: Resnick MA, Vig BK, editors. Mechanisms of Chromosome Distribution and Aneuploidy. New York, NY: Wiley; p. 377–384.
Karami S, Bassig B, Stewart PA, Lee KM, Rothman N, Moore LE, Lan Q. 2013. Occupational trichloroethylene exposure and risk of lymphatic and haematopoietic cancers: A meta-analysis. Occup Environ Med. 70(8):591–599. 10.1136/oemed-2012-101212 23723297
Karami S, Lan Q, Rothman N, Stewart PA, Lee KM, Vermeulen R, Moore LE. 2012. Occupational trichloroethylene exposure and kidney cancer risk: A meta-analysis. Occup Environ Med. 69(12):858–867. 10.1136/oemed-2012-100932 23000822
Kargalioglu Y, McMillan BJ, Minear RA, Plewa MJ. 2002. Analysis of the cytotoxicity and mutagenicity of drinking water disinfection by-products in Salmonella typhimurium. Teratog Carcinog Mutagen. 22(2):113–128. 10.1002/tcm.10010 11835289
Kato I, Koenig KL, Watanabe-Meserve H, Baptiste MS, Lillquist PP, Frizzera G, Burke JS, Moseson M, Shore RE. 2005. Personal and occupational exposure to organic solvents and risk of non-Hodgkin’s lymphoma (NHL) in women (United States). Cancer Causes Control. 16(10):1215–1224. 10.1007/s10552-005-0385-4 16215872
Kauffmann BM, White KL Jr, Sanders VM, Douglas KA, Sain LE, Borzelleca JF, Munson AE. 1982. Humoral and cell-mediated immune status in mice exposed to chloral hydrate. Environ Health Perspect. 44:147–151. 10.1289/ehp.8244147 6979478
Kauppinen T, Heikkilä P, Plato N, Woldbæk T, Lenvik K, Hansen J, Kristjansson V, Pukkala E. 2009. Construction of job-exposure matrices for the Nordic Occupational Cancer Study (NOCCA). Acta Oncol. 48(5):791–800. 10.1080/02841860902718747 19225948
Keil DE, Peden-Adams MM, Wallace S, Ruiz P, Gilkeson GS. 2009. Assessment of trichloroethylene (TCE) exposure in murine strains genetically-prone and non-prone to develop autoimmune disease. J Environ Sci Health Part A Tox Hazard Subst Environ Eng. 44(5):443–453. 10.1080/10934520902719738 19241258
Keller DA, Heck HD. 1988. Mechanistic studies on chloral toxicity: Relationship to trichloroethylene carcinogenesis. Toxicol Lett. 42(2):183–191. 10.1016/0378-4274(88)90076-8 3406960
Kelsh MA, Alexander DD, Mink PJ, Mandel JH. 2010. Occupational trichloroethylene exposure and kidney cancer: A meta-analysis. Epidemiology. 21(1):95–102. 10.1097/EDE.0b013e3181c30e92 20010212
Keshava N, Caldwell JC. 2006. Key issues in the role of peroxisome proliferator-activated receptor agonism and cell signaling in trichloroethylene toxicity. Environ Health Perspect. 114(9):1464–1470. 10.1289/ehp.8693 16966106
Khan MF, Kaphalia BS, Prabhakar BS, Kanz MF, Ansari GAS.1995. Trichloroethene-induced autoimmune response in female MRL +/+ mice. Toxicol App Pharmacol. 134:155-160. 10.1006/taap.1995.1179
Khan MF, Wu X, Ansari GAS.2001. Anti-malondialdehyde antibodies in mrl1/1 mice treated with trichloroethene and dichloroacetyl chloride: Possible role of lipid peroxidation in autoimmunity. Toxicol App Pharmacol. 170:88-92. 10.1006/taap.2000.9086
Kim HR, Kim TW. 2010. Occupational hepatic disorders in Korea. J Korean Med Sci. 25 Suppl:S36–S40. 10.3346/jkms.2010.25.S.S36 21258588
Kim S, Collins LB, Boysen G, Swenberg JA, Gold A, Ball LM, Bradford BU, Rusyn I. 2009 a. Liquid chromatography electrospray ionization tandem mass spectrometry analysis method for simultaneous detection of trichloroacetic acid, dichloroacetic acid, S-(1,2-dichlorovinyl)glutathione and S-(1,2-dichlorovinyl)-L-cysteine. Toxicology. 262(3):230–238. 10.1016/j.tox.2009.06.013 19549554
Kim S, Kim D, Pollack GM, Collins LB, Rusyn I. 2009 b. Pharmacokinetic analysis of trichloroethylene metabolism in male B6C3F1 mice: Formation and disposition of trichloroacetic acid, dichloroacetic acid, S-(1,2-dichlorovinyl)glutathione and S-(1,2-dichlorovinyl)-L-cysteine. Toxicol Appl Pharmacol. 238(1):90–99. 10.1016/j.taap.2009.04.019 19409406
Klaunig JE, Babich MA, Baetcke KP, Cook JC, Corton JC, David RM, DeLuca JG, Lai DY, McKee RH, Peters JM, et al. 2003. PPARalpha agonist-induced rodent tumors: Modes of action and human relevance. Crit Rev Toxicol. 33(6):655–780. 10.1080/713608372 14727734
Klaunig JE, Xu Y, Isenberg JS, Bachowski S, Kolaja KL, Jiang J, Stevenson DE, Walborg EF Jr. 1998. The role of oxidative stress in chemical carcinogenesis. Environ Health Perspect. 106 Suppl 1:289–295. 9539021
Kligerman AD, Bryant MF, Doerr CL, Erexson GL, Evansky PA, Kwanyuen P, McGee JK. 1994. Inhalation studies of the genotoxicity of trichloroethylene to rodents. Mutat Res. 322(2):87–96. 10.1016/0165-1218(94)00013-1 7519326
Knadle SA, Green CE, Baugh M, Vidensek M, Short SM, Partos X, Tyson CA. 1990. Trichloroethylene biotransformation in human and rat primary hepatocytes. Toxicol In Vitro. 4(4-5):537–541. 10.1016/0887-2333(90)90114-9 20702228
Koch R, Schlegelmilch R, Wolf HU. 1988. Genetic effects of chlorinated ethylenes in the yeast Saccharomyces cerevisiae. Mutat Res. 206(2):209–216. 10.1016/0165-1218(88)90162-0 3050501
Kondraganti S, König R, Boor PJ, Khan S, Kaphalia BS, Firoze Khan M, Ansari GAS. 2012. Mechanistic evaluation of trichloroethene-mediated autoimmune hepatitis-like disease in female MRL+/+ Mice. Open Toxicol J. 5(1):1–10.
Krause RJ, Lash LH, Elfarra AA. 2003. Human kidney flavin-containing monooxygenases and their potential roles in cysteine s-conjugate metabolism and nephrotoxicity. J Pharmacol Exp Ther. 304(1):185–191. 10.1124/jpet.102.042911 12490590
Kringstad KP, Ljungquist PO, De Sousa F, Stroemberg LM. 1981. Identification and mutagenic properties of some chlorinated aliphatic compounds in the spent liquor from kraft pulp chlorination. Environ Sci Technol. 15(5):562–566. 10.1021/es00087a006 22283948
Kumar M, Tewari S, Sharma P, Verma VK, Chauhan LK, Agarwal SK, Dwivedi UN, Goel SK. 2009. Study of genetic polymorphism in solvent exposed population and its correlation to in vitro effect of trichloroethylene on lymphocytes. J Environ Biol. 30(5):685–691. 20136049
Lacey JV Jr, Garabrant DH, Laing TJ, Gillespie BW, Mayes MD, Cooper BC, Schottenfeld D. 1999. Petroleum distillate solvents as risk factors for undifferentiated connective tissue disease (UCTD). Am J Epidemiol. 149(8):761–770. 10.1093/oxfordjournals.aje.a009885 10206626
Lan Q, Zhang L, Tang X, Shen M, Smith MT, Qiu C, Ge Y, Ji Z, Xiong J, He J, et al. 2010. Occupational exposure to trichloroethylene is associated with a decline in lymphocyte subsets and soluble CD27 and CD30 markers. Carcinogenesis. 31(9):1592–1596. 10.1093/carcin/bgq121 20530238
Lan Q, Zheng T, Rothman N, Zhang Y, Wang SS, Shen M, Berndt SI, Zahm SH, Holford TR, Leaderer B, et al. 2006. Cytokine polymorphisms in the Th1/Th2 pathway and susceptibility to non-Hodgkin lymphoma. Blood. 107(10):4101–4108. 10.1182/blood-2005-10-4160 16449530
Laque WE, Ronneberg CE. 1970. A study of the decarboxylation of trichloroacetic acid in solutions of water and dimethylsulfide. Ohio J Sci. 70(2):97–106.
Larson JL, Bull RJ. 1992. Metabolism and lipoperoxidative activity of trichloroacetate and dichloroacetate in rats and mice. Toxicol Appl Pharmacol. 115(2):268–277. 10.1016/0041-008X(92)90332-M 1641860
Lash LH, Chiu WA, Guyton KZ, Rusyn I.2014. Trichloroethylene biotransformation and its role in mutagenicity, carcinogenicity and target organ toxicity. Mutat Res. (In Press). 10.1016/j.mrrev.2014.04.003
Lash LH, Elfarra AA, Anders MW. 1986. Renal cysteine conjugate beta-lyase. Bioactivation of nephrotoxic cysteine S-conjugates in mitochondrial outer membrane. J Biol Chem. 261(13):5930–5935. 10.1016/S0021-9258(17)38472-7 3700378
Lash LH, Fisher JW, Lipscomb JC, Parker JC. 2000 a. Metabolism of trichloroethylene. Environ Health Perspect. 108 Suppl 2:177–200. 10.1289/ehp.00108s2177 10807551
Lash LH, Lipscomb JC, Putt DA, Parker JC. 1999 a. Glutathione conjugation of trichloroethylene in human liver and kidney: Kinetics and individual variation. Drug Metab Dispos. 27(3):351–359. 10064565
Lash LH, Parker JC, Scott CS. 2000 b. Modes of action of trichloroethylene for kidney tumorigenesis. Environ Health Perspect. 108 Suppl 2:225–240. 10.1289/ehp.00108s2225 10807554
Lash LH, Putt DA, Brashear WT, Abbas R, Parker JC, Fisher JW. 1999 b. Identification of S-(1,2-dichlorovinyl)glutathione in the blood of human volunteers exposed to trichloroethylene. J Toxicol Environ Health A. 56(1):1–21. 10.1080/009841099158204 9923751
Lash LH, Putt DA, Hueni SE, Horwitz BP. 2005. Molecular markers of trichloroethylene-induced toxicity in human kidney cells. Toxicol Appl Pharmacol. 206(2):157–168. 10.1016/j.taap.2004.09.023 15967204
Lash LH, Putt DA, Parker JC. 2006. Metabolism and tissue distribution of orally administered trichloroethylene in male and female rats: Identification of glutathione- and cytochrome P-450-derived metabolites in liver, kidney, blood, and urine. J Toxicol Environ Health A. 69(13):1285–1309. 10.1080/15287390500360133 16754541
Lash LH, Qian W, Putt DA, Jacobs K, Elfarra AA, Krause RJ, Parker JC. 1998. Glutathione conjugation of trichloroethylene in rats and mice: Sex-, species-, and tissue-dependent differences. Drug Metab Dispos. 26(1):12–19. 9443846
Laughter AR, Dunn CS, Swanson CL, Howroyd P, Cattley RC, Christopher Corton J. 2004. Role of the peroxisome proliferator-activated receptor α (PPARα) in responses to trichloroethylene and metabolites, trichloroacetate and dichloroacetate in mouse liver. Toxicology. 203(1-3):83–98. 10.1016/j.tox.2004.06.014 15363585
Leavitt SA, DeAngelo AB, George MH, Ross JA. 1997. Assessment of the mutagenicity of dichloroacetic acid in lacI transgenic B6C3F1 mouse liver. Carcinogenesis. 18(11):2101–2106. 10.1093/carcin/18.11.2101 9395208
Lee YC, Cohet C, Yang YC, Stayner L, Hashibe M, Straif K. 2009. Meta-analysis of epidemiologic studies on cigarette smoking and liver cancer. Int J Epidemiol. 38(6):1497–1511. 10.1093/ije/dyp280 19720726
Lehmann I, Rehwagen M, Diez U, Seiffart A, Rolle-Kampczyk U, Richter M, Wetzig H, Borte M, Herbarth O, Leipzig Allergy Risk Children S. 2001. Enhanced in vivo IgE production and T cell polarization toward the type 2 phenotype in association with indoor exposure to VOC: Results of the LARS study. Int J Hyg Environ Health. 204(4):211–221. 10.1078/1438-4639-00100 11833293
Lehmann I, Thoelke A, Rehwagen M, Rolle-Kampczyk U, Schlink U, Schulz R, Borte M, Diez U, Herbarth O. 2002. The influence of maternal exposure to volatile organic compounds on the cytokine secretion profile of neonatal T cells. Environ Toxicol. 17(3):203–210. 10.1002/tox.10055 12112628
Leopardi P, Zijno A, Bassani B, Pacchierotti F. 1993. In vivo studies on chemically induced aneuploidy in mouse somatic and germinal cells. Mutat Res. 287(1):119–130. 10.1016/0027-5107(93)90151-5 7683378
Leuschner J, Leuschner F. 1991. Evaluation of the mutagenicity of chloral hydrate in vitro and in vivo. Arzneimittelforschung. 41(10):1101–1103. 1799393
Li W, Gu Y, James MO, Hines RN, Simpson P, Langaee T, Stacpoole PW. 2012. Prenatal and postnatal expression of glutathione transferase ζ 1 in human liver and the roles of haplotype and subject age in determining activity with dichloroacetate. Drug Metab Dispos. 40(2):232–239. 10.1124/dmd.111.041533 22028318
Lingohr MK, Bull RJ, Kato-Weinstein J, Thrall BD. 2002. Dichloroacetate stimulates glycogen accumulation in primary hepatocytes through an insulin-independent mechanism. Toxicol Sci. 68(2):508–515. 10.1093/toxsci/68.2.508 12151648
Lipscomb JC, Fisher JW, Confer PD, Byczkowski JZ. 1998 a. In vitro to in vivo extrapolation for trichloroethylene metabolism in humans. Toxicol Appl Pharmacol. 152(2):376–387. 10.1006/taap.1998.8485 9853006
Lipscomb JC, Garrett CM, Snawder JE. 1997. Cytochrome P450-dependent metabolism of trichloroethylene: Interindividual differences in humans. Toxicol Appl Pharmacol. 142(2):311–318. 10.1006/taap.1996.8040 9070354
Lipscomb JC, Garrett CM, Snawder JE. 1998 b. Use of kinetic and mechanistic data un species extrapolation of bioactivation: Cytochrome P-540 dependent trichloroethylene metabolism at occupationally relevant concentrations. J Occup Health. 40:110–117. 10.1539/joh.40.110
Lipscomb JC, Mahle DA, Brashear WT, Garrett CM. 1996. A species comparison of chloral hydrate metabolism in blood and liver. Biochem Biophys Res Commun. 227(2):340–350. 10.1006/bbrc.1996.1511 8878519
Lipworth L, Sonderman JS, Mumma MT, Tarone RE, Marano DE, Boice JD Jr, McLaughlin JK. 2011. Cancer mortality among aircraft manufacturing workers: An extended follow-up. J Occup Environ Med. 53(9):992–1007. 10.1097/JOM.0b013e31822e0940 21866047
Lipworth L, Tarone RE, McLaughlin JK. 2006. The epidemiology of renal cell carcinoma. J Urol. 176(6 Pt 1):2353–2358. 10.1016/j.juro.2006.07.130 17085101
Liu J, Xing X, Huang H, Jiang Y, He H, Xu X, Yuan J, Zhou L, Yang L, Zhuang Z. 2009. Identification of antigenic proteins associated with trichloroethylene-induced autoimmune disease by serological proteome analysis. Toxicol Appl Pharmacol. 240(3):393–400. 10.1016/j.taap.2009.07.031 19647757
Liu R, Wang XH, Liu L, Zhou Q. 2012. No association between the GSTM1 null genotype and risk of renal cell carcinoma: A meta-analysis. Asian Pac J Cancer Prev. 13(7):3109–3112. 10.7314/APJCP.2012.13.7.3109 22994718
Liver cancer incidence statistics. 2014a. Cancer Research UK; [accessed Accessed on 10/21/14]. https://www.cancerresearchuk.org/cancer-info/cancerstats/types/liver/incidence/uk-liver-cancer-incidence-statistics
Liviac D, Creus A, Marcos R. 2010. DNA damage induction by two halogenated acetaldehydes, byproducts of water disinfection. Water Res. 44(8):2638–2646. 10.1016/j.watres.2010.01.026 20189624
Liviac D, Creus A, Marcos R. 2011. Mutagenic analysis of six disinfection by-products in the Tk gene of mouse lymphoma cells. J Hazard Mater. 190(1-3):1045–1052. 10.1016/j.jhazmat.2011.04.062 21561708
Loprieno N, Abbondandolo A. 1980. Comparative mutagenic evaluation of some industrial compounds. In: Norpoth KH, Garner RC, editors. Short-term Test Systems for Detecting Carcinogens. Berlin, Germany: Springer-Verlag; p. 333–356. 10.1007/978-3-642-67202-6_26
Lynch AM, Parry JM. 1993. The cytochalasin-B micronucleus/kinetochore assay in vitro: Studies with 10 suspected aneugens. Mutat Res. 287(1):71–86. 10.1016/0027-5107(93)90146-7 7683386
Mackay JM, Fox V, Griffiths K, Fox DA, Howard CA, Coutts C, Wyatt I, Styles JA. 1995. Trichloroacetic acid: Investigation into the mechanism of chromosomal damage in the in vitro human lymphocyte cytogenetic assay and the mouse bone marrow micronucleus test. Carcinogenesis. 16(5):1127–1133. 10.1093/carcin/16.5.1127 7767975
Mally A, Walker CL, Everitt JI, Dekant W, Vamvakas S. 2006. Analysis of renal cell transformation following exposure to trichloroethene in vivo and its metabolite S-(dichlorovinyl)-L-cysteine in vitro. Toxicology. 224(1-2):108–118. 10.1016/j.tox.2006.04.036 16730402
Mandel JH, Kelsh MA, Mink PJ, Alexander DD, Kalmes RM, Weingart M, Yost L, Goodman M. 2006. Occupational trichloroethylene exposure and non-Hodgkin’s lymphoma: A meta-analysis and review. Occup Environ Med. 63(9):597–607. 10.1136/oem.2005.022418 16644896
Manton KG, Akushevich I, Kravchenko J.2009. Cancer Mortality and Morbidity Patterns in the U.S. Population. New York, NY: Springer Science+Business Media.
Marano DE, Boice JD Jr, Fryzek JP, Morrison JA, Sadler CJ, McLaughlin JK. 2000. Exposure assessment for a large epidemiological study of aircraft manufacturing workers. Appl Occup Environ Hyg. 15(8):644–656. 10.1080/10473220050075653 10957820
Marie I, Gehanno JF, Bubenheim M, Duval-Modeste AB, Joly P, Dominique S, Bravard P, Noël D, Cailleux AF, Weber J, et al. 2014. Prospective study to evaluate the association between systemic sclerosis and occupational exposure and review of the literature. Autoimmun Rev. 13(2):151–156. 10.1016/j.autrev.2013.10.002 24129037
Marrazzini A, Betti C, Bernacchi F, Barrai I, Barale R. 1994. Micronucleus test and metaphase analyses in mice exposed to known and suspected spindle poisons. Mutagenesis. 9(6):505–515. 10.1093/mutage/9.6.505 7854141
Mazzullo M, Bartoli S, Bonora B, Colacci A, Lattanzi G, Niero A, Silingardi P, Grilli S. 1992. In vivo and in vitro interaction of trichloroethylene with macromolecules from various organs of rat and mouse. Res Commun Chem Pathol Pharmacol. 76:192–208. 1376481
McGregor DB, Reynolds DM, Zeiger E. 1989. Conditions affecting the mutagenicity of trichloroethylene in Salmonella. Environ Mol Mutagen. 13(3):197–202. 10.1002/em.2850130302 2651116
McMichael AJ, Spirtas R, Gamble JF, Tousey PM. 1976. Mortality among rubber workers: Relationship to specific jobs. J Occup Med. 18(3):178–185. 10.1097/00043764-197603000-00012 1255279
McMichael AJ, Spirtas R, Kupper LL. 1974. An epidemiologic study of mortality within a cohort of rubber workers, 1964-72. J Occup Med. 16(7):458–464. 4842655
Mersch-Sundermann V, Muller G, Hofmeister J. 1989. [Examination of mutagenicity of organic microcontaminations of the environment. IV. Communication: The mutagenicity of halogenated aliphatic hydrocarbons with the SOS-chromotest]. Zbl Hyg. 189:266–271.
Meza-Junco J, Montaño-Loza AJ, Martínez-Benitez B, Kimura-Hayama E. 2007. Hepatocellular carcinoma in patients with autoimmune liver diseases: Two case reports and literature review. Ann Hepatol. 6(2):122–126. 10.1016/S1665-2681(19)31945-3 17519838
Miligi L, Costantini AS, Benvenuti A, Kriebel D, Bolejack V, Tumino R, Ramazzotti V, Rodella S, Stagnaro E, Crosignani P, et al. 2006. Occupational exposure to solvents and the risk of lymphomas. Epidemiology. 17(5):552–561. 10.1097/01.ede.0000231279.30988.4d 16878041
Miller BM, Adler ID. 1992. Aneuploidy induction in mouse spermatocytes. Mutagenesis. 7(1):69–76. 10.1093/mutage/7.1.69 1635458
Miller RE, Guengerich FP. 1983. Metabolism of trichloroethylene in isolated hepatocytes, microsomes, and reconstituted enzyme systems containing cytochrome P-450. Cancer Res. 43(3):1145–1152. 6825087
Milman HA, Story DL, Riccio ES, Sivak A, Tu AS, Williams GM, Tong C, Tyson CA. 1988. Rat liver foci and in vitro assays to detect initiating and promoting effects of chlorinated ethanes and ethylenes. Ann N Y Acad Sci. 534:521–530. 10.1111/j.1749-6632.1988.tb30143.x 3389679
Mirsalis JC, Tyson CK, Steinmetz KL, Loh EK, Hamilton CM, Bakke JP, Spalding JW. 1989. Measurement of unscheduled DNA synthesis and S-phase synthesis in rodent hepatocytes following in vivo treatment: Testing of 24 compounds. Environ Mol Mutagen. 14(3):155–164. 10.1002/em.2850140305 2792091
Moore LE, Boffetta P, Karami S, Brennan P, Stewart PS, Hung R, Zaridze D, Matveev V, Janout V, Kollarova H, et al. 2010. Occupational trichloroethylene exposure and renal carcinoma risk: Evidence of genetic susceptibility by reductive metabolism gene variants. Cancer Res. 70(16):6527–6536. 10.1158/0008-5472.CAN-09-4167 20663906
Moore LE, Nickerson ML, Brennan P, Toro JR, Jaeger E, Rinsky J, Han SS, Zaridze D, Matveev V, Janout V, et al. 2011. Von Hippel-Lindau (VHL) inactivation in sporadic clear cell renal cancer: Associations with germline VHL polymorphisms and etiologic risk factors. PLoS Genet. 7(10):e1002312. 10.1371/journal.pgen.1002312 22022277
Moore MM, Harrington-Brock K. 2000. Mutagenicity of trichloroethylene and its metabolites: Implications for the risk assessment of trichloroethylene. Environ Health Perspect. 108 Suppl 2:215–223. 10.1289/ehp.00108s2215 10807553
Morgan RW, Kelsh MA, Zhao K, Heringer S. 1998. Mortality of aerospace workers exposed to trichloroethylene. Epidemiology. 9(4):424–431. 10.1097/00001648-199807000-00013 9647907
Morgenstern H, Froines J, Ritz B, Young B. 1997. Epidemiological study to determine possible adverse effects to rocketdyne/atomics international workers from exposure to ionizing radiation. Berkely, CA: Public Health Institute.
Mortelmans K, Haworth S, Lawlor T, Speck W, Tainer B, Zeiger E. 1986. Salmonella mutagenicity tests: II. Results from the testing of 270 chemicals. Environ Mutagen. 8 Suppl 7:1–119. 10.1002/em.2860080802 3516675
Morton LM, Turner JJ, Cerhan JR, Linet MS, Treseler PA, Clarke CA, Jack A, Cozen W, Maynadie M, Spinelli JJ, et al. 2007. Proposed classification of lymphoid neoplasms for epidemiologic research from the Pathology Working Group of the International Lymphoma Epidemiology Consortium (InterLymph). Blood. 110(2):695–708. 10.1182/blood-2006-11-051672 17389762
Muller AM, Ihorst G, Mertelsmann R, Engelhardt M. 2005. Epidemiology of non-Hodgkin’s lymphoma (NHL): Trends, geographic distribution, and etiology. Ann Hematol. 84(1):1–12. 10.1007/s00277-004-0939-7 15480663
Muller M, Birner G, Sander M, Dekant W. 1998. Reactivity of haloketenes and halothioketenes with nucleobases: Reactions in vitro with DNA. Chem Res Toxicol. 11(5):464–470. 10.1021/tx9701440 9585477
Nagaya T, Ishikawa N, Hata H. 1989. Sister-chromatid exchanges in lymphocytes of workers exposed to trichloroethylene. Mutat Res. 222(3):279–282. 10.1016/0165-1218(89)90144-4 2922011
Nakahama T, Maruyama I, Endo M, Inouye Y. 2001. Specificity in the metabolic activation of chlorinated ethylenes by cytochromes P450 in primary rat hepatocytes. J Health Sci. 47(1):36–39. 10.1248/jhs.47.36
National Research Council (NRC). 2006. Assessing the Human Health Risks of Trichloroethylene: Key Scientific Issues. Washington, D.C.: National Academies Press.
National Toxicology Program (NTP).1976. Carcinogenesis bioassay of trichloroethylene. Bethesda, MD: National Institutes of Health. NTP TR-2.https://ntp.niehs.nih.gov/ntp/htdocs/lt_rpts/tr002.pdf.
National Toxicology Program (NTP).1988. Toxicology and carcinogenesis studies of trichloroethylene (CAS No. 79-01-6) in four strains of rats (ACI, August, Marshall, Osborne-Mendel) (gavage studies). Research Triangle Park, NC: National Toxicology Program. NTP TR-273
National Toxicology Program (NTP).1990. Carcinogenesis studies of trichloroethylene (without epichlorohydrin) (CAS No. 79-01-6) in F344/N Rats and B6C3F1 mice (gavage studies). Research Triangle Park, NC: National Toxicology Program. NTP TR-243
National Toxicology Program (NTP).1999. NTP technical report on the toxicity and metabolism studies of chloral hydrate (CAS No. 302-17-0) administered by gavage to F344/N rats and B6C3F1 mice. Rockville, MD: U.S. Dept. of Health and Human Services, National Institutes of Health.https://ntp.niehs.nih.gov/ntp/htdocs/st_rpts/tox059.pdf.
National Toxicology Program (NTP). 2011. Trichloroethylene. Rep Carcinog. 12th ed. Research Triangle Park, NC: National Toxicology Program; p. 420–423.
Nelson MA, Bull RJ. 1988. Induction of strand breaks in DNA by trichloroethylene and metabolites in rat and mouse liver in vivo. Toxicol Appl Pharmacol. 94(1):45–54. 10.1016/0041-008X(88)90335-3 3376113
Nelson MA, Lansing AJ, Sanchez IM, Bull RJ, Springer DL. 1989. Dichloroacetic acid and trichloroacetic acid-induced DNA strand breaks are independent of peroxisome proliferation. Toxicology. 58(3):239–248. 10.1016/0300-483X(89)90139-X 2799828
Nestmann ER, Chu I, Kowbel DJ, Matula TI. 1980. Short-lived mutagen in Salmonella produced by reaction of trichloroacetic acid and dimethyl sulphoxide. Can J Genet Cytol. 22(1):35–40. 10.1139/g80-006 6992961
Ni YC, Kadlubar FF, Fu PP. 1995. Formation of malondialdehyde-modified 2′-deoxyguanosinyl adduct from metabolism of chloral hydrate by mouse liver microsomes. Biochem Biophys Res Commun. 216(3):1110–1117. 10.1006/bbrc.1995.2735 7488187
Nietert PJ, Sutherland SE, Silver RM, Pandey JP, Knapp RG, Hoel DG, Dosemeci M.1998. Is occupational organic solvent exposure a risk factor for scleroderma? Arthritis Rheum. 41(6):1111-1118. 10.1002/1529-0131(199806)41:6<1111:AID-ART19>3.0.CO;2-J
Nishiyama R, Kanai T, Abe J, Hara R, Watahiki Y, Sakaguchi T, Nakamura S. 2004. Hepatocellular carcinoma associated with autoimmune hepatitis. J Hepatobiliary Pancreat Surg. 11(3):215–219. 10.1007/s00534-003-0878-z 15235898
Non-Hodgkin lymphoma incidence statistics. 2014b. Cancer Research UK; [accessed Accessed on 10/21/14]. http://www.cancerresearchuk.org/cancer-info/cancerstats/types/nhl/incidence/uk-nonhodgkin-lymphoma-incidence-statistics#trends%29
Nordström M, Hardell L, Magnuson A, Hagberg H, Rask-Andersen A. 1998. Occupational exposures, animal exposure and smoking as risk factors for hairy cell leukaemia evaluated in a case-control study. Br J Cancer. 77(11):2048–2052. 10.1038/bjc.1998.341 9667691
Nutley EV, Tcheong AC, Allen JW, Collins BW, Ma M, Lowe XR, Bishop JB, Moore DH 2nd, Wyrobek AJ.1996. Micronuclei induced in round spermatids of mice after stem-cell treatment with chloral hydrate: Evaluations with centromeric DNA probes and kinetochore antibodies. Environ Mol Mutagen. 28(2):80-89. 10.1002/(SICI)1098-2280(1996)28:2<80:AID-EM3>3.0.CO;2-I
Odum J, Green T, Foster JR, Hext PM. 1988. The role of trichloroacetic acid and peroxisome profliferation in the differences in carcinogenicity of perchloroethylene in the mouse and rat. Toxicol Appl Pharmacol. 92:103–112. 10.1016/0041-008X(88)90232-3 3341020
Ono Y, Somiya I, Kawamura M. 1991. The evaluation of genotoxicity using DNA repairing test for chemicals produced in chlorination and ozonation processes. Water Sci Technol. 23:329–338. 10.2166/wst.1991.0431
Orsi L, Monnereau A, Dananche B, Berthou C, Fenaux P, Marit G, Soubeyran P, Huguet F, Milpied N, Leporrier M, et al. 2010. Occupational exposure to organic solvents and lymphoid neoplasms in men: Results of a French case-control study. Occup Environ Med. 67(10):664–672. 10.1136/oem.2009.049460 20837648
Parchman LG, Magee PN. 1982. Metabolism of [14C]trichloroethylene to 14CO2 and interaction of a metabolite with liver DNA in rats and mice. J Toxicol Environ Health. 9(5-6):797–813. 10.1080/15287398209530204 6811765
Parrish JM, Austin EW, Stevens DK, Kinder DH, Bull RJ. 1996. Haloacetate-induced oxidative damage to DNA in the liver of male B6C3F1 mice. Toxicology. 110(1-3):103–111. 10.1016/0300-483X(96)03342-2 8658551
Parry EM, Hague A, Parry JM. 1990. A study of mitotic division fidelity and numerical chromosome changes in ageing Syrian hamster dermal cells. Mutat Res. 237(2):83–93. 10.1016/0921-8734(90)90014-I 2366802
Peden-Adams MM, Eudaly JG, Heesemann LM, Smythe J, Miller J, Gilkeson GS, Keil DE. 2006. Developmental immunotoxicity of trichloroethylene (TCE): Studies in B6C3F1 mice. J Environ Sci Health Part A Tox Hazard Subst Environ Eng. 41(3):249–271. 10.1080/10934520500455289 16484062
Peden-Adams MM, Eudaly JG, Lee AM, Miller J, Keil DE, Gilkeson GS. 2008. Lifetime exposure to trichloroethylene (TCE) does not accelerate autoimmune disease in MRL +/+ mice. J Environ Sci Health Part A Tox Hazard Subst Environ Eng. 43(12):1402–1409. 10.1080/10934520802232063 18780217
Perocco P, Prodi G. 1981. DNA damage by haloalkanes in human lymphocytes cultured in vitro. Cancer Lett. 13(3):213–218. 10.1016/0304-3835(81)90020-3 6457684
Persson B, Dahlander AM, Fredriksson M, Brage HN, Ohlson CG, Axelson O. 1989. Malignant lymphomas and occupational exposures. Br J Ind Med. 46(8):516–520. 2775671
Persson B, Fredrikson M. 1999. Some risk factors for non-Hodgkin’s lymphoma. Int J Occup Med Environ Health. 12(2):135–142. 10465904
Persson B, Fredriksson M, Olsen K, Boeryd B, Axelson O.1993. Some occupational exposures as risk factors for malignant lymphomas. Cancer. 72(5):1773-1778. 10.1002/1097-0142(19930901)72:5<1773:AID-CNCR2820720542>3.0.CO;2-6
Pesch B, Haerting J, Ranft U, Klimpel A, Oelschlagel B, Schill W. 2000 a. Occupational risk factors for urothelial carcinoma: Agent-specific results from a case-control study in Germany. MURC Study Group. Multicenter Urothelial and Renal Cancer. Int J Epidemiol. 29(2):238–247. 10.1093/ije/29.2.238 10817119
Pesch B, Haerting J, Ranft U, Klimpel A, Oelschlagel B, Schill W, Barth W, Brettschneider U, Bronder E, Farker K, et al. 2000 b. Occupational risk factors for renal cell carcinoma: Agent-specific results from a case-control study in Germany. Int J Epidemiol. 29(6):1014–1024. 10.1093/ije/29.6.1014 11101542
Plewa MJ, Kargalioglu Y, Vankerk D, Minear RA, Wagner ED. 2002. Mammalian cell cytotoxicity and genotoxicity analysis of drinking water disinfection by-products. Environ Mol Mutagen. 40(2):134–142. 10.1002/em.10092 12203407
Plewa MJ, Simmons JE, Richardson SD, Wagner ED. 2010. Mammalian cell cytotoxicity and genotoxicity of the haloacetic acids, a major class of drinking water disinfection by-products. Environ Mol Mutagen. 51(8-9):871–878. 10.1002/em.20585 20839218
Poet TS, Corley RA, Thrall KD, Edwards JA, Tanojo H, Weitz KK, Hui X, Maibach HI, Wester RC. 2000. Assessment of the percutaneous absorption of trichloroethylene in rats and humans using MS/MS real-time breath analysis and physiologically based pharmacokinetic modeling. Toxicol Sci. 56(1):61–72. 10.1093/toxsci/56.1.61 10869454
Ponce RA, Gelzleichter T, Haggerty HG, Heidel S, Holdren MS, Lebrec H, Mellon RD, Pallardy M. 2014. Immunomodulation and lymphoma in humans. J Immunotoxicol. 11(1):1–12. 10.3109/1547691X.2013.798388 23746314
Price PJ, Hassett CM, Mansfield JI. 1978. Transforming activities of trichloroethylene and proposed industrial alternatives. In Vitro. 14(3):290–293. 10.1007/BF02616038 669729
Pukkala E, Martinsen JI, Lynge E, Gunnarsdottir HK, Sparén P, Tryggvadottir L, Weiderpass E, Kjaerheim K. 2009. Occupation and cancer - follow-up of 15 million people in five Nordic countries. Acta Oncol. 48(5):646–790. 10.1080/02841860902913546 19925375
Purdue MP, Bakke B, Stewart P, De Roos AJ, Schenk M, Lynch CF, Bernstein L, Morton LM, Cerhan JR, Severson RK, et al. 2011 a. A case-control study of occupational exposure to trichloroethylene and non-Hodgkin lymphoma. Environ Health Perspect. 119(2):232–238. 10.1289/ehp.1002106 21370516
Purdue MP, Lan Q, Bagni R, Hocking WG, Baris D, Reding DJ, Rothman N. 2011 b. Prediagnostic serum levels of cytokines and other immune markers and risk of non-hodgkin lymphoma. Cancer Res. 71(14):4898–4907. 10.1158/0008-5472.CAN-11-0165 21632552
Purdue MP, Lan Q, Kricker A, Grulich AE, Vajdic CM, Turner J, Whitby D, Chanock S, Rothman N, Armstrong BK. 2007. Polymorphisms in immune function genes and risk of non-Hodgkin lymphoma: Findings from the New South Wales non-Hodgkin Lymphoma Study. Carcinogenesis. 28(3):704–712. 10.1093/carcin/bgl200 17056605
Raaschou-Nielsen O, Hansen J, Christensen JM, Blot WJ, McLaughlin JK, Olsen JH.2001. Urinary concentrations of trichloroacetic acid in Danish workers exposed to trichloroethylene, 1947-1985. Am J Ind Med. 39(3):320-327. 10.1002/1097-0274(200103)39:3<320:AID-AJIM1020>3.0.CO;2-8
Raaschou-Nielsen O, Hansen J, McLaughlin JK, Kolstad H, Christensen JM, Tarone RE, Olsen JH. 2003. Cancer risk among workers at Danish companies using trichloroethylene: A cohort study. Am J Epidemiol. 158(12):1182–1192. 10.1093/aje/kwg282 14652303
Raaschou-Nielsen O, Hansen J, Thomsen BL, Johansen I, Lipworth L, McLaughlin JK, Olsen JH. 2002. Exposure of Danish workers to trichloroethylene, 1947-1989. Appl Occup Environ Hyg. 17(10):693–703. 10.1080/10473220290096186 12363210
Radican L, Blair A, Stewart P, Wartenberg D. 2008. Mortality of aircraft maintenance workers exposed to trichloroethylene and other hydrocarbons and chemicals: Extended follow-up. J Occup Environ Med. 50(11):1306–1319. 10.1097/JOM.0b013e3181845f7f 19001957
Ramdhan DH, Kamijima M, Wang D, Ito Y, Naito H, Yanagiba Y, Hayashi Y, Tanaka N, Aoyama T, Gonzalez FJ, et al. 2010. Differential response to trichloroethylene-induced hepatosteatosis in wild-type and PPARalpha-humanized mice. Environ Health Perspect. 118(11):1557–1563. 10.1289/ehp.1001928 20709644
Rasmussen K, Sabroe S, Wohlert M, Ingerslev HJ, Kappel B, Nielsen J. 1988. A genotoxic study of metal workers exposed to trichloroethylene. Sperm parameters and chromosome aberrations in lymphocytes. Int Arch Occup Environ Health. 60(6):419–423. 10.1007/BF00381389 3410552
Ravel G, Christ M, Perron-Lepage MF, Condevaux F, Descotes J. 2004. Trichloroethylene does not Accelerate autoimmune diabetes in NOD mice. J Immunotoxicol. 1(3):141–148. 18958647
Ripp SL, Itagaki K, Philpot RM, Elfarra AA. 1999. Species and sex differences in expression of flavin-containing monooxygenase form 3 in liver and kidney microsomes. Drug Metab Dispos. 27(1):46–52. 9884308
Ritz B. 1999. Cancer mortality among workers exposed to chemicals during uranium processing. J Occup Environ Med. 41(7):556–566. 10.1097/00043764-199907000-00004 10412097
Ritz B, Morgenstern H, Froines J, Moncau J. 1999. Chemical exposures of rocket-engine test-stand personnel and cancer mortality in a cohort of aerospace workers. J Occup Environ Med. 41(10):903–910. 10.1097/00043764-199910000-00011 10529946
Robbiano L, Baroni D, Carrozzino R, Mereto E, Brambilla G. 2004. DNA damage and micronuclei induced in rat and human kidney cells by six chemicals carcinogenic to the rat kidney. Toxicology. 204(2-3):187–195. 10.1016/j.tox.2004.06.057 15388244
Roldan-Arjona T, Garcia-Pedrajas MD, Luque-Romero FL, Hera C, Pueyo C. 1991. An association between mutagenicity of the Ara test of Salmonella typhimurium and carcinogenicity in rodents for 16 halogenated aliphatic hydrocarbons. Mutagenesis. 6(3):199–205. 10.1093/mutage/6.3.199 1881351
Rossi AM, Migliore L, Barale R, Loprieno N.1983. In vivo and in vitro mutagenicity studies of a possible carcinogen, trichloroethylene, and its two stabilizers, epichlorohydrin and 1,2-epoxybutane. Teratog Carcinog Mutagen. 3(1):75-87. 10.1002/1520-6866(1990)3:1<75:AID-TCM1770030109>3.0.CO;2-5
Rothman N, Skibola CF, Wang SS, Morgan G, Lan Q, Smith MT, Spinelli JJ, Willett E, De Sanjose S, Cocco P, et al. 2006. Genetic variation in TNF and IL10 and risk of non-Hodgkin lymphoma: A report from the InterLymph Consortium. Lancet Oncol. 7(1):27–38. 10.1016/S1470-2045(05)70434-4 16389181
Russo A, Levis AG. 1992. Further evidence for the aneuploidogenic properties of chelating agents: Induction of micronuclei in mouse male germ cells by EDTA. Environ Mol Mutagen. 19(2):125–131. 10.1002/em.2850190206 1541253
Russo A, Pacchierotti F, Metalli P. 1984. Nondisjunction induced in mouse spermatogenesis by chloral hydrate, a metabolite of trichloroethylene. Environ Mutagen. 6(5):695–703. 10.1002/em.2860060507 6479114
Russo A, Stocco A, Majone F. 1992. Identification of kinetochore-containing (CREST+) micronuclei in mouse bone marrow erythrocytes. Mutagenesis. 7(3):195–197. 10.1093/mutage/7.3.195 1602974
Rusyn I, Chiu WA, Lash LH, Kromhout H, Hansen J, Guyton KZ. 2014. Trichloroethylene: Mechanistic, epidemiologic and other supporting evidence of carcinogenic hazard. Pharmacol Ther. 141(1):55–68. 10.1016/j.pharmthera.2013.08.004 23973663
Sanders VM, Tucker AN, White KL, Kauffmann BM, Hallett P, Carchman RA, Borzelleca JF, Munson AE. 1982. Humoral and cell-mediated immune status in mice exposed to ttrichloroethylene in the drinking water. Toxicol Appl Pharmacol. 62:358–368. 10.1016/0041-008X(82)90138-7 7071855
Sano Y, Nakashima H, Yoshioka N, Etho N, Nomiyama T, Nishiwaki Y, Takebayashi T, Oame K. 2009. Trichloroethylene liver toxicity in mouse and rat: Microarray analysis reveals species differences in gene expression. Arch Toxicol. 83(9):835–849. 10.1007/s00204-009-0431-1 19448997
Schultz IR, Merdink JL, Gonzalez-Leon A, Bull RJ. 2002. Dichloroacetate toxicokinetics and disruption of tyrosine catabolism in B6C3F1 mice: Dose-response relationships and age as a modifying factor. Toxicology. 173(3):229–247. 10.1016/S0300-483X(02)00034-3 11960676
Scott CS, Jinot J. 2011. Trichloroethylene and cancer: Systematic and quantitative review of epidemiologic evidence for identifying hazards. Int J Environ Res Public Health. 8(11):4238–4272. 10.3390/ijerph8114238 22163205
Seidler A, Mohner M, Berger J, Mester B, Deeg E, Elsner G, Nieters A, Becker N. 2007. Solvent exposure and malignant lymphoma: A population-based case-control study in Germany. J Occup Med Toxicol. 2:1–11. 10.1186/1745-6673-2-2 17261183
Seiji K, Jin C, Watanabe T, Nakatsuka H, Ikeda M. 1990. Sister chromatid exchanges in peripheral lymphocytes of workers exposed to benzene, trichloroethylene, or tetrachloroethylene, with reference to smoking habits. Int Arch Occup Environ Health. 62(2):171–176. 10.1007/BF00383594 2323835
Seldén A, Ahlborg G Jr. 1991. Mortality and cancer morbidity after exposure to military aircraft fuel. Aviat Space Environ Med. 62(8):789–794. 1930063
Selgrade MK, Gilmour MI. 2010. Suppression of pulmonary host defenses and enhanced susceptibility to respiratory bacterial infection in mice following inhalation exposure to trichloroethylene and chloroform. J Immunotoxicol. 7(4):350–356. 10.3109/1547691X.2010.520139 20925451
Shelby MD, Erexson GL, Hook GJ, Tice RR. 1993. Evaluation of a three-exposure mouse bone marrow micronucleus protocol: Results with 49 chemicals. Environ Mol Mutagen. 21(2):160–179. 10.1002/em.2850210210 8444144
Shimada T, Swanson AF, Leber P, Williams GM. 1985. Activities of chlorinated ethane and ethylene compounds in the Salmonella/rat microsome mutagenesis and rat hepatocyte/DNA repair assays under vapor phase exposure conditions. Cell Biol Toxicol. 1(3):159–179. 10.1007/BF00120162 3917197
Shirai N, Ohtsuji M, Hagiwara K, Tomisawa H, Ohtsuji N, Hirose S, Hagiwara H. 2012. Nephrotoxic effect of subchronic exposure to S-(1,2-dichlorovinyl)-L-cysteine in mice. J Toxicol Sci. 37(5):871–878. 10.2131/jts.37.871 23037997
Siemiatycki J. 1991. Risk Factors for Cancer in the Workplace. Boca Raton, FL: CRC Press.
Silver SR, Pinkerton LE, Fleming DA, Jones JH, Allee S, Luo L, Bertke SJ. 2014. Retrospective cohort study of a microelectronics and business machine facility. Am J Ind Med. 57(4):412–424. 10.1002/ajim.22288 24375784
Simmon V, Kauhanen K, Tardiff R. 1977. Mutagenic activity of chemicals identified in drinking water. Progress in Genetic Toxicology. New York, Amsterdam: Elsevier/North Holland Press; p. 249–268.
Sinks T, Lushniak B, Haussler BJ, Sniezek J, Deng JF, Roper P, Dill P, Coates R. 1992. Renal cell cancer among paperboard printing workers. Epidemiology. 3(6):483–489. 10.1097/00001648-199211000-00004 1420513
Slacik-Erben R, Roll R, Franke G, Uehleke H. 1980. Trichloroethylene vapours do not produce dominant lethal mutations in male mice. Arch Toxicol. 45(1):37–44. 10.1007/BF00303293 6893145
Sofuni T, Hayashi M, Matsuoka A, Sawada M, Hatanaka M, Ishidate M Jr. 1985. [Mutagenicity tests on organic chemical contaminants in city water and related compounds. II. Chromosome aberration tests in cultured mammalian cells]. Eisei Shikenjo Hokoku.(103):64–75. 3830315
Sora S, Agostini Carbone ML. 1987. Chloral hydrate, methylmercury hydroxide and ethidium bromide affect chromosomal segregation during meiosis of Saccharomyces cerevisiae. Mutat Res. 190(1):13–17. 10.1016/0165-7992(87)90075-3 3540660
Souček B, Vlachová D. 1960. Excretion of trichloroethylene metabolites in human urine. Br J Ind Med. 17:60–64. 10.1136/oem.17.1.60 13832993
Spirtas R, Stewart PA, Lee JS, Marano DE, Forbes CD, Grauman DJ, Pettigrew HM, Blair A, Hoover RN, Cohen JL. 1991. Retrospective cohort mortality study of workers at an aircraft maintenance facility. I. Epidemiological results. Br J Ind Med. 48(8):515–530. 10.1136/oem.48.8.515 1878308
Stacpoole PW. 2011. The dichloroacetate dilemma: Environmental hazard versus therapeutic goldmine—both or neither? Environ Health Perspect. 119(2):155–158. 10.1289/ehp.1002554 20920954
Stacpoole PW, Kurtz TL, Han Z, Langaee T. 2008. Role of dichloroacetate in the treatment of genetic mitochondrial diseases. Adv Drug Deliv Rev. 60(13-14):1478–1487. 10.1016/j.addr.2008.02.014 18647626
Stat Fact Sheets SEER.Kidney and Renal Pelvis Cancer. 2014a. National Cancer Institute; [accessed Accessed on 10/21/14]. https://seer.cancer.gov/statfacts/html/kidrp.html
Stat Fact Sheets SEER.Liver and Intrahepatic Bile Duct Cancer. 2014b. National Cancer Institute; [accessed Accessed on 10/22/14]. https://seer.cancer.gov/statfacts/html/livibd.html
Stat Fact Sheets SEER.Myeloma. 2014c. National Cancer Institute; [accessed Accessed on 10/21/14]. https://seer.cancer.gov/statfacts/html/mulmy.html
Stat Fact Sheets SEER.Non-Hodgkin Lymphoma. 2014d. National Cancer Institute; [accessed Accessed on 10/21/14]. https://seer.cancer.gov/statfacts/html/nhl.html
Stevens JL, Hatzinger PB, Hayden PJ. 1989. Quantitation of multiple pathways for the metabolism of nephrotoxic cysteine conjugates using selective inhibitors of L-alpha-hydroxy acid oxidase (L-amino acid oxidase) and cysteine conjugate beta-lyase. Drug Metab Dispos. 17(3):297–303. 2568912
Stewart PA, Lee JS, Marano DE, Spirtas R, Forbes CD, Blair A. 1991. Retrospective cohort mortality study of workers at an aircraft maintenance facility. II. Exposures and their assessment. Br J Ind Med. 48(8):531–537. 10.1136/oem.48.8.531 1878309
Storchova Z, Kuffer C. 2008. The consequences of tetraploidy and aneuploidy. J Cell Sci. 121(Pt 23):3859–3866. 10.1242/jcs.039537 19020304
Stott WT, Quast JF, Watanabe PG. 1982. The pharmacokinetics and macromolecular interactions of trichloroethylene in mice and rats. Toxicol Appl Pharmacol. 62(1):137–151. 10.1016/0041-008X(82)90110-7 7064149
Styles JA, Wyatt I, Coutts C. 1991. Trichloroacetic acid: Studies on uptake and effects on hepatic DNA and liver growth in mouse. Carcinogenesis. 12(9):1715–1719. 10.1093/carcin/12.9.1715 1893532
Sweeney C, Farrow DC, Schwartz SM, Eaton DL, Checkoway H, Vaughan TL. 2000. Glutathione S-transferase M1, T1, and P1 polymorphisms as risk factors for renal cell carcinoma: A case-control study. Cancer Epidemiol Biomarkers Prev. 9(4):449–454. 10794492
Swenberg JA, Lehman-McKeeman LD. 1999. alpha 2-Urinary globulin-associated nephropathy as a mechanism of renal tubule cell carcinogenesis in male rats. IARC Sci Publ.(147):95–118. 10457913
Tabrez S, Ahmad M. 2009. Toxicity, biomarkers, genotoxicity, and carcinogenicity of trichloroethylene and its metabolites: A review. J Environ Sci Health Part C Environ Carcinog Ecotoxicol Rev. 27(3):178–196. 10.1080/10590500903091340 19657920
Tabrez S, Ahmad M. 2012. Genotoxicity of trichloroethylene in the natural milieu. Int J Hyg Environ Health. 215(3):333–338. 10.1016/j.ijheh.2011.08.004 21920816
Tabrez S, Ahmad M. 2013. Cytochrome P450 system as potential biomarkers of certain toxicants: Comparison between plant and animal models. Environ Monit Assess. 185(4):2977–2987. 10.1007/s10661-012-2765-z 22773083
Tan TT, Coussens LM. 2007. Humoral immunity, inflammation and cancer. Curr Opin Immunol. 19(2):209–216. 10.1016/j.coi.2007.01.001 17276050
Tang X, Que B, Song X, Li S, Yang X, Wang H, Huang H, Kamijima M, Nakajima T, Lin Y, et al. 2008. Characterization of liver injury associated with hypersensitive skin reactions induced by trichloroethylene in the guinea pig maximization test. J Occup Health. 50(2):114–121. 10.1539/joh.L7114 18403861
Tanguay RM, Jorquera R, Poudrier J, St-Louis M. 1996. Tyrosine and its catabolites: From disease to cancer. Acta Biochim Pol. 43(1):209–216. 10.18388/abp.1996_4530 8790725
Tola S, Vilhunen R, Jarvinen E, Korkala ML. 1980. A cohort study on workers exposed to trichloroethylene. J Occup Med. 22(11):737–740. 7441393
Toraason M, Clark J, Dankovic D, Mathias P, Skaggs S, Walker C, Werren D. 1999. Oxidative stress and DNA damage in Fischer rats following acute exposure to trichloroethylene or perchloroethylene. Toxicology. 138(1):43–53. 10.1016/S0300-483X(99)00083-9 10566590
Tu AS, Murray TA, Hatch KM, Sivak A, Milman HA. 1985. In vitro transformation of BALB/c-3T3 cells by chlorinated ethanes and ethylenes. Cancer Lett. 28(1):85–92. 10.1016/0304-3835(85)90096-5 4027960
U.S. Environmental Protection Agency (USEPA).2006. Approaches for the application of physiologically based pharmacokinetic (PBPK) models and supporting data in risk assessment. Washington, D.C.: U.S. Environmental Protection Agency. EPA/600/R-05/043F
U.S. Environmental Protection Agency (USEPA).2011a. Toxicological review of trichloroethylene (CAS No. 79-01-6) in support of summary information on the integrated risk information system (IRIS). U.S. Environmental Protection Agency. EPA/635/R-09/011F
U.S. Environmental Protection Agency (USEPA).2011b. Toxicological review of trichloroethylene appendices (CAS No. 79-01-6) in support of summary information on the integrated risk information system (IRIS). U.S. Environmental Protection Agency. EPA/635/R-09/011F
U.S. Environmental Protection Agency (USEPA).2014. Trichloroethylene: Degreasing, spot cleaning and arts & crafts uses. U.S. Environmental Protection Agency. EPA Document #740-R1-4002
Vamvakas S, Brüning T, Thomasson B, Lammert M, Baumüller A, Bolt HM, Dekant W, Birner G, Henschler D, Ulm K. 1998. Renal cell cancer correlated with occupational exposure to trichloroethene. J Cancer Res Clin Oncol. 124(7):374–382. 10.1007/s004320050186 9719500
Vamvakas S, Dekant W, Berthold K, Schmidt S, Wild D, Henschler D. 1987. Enzymatic transformation of mercapturic acids derived from halogenated alkenes to reactive and mutagenic intermediates. Biochem Pharmacol. 36(17):2741–2748. 10.1016/0006-2952(87)90258-9 3307787
Vamvakas S, Dekant W, Henschler D. 1989. Assessment of unscheduled DNA synthesis in a cultured line of renal epithelial cells exposed to cysteine S-conjugates of haloalkenes and haloalkanes. Mutat Res. 222(4):329–335. 10.1016/0165-1218(89)90108-0 2704384
Vamvakas S, Dekant W, Schiffmann D, Henschler D. 1988 a. Induction of unscheduled DNA synthesis and micronucleus formation in Syrian hamster embryo fibroblasts treated with cysteine S-conjugates of chlorinated hydrocarbons. Cell Biol Toxicol. 4(4):393–403. 10.1007/BF00117768 3228710
Vamvakas S, Elfarra AA, Dekant W, Henschler D, Anders MW. 1988 b. Mutagenicity of amino acid and glutathione S-conjugates in the Ames test. Mutat Res. 206(1):83–90. 10.1016/0165-1218(88)90144-9 2901035
Vamvakas S, Richter H, Bittner D. 1996. Induction of dedifferentiated clones of LLC-PK1 cells upon long-term exposure to dichlorovinylcysteine. Toxicology. 106(1-3):65–74. 10.1016/0300-483X(95)03166-D 8571403
Varshney M, Chandra A, Chauhan LK, Goel SK. 2013 a. In vitro cytogenetic assessment of trichloroacetic acid in human peripheral blood lymphocytes. Environ Sci Pollut Res Int. 23812791
Varshney M, Chandra A, Chauhan LK, Goel SK.2013b. Micronucleus induction by oxidative metabolites of trichloroethylene in cultured human peripheral blood lymphocytes: A comparative genotoxicity study. Environ Sci Pollut Res Int. 10.1007/s11356-013-1806-7
Vermeulen R, Hosnijeh FS, Portengen L, Krogh V, Palli D, Panico S, Tumino R, Sacredote C, Purdue M, Lan Q, et al. 2011. Circulating soluble CD30 and future risk of lymphoma; evidence from two prospective studies in the general population. Cancer Epidemiol Biomarkers Prev. 20(9):1925–1927. 10.1158/1055-9965.EPI-11-0396 21784955
Vermeulen R, Zhang L, Spierenburg A, Tang X, Bonventre JV, Reiss B, Shen M, Smith MT, Qiu C, Ge Y, et al. 2012. Elevated urinary levels of kidney injury molecule-1 among Chinese factory workers exposed to trichloroethylene. Carcinogenesis. 33(8):1538–1541. 10.1093/carcin/bgs191 22665366
Vlaanderen J, Straif K, Pukkala E, Kauppinen T, Kyyrönen P, Martinsen JI, Kjaerheim K, Tryggvadottir L, Hansen J, Sparén P, et al. 2013. Occupational exposure to trichloroethylene and perchloroethylene and the risk of lymphoma, liver, and kidney cancer in four Nordic countries. Occup Environ Med. 70(6):393–401. 10.1136/oemed-2012-101188 23447073
von der Hude W, Behm C, Gurtler R, Basler A. 1988. Evaluation of the SOS chromotest. Mutat Res. 203(2):81–94. 10.1016/0165-1161(88)90023-4 3280989
Von Tungeln LS, Yi P, Bucci TJ, Samokyszyn VM, Chou MW, Kadlubar FF, Fu PP. 2002. Tumorigenicity of chloral hydrate, trichloroacetic acid, trichloroethanol, malondialdehyde, 4 hydroxy-2-nonenal, crotonaldehyde, and acrolein in the B6C3F1 neonatal mouse. Cancer Lett. 185:13–19. 10.1016/S0304-3835(02)00231-8 12142074
Walles SA. 1986. Induction of single-strand breaks in DNA of mice by trichloroethylene and tetrachloroethylene. Toxicol Lett. 31(1):31–35. 10.1016/0378-4274(86)90191-8 3715914
Wang G, Ansari GA, Khan MF. 2007 a. Involvement of lipid peroxidation-derived aldehyde-protein adducts in autoimmunity mediated by trichloroethene. J Toxicol Environ Health A. 70(23):1977–1985. 10.1080/15287390701550888 17966069
Wang G, Cai P, Ansari GA, Khan MF. 2007 b. Oxidative and nitrosative stress in trichloroethene-mediated autoimmune response. Toxicology. 229(3):186–193. 10.1016/j.tox.2006.10.014 17123686
Wang G, Hou J, Ma L, Xie J, Yin J, Xu D, Chang W, Tan X, Su T, Zhang H, et al. 2012 a. Risk factor for clear cell renal cell carcinoma in Chinese population: A case-control study. Cancer Epidemiol. 36(2):177–182. 10.1016/j.canep.2011.09.006 22000673
Wang G, Konig R, Ansari GA, Khan MF. 2008. Lipid peroxidation-derived aldehyde-protein adducts contribute to trichloroethene-mediated autoimmunity via activation of CD4+ T cells. Free Radic Biol Med. 44(7):1475–1482. 10.1016/j.freeradbiomed.2008.01.012 18267128
Wang G, Wang J, Fan X, Ansari GA, Khan MF. 2012 b. Protein adducts of malondialdehyde and 4-hydroxynonenal contribute to trichloroethene-mediated autoimmunity via activating Th17 cells: Dose- and time-response studies in female MRL+/+ mice. Toxicology. 292(2-3):113–122. 10.1016/j.tox.2011.12.001 22178267
Wang G, Wang J, Ma H, Ansari GA, Khan MF. 2013. N-Acetylcysteine protects against trichloroethene-mediated autoimmunity by attenuating oxidative stress. Toxicol Appl Pharmacol. 273(1):189–195. 10.1016/j.taap.2013.08.020 23993974
Wang G, Wang J, Ma H, Khan MF. 2009 a. Increased nitration and carbonylation of proteins in MRL+/+ mice exposed to trichloroethene: Potential role of protein oxidation in autoimmunity. Toxicol Appl Pharmacol. 237(2):188–195. 10.1016/j.taap.2009.03.010 19332086
Wang GD, Li H, Khan MF. 2012 c. Differential oxidative modification of proteins in MRL+/+ and MRL/lpr mice: Increased formation of lipid peroxidation-derived aldehyde-protein adducts may contribute to accelerated onset of autoimmune response. Free Radic Res. 46(12):1472–1481. 10.3109/10715762.2012.727209 22950782
Wang JL, Chen WL, Tsai SY, Sung PY, Huang RN. 2001. An in vitro model for evaluation of vaporous toxicity of trichloroethylene and tetrachloroethylene to CHO-K1 cells. Chem Biol Interact. 137(2):139–154. 10.1016/S0009-2797(01)00226-5 11551530
Wang KK, Czaja AJ. 1988. Hepatocellular carcinoma in corticosteroid-treated severe autoimmune chronic active hepatitis. Hepatology. 8(6):1679–1683. 10.1002/hep.1840080635 2461338
Wang R, Zhang YW, Lan Q, Holford TR, Leaderer B, Zahm SH, Boyle P, Dosemeci M, Rothman N, Zhu Y, et al. 2009 b. Occupational exposure to solvents and risk of non-Hodgkin lymphoma in Connecticut women. Am J Epidemiol. 169(2):176–185. 10.1093/aje/kwn300 19056833
Wang SS, Cozen W, Cerhan JR, Colt JS, Morton LM, Engels EA, Davis S, Severson RK, Rothman N, Chanock SJ, et al. 2007 c. Immune mechanisms in non-Hodgkin lymphoma: Joint effects of the TNF G308A and IL10 T3575A polymorphisms with non-Hodgkin lymphoma risk factors. Cancer Res. 67(10):5042–5054. 10.1158/0008-5472.CAN-06-4752 17510437
Wartenberg D, Reyner D.2000. TCE Meta-Analyses: Wartenberg et al.'s Response. Environ Health Perspect. 108(12):A543-A544. 10.1289/ehp.108-a543
Wartenberg D, Reyner D, Scott CS. 2000. Trichloroethylene and cancer: Epidemiologic evidence. Environ Health Perspect. 108 Suppl 2:161–176. 10.1289/ehp.00108s2161 10807550
Waskell L. 1978. A study of the mutagenicity of anesthetics and their metabolites. Mutat Res. 57(2):141–153. 10.1016/0027-5107(78)90261-0 351387
Watanabe H. 2011. Hypersensitivity syndrome due to trichloroethylene exposure: A severe generalized skin reaction resembling drug-induced hypersensitivity syndrome. J Dermatol. 38(3):229–235. 10.1111/j.1346-8138.2010.01155.x 21342224
Watanabe T, Soga K, Hirono H, Hasegawa K, Shibasaki K, Kawai H, Aoyagi Y. 2009. Features of hepatocellular carcinoma in cases with autoimmune hepatitis and primary biliary cirrhosis. World J Gastroenterol. 15(2):231–239. 10.3748/wjg.15.231 19132775
Weinhold B. 2009. A clearer view of TCE: Evidence supports autoimmune link. Environ Health Perspect. 117(5):A210. 10.1289/ehp.117-a210a 19478988
White AE, Takehisa S, Eger EI 2nd, Wolff S, Stevens WC. 1979. Sister chromatid exchanges induced by inhaled anesthetics. Anesthesiology. 50(5):426–430. 10.1097/00000542-197905000-00010 453561
Wiesenhutter B, Selinski S, Golka K, Bruning T, Bolt HM. 2007. Re-assessment of the influence of polymorphisms of phase-II metabolic enzymes on renal cell cancer risk of trichloroethylene-exposed workers. Int Arch Occup Environ Health. 81(2):247–251. 10.1007/s00420-007-0200-5 17479278
Wilcosky TC, Checkoway H, Marshall EG, Tyroler HA. 1984. Cancer mortality and solvent exposures in the rubber industry. Am Ind Hyg Assoc J. 45(12):809–811. 10.1080/15298668491400683 6549104
Williams GM, Mori H, McQueen CA. 1989. Structure-activity relationships in the rat hepatocyte DNA-repair test for 300 chemicals. Mutat Res. 221(3):263–286. 10.1016/0165-1110(89)90039-0 2682231
Wilmer JW, Spencer PJ, Ball N, Bus JS. 2014. Assessment of the genotoxicity of trichloroethylene in the in vivo micronucleus assay by inhalation exposure. Mutagenesis. 29(3):209–214. 10.1093/mutage/geu006 24618993
Wong O, Morgan R.1990. Final report: Historical prospective mortality study of Hughes Aircraft employment at Air Force Plant, no. 44. Alameda, CA: ENSR Health Sciences.
Wright PF, Thomas WD, Stacey NH. 1991. Effects of trichloroethylene on hepatic and splenic lymphocytotoxic activities in rodents. Toxicology. 70(2):231–242. 10.1016/0300-483X(91)90049-7 1763417
Wu Y, Antony S, Meitzler JL, Doroshow JH. 2013. Molecular mechanisms underlying chronic inflammation-associated cancers. Cancer Lett. 23988267
Xu F, Papanayotou I, Putt DA, Wang J, Lash LH. 2008. Role of mitochondrial dysfunction in cellular responses to S-(1,2-dichlorovinyl)-L-cysteine in primary cultures of human proximal tubular cells. Biochem Pharmacol. 76(4):552–567. 10.1016/j.bcp.2008.05.016 18602084
Xu W, Adler ID. 1990. Clastogenic effects of known and suspect spindle poisons studied by chromosome analysis in mouse bone marrow cells. Mutagenesis. 5(4):371–374. 10.1093/mutage/5.4.371 2398818
Yang X, Long S, Deng J, Deng T, Gong Z, Hao P. 2013. Glutathione S-transferase polymorphisms (GSTM1, GSTT1 and GSTP1) and their susceptibility to renal cell carcinoma: An evidence-based meta-analysis. PLoS One. 8(5):e63827. 10.1371/journal.pone.0063827 23717494
Yaqoob N, Evans A, Foster JR, Lock EA. 2014. Trichloroethylene and trichloroethanol-induced formic aciduria and renal injury in male F-344 rats following 12 weeks exposure. Toxicology. Forthcoming. 10.1016/j.tox.2014.06.004 24923549
Yaqoob N, Evans AR, Lock EA. 2013. Trichloroethylene-induced formic aciduria: Effect of dose, sex and strain of rat. Toxicology. 304:49–56. 10.1016/j.tox.2012.11.014 23211455
Yiin JH, Anderson JL, Daniels RD, Seel EA, Fleming DA, Waters KM, Chen PH. 2009. A nested case-control study of multiple myeloma risk and uranium exposure among workers at the Oak Ridge gaseous diffusion plant. Radiat Res. 171(6):637–645. 10.1667/RR1607.1 19580470
Zahm SH. 1992. Computerized Occupational Referent Population System (CORPS): Study documentation. Rockville, MD: National Cancer Institute, National Institute for Occupational Safety and Health.
Zhang JQ, Wan YN, Peng WJ, Yan JW, Li BZ, Mei B, Chen B, Yao H, Yang GJ, Tao JH, et al. 2013 a. The risk of cancer development in systemic sclerosis: A meta-analysis. Cancer Epidemiol. 37(5):523–527. 10.1016/j.canep.2013.04.014 23725641
Zhang L, Bassig BA, Mora JL, Vermeulen R, Ge Y, Curry JD, Hu W, Shen M, Qiu C, Ji Z, et al. 2013 b. Alterations in serum immunoglobulin levels in workers occupationally exposed to trichloroethylene. Carcinogenesis. 34(4):799–802. 10.1093/carcin/bgs403 23276795
Zhang L, Xu L, Zeng Q, Zhang SH, Xie H, Liu AL, Lu WQ. 2012. Comparison of DNA damage in human-derived hepatoma line (HepG2) exposed to the fifteen drinking water disinfection byproducts using the single cell gel electrophoresis assay. Mutat Res. 741(1-2):89–94. 10.1016/j.mrgentox.2011.11.004 22108252
Zhang SH, Chen Z, Liao J, Wei W, Liu AL, Lu WQ. 2010. [Application of two assays for damage assessment of damage caused by drinking water disinfection by-products in HepG2 cells]. Zhongguo Huanjing Kexue. 30(2):275–278.
Zhao Y, Krishnadasan A, Kennedy N, Morgenstern H, Ritz B. 2005. Estimated effects of solvents and mineral oils on cancer incidence and mortality in a cohort of aerospace workers. Am J Ind Med. 48(4):249–258. 10.1002/ajim.20216 16167347
Zordan M, Osti M, Pesce M, Costa R. 1994. Chloral hydrate is recombinogenic in the wing spot test in Drosophila melanogaster. Mutat Res. 322(2):111–116. 10.1016/0165-1218(94)00017-4 7519317