# Introduction

Trichloroethylene has been listed in the Report on Carcinogens (RoC) as reasonably anticipated to be a human carcinogen since 2000 based on limited evidence of carcinogenicity from studies in humans and sufficient evidence of carcinogenicity from studies in experimental animals. Since that time, several cancer studies in humans have been published in the peer-reviewed literature, and the International Agency for Research on Cancer (2014) has concluded that trichloroethylene is carcinogenic to humans (Group 1). Trichloroethylene has been selected as a candidate substance for review for possible change in listing status in the RoC based on evidence of exposure to a significant number of persons residing in the United States and an adequate database of cancer studies.

Trichloroethylene (TCE, CASRN 79-01-6) is a volatile, chlorinated alkene used mainly as an intermediate for hydrofluorocarbon production and as a degreaser for metal parts (USEPA 2014), although its use as a degreaser has decreased in the United States since the 1970s (Bakke et al. 2007). It also is used as a modifier for polyvinyl chloride polymerization and in clear protective spray coatings for use by arts and craft hobbyists. Past uses of trichloroethylene include use as a solvent in the rubber industry, adhesive formulations, dyeing and finishing operations, printing inks, paints, lacquers, varnishes, adhesives, and paint strippers; in the production of agricultural chemicals such as fungicides and insecticides; as an extraction solvent to remove natural fats and oils from plant materials, to manufacture flavoring extracts from spices and hops, and to decaffeinate coffee; and as an anesthetic and analgesic in obstetrics and for minor surgical procedures.

A significant number of people living in the United States are or have been exposed to trichloroethylene because of its widespread presence in the environment from past and present use, particularly in some drinking-water supplies, and in the workplace. Due to its volatility, the principal route of exposure is through inhalation although absorption from dermal and oral exposure also occurs. Exposure has been documented by direct measurements of trichloroethylene in ambient air in the general environment and in workplaces where it is used. The presence of trichloroethylene in groundwater and drinking-water supplies near sites of past use of trichloroethylene has also been confirmed. Additional information on occupational and environmental exposure to trichloroethylene is described in RoC substance profile (https://ntp.niehs.nih.gov/ntp/roc/content/profiles/trichloroethylene.pdf).

## Chemical and Physical Properties

Trichloroethylene (Figure 1) is a chlorinated alkene. Table 1 contains some chemical identification information for trichloroethylene.

Figure 1

Chemical Structure of Trichloroethylene

Table 1 Chemical Identification of Trichloroethylene

Characteristic | Information
Chemical Abstracts index name | 1,1,2-Trichloroethene
CAS Registry number | 79-01-6
Molecular formula | C_2_HCl_3_
Synonyms | TCE; TRI; 1,1,2-trichloroethylene; trichloroethene; ethylene trichloride; acetylene trichloride

Source: HSDB (2012), IARC (2014).

Trichloroethylene exists at room temperature as a clear, colorless, nonflammable liquid with an ethereal odor. It is slightly soluble in water, soluble in ethanol, acetone, diethyl ether, and chloroform, and miscible in oil. Trichloroethylene evaporates easily (Dow 2008). It is relatively stable, but oxidizes slowly when exposed to sunlight in air (IARC 1976). Physical and chemical properties of trichloroethylene are listed in Table 2.

Table 2 Physical and Chemical Properties of Trichloroethylene

Property | Information
Molecular weight | 131.4
Specific gravity | 1.4642 at 20°C/4°C
Melting point | −84.7°C
Boiling point | 87.2°C
Log K_ow_ | 2.61
Water solubility | 1.28 g/L at 25°C
Vapor pressure | 69 mm Hg at 25°C
Vapor density relative to air (air = 1) | 4.53

Source: HSDB (2012).