# Appendix F Mechanisms of Action Tables

Table F-1 Superoxide Anion Production in Male B6C3F_1_ Mice Administered Acute, Subacute, and Subchronic Doses of Dichloroacetic Acid or Trichloroacetic Acid

Compound | Dose (mg/kg/day) | Time | PLCs^a^ | Liver^a^ | Reference
Dichloroacetic acid | 300 (single dose) | 6 hr 12 hr | 1.5* 1.4* | 1.4* INS | Hassoun and Dey (2008)
Dichloroacetic acid | 7.7 77 154 410 | 4 wk | INS 1.8* 2.5* 3.7* | 1.2* 2.5* 4.0* 4.3* | Hassoun and Cearfoss (2011); Hassoun et al. (2010a); Hassoun et al. (2010b)
Dichloroacetic acid | 7.7 77 154 410 | 13 wk | 1.8* 2.4* 2.1* INS | 1.4* 3.2* 4.3* 2.2* | Hassoun and Cearfoss (2011); Hassoun et al. (2010a); Hassoun et al. (2010b)
Dichloroacetic acid | 7.5 15 30 | 13 wk | 1.8* 2.0* 2.2* | 1.4* 1.9* 2.3* | Hassoun et al. (2013) Hassoun et al. (2014)
Trichloroacetic acid | 300 (single dose) | 6 hr 12 hr | INS 1.5* | INS 1.2* | Hassoun and Dey (2008)
Trichloroacetic acid | 7.7 77 154 410 | 4 wk | INS 1.4* 1.9* 2.5* | INS INS 1.3* 2.8* | Hassoun and Cearfoss (2011); Hassoun et al. (2010a); Hassoun et al. (2010b)
Trichloroacetic acid | 7.7 77 154 410 | 13 wk | INS 2.0* INS INS | 1.2* 1.8* 2.5* 2.8* | Hassoun and Cearfoss (2011); Hassoun et al. (2010a); Hassoun et al. (2010b)
Trichloroacetic acid | 12.5 25 50 | 13 wk | 1.5* 1.6* 1.8* | 1.3* 1.5* 1.7* | Hassoun et al. (2013) Hassoun et al. (2014)
Mixtures | 7.5/12.5^b^ 15/25 30/50 | 13 wk | 2.1* 2.7* 2.6* | 1.7* 2.6* 3.2* | Hassoun et al. (2013) Hassoun et al. (2014)

* p < 0.05.

– = Not measured; INS = insignificant change compared to controls; PLCs = peritoneal lavage cells.

^a^ Superoxide anion production measured as cytochrome c reduced/min/mg protein and expressed as the approximate fold increase over control values (some values estimated from figures).

^b^ Concentration of dichloroacetic acid/trichloroacetic acid in the mixture.

Table F-2 Lipid Peroxidation and DNA Single-strand Breaks in the Liver of Male B6C3F_1_ Mice Administered Dichloroacetic Acid or Trichloroacetic Acid Acutely, Subacutely, and Subchronically

Compound | Dose (mg/kg/day) | Time | LP^a^ | SSBs^a^ | Reference
Dichloroacetic acid | 300 (single dose) | 6 hr 12 hr | 1.3* 1.4* | 2.6* 3.9* | Hassoun and Dey (2008)
Dichloroacetic acid | 7.7 77 154 410 | 4 wk | 2.5* 5.0* 7.5* 14.0* | INS 3.5* 7.2* 7.2* | Hassoun and Cearfoss (2011); Hassoun et al. (2010a)
Dichloroacetic acid | 7.7 77 154 410 | 13 wk | 3.5* 12.5* 15.0* 4.0* | 1.6* 5.6* 5.6* 4.0* | Hassoun and Cearfoss (2011); Hassoun et al. (2010a)
Dichloroacetic acid | 7.5 15 30 | 13 wk | 2.8* 4.0* 7.2* | 1.6* 2.8* 4.0* | Hassoun et al. (2014)
Trichloroacetic acid | 300 (single dose) | 6 hr 12 hr | INS 1.3* | INS 2.8* | Hassoun and Dey (2008)
Trichloroacetic acid | 7.7 77 154 410 | 4 wk | INS 2.0* 2.5* 11.0* | INS 1.8* 2.3* 4.3* | Hassoun and Cearfoss (2011); Hassoun et al. (2010a)
Trichloroacetic acid | 7.7 77 154 410 | 13 wk | 1.5* 7.0* 8.5* 13.5* | INS 2.3* 3.3* 4.3* | Hassoun and Cearfoss (2011); Hassoun et al. (2010a)
Trichloroacetic acid | 12.5 25 50 | 13 wk | 1.6* 2.6* 4.0* | INS 1.6* 2.0* | Hassoun et al. (2014)
Mixture | 7.5/12.5^b^ 15/25 30/50 | 13 wk | 3.2* 6.2* 13* | 1.7* 3.6* 6.2* | Hassoun et al. (2014)

* p < 0.05.

INS = insignificant change compared to controls; LP = lipid peroxidation (measured a nmole TBARS/mg protein and expressed as the approximate fold increase over control values); SSBs = single-strand breaks (alkaline elution technique, data reported as fold increase over control values).

^a^ Data are the ratio of treated/controls (some values estimated from figures).

^b^ Concentration of dichloroacetic acid/trichloroacetic acid in the mixture.

Table F-3 Phagocytic Activation and Antioxidant Enzyme Activity in Peritoneal Lavage Cells from Male B6C3F_1_ Mice Administered Subacute and Subchronic Doses of Dichloroacetic Acid or Trichloroacetic Acid

Compound | Dose (mg/kg/day) | Time | SOD^a^ | MPO^a^ | TNF-α^a^ | Reference
Dichloroacetic acid | 7.7 77 154 410 | 4 wk | INS 2.5* 4.1* 6.5* | 5.0* 4.3* 12.3* 12.3* | INS 2.0* 3.0* 6.8* | Hassoun et al. (2010b)
Dichloroacetic acid | 7.7 77 154 410 | 13 wk | 1.7* 3.7* 4.5* 5.2* | 6.3* 10.8* 9.0* INS | 2.4* 6.2* 5.2* INS | Hassoun et al. (2010b)
Dichloroacetic acid | 7.5 15 30 | 13 wk | – – – | 5.3* 7.8* 9.3* | 2.1* 2.7* 3.3* | Hassoun et al. (2013)
Trichloroacetic acid | 7.7 77 154 410 | 4 wk | INS 2.1* 4.0* 5.0* | 36*^b^ 52*^b^ 66*^b^ 18*^b^ | INS 2.6* 4.3* 11.8* | Hassoun et al. (2010b)
Trichloroacetic acid | 7.7 77 154 410 | 13 wk | 1.7* 2.6* 4.2* 5.2* | 6*^b^ 16*^b^ 4*^b^ INS | INS 3.0* INS INS | Hassoun et al. (2010b)
Trichloroacetic acid | 12.5 25 50 | 13 wk | – – – | 5.7* 7.0* 9.5* | 1.9* 2.2* 2.6* | Hassoun et al. (2013)
Mixtures | 7.5/12.5^b^ 15/25 30/50 | 13 wk | – – – | 9.5* 13.2* 12.5* | 3.1* 4.1* 4.1* | Hassoun et al. (2013)

* p < 0.05.

– = Not measured; INS = insignificant change compared to controls; MPO = myeloperoxidase (units/mg); SOD = superoxide dismutase (units/mg); TNF-α = tumor necrosis factor-alpha (pg/mg).

^a^ Data are the ratio of treated/controls (all values estimated from figures).

^b^ Ratios are highly uncertain because the control levels were very small.

Table F-4 Antioxidant Enzyme Activity in Liver from Male B6C3F_1_ Mice Administered Dichloroacetic Acid or Trichloroacetic Acid Subacutely or Subchronically

Compound | Dose (mg/kg/day) | Time | SOD^a^ | CAT^a^ | GPO^a^ | GSH^a^
Dichloroacetic acid | 7.7 77 154 410 | 4 wk | 0.05* 0.05* 0.1* 0.5* | INS INS INS INS | INS INS INS INS | INS INS INS INS
Dichloroacetic acid | 7.7 77 154 410 | 13 wk | 0.4* 0.4* 2.1* 3.6* | INS INS 1.9* 2.2* | 0.29* 0.29* 1.8* 2.5* | INS 0.73* 0.66* INS
Trichloroacetic acid | 7.7 77 154 410 | 4 wk | 1.3* 1.8* 3.0* 4.9* | INS 1.5* 1.7* 1.9* | 0.34* 0.39* 0.37* 0.42* | INS INS INS INS
Trichloroacetic acid | 7.7 77 154 410 | 13 wk | 2.4* 3.6* 6.4* 8.1* | 1.7* 1.9* 2.3* 2.7* | 0.62* 0.30* 0.20* 0.24* | INS INS INS INS

* p < 0.05.

Source: Hassoun and Cearfoss (2011).

CAT = catalase (units × 10/mg protein); GPO = glutathione peroxidase (nmoles NADPH oxidized/min/mg protein); GSH = total glutathione (nmoles/g tissue); INS = insignificant change compared to controls; SOD = superoxide dismutase (units/mg).

^a^ Data are the ratio of treated/controls (all values estimated from figures).