# Appendix E Immune Effects (Animals)

This section has the tables summarizing the findings of immune effects in experimental animals. It also has tables related to methods, including study design and endpoints measured.

Table E-1 Designs of Studies Evaluated for Trichloroethylene or Metabolite Induced Immunomodulation Relevant to Lymphoma and Liver Cancer

Species | Strain | Route | Chemical | Number of Studies
Mouse | MRL+/+ | Drinking Water | TCE | 12^a^
Mouse | MRL+/+ | Drinking Water | TCA | 1
Mouse | MRL+/+ | Drinking Water | TCAH | 2
Mouse | MRL+/+ | IP | TCE | 5^b^
Mouse | MRL+/+ | IP | DCAA | 1
Mouse | MRL+/+ | IP | DCAC | 3
Mouse | MRL+/+ | SC | Formyl-albumin adduct | 1
Mouse | MRL+/+ | SC | Dichloroacetyl-albumin adduct | 1
Mouse | MRL+/+ | SC | Trichloroethene oxide-albumin adduct | 1
Mouse | MRL+/+ | Inhalation | TCE | 1
Mouse | NOD/Born | Drinking water | TCE | 1
Mouse | NZBWF1 | Drinking water | TCE | 1
Mouse | SV/129 (PPAR-null) | Inhalation | TCE | 1
Mouse | C3H/HeJ | Drinking water | TCAH | 1
Mouse | B6C3F_1_ | Drinking water | TCE | 2
Mouse | B6C3F_1_ | IP | TCE | 1
Mouse | CD-1 | Drinking water | TCE | 1
Mouse | CD-1 | Drinking water | CH | 1
Mouse | CD-1 | Gavage | CH | 1
Mouse | CD-1 | Inhalation | TCE + bacteria | 4
Rat | Sprague-Dawley | IP | TCE | 2
Rat | Sprague-Dawley | Intradermal | TCE | 1
Guinea pig | FMMU | Dermal | TCE | 1
Guinea pig | FMMU | Intradermal | TCE | 2
Dog | Cross-bred | Intratracheal intubation | TCE | 2
Dog | Cross-bred | IV | TCE | 1

TCE = trichloroethylene; TCA = trichloroacetic acid; TCAH = trichloroacetyl hydrate; DCAA = dichloroacetyl chloride; DCAC = dichloroacetyl anhydride; CH = chloral hydrate; SC = subcutaneous injection; IP = intraperitoneal injection; IV = intravenous injection.

^a^ One study had a group co-exposed to diallyl sulfide, a CYP2E1 inhibitor.

^b^ One study had a group co-exposed to N-acetylcysteine, an enhancer of the antioxidant activity of glutathione.

Table E-2 Immunomodulatory Endpoints Relevant to Cancer

Endpoint | + | − | = | +/−
Serum
dichloroacetyl-protein adducts | 1
dichloroacetyl-albumin adducts | 1
dichloroacetyl-CYP2E1 adducts | 1
hydroxynonenal-protein adducts | 2
malondialdehyde-protein adducts | 2
IgG | 6 | 1 | 2
anti-dichloroacetyl-protein adduct antibody | 2 | | 1
anti-dichloroacetyl-albumin adduct antibody | 4^e^ | | 1
anti-formyl-albumin adduct antibody | 3^e^
anti-trichloroethene oxide-albumin adduct antibody | 3^e^
anti-albumin antibody | 3^e^ | | 2
anti-hydroxynonenal-protein adduct antibody | 4^a^
anti-malondialdehyde-protein adduct antibody | 5^a^ | | 1
anti-liver antibody | 1 | | 1
anti-nuclear antibody | 9 | | 3
anti-DNA antibody | 1^a^ | | 2
anti-ssDNA antibody | 6^a^ | | 7^d^
anti-dsDNA antibody | 3^a^ | | 4^d^
anti-sheep RBC IgM response | | | 1 | 1
Peripheral blood
leukocyte number | | 4 | 1
neutrophil number | | 3
lymphocyte number | | 1 | 3
CD4 T-cell number | | 2
CD8 T-cell number | | 1 | 1
B-cell number | | 1
Spleen
lymphocyte number | 2
lymphocyte proliferation | 1
T-cell proliferation | | | 4^d^
CD4 T-cell number | | 2^d^ | 1 | 1^d^
CD4 T-cell proliferation | 2^b^ | | 1^d^
CD8 T-cell number | | 1^d^ | 6^d^
CD8 T-cell proliferation | | | 2^a,d^
B-cell number | | 2^d^ | 5
B-cell proliferation | | | 6^d^
B-cell activation | | | 4^d^
anti-sheep RBC IgM response | 1 | 2^d^
NK cell proliferation | | | 2^d^
NK cell cytolytic activity | | | 3
Splenocytes stimulated with hydroxynonenal-albumin adduct - IFN-gamma | 2
Splenocytes stimulated with malondialdehyde-albumin adduct - IFN-gamma | 2
Splenocytes stimulated with hydroxynonenal-albumin adduct - IL-2 | 2 | | 1
Splenocytes stimulated with malondialdehyde-albumin adduct - IL-2 | 2 | | 1
Lymph node
CD4 T-cell number | | | 5
CD8 T-cell number | | | 4
B-cell number | | | 2
B-cell activation NOS | | | 2
Liver
TCE-protein adduct | 1
dichloroacetyl-protein adducts | 2^b^
dichloroacetyl-CYP2E1 adducts | 1
hydroxynonenal-protein adducts | 2^a^
malondialdehyde-protein adducts | 2^a^
Inflammation | 7^c^ | | 5
T-cell infiltration | 2
NK cell cytolytic activity | | 2
hepatocyte proliferation | 2^c^
Kidney
glomerular antibody deposits | 1
hydroxynonenal-protein adducts | 1^a^
Malondialdehyde-protein adducts | 1^a^
Inflammation | 1 | | 1
Bacterial infection
Death from bacterial infection | 2
Lung - bacterial infection/bacteria clearance | 1 | | | 1
Lung - macrophage phagocytosis of bacteria | | 1

+ = increased effect; − = decreased effect; = = no change in effect; +/− = both increases and decreases in effect were seen depending on dose or time point.

^a^ Prevented by N-acetylcysteine.

^b^ Prevented by diallyl sulfide.

^c^ PPAR^-/-^ had no effect.

^d^ Exposure started before conception.

^e^ Exposed to TCE albumin adducts (formyl-, trichlorethene oxide-, diacetyl-).

The tables below provide study-by-study information on the immune effects of trichloroethylene in experimental animals (see Sections 5.2.2.2 and 6.2.1.5). The designs of 51 studies are reported along with the results of 62 endpoints. The five tables are divided by the endpoints studied (Table E-3. Blood – Adducts and Leukocytes; Table E-4. Blood – Antibodies; Table E-5. Spleen; Table E-6. Liver and Kidney; Table E-7. Splenic Ex Vivo Cytokines, Lymph Node, and Anti-bacterial Response).

Table E-3 Blood – Adducts and Leukocytes

Reference | Design | Dichloroacetyl-protein Adducts | Dichloroacetyl-albumin Adduct | Dichloroacetyl-CYP2E1 Adducts | Hydroxynonenal-protein Adducts | Malondialdehyde-protein Adducts | Leukocyte Number | Neutrophil Number | Lymphocyte Number | CD4 T-cell Number | CD8 T-cell Number | B-cell Number
Trichloroethylene; Mouse (MRL+/+); Drinking water
Wang et al. (2007b) | 48 wk | | | | + | +
Wang et al. (2012a) | 12, 24, 36 wk | | | | + | +
Trichloroethylene; Mice (NOD/Born); Drinking water
Ravel et al. (2004) | 4, 8, 12 wk | | | | | | − | | − | − | − | −
Chloral hydrate; Mice (CD-1); Drinking water
Kauffmann et al. (1982) | 90 d | | | | | | =
Trichloroethylene; Rat (Sprague-Dawley); IP
Halmes et al. (1997) | 4 hr | + | + | +
Chen et al. (2006) | 5, 7 wk | | | | | | | | | − | =
Trichloroethylene; Dog (cross-bred); Intratracheal intubation
Hobara et al. (1984) | 1 hr | | | | | | − | − | =
Hobara et al. (1984) | 1, 4 hr | | | | | | − | − | =
Trichloroethylene; Dog (cross-bred); IV
Hobara et al. (1984) | Single dose | | | | | | − | − | =

+ = increased effect; − = decreased effect; = = no change in effect.

Table E-4 Blood – Antibodies

Reference | Design | IgG | Anti-dichloroacetyl-protein Adduct Antibody | Anti-dichloroacetyl-albumin Adduct Antibody | Anti-formyl-albumin Adduct Antibody | Anti-trichloroethene Oxide-albumin Adduct Antibody | Anti-albumin Antibody | Anti-hydroxynonenal-protein Adduct Antibody | Anti-malondialdehyde-protein Adduct Antibody | Anti-liver Antibody | Anti-nuclear Antibody | Anti-DNA Antibody | Anti-ssDNA Antibody | Anti-dsDNA Antibody | Anti-sheep Red Blood Cell IgM Response
Trichloroethylene; Mice (MRL+/+); Drinking water
Blossom and Doss (2007) | Preconception to 4, 6, 8 wk old | | | | | | | | | | | | =
Cai et al. (2008) | 36, 48 wk | | | | | | | | | | =
Gilbert et al. (2009) | 10, 18, 26 wk | | | | | | | | | +
Gilbert et al. (2011) | 8 wk | | | | | | | | | = | =
Griffin et al. (2000a) | 4, 6, 8, 22 wk | + | + | | | | | | | | +
Griffin et al. (2000c) | 4, 32 wk | | | | | | | | | | +
Wang et al. (2007b) | 48 wk | | | | | | | | | | + | | =
Wang et al. (2012a) | 12, 24, 36 wk | | | | | | | + | + | | + | | +
Trichloroacetic acid; Mice (MRL+/+); Drinking water
Blossom et al. (2004) | 4 wk | | | | | | | | | | | | =
Trichloroacetaldehyde hydrate
Blossom et al. (2004) | 4 wk | | | | | | | | | | | | =
Blossom et al. (2007) | 4, 40 wk | | | | | | | | | | | | = | =
Trichloroethylene; Mice (MRL+/+); IP
Khan et al. (1995) | 6 wk | + | = | | | | | | | | + | = | +
Khan et al. (2001) | 6 wk | | | | | | | | =
Wang et al. (2007a) | 6, 12 wk | | | | | | | + | + | | + | | + | +
Wang et al. (2008) | 4 wk | + | | | | | | + | + | | +
Wang et al. (2013) ^a^ | 6 wk | | | | | | | + | + | | | + | + | +
Dichloroacetyl anhydride; Mice (MRL+/+); IP
Cai et al. (2006) | 6 wk | = | | = | | | = | | | | +
Dichloroacetyl chloride; Mice (MRL+/+); IP
Cai et al. (2006) | 6 wk | + | | + | | | = | | | | +
Khan et al. (1995) | 6 wk | + | + | | | | | | | | = | = | +
Khan et al. (2001) | 2, 4, 6, 8 wk | | | | | | | | +
Trichloroethylene; Mice (MRL+/+); Inhalation
Kaneko et al. (2000) | 4, 6, 8 wk | −
Formyl-albumin adduct; Mice (MRL+/+); SC
Cai et al. (2007b) | 4 wk | | | + | + | + | +
Dichloroacetyl-albumin adduct; Mice (MRL+/+); SC
Cai et al. (2007b) | 4 wk | | | + | + | + | +
Trichloroethene oxide-albumin adduct; Mice (MRL+/+); SC
Cai et al. (2007b) | 4 wk | | | + | + | + | +
Trichloroethylene; Mice (NZBWF1); Drinking water
Keil et al. (2009) | 2, 9, 10, 13, 19, 22, 24, 27 wk | = | | | | | | | | | | | = | =
Trichloroacetaldehyde hydrate; Mice (C3H/HeJ); Drinking water
Blossom et al. (2006) | 4, 40 wk | | | | | | | | | | | | = | =
Trichloroethylene; Mice (B6C3F_1_); Drinking water
Keil et al. (2009) | 30 wk | + | | | | | | | | | | | + | +
Peden-Adams et al. (2006) | Preconception to 3 or 8 wk | | | | | | | | | | | | | =
Trichloroethylene; Mice (CD-1); Drinking water
Sanders et al. (1982) | 4, 6 mo | | | | | | | | | | | | | | +/−
Chloral hydrate; Mice (CD-1); Drinking water
Kauffmann et al. (1982) | 90 d | | | | | | | | | | | | | | =

+ = increased effect; − = decreased effect; = = no change in effect; +/− = both increases and decreases in effect were seen depending on dose or time point.

^a^ Included a group co-exposed to N-acetylcystine, an enhancer of the antioxidant activity of glutathione, which prevented the results.

Table E-5 Spleen

Reference | Design | Lymphocyte Numbers | Lymphocyte Proliferation | T-cell Proliferation | CD4 T-cell Numbers | CD4 T-cell Proliferation | CD8 T-cell Numbers | CD8 T-cell Proliferation | B-cell Numbers | B-cell Proliferation | B-cell Activation | Anti-sheep Red Blood Cell IgM Response | NK-cell Proliferation | NK-cell Cytolytic Activity
Trichloroethylene; Mice (MRL+/+); Drinking water
Blossom and Doss (2007) | Preconception to 4, 6, 8 wk old | | | | − | | − | | − | | =
Gilbert et al. (2011) | 8 wk | | | | = | | = | | =
Griffin et al. (2000a) | 4, 6, 8, 22 wk | | | | = | | | | | | =
Griffin et al. (2000b) ^a^ | | | | | | +
Peden-Adams et al. (2008) | Preconception to 12 mo | | | | | = | | = | | =
Trichloroacetic acid; Mice (MRL+/+); Drinking water
Blossom et al. (2004) | 4 wk | | | | = | | = | | = | | =
Trichloroacetaldehyde hydrate; Mice (MRL+/+); Drinking water
Blossom et al. (2004) | 4 wk | | | | = | | = | | = | | =
Blossom et al. (2007) | 4, 40 wk | | | | − | | = | | =
Trichloroethylene; Mice (MRL+/+); IP
Wang et al. (2008) | 4 wk | | | | | + | | = | | =
Dichloroacetyl anhydride; Mice (MRL+/+); IP
Cai et al. (2006) | 6 wk | +
Dichloroacetyl chloride; Mice (MRL+/+); IP
Cai et al. (2006) | 6 wk | +
Trichloroethylene; Mice (NZBWF1); Drinking water
Keil et al. (2009) | 2, 9, 10, 13, 19, 22, 24, 27 wk | | | = | | | | | | = | | | | =
Trichloroacetaldehyde hydrate; Mice (C3H/HeJ); Drinking water
Blossom et al. (2006) | 4, 40 wk | | | | = | | =
Trichloroethylene; Mice (B6C3F_1_); Drinking water
Peden-Adams et al. (2006) | Preconception to 3, 8 wk | | | = | +/− | | = | | − | = | | − | =
Keil et al. (2009) | 30 wk | | | = | | | | | | = | | | =
Wright et al. (1991) | 3 d | | | | | | | | | | | | | =
Trichloroethylene; Mice (CD-1); Drinking water
Sanders et al. (1982) | 4, 6 mo | | + | | | | | | | | | +
Chloral hydrate; Mice (CD-1); Drinking water
Kauffmann et al. (1982) | 90 d | | | = | | | | | | = | | -
Chloral hydrate; Mice (CD-1); Gavage
Kauffmann et al. (1982) | 15 d | | | | | | | | =
Trichloroethylene; Rat (Sprague-Dawley); IP
Wright et al. (1991) | 3 d | | | | | | | | | | | | | =

+ = increased effect; − = decreased effect; = = no change in effect; +/− = both increases and decreases in effect were seen depending on dose or time point.

^a^ Included a group co-exposed to diallyl sulfide, a CYP2E1 inhibitor, which prevented the effect.

Table E-6 Liver and Kidney

Reference | Design | Trichloroethylene-protein Adducts | Dichloroacetyl-protein Adducts | Dichloroacetyl-CYP2E1 Adducts | Hydroxynonenal-protein Adduct | Malondialdehyde-protein Adducts | Inflammation | T-cell Infiltration | NK-cell Cytolytic Activity | Hepatocyte Proliferation | Glomerular Antibody Deposits | Hydroxynonenal-protein Adduct | Malondialdehyde-protein Adduct | Inflammation
| | Liver | | | | | | | | | Kidney
Trichloroethylene; Mice (MRL+/+); Drinking water
Cai et al. (2008) | 36, 48 wk | | | | | | + | | | + | + | | | +
Gilbert et al. (2009) | 10, 18, 26 wk | | | | | | +
Griffin et al. (2000a) | 4, 6, 8, 22 wk | +
Griffin et al. (2000c) | 4, 32 wk | | + | | | | | + | | | | | | =
Griffin et al. (2000b) ^a^ | 4, 32 wk | | +
Kondraganti et al. (2012) | 24, 36, 48 wk | | | | | | + | +
Trichloroethylene; Mice (MRL+/+); IP
Wang et al. (2007a) | 6, 12 wk | | | | + | +
Wang et al. (2013) ^b^ | 6 wk | | | | + | + | | | | | | + | +
Formyl-albumin adduct; Mice (MRL+/+); SC
Cai et al. (2007b) | 4 wk | | | | | | +
Dichloroacetyl-albumin adduct; Mice (MRL+/+); SC
Cai et al. (2007b) | 4 wk | | | | | | =
Trichloroethene oxide-albumin adduct; Mice (MRL+/+); SC
Cai et al. (2007b) | 4 wk | | | | | | =
Trichloroethylene; Mice (MRL+/+); Inhalation
Kaneko et al. (2000) | 4, 6, 8 wk | | | | | | +
Trichloroethylene; Mice (NOD/Born); Drinking water
Ravel et al. (2004) | 4,8, 12 wk | | | | | | =
Trichloroethylene; Mice (SV/129) [wt/PPAR-null/PPAR-tet-off]; Inhalation
Ramdhan et al. (2010) | 7 d | | | | | | + | | | +
Trichloroethylene; Mice (B6C3F_1_); IP
Wright et al. (1991) | 3 d | | | | | | | | −
Trichloroethylene; Rat (Sprague-Dawley); IP
Halmes et al. (1997) | 4 hr | | | +
Wright et al. (1991) | 3 d | | | | | | | | −
Trichloroethylene; Guinea pig (FMMU); Dermal
Tang et al. (2008) | 48 hr | | | | | | =
Trichloroethylene; Guinea pig (FMMU); Intradermal/Dermal
Tang et al. (2008) | 23 d | | | | | | =
Trichloroethylene; Guinea pig (FMMU); Intradermal
Tang et al. (2008) | 48 hr | | | | | | +

+ = increased effect; − = decreased effect; = = no change in effect.

^a^ Included a group co-exposed to diallyl sulfide, a CYP2E1 inhibitor, which prevented the results.

^b^ Included a group co-exposed to N-acetylcystine, an enhancer of the antioxidant activity of glutathione, which prevented the results.

Table E-7 Splenic Ex Vivo Cytokines, Lymph Node, and Anti-bacterial Response

Reference | Design | Splenocytes Stimulated with Hydroxynonenal-albumin Adduct – IFN-gamma | Splenocytes Stimulated with Malondialdehyde-albumin Adduct – IFN-gamma | Splenocytes Stimulated with Hydroxynonenal-albumin Adduct – IL-2 | Splenocytes Stimulated with Malondialdehyde-albumin Adduct – IL-2 | CD4 T-cell Number | CD8 T-cell Number | B-cell Number | B-cell Activation | Death from Bacterial Infection | Lung-bacterial Infection | Lung-macrophage Phagocytosis of Bacteria
Trichloroethylene; Mice (MRL+/+); Drinking water
Gilbert et al. (2011) | 8 wk | | | | | = | =
Gilbert et al. (2012) | 12, 17 wk | | | | | =
Wang et al. (2012a) | 12, 24, 36 wk | + | +
Trichloroacetic acid; Mice (MRL+/+); Drinking water
Blossom et al. (2004) | 4 wk | | | | | = | = | = | =
Trichloroacetaldehyde hydrate; Mice (MRL+/+); Drinking water
Blossom et al. (2004) | 4 wk | | | | | = | = | = | =
Trichloroethylene; Mice (MRL+/+); IP
Wang et al. (2008) | 4 wk | + | + | + | +
Dichloroacetyl anhydride; Mice (MRL+/+); IP
Cai et al. (2006) | 6 wk | | | = | =
Dichloroacetyl chloride; Mice (MRL+/+); IP
Cai et al. (2006) | 6 wk | | | + | +
Trichloroethylene; Mice (C3H/HeJ); Drinking water
Blossom et al. (2006) | 4, 40 wk | | | | | = | =
Trichloroethylene + Streptococcus zooepidermicus; Mice (CD-1); Inhalation
Aranyi et al. (1986) | 3 hr; 5 d | | | | | | | | | +
Selgrade and Gilmour (2010) | 24, 72 hr; 20 d | | | | | | | | | + | +
Trichloroethylene + Streptococcus zooepidermicus; Mice (CD-1); Inhalation + intratracheal instillation
Selgrade and Gilmour (2010) | 3.5 hr | | | | | | | | | | | −
Trichloroethylene + kiebsiella pneumonia; Mice (CD-1); Inhalation
Aranyi et al. (1986) | 3 hr; 5 d | | | | | | | | | | +/−

+ = increased effect; − = decreased effect; = = no change in effect; +/− = both increases and decreases in effect were seen depending on dose or time point.