# Appendix D Human Cancer Study Tables

This appendix contains background information related to the cancer assessment on trichloroethylene in humans including detailed (1) data information on study design, methods, and findings for human cancer studies (Table D-1, Table D-2, and Table D-3) and (2) detailed information on the quality assessment of the individual studies (Table D-4, Table D-5, Table D-6, Table D-7, Table D-8, and Table D-9) and (3) studies included in several meta-analyses (Table D-10).

## D.1 Methodologies and Study Characteristics of the Selected Epidemiologic Studies and Identification of Cancer Endpoints

The data from the 16 cohort studies, which include two nested case-control studies (Table D-1), 7 kidney case-control studies, including 1 that reported on liver cancer (Table D-2), and 11 NHL or related subtypes case-control studies (Table D-3), which includes 1 pooled study and the 3 constituent studies, were systematically extracted from relevant publications and are summarized in the tables below. The cohort studies are organized according to several broad occupational groups related to the exposure scenarios or occupations similar to Table 3-1, and the case-control studies are organized similar to Table 3-2 and Table 3-3.

Table D-1 Study Descriptions and Methodologies: Cohort Studies of Trichloroethylene Exposure

| Study Description and Methodology
Vlaanderen et al. (2013)
Related References | Kauppinen et al. (2009); Pukkala et al. (2009)
Geographic Location | Denmark, Finland, Iceland, Norway, Sweden
Population Characteristics
Cases: selection and ascertainment | [underlined: Cases]: Kidney cancer: 44,708 M, 31,422 F; Liver cancer: 14,702 M, 9,194 F; NHL: 36,487 M, 32,767 F; MM 187,777 M, 16,757 F [underlined: Eligibility criteria (cohort)]: All men and women aged 30–64 years old participating in the 1960, 1970, 1980–1981 and/or 1990 censuses in participating countries and alive on Jan 1 of year following the census [underlined: Cohort]: NOCCA Cohort: 45 years of cancer incidence and follow-up for 15 million people [underlined: Case identification and ascertainment]: Linkage to cancer registries (incident cases) and followed by linkage to population registries
Controls: selection and ascertainment | [underlined: Referents]: Kidney cancer: 223,540 M, 157,110 F; Liver cancer: 73,510 M, 45,970 F; NHL: 182,435 M, 163,835 F; MM: 93,885 M, 83,785 F [underlined: Referent eligibility criteria]: Randomly selected from NOCCA database; alive and free of cancer [underlined: Matching criteria]: Age (±1 yr), sex, country; 5 controls per case and without cancer at time of case diagnosis
Follow-up | Date of 1st entry into census to emigration, death, or end of 2003 (Norway), 2004 (Iceland), 2005 (Sweden, Finland)
Study Design and Analytical Methods | Cancer registry and census record linkage study (Pukkala et al. 2009); Nested case-control design; Analysis of hazard ratio by exposure to TCE using conditional logistic regression for tertiles of cumulative exposure and continuous cumulative exposure (spline or linear); Non-exposed participants as internal controls; 1-, 5-, 10- and 20-year lagging explored but had minimal effect and thus unlagged models used
Exposure Data and Information Assessment
Exposure: levels and co-exposures | Levels: NR. Overall prevalence of exposure to TCE low (5%) High estimated levels of exposure to TCE were found in shoe and leather industry workers, mechanics, laundry and smelting workers Moderate correlation between TCE and tetrachloroethylene (r = 0.58–0.63), chlorinated hydrocarbons (r = 0.56–0.61) and 1,1,1-trichloroethane (r = 0.37–0.43); No association between TCE and benzene and ionizing radiation
Exposure assessment | Census questionnaire data was used to construct country-specific and calendar time-specific quantitative JEM for 29 agents for NOCCA Person-yr of exposure started at age 20 or age at first job until death, emigration, cancer diagnosis or age 65. Assume same exposure between census reports. Exposures before first census report assumed same since age of first entry into cohort Cumulative exposure = prevalence × level of exposure by calendar year × lifetime employment duration. High exposure = exposure to levels >90th percentile of cumulative exposure or average intensity × prevalence
Assessment of potential confounders | NR
Disease assessment | ICD-7; NHL 200+202, MM 203
Hansen et al. (2013)
Related References | Anttila et al. (1995); Axelson et al. (1978); Axelson et al. (1994); Hansen et al. (2001); Tola et al. (1980)
Geographic Location | Sweden, Finland, Denmark
Population Characteristics
Exposed cohort and ascertainment | [underlined: Eligibility criteria]: All workers provided with urine TCA monitoring in Sweden (1955–1975), Finland (1965–1982), and Denmark (1947–1989) ≥1 U-TCA measurement [underlined: Exposed cohort]: 5,553 workers (3,776 men; 1,777 women); total 154,778 person-yr of observation [underlined: Follow-up]: Sweden, 1958–2003; Finland, 1967–2004; Denmark, 1968–2008 [underlined: Loss to follow-up]: 0.1%
Reference population | National rates (Sweden, Finland, Denmark)
All-cause and all-cancer mortality/incidence | All-cause incidence (SIR): NR All-cancer incidence (SIR) = 1.06 (0.99–1.13); 997
Study Design and Analytical Methods/Control for Confounding | Pooled and extended analysis of three historical cohort cancer incidence (registry) studies External analysis (by sex, age, and calendar period) with 10- and 20-year exposure lagging; Internal analysis by U-TCA category (average level) using Cox regression to estimate hazard rate ratios adjusted for age, sex, calendar period, country; Indirectly evaluated potential confounding by smoking and alcohol consumption by calculating combined SIR of smoking- or alcohol-related cancers) Additional analyses in earlier updates for the 3 cohorts: Swedish study evaluated risk (SIR, SMR) of U-TCA stratified by exposure time (< and >2 years). Danish study also evaluated cancer risk by period of first employment, duration of employment, mean and cumulative exposure (air calculated from U-TCA) with 10- and 20-year lagging and stratified by sex
Exposure Data and Information Assessment
Exposure: levels and co-exposures | Mean/median urine TCA levels (mg/L)^a^ Mean ± SD Median % samples >50 mg/L Sweden: 28.2 ± 40 13.0 17.7 Finland: 30.3 ± 82 9.2 13.3 Denmark: 39.2 ± 78 15.0 20.7 No data on cumulative exposure or exposure duration; Mean duration of employment: 5.5 yr (Sweden) and 6.3 (Denmark), NR for Finland, ~81% of Swedish cohort with <20 ppm ambient TCE Finland: Estimated TCE exposures were ~4 ppm (median) and 6 ppm (mean). Denmark: Overall calculated air concentrations (urinary TCA to air) = 1–2 ppm (65 mg/m^3^) mean, 3.53 ppm (19 mg/m^3^) median
Exposure assessment | Individual Urine TCA measurements (national surveillance program); Most (65%–66%) of the first U-TCA samples were taken after 1970. Few measurements (usually 2 or 3) were available for each individual. Employment history was available in the Denmark cohort Co-exposures (Finland) [underlined: TCA] [underlined: Perc] [underlined: TCE] Urine (μmol/L) 48–53 NR NR Air (ppm) 6 avg <50 79 avg Blood (μmol/L) NR 0.4–0.7 20–25
Assessment of potential confounders | NR
Disease assessment | Personal identification number linked to Central Person Registers to ascertain vital status; linkage to national cancer registries. ICD-7 (modified)
Raaschou-Nielsen et al. (2003)
Related References | Raaschou-Nielsen et al. (2001); Raaschou-Nielsen et al. (2002); Note: cohort partly overlaps that of Hansen et al. (2001)
Geographic Location | Denmark
Population Characteristics
Exposed cohort and ascertainment | [underlined: Eligibility criteria]: All male and female blue-collar workers employed ≥3 months in 347 companies using TCE with <200 employees; Potentially higher exposed workers had >1 year duration of employment and were first employed before 1980 [underlined: Potentially exposed cohort]: 40,049 blue-collar workers in 347 TCE-using companies; 588,047 person-yr of exposure (men), 118,270 person-yr (women); 14,360 with potential higher exposure to TCE; TCE-using companies identified via Danish Institute for Occupational Health, Danish Product Registry, dry cleaning survey and files of main TCE producer [underlined: Follow-up]: 1968–1997 [underlined: Loss to follow-up]: NR, “Virtually complete”
Reference population | Danish population
All-cause and all-cancer mortality/incidence | All cause incidence (SIR): NR All-cancer incidence: SIR: 1.08 (1.04–1.12); 2,620 (men) SIR: 1.23 (1.14–1.33); 624 (women)
Study Design and Analytical Methods/Control for Confounding | Historical cohort incidence (registry) study; External SIR analysis, adjusted for sex, age, and calendar year, by lag time, calendar period, duration of employment, size of company; Separate analysis on potential high exposure by the same variables; No analysis for potential confounding from co-exposure or lifestyle factors; Sensitivity analysis on excluded workers (<3 months employment)
Exposure Data and Information Assessment
Exposure: levels and co-exposures | All workers in Danish TCE measurement registry: (Raaschou-Nielsen et al. 2001; Raaschou-Nielsen et al. 2002) 1960–1964: mean U-TCA = 58 mg/L (21 ppm TCE air)^a^ 1960s: mean air TCE = 318 mg/m^3^ (59 ppm TCE air) 1980–1985: mean U-TCA = 14 mg/L (5 ppm TCE air)^a^ 1980s: mean air TCE = 75 mg/m^3^ (14 ppm) Co-exposures NR, Industries include iron and metal (>50%), electronics, painting, printing, chemicals, dry cleaning
Exposure assessment | Potentially exposed workers identified from Central Population Registry (1968 on) and Danish Pension Fund (compulsory membership since 1964) Job title and individual employment history (duration and year of first employment) obtained from Danish Pension Fund. Size of company also used as a surrogate for prevalence of TCE. 81%, 51%, and 19% of the blue-collar workers in small (<50 employees) medium (50–100) and large (>100) companies, respectively, estimated to be exposed to TCE No exposure data on individual workers
Assessment: other exposures | NR
Disease assessment | Danish Cancer Registry Modified ICD-7
Lipworth et al. (2011)
Related References | Boice et al. (1999) (errata published in Boice and McLaughlin (2001)); Marano et al. (2000)
Geographic Location | Burbank, CA (USA)
Population Characteristics
Exposed cohort and ascertainment | [underlined: Eligibility criteria]: All aircraft manufacturing workers employed ≥1 year from 1960 [underlined: Exposed cohort]: 5,443 M+F (180,704 person-yr) [underlined: Total cohort]: 77,943 Aircraft mfg. workers at Lockheed Martin (Burbank) [underlined: Follow-up]: 1960–2008 or age 95 (avg 32 yr) [underlined: Loss to follow-up]: 1.7% total cohort
Reference population | California (white workers) and USA (non-white workers)
All-cause and all-cancer mortality/incidence | All-cause mortality: SMR: 0.91 (0.88–0.93); 4,070 All-cancer mortality: SMR: 0.92 (0.86–0.97); 986
Study Design and Analytical Methods/Control for Confounding | Historical cohort mortality study; External analysis: adjusted for age, sex, and calendar period; Internal analyses: Cox proportional hazard models for specific cancer by duration of exposure and exposure pattern adjusting for age, date of birth, date of hire, termination date, sex, and race; No control for potential confounding from co-exposures and lifestyle factors
Exposure Data and Information Assessment
Exposure: levels and co-exposures | No quantitative exposure assessment TCE used for vapor degreasing up to 1966, replaced by tetrachloroethylene Approx. 12% workers with routine TCE exposure, 30% routine or intermittent TCE exposure Co-exposures: PCE, chromate, mixed solvents (including methyl ethyl ketone, alcohols, petroleum distillates, 1,1,1-trichloroethane, methylene chloride, methyl isobutyl ketone, acetone, toluene, xylene, freons), cutting fluids, lubricants
Exposure assessment | Qualitative JEM; Occupational job groups developed by industrial hygienists based on walk-through survey, veteran employee interviews and historical industrial hygiene surveys and reports Individuals classified as ever/never, routine, or intermittent exposure to TCE and co-exposures (PCE, and mixed solvents) (Boice et al. 1999) and by duration of potential exposure to each substance (Lipworth et al. 2011)
Assessment: other exposures | NR
Disease assessment | California death files, National Death Index, state vital statistics records, vital records search company; Pension Benefit Information Files, Social Security Death Index, Health Care Financing Administration beneficiary files, California DMV, work and pension records Nosologist coded cause of death from death certificates using ICD in use at time of death, underlying cause of death
Radican et al. (2008)
Related References | Spirtas et al. (1991), Stewart et al. (1991), Blair et al. (1998) (mortality and incidence)
Geographic Location | Utah (USA)
Population Characteristics
Exposed cohort and ascertainment | [underlined: Eligibility criteria]: employed ≥1 year 1952–1956 [underlined: Exposed cohort]: 7,204 (6,153 men, 1,051 women) TCE-exposed workers [underlined: Total cohort]: 10,730 male and 3,725 female civilian aircraft maintenance workers (at Hill Force military base) [underlined: Follow-up]: mortality1991–2000; incidence 1973–1990 [underlined: Loss to follow-up]: NR
Reference population | USA (mortality; Radican et al. (2008)) and Utah (cancer registry; Blair et al. (1998)) Non-chemical-exposed workers (internal analysis)
All-cause and all-cancer mortality/incidence | Radican et al. (2008) (internal analysis) All-cause mortality HR = 1.04 (0.98–1.11); 3,628 All-cancer mortality HR = 1.12 (0.96–1.30); 729
Study Design and Analytical Methods/Control for Confounding | Historical cohort mortality/incidence study; Internal analyses (External analysis reported for 1990 follow-up for mortality only) 2000 follow-up (mortality): Cox proportional hazards model, using age as variable and adjusting for race, stratified by sex and considering calendar year; 1990 follow-up (mortality and incidence): Poisson multivariate regression analysis adjusted for age, calendar year, and sex. Both models were used to evaluate TCE exposure-response by cumulative exposure and exposure patterns (mortality only). Separate analysis for other chemical exposures, no multivariate analysis controlling for potential confounding from exposure to other substances or lifestyle factors
Exposure Data and Information Assessment
Exposure: level and co-exposures | No quantitative exposure (air) assessment specific for TCE, but air measurements available on vapor degreasing and other solvents. Estimated TCE exposures (ppm) were: Peak Low level 1939–54 600 10 1955–67 400 10 1968–78 200 0 1979–83 0 0 Cherrie et al. (2001) estimated long-term exposure as 50 ppm and short term up to 600 ppm. The NAS concluded the cohort had a modest number of highly exposed (~100 ppm), but most were exposed to low TCE concentrations (~10 ppm) Co-exposures: Ever/never exposure for 1,1,1-trichloroethane, methylene chloride, carbon tetrachloride, freon, isopropyl alcohol, acetone, ketone, toluene, methyl ethyl ketone, o-dichlorobenzene, perchloroethylene, chloroform, Stoddard solvent, xylene, styrene, JP4 gasoline, metal fumes/dust, silica, zinc chromate, nitroglycerine, solder flux
Exposure assessment | All exposures: Walk-through surveys; veteran employee assessment; individual work and job histories from personnel records; Process descriptions were used to develop ever vs. never exposure to 21 solvents and chemicals for each job -department combination TCE: Semi-quantitative individual exposure assessment, calendar-year specific; Detailed job task descriptions used to develop exposure score for each job based on relative exposure intensity for each calendar period, frequency of use and duration of use. Cumulative exposure (unit-years) was the sum of exposure scores × job duration across jobs (Stewart et al. 1991). Workers also assigned to patterns or types of exposure (e.g., low level, peak, continuous, or intermittent)
Boice et al. (2006)
Related References | Overlaps cohort of Ritz et al. (1999) and Zhao et al. (2005) (see above)
Geographic Location | Los Angeles (USA)
Population Characteristics
Exposed cohort and ascertainment | [underlined: Eligibility criteria]: male Rocketdyne rocket engine testing workers employed ≥6 months from Jan 1, 1948 on and with adequate work histories and identifying data [underlined: Exposed cohort]: 1,111 test stand mechanics with any estimated exposure to TCE or hydrazine [underlined: Total cohort]: 8,372 Rocketdyne Aerospace workers (7,083 M, 1,289 F) at the SSFL facility; 1,651 were test-stand mechanics [underlined: Follow-up]: 1948–1999; ~88% of test stand mechanics were followed for over 20 years. [underlined: Loss to follow-up]: 0.4% test stand mechanics
Reference population | External: US population Internal: Hourly non-administrative Rocketdyne workers at SSFL and adjacent facilities
All-cause and all-cancer mortality/incidence | All-cause mortality: SMR = 0.87 (0.78–0.96); 391 All-cancer mortality: SMR = 1.00 (0.83–1.19); 121
Study Design and Analytical Methods/Control for Confounding | Historical cohort mortality study; External (all cancers) adjusted for age, race, calendar year. Internal analysis (selected cancers including kidney but not NHL or liver cancer) using Cox proportional hazard models, adjusting for date of birth, year of hire, pay type (surrogate for SES) and exposure to hydrazine (for TCE analyses and TCE for hydrazine analyses) for any exposure, duration of employment with potential exposure to TCE or hydrazine, and number of engine test flushes using TCE
Exposure Data and Information Assessment
Exposure: levels and co-exposures | No quantitative exposure assessment TCE used for engine flush to mid-1960s, used as utility solvent to 1974. Approx. 58% exposed to TCE during engine flushing/cleaning (high exposure); Approx. 42% exposed to TCE during utility cleaning (lower exposure). PPE only used in later years Co-exposures: hydrazine, mixed solvents, rocket fuels, oxidizers, exhaust gases, other chemicals, radiation 8.4% (N = 121) exposed to both hydrazine and TCE
Exposure assessment | Qualitative exposure assessment to TCE; Walk-through surveys and veteran employees’ assessments used to determine dates that TCE was used at test strands as a utility solvent or to flush engines. Did not consider PPE. Comprehensive job history based on dates and job titles used to assign workers to specific test stands Workers assigned to (1) duration of employment for potential exposure to TCE and (2) duration (test years) of exposure to TCE from engine flush, which was weighted by number of engine tests per year accounting for the number of workers that year
Assessment: other exposures | Smoking history (pack-yr) among subsample of 600 workers
Disease assessment | SSA, California death index, NDI, state vital records, Pension Benefit Information Files, Medicare and Medicaid Services data, company personnel, pension and retirement records ICD in use at time of death
Zhao et al. (2005)
Related References | Morgenstern et al. (1997); Ritz et al. (1999). Members of cohort also part of separate larger mortality cohort study of Boice et al. (2006)
Geographic Location | Los Angeles, CA (USA)
Population Characteristics
Exposed cohort and ascertainment | [underlined: Eligibility criteria]: Male workers at Rocketdyne aerospace facility 1950–1980 with ≥2 years’ employment and no radiation exposure [underlined: Exposed cohort]: 6,107 male aerospace workers at SSFL; mortality: 6,044; incidence: 5,049 workers; TCE-exposed workers (greater than intensity score 3): mortality 2,648; incidence 2,236 [underlined: Total cohort]: 55,000 Rockwell/Rocketdyne aerospace workers [underlined: Follow-up]: 1950–2001 (mortality) 1988–2000 (incidence) Average follow-up 29 yr [underlined: Loss to follow-up]: <1% for mortality
Reference population | Mortality: US population Incidence: California and 8 other state incidence rates Internal analysis: Low TCE exposure category
All-cause and all-cancer mortality/incidence | All-cause and all cancer mortality (SMR): NR All-cause and all cancer incidence (SIR): NR
Study Design and Analytical Methods/Control for Confounding | Historical cohort mortality/incidence study; internal analyses; proportional hazards modeling with fixed and time-dependent variables; multivariate models for cumulative exposure (low-, medium-, and high-exposure intensity) in lagged and unlagged analyses included pay type (surrogate for SES), time since first employment (surrogate for survival), age, and co-exposures to other chemicals
Exposure Data and Information Assessment
Exposure: levels and co-exposures | Limited quantitative exposure assessment Co-exposures: hydrazine, PAH, benzene (early years), mineral oil, gasoline, fuel oils
Exposure assessment | Semi-quantitative JEM developed by industrial hygienists based on walk-through surveys; employees’ assessments, job task manuals, review of company records for TCE, hydrazine, PAH, mineral oil; Work histories for each individual linked to JEM to generate calendar time-dependent intensity scores for each chemical exposure for each worker. Individual cumulative intensity scores (low/medium/high) based on estimated intensity of exposure in job/task × time in job 1% workers missing job description; 3% workers with insufficient job description—exposure imputed from job title
Assessment: other exposures | Smoking data for subsample of 200 workers with medical questionnaire data
Disease assessment | Mortality: ICD-9 and 10; underlying and contributing causes of death Incidence: California Cancer Registry and 8 other state cancer registries. ICD-O (incidence). Reports all lymphohematopoietic cancers (excluding CLL) only, not NHL
Morgan et al. (1998)
Related References | Wong and Morgan (1990)
Geographic Location | Arizona (USA)
Population Characteristics
Exposed cohort and ascertainment | [underlined: Eligibility criteria]: All male and female aircraft manufacturing workers employed ≥6 months 1950–1985 [underlined: Exposed cohort]: 4,733 (2,555 men; 2,178 women) [underlined: Total cohort]: 20,508 aircraft manufacturing workers at the Hughes Aircraft Manufacturing Site [underlined: Follow-up]: 1950(?)–1993 (approx. 66% followed for >20 yr) [underlined: Loss to follow-up]: 0.1% excluded due to missing data (not clear if vital status or other data)
Reference population | External analysis: NR (assume U.S. population) Internal analysis: 11,187 male and 4,588 female unexposed workers; peak exposure—used unexposed and low exposed workers as the reference group
All-cause and all-cancer mortality/incidence | All-cause mortality: SMR = 0.84 (0.79–0.90); 917 All-cancer mortality/incidence: SMR: 0.92 (0.81–1.03); 270
Study Design and Analytical Methods/Control for Confounding | Historical cohort mortality study; External (SMR) analysis for TCE-exposed cohort, low and high exposure for multiple cancer sites; Internal analyses using Cox proportional hazards adjusting for age at hire, and sex used to evaluate cumulative (low and high) and peak exposure and selected cancer sites. No control for potential confounding from co-exposures and lifestyle habits
Exposure Data and Information Assessment
Exposure: levels and co-exposures | Limited quantitative exposure levels available, especially before 1975. Before 1981, plant had contaminated well water estimated between 730 and 2,200 ppb TCE for showers and drinking High exposure = work on degreaser machines using TCE (estimated to be 50 ppm); medium exposure = jobs near degreasing area (occasional contact); low exposure = jobs away from degreaser work TCE used for vapor degreasing 1952–1977 Co-exposures: NR
Exposure assessment | Semi-quantitative individual JEM based on veteran employees’ plus company industrial hygienists’ exposure rankings. Jobs classified into no, low, medium, high exposure scores Cumulative exposure score (low, high) = exposure category × duration of exposure. Peak exposure = jobs with medium and high exposure Medium/low exposures may be misclassified
Assessment: other exposures | NR
Disease assessment | SSA; NDI; State death certificates; ICD-7, 8 or 9 in use at time of death
Silver et al. (2014)
Related References | Clapp and Hoffman (2008); Fleming et al. (2014)
Geographic Location | New York State, USA
Population Characteristics
Exposed cohort and ascertainment | [underlined: Eligibility criteria]: Workers with 91 or more days of employment 1969–2001; contract and foreign national workers (or without SSN) excluded [underlined: Exposed cohort]: 3,113 ever exposed to TCE [underlined: Total cohort]: 34,494 (24,037 men, 10,457 women) employed a microelectronics business facility; hourly workers = 15,447 M and 8,934 W [underlined: Follow-up]: 1969–2009; average 25.7 years (total cohort) [underlined: Loss to follow-up:] NR
Reference population | US mortality rates, NY State mortality rates (excluding New York City)
All-cause and all-cancer mortality/incidence | All-cause mortality: SMR (all hourly workers) M: 0.76 (0.73–0.78) 3571; F: 0.73 (0.68–0.79) 823 All-cancer mortality: SMR (all hourly workers) M: 0.83 (0.78–0.88) 1005; F: 0.86 (0.76–0.96) 291
Study Design and Analytical Methods/Control for Confounding | Historical cohort mortality study. External analyses: SMR for all workers only calculated using NIOSH life table analysis system (race, sex, and calendar year) and Poisson distribution Internal (conditional forward Cox regression) analyses for workers exposed to TCE, tetrachloroethylene, methylene chloride, lead, or classes of agents, by cumulative probability of exposure or duration of exposure; analyses controlled for age in risk set selection. Univariate models included sex, paycode, and chemical exposure. Multivariate models included those variables with significant findings in univariate models and birth cohort, time since last exposure (healthy worker survivor), employment duration prior to 1966, and hire era. No control for other potential confounders
Exposure Data and Information Assessment
Exposure: levels and co-exposures | Trichloroethylene was used from 1969 to 1987. Some sampling of levels available from 1980 to 1984, which was not thought to be representative of earlier time periods (levels NR) Lead, tetrachloroethylene, methylene chloride, methyl chloroform, classes of chlorinated and other hydrocarbons, acids, bases used in plant. Information on co-exposures not reported
Exposure assessment | Company industrial hygiene monitoring and related records, veteran employees’ information and expert assessment used to identify dept. in which chemical agents were used over time Individual work history linked to dept.-year exposure matrix. Cumulative exposure score for each worker assigned by (i) extent of chemical use based on dept. (none, intermittent, routine), (ii) employment duration in dept. (iii) potential of exposure based on broad job category within department (processing vs. clerical or administrative), and (iv) chemical usage in dept.-during time period
Assessment: other exposures | NR
Disease assessment | State vital records or NDI; ICD code in use at time of death
Yiin et al. (2009)
Related References | None
Geographic Location | Tennessee (USA)
Population Characteristics
Exposed cohort and ascertainment | [underlined: Eligibility criteria]: hired before 1985, employed 30 days or longer [underlined: Total cohort]: 47,941 Uranium enrichment (gaseous diffusion) plant workers; TCE-exposed NR [underlined: Cases]: 98 multiple myeloma deaths [underlined: Follow-up]: 1985–1998 [underlined: Loss to follow-up]: NR
Reference population | 419 controls (219 deaths) 5:1 controls to cases, matched on age, sex, race Selected by incidence density sampling from risk set of all workers at risk of mortality from multiple myeloma
All-cause and all-cancer mortality/incidence | Not applicable
Study Design and Analytical Methods/Control for Confounding | Nested case-control mortality study Conditional logistic regression (univariate and multivariate analyses focusing on ionizing radiation dose adjusted for external radiation, X-rays, and TCE, mercury, and nickel as potential confounders; 15 year lagging. Also conducted separate analyses for TCE and other chemicals
Exposure Data and Information Assessment
Exposure: levels and co-exposures | Historical area air monitoring data available but inadequate information (e.g., building work location) to link to employees Estimated cumulative exposure levels to TCE (mean); 183.8 cases, and 113.4 controls (units not reported) Internal and external radiation dose estimated: average cumulative exposure = 0.026 mGy cases, 0.012 mGy controls Other exposures: Mercury and nickel
Exposure assessment | Exposure to TCE, mercury, nickel: modified job-exposure matrix using site records to identify exposure activities for TCE and other chemicals. Mean air levels estimated for each activity by decade. Activities associated with dept. based on workforce information Cumulative exposure scores (ranks) based on estimated exposure level for activity, employment duration (days) in dept. associated with exposure activity, and fraction of the day in exposure activity work area based on expert assessment (industrial hygienists)
Assessment: other exposures | NR
Disease assessment | Source of mortality data NR ICD-8 203; underlying and contributory cause of death
Ritz (1999)
Related References | None
Geographic Location | Ohio (USA)
Population Characteristics
Exposed cohort and ascertainment | [underlined: Eligibility criteria]: All white males employed from 1951 to 1972 for ≥3 months with chemical exposure data and monitoring data for radiation (N = 3,814) [underlined: Exposed cohort]: 2,971 (of 3,814 eligible) white male uranium-processing workers [underlined: Follow-up]: 1951–1989; mean length: 31.5 years [underlined: Loss to follow-up]: NR
Reference population | U.S. population; NIOSH-CORPS reference data (Zahm 1992)
All-cause and all-cancer mortality/incidence | Total cohort only: mortality (SMR) All-cause mortality: 0.84 (0.79–0.90); 1,045 deaths All-cancer mortality: 1.10 (0.99–1.23) 328 deaths
Study Design and Analytical Methods/Control for Confounding | Historical cohort mortality study; external (SMR) adjusted for age and calendar year. Internal (risk-set) analyses by level (category) and duration of exposure in l5 lagged and unlagged analyses using conditional Cox proportional hazards modeling matching by age to index case age, and adjusting for time since first hired, pay status (surrogate for SES), using time since first hired (surrogate for healthy worker survival effects, radiation dose and exposure to other chemicals)
Exposure Data and Information Assessment
Exposure: levels and co-exposures | No quantitative exposure assessment Only 6% of cohort had moderate exposure and no workers had heavy exposure Co-exposures: cutting fluids, kerosene, carbon (approx. 50% TCE-exposed workers exposed to cutting fluids, some to kerosene or carbon), and external and internal radiation (badge dosimetry, urine, area monitoring) (mainly uranium and thorium isotopes) 287 workers excluded because of missing radiation exposure data
Exposure assessment | JEM based on in-plant industrial hygiene assessment by hygienists, veteran workers, engineers in 1970s and 1980s to estimate probability of chemical exposures by job title and department Workers classified by estimated exposure level categories (light, moderate, heavy) and exposure duration
Assessment: other exposures | Smoking history available for approx. 20% subsample of workers from 1968; used to indirectly estimate smoking prevalence by exposure status among workforce
Disease assessment | Social Security Administration (prior to 1979) National Death Index Internal analysis: ICD-9 codes
Henschler et al. (1995)
Related References | None
Geographic Location | Germany
Population Characteristics
Exposed cohort and ascertainment | [underlined: Eligibility criteria]: All workers exposed to TCE ≥1 year 1956–1975 [underlined: Exposed cohort]: 169 (of eligible 183) male cardboard manufacturing workers exposed to TCE (5,188 person-yr) [underlined: Total cohort]: 169 TCE exposed and 190 unexposed workers (6,100 person-yr); Median age 59 years for exposed and 62 for unexposed [underlined: Follow-up]: 1956–1992; Average follow-up >30 years for both exposed and unexposed; (Note: 2 exposed cases identified outside follow-up period, included in additional analysis) [underlined: Loss to follow-up]: 7.7% (169 of 183 analyzed) includes refusals, unable to participate, loss to follow-up) for exposed cohort; NR for unexposed workers
Reference population | External analysis: local population (mortality) Danish and German Democratic Republic cancer rates (renal-cell cancer incidence) Internal analysis: 190 workers in factory not exposed to TCE matched as group for age and physical activity; excluding office workers
All-cause and all-cancer mortality/incidence | All-cause mortality Exposed: SMR = 0.68 (0.48–0.93); 50 deaths Unexposed: SMR = 1.03 (0.77–1.35); 52 deaths All-cancer mortality: Exposed: SMR = 0.96 (0.51–1.67); 15 deaths Unexposed: SMR = 1.16 (0.65–1.91): 15 deaths All cause and all cancer incidence not reported
Study Design and Analytical Methods/Control for Confounding | Historical cohort mortality and incidence study (renal cancer); external and internal analysis (Mantel-Haenszel test statistics ignoring age stratification)
Exposure Data and Information Assessment
Exposure: levels and co-exposures | No quantitative air levels or urine measurements of TCE. Subanaesthetic symptoms usually associated with TCE concentrations above 37 ppm; Cherrie et al. (2001) estimate peak exposures were >2,000 ppm with average long-term exposure 10 to 225 ppm. In cold degreasing process, estimated average chronic exposure was ~100 ppm Long exposure periods (17.8 months) TCE used from 1956–1975 Cardboard machine area cleaned with TCE every 2 weeks for 4–5 hours, open system, and poor ventilation, no protective gloves and presumed high exposure, odor recorded and sweet taste in mouth and adverse effects (headache, dizziness, vertigo) TCE used in locksmith’s and electrical workshop for degreasing metal parts and involved “continuous exposure” at lower levels than in cardboard machine area without personal protective equipment Other solvents, including halogenated and non-halogenated hydrocarbons, pentachlorophenol, 1,1,1-trichloroethane, tetrachloroethane used in “negligible” amounts compared with TCE from 1967
Exposure assessment | Walk-through survey and employee interview used to identify three locations of exposure: cardboard machine area, locksmith’s area, and electrical workshop areas. TCE also used for general cleaning purpose to clean floors, clothes, and hands Individual employee questionnaire on job history, tasks, materials used
Assessment: other exposures | Smoking, alcohol intake, diuretics, body weight, height, blood pressure (individual employee questionnaire)
Disease assessment | Mortality: vital status from medical, personnel, and pension depts, relatives’ interview; cause of death from hospital or physician records, not based on death certificates (ICD-9) Incidence: hospital and physician records; Physical examination by abdominal sonography; Renal tumors histologically confirmed
Greenland et al. (1994)
Related References | None
Geographic Location | Massachusetts (USA)
Population Characteristics
Exposed cohort and ascertainment | [underlined: Eligibility criteria (“cohort”)]: 1,821 white males at electrical manufacturing plant (transformers, plastics, ordnance systems) employed before 1984, terminated working after 1946, 21–90 years old, date of death benefit claims between 1969–1984 with insurance death records and exposure information; (total # NR) [underlined: Cases]: 512 cancer deaths, 15 NHL and Hodgkin lymphoma combined, 12 kidney, 9 liver cancers [underlined: Follow-up]: Workers who died between 1969–1984 [underlined: Loss to follow-up]: NR
Reference population | Controls: 1,202 non-cancer deaths “unrelated to exposures under study” (primarily circulatory [78%], respiratory [10%], injury [6%], and other causes [6%])
All-cause and all-cancer mortality/incidence | All-cause mortality: SMR NR
Study Design and Analytical Methods/Control for Confounding | Nested case-control analysis among workers at a plant with death benefit claims Separate analyses by specific exposure for cancers with more than 8 cases that adjusted for age and date of death, and covariates (related to employment that changed the risk estimate by >20%); No multivariate control for potential confounding from co-exposures or lifestyle habits
Exposure Data and Information Assessment
Exposure: levels and co-exposures | No industrial hygiene data TCE used 1930–1977 NAS (2006) noted low likelihood of TCE potential exposure among subjects 30 chemicals with carcinogenic potential identified; 6 selected with large volume or number of jobs in addition to TCE: Pyranol (PCBs and trichlorobenzene), benzene, other solvents, machining fluids, asbestos, resins (mostly phenol formaldehyde, polyvinyl resin)
Exposure assessment | Interviews with employees and combination of job titles and department and building used by industrial hygienist to construct qualitative JEM for seven exposures. JEM combined with work history to assign exposure to TCE to each individual (ever/never exposure)
Assessment: other exposures | NR
Disease assessment | Death records in company pensions system; subset of death certificate diagnoses for cancers with <90% confirmation rate verified using hospital records ICDA-8 (combined NHL and Hodgkin lymphomas only)
Wilcosky et al. (1984)
Related References | Arp et al. (1983); McMichael et al. (1976); McMichael et al. (1974)
Geographic Location | Ohio (USA)
Population Characteristics
Exposed cohort and ascertainment | [underlined: Eligibility criteria (exposed cohort)]: 6,678 current and retired rubber manufacturing workers 40–84 years old in 1964 exposed to selected solvents >1 year [underlined: Cases]: Deaths for cancers in excess in cohort study (McMichael et al. 1976); NHL (ICD 200): stomach (30), prostate (333), lymphosarcoma and reticulum cell sarcoma (9) and lymphatic leukemia (10) [underlined: Follow-up]: 1964–1974 [underlined: Loss to follow-up]: NR
Reference population | [underlined: Controls]: 20% age-stratified sample of cohort
All-cause and all-cancer mortality/incidence | N/A All-cancer mortality/incidence: N/A SMR: N/A SIR: N/A
Study Design and Analytical Methods/Control for Confounding | Nested case-control study; separate age-adjusted analyses stratified by race for any vs. no exposure to each of 20+ solvents; No adjustment for potential confounding from co-exposure or lifestyle factors
Exposure Data and Information Assessment
Exposure: levels and co-exposures | No quantitative exposure assessment or industrial hygiene measurements available Co-exposures: 25 solvents identified in different processes
Exposure assessment | Review of product specifications for solvents authorized for use in specified processes and operations by calendar year used to develop JEM. It is not known whether the solvents were actually used. Work histories constructed from job title/dept. (company records) and linked to JEM Exposure defined as ever/never work in a process area where one or more of 25 solvents (including TCE) authorized for use
Assessment: other exposures | NR
Disease assessment | Death certificates; ICD-8 (coded by nosologist)
Bove et al. (2014)
Related References | None
Geographic Location | Camp Lejeune, NC, Camp Pendleton, CA (USA)
Population Characteristics
Exposed cohort and ascertainment | [underlined: Eligibility criteria]: All Marine and Navy personnel on active duty and stationed at Camp Lejeune between April 1975–December 1985 [underlined: Exposed cohort]: 154,932 M+F stationed at Camp Lejeune; 97% under the age of 55 and <6% had died by the end of the study [underlined: Follow-up]: 1979–2008 [underlined: Loss to follow-up]: 1.3% Camp Lejeune, 1.5% Camp Pendleton
Reference population | [underlined: Eligibility criteria]: All Marine and Navy personnel on active duty April 1975–December 1985 and stationed at Camp Pendleton, CA any time during this period “Unexposed cohort”: Camp Pendleton
All-cause and all-cancer mortality/incidence | All-cause mortality: SMR = 0.83 (0.81–0.84); 8,964 All-cancer mortality: SMR = 0.85 (0.80–0.90); 1,078
Study Design and Analytical Methods/Control for Confounding | Retrospective cohort study using ecological exposure assessment; Two types of analyses: Evaluation of contaminated water comparing the exposed (Camp Lejeune) and non-exposed population (Camp Pendleton): Hazard Ratio using Cox extended regression models with age and time as a variable that compared mortality rates (SMR) between the 2 cohorts. SMR were calculated using Life Table Analysis System that adjusted for age, sex, and calendar period and accounted for latency Evaluation of individual water contaminants within the Camp Lejeune cohort: Evaluation of exposure response relationships of cumulative exposure (untransformed, log10 transformed and continuous) for each contaminant using Cox extended regression adjusting for age, and accounting for latency. Other analyses included duration of exposure and restricted cubic spline Models were adjusted for sex, race, and education. Other variables considered in the model (did not change risk estimates by 10%) include marital status, birth cohort, date of death, duty occupation. Smoking was considered by subtracting the log HR among smoking-related diseases from the log HR of disease of interest
Exposure Data and Information Assessment
Exposure: levels and co-exposures | Two of the eight drinking water systems at Camp Lejeune were contaminated with solvents based on sampling data from 1980 to 1984 [underlined: Tarawa Terrace]: Contaminated by off-base dry-cleaning business: Primary contaminant PCE Estimated mean level (μg/L): TCE: 3.1, PCE: 75.7 [underlined: Hadnot Point]: Contaminated by on-base sources (underground storage tank, industrial spills): Primary contaminant TCE (up to 1,400 μg/L, ~0.04 ppm air equivalent^b^) Estimated mean levels (μg/L): TCE: 358.7, PCE: 14.7, Vinyl Chloride: 24, Benzene: 5.4 TCE and PCE highly correlated with each other Overall cumulative exposure, μg/L-months (ppm-months^b^), for TCE, mean = 6,369 (0.17); median = 5,289 (0.14); 20% were exposed to levels between 7,700 and 39,745 (0.21–1.06) Potential daily exposure from Hadnot Point could be as high as 3.6 mg/day (0.07 ppm^b^) (showering and drinking water)
Exposure assessment | TCE and other contaminant levels: Historical reconstruction using historical samples, and modeling based on water fate and distribution modeling Tarawa Terrace water system served on-base houses and Hadnot Point mainly served bachelor quarters Each individual at Camp Lejeune was assigned an estimated average contaminant concentration in the drinking water system serving their residence for the period of their residence. Several sources were used to determine the individual residence. Probability and matching were used to link married cohort members to base housing Cumulative exposure (μg/L-months) was calculated using the estimated monthly average contaminants, in the water serving the individual residence and occupancy dates. No information on water consumption
Assessment: other exposures | Tetrachloroethylene 1,2-Dichloroethylene Vinyl chloride
Disease assessment | Multiple sources (such as Social Security, Death Master File, National Death Index) used to determine vital status

NHL = non-Hodgkin lymphoma; M = males/men; F = females; W = women; MM = multiple myeloma; NOCCA = Nordic Occupational Cancer; TCE = trichloroethylene; NR = not reported; JEM = job exposure matrix; ICD = International Classification of Diseases; TCA = trichloroacetic acid; SIR = standardized incidence ratio; U-TCA = urine trichloroacetic acid; SMR = standardized mortality ratio; SD = standard deviation; ppm = parts per million; Perc = perchloroethylene (tetrachloroethylene); PCE = perchloroethylene (tetrachloroethylene); DMV = Department of Motor Vehicles; NAS = National Academy of Science; JP4 = jet propellant-4; SSFL = Santa Susanna Field Laboratory; SES = socioeconomic status; PPE = personal protective equipment; SSA = Social Security Administration; NDI = National Death Index; PAH = polycyclic aromatic hydrocarbon; CLL = chronic lymphocytic lymphoma; ppb = parts per billion; SSN = Social Security Number; mGy = milligray; NIOSH = National Institute for Occupational Safety and Health; CORPS = Computerized Occupational Referent Population System; N/A = not applicable; HR = hazard ratio; TWA = time-weighted average; PCBs = polychlorinated biphenyls; EAC = equivalent airborne concentrations (mg/m^3^); OD = oral dose (mg/kg); BW = body weight; MV = minute volume (mL/min); AF = fraction of inhaled substance absorbed (default = 1); EL = exposure length (min).

^a^ U-TCA (half-life 100 hrs) is approx. linear with air TCE <375 mg/m^3^ (70 ppm), according to formula TCE mg/m^3^ = [1.96 × U-TCA (mg/L) – 0.7] (Hansen et al. 2001).

^b^ Oral dose of TCE in drinking water converted to equivalent of airborne occupational exposure (ppm, 8-hr TWA) assuming average 1.5 L day intake, 70 kg body weight, minute volume for typical 8-hr shift = 10 m^3^, according to formula: EAC = (OD × BW)/(MV × AF × EL × 10E-06); 10E-06 = conversion factor (mL to m^3^); 1 mg/m^3^ TCE = 0.186 ppm.

Table D-2 Study Descriptions and Methodologies: Case-control Studies of Trichloroethylene Exposure and Kidney Cancer

| Study Description and Methodology
Moore et al. (2010)
Related References | Brennan et al. (2008); Hung et al. (2007)
Geographic Location | Central and Eastern Europe (7 centers, 4 countries)
Population Characteristics
Cases: selection and ascertainment | [underlined: Cases]: 1,097 RCC [underlined: Case eligibility criteria]: Cases at participating hospitals 1999–2003; living in area for at least 1 yr [underlined: Participation rate]: NR
Controls: selection and ascertainment | Referents: 1,476 Referent eligibility criteria: Inpatients or outpatients with non-tobacco-related conditions at same hospitals without cancer or genitourinary disorders (except benign prostate hyperplasia) Matching criteria: age, sex, study center
Study Design and Analytical Methods | Hospital-based: Unconditional logistic regression evaluating ever and categories of different exposure metrics: duration (hr, yr), average intensity and cumulative for all subjects and for subjects with high confidence exposure assessment; Lagged analysis: Analyses were lagged and controlled for sex, age, study center; residence, smoking, BMI, and history of hypertension considered but did not affect risk estimate. Analysis by GST genotypes
Exposure Data and Information Assessment
Exposure: levels and co-exposures | Chlorinated and other solvents Intensity and prevalence of occupational exposures have been higher in central and eastern Europe than other industrial areas Estimated median exposure and IQR Cumulative exposure (ppm-yr): IQR = 0.77–2.87 for controls; median = 1.95, IQR = 0.83–7.25 for cases Average intensity (ppm): IQR = 0.08–0.16 for controls; median = 0.08, IQR = 0.08–0.44 for cases
Exposure assessment | In-person interviews using structured and occupational specific and detailed questionnaires (e.g., tasks, working environment, time on each task) for lifetime jobs held at least 1 year. Expert assessment (blinded) by exposure assessment teams (with knowledge of plants in their study area) coded jobs for exposure to specific agent and assessed the frequency, confidence, intensity of exposure. Cumulative exposure defined as product of intensity, duration, and frequency of exposure. Confidence = expected percent of workers exposed in a given job (possible, probable, definite) Assessment of organic exposures were reevaluated at a later date blinded to the previous assessment and disease status. For TCE, the agreement was 83% in 1 country and 100% in 2 countries (not done in the 4th country because of unlikely exposure to TCE)
Assessment of potential confounders | Interviews: Lifestyle factors, especially tobacco consumption, anthropometric measures 1 year before diagnosis, and personal and familial medical history
Disease assessment | Histologically confirmed by study experts using standard confirmation and disease classification. ICD-0-2, Code C.64
Charbotel et al. (2006); Charbotel et al. (2009)
Related References | Fevotte et al. (2006)
Geographic Location | Arve Valley, France
Population Characteristics
Cases: selection and ascertainment | [underlined: Cases]: 86 cases RCC (19 deceased), 67% men [underlined: Case eligibility criteria]: Deceased or living identified retrospectively from medical (urology and oncology) practitioners 1993–2003 [underlined: Participation rate]: Cases 74%; controls 78%; follow-up questionnaire sent to non-participants
Controls: selection and ascertainment | [underlined: Referents]: 326 (7 deceased); 70% men [underlined: Referent eligibility criteria]: Patients (without kidney cancer or disease or urinary tract cancer) randomly selected from the same practitioners as cases [underlined: Matching criteria]: Age, gender (matched 4:1)
Study Design and Analytical Methods | Hospital-based: Multivariate analysis using variables with 10% differences (4 classes of smoking and 3 classes of BMI) between cases and controls; Analysis performed for ever exposure, cumulative exposure, and combined cumulative & peak exposure. Additional analyses for higher TWA exposure thresholds (35, 50, and 75 ppm) and for co-exposure to cutting, petroleum and/or other mineral oils (Charbotel et al. 2009); Sensitivity analysis to assess sources of misclassification (proxy, older patients, jobs with high confidence)
Exposure Data and Information Assessment
Exposure: levels and co-exposures | Region has high prevalence and high degree of exposure to TCE because of its use as a degreaser in the widespread screw-cutting industry Estimated TCE concentrations associated with quantitative ranking: low = 5–150 ppm-yr; medium = 155–335 ppm-yr; high ≥335 ppm-yr. Among controls the median exposure for low, medium, and high categories = 60, 252, and 630 ppm, respectively. Among cases median exposure = 30, 300, and 885 ppm, respectively Co-exposure to cutting oils, petroleum oils, and other mineral oils
Exposure assessment | Telephone interviews using medical and occupational questionnaires, with subject or next of kin, focusing on screw-cutting industry (TCE used); Exposure to TCE and other substances assigned using expert and task exposure matrix (JTEM) for screw-cutting industry. Exposure to TCE was semi-quantitative; ranked categories
Assessment of potential confounders | Questionnaire: familial kidney disease and medical history, such as kidney stones, infection, chronic dialysis, hypertension and use of drugs (anti-hypertensive drugs, diuretics, and analgesics); BMI, lifestyle considered smoking habits (pack-years) and coffee consumption. No significant differences in most of these characteristics were found in univariate analysis except for BMI and smoking
Disease assessment | Mainz classification; histologically confirmed
Brüning et al. (2003)
Related References | Vamvakas et al. (1998) (same area but no overlap)
Geographic Location | Arnsberg and 30 km surrounding area, Germany
Population Characteristics
Cases: selection and ascertainment | [underlined: Cases]: 134 RCC (113 incident, 21 deceased) [underlined: Case eligibility criteria]: People with nephrectomy 1992–2000 from urology department serving the area (1 hospital) [underlined: Participation rate]: 83% cases, controls NR
Controls: selection and ascertainment | Referents: 401 Referent eligibility criteria: People in hospital for surgery or geriatrics without dementia or diagnosis of cancer Matching criteria: sex, age (5 yr) 3:1 ratio (frequency-matched)
Study Design and Analytical Methods | Hospital-based: Conditional logistic regression for three types of exposure assessments, and for duration and time since first and last exposure for self-assessed exposure Adjusted for sex, age (from matching), and smoking
Exposure Data and Information Assessment
Exposure: levels and co-exposures | Levels NR but estimated to be 400 to 600 ppm during hot dipping and >100 ppm overall (Cherrie et al. 2001) Arnsberg area is a small geographical area with large number of companies in the metal process industries. TCE use was widespread and only two solvents were used in the industry. Exposure prevalence among controls varied by exposure assessment: Very high (for jobs associated with TCE exposure) using CAREX (80%) to 10% using self-reported exposure Regulatory measures were enforced starting in the 1980s
Exposure assessment | Interview questionnaire (as used by Vamvakas et al. (1998)) (approx. 16% proxies for deceased cases used, no proxies for controls); No information on whether interviewers blinded to case status Exposure assessed via three methods: (1) job/industry (ever and longest held) associated with exposure using CAREX database (which is based on expert assessment) and applying JEM, (2) agent-specific (not specific for TCE) using British JEM (duration, probability, and intensity) for jobs held for >1 year, (3) self-assessed frequency and duration of exposure to TCE and narcotic symptoms (comparable to Vamvakas et al. (1998) exposure assessment)
Assessment of potential confounders | Questionnaire/interview: Smoking, BMI, analgesics use. Cases and controls similar with respect to obesity (BMI >30), analgesics use, sex, and age
Disease assessment | Histologically confirmed
Vamvakas et al. (1998)
Related References | None (same area but no overlap with Brüning et al. (2003))
Geographic Location | Arnsberg (city), Germany
Population Characteristics
Cases: selection and ascertainment | [underlined: Cases]: 58 RCC [underlined: Case eligibility criteria]: People with nephrectomy between 1987 and 1992 at a county hospital [underlined: Participation rate]: 87% cases, 75% controls
Controls: selection and ascertainment | Referents: 84 Referent eligibility criteria: Accident patients at 3 nearby hospitals (not the same hospital as cases) in 1993 without kidney cancer (sonograph) Matching criteria: None
Study Design and Analytical Methods | Hospital-based: Multivariate logistic regression by exposure category (no, low, medium, high). Stratified by age analysis (Mantel-Haenszel). Adjusted for age, gender, smoking, blood pressure, and diuretic intake
Exposure Data and Information Assessment
Exposure: levels and co-exposures | Levels NR but estimated to be 400 to 600 ppm during hot dipping and >100 ppm overall (Cherrie et al. 2001) Arnsberg area is a small geographical area with a large number of companies doing metal and electronics work. TCE use was widespread and one of only two solvents (other was carbon tetrachloride) used in the industry Most subjects were involved in metal degreasing, without personal protective equipment. According to walkthrough surveys and interviews with employees and health professionals, degreasing procedures were done in open conditions above 60°C, and TCE was used to clean arms and hands, cloths, floors, etc.
Exposure assessment | Interview using structured questionnaire (not blinded) by physician on occupational history and exposure to multiple substances with subject or proxy. Follow-up info on exposure to TCE and tetrachloroethylene; Detailed info obtained from employer liability insurance Exposure level based on combination of exposure duration and frequency and severity of acute pre-narcotic symptoms
Assessment of potential confounders | Interview: smoking, alcohol consumption, BMI, blood pressure, diuretics intake, and exposure to other known carcinogens—asbestos, cadmium, gasoline and/or other petroleum products. Cases and controls similar with respect to alcohol consumption, BMI, percentage of males
Disease assessment | Histologically re-confirmed (double blind). All cases arose from tubule epithelium
Christensen et al. (2013)
Related References | Siemiatycki (1991)
Geographic Location | Montreal (Canada)
Population Characteristics
Cases: selection and ascertainment | [underlined: Cases:] 177 RCC; 48 liver cancer [underlined: Case eligibility criteria]: Male Canadian citizens, ages 35–70, incident cases 1979–1985 identified from 18 major hospitals [underlined: Participation rate]: 82% cases, 72% controls (total study population)
Controls: selection and ascertainment | [underlined: Referents]: 533 population controls; 1,999 cancer controls for kidney cancer and 1,834 for liver cancer [underlined: Referent eligibility criteria]: Population controls randomly selected from electoral records. Cancer controls - no more than 20% of one cancer, excluded lung and contiguous sites for the index cancer; Specific cancers not reported [underlined: Matching criteria]: Age, sex
Study Design and Analytical Methods | Hospital and population-based: Unconditional logistic regression using each type of control and pooled (weighted) controls and controlling for SES, ethnicity, interview type (self or proxy), smoking, coffee, alcohol; Risk calculated for any and substantial exposure. Exposures occurring 5 years before diagnosis were excluded
Exposure Data and Information Assessment
Exposure: levels and co-exposures | NR Exposure prevalence to TCE: ≤2% of cancer controls or population controls had substantial exposure and 3% had any exposure Occupations considered to have the highest exposure were mechanics and repairmen, metal machining occupations, electrical and electronics and metal shaping and formulation
Exposure assessment | In person interviews (with subject or proxy) obtaining detailed information on lifetime occupational history and duration in 13 specific occupations/industries and seven jobs with specific exposures, and PPE. Proxy interviews were done for 12% of population controls and 14% of kidney cancer cases Expert (team) assigned exposures based on reported job histories for close to 300 substances and rated the confidence, frequency, and intensity of each exposure. Assessor blinded to case-control status. Substantial exposure based on duration, frequency, confidence, and concentration
Assessment of potential confounders | Questionnaire/interviews: age, SES, ethnicity, interview type (self or proxy), and lifestyle factors (such as smoking, alcohol consumption)
Disease assessment | Histologically confirmed
Pesch et al. (2000b)
Related References | Pesch et al. (2000a)
Geographic Location | Germany
Population Characteristics
Cases: selection and ascertainment | [underlined: Cases]: 935 RCC (570 males and 365 females) [underlined: Case eligibility criteria]: German nationals (no age limit) from large hospitals 1990–1995 [underlined: Participation rate]: 88% cases, 71% controls
Controls: selection and ascertainment | Referents: 4,298 Referent eligibility criteria: German nationals randomly selected from local residency registers Matching criteria: Region, sex, age (5 yr) (1:4)
Study Design and Analytical Methods | Population-based: Conditional logistic regression adjusting for smoking (pack-years) and matching variables (region, sex, age) for exposure index (medium, high, substantial) using the low-exposure group as the reference
Exposure Data and Information Assessment
Exposure: levels and co-exposures | NR; no information on the types of job exposed to TCE Prevalence of substantial TCE exposure was low among cases (4% to 10%) and varied by type of JEM Includes the Arnsberg and other regions; NAS (2006) estimated that most subjects had minimal contact with TCE, averaging concentrations of 10 ppm or less
Exposure assessment | Interview using structured questionnaires; Exposure assessed using two JEM (British, German) and a job task-exposure matrix (JTEM), which provided an expert assessment of probability of exposure and intensity to a given agent Life-time exposure (exposure index) was the product of probability, duration, and intensity of exposure summarized across jobs for both JEM and JTEM
Assessment of potential confounders | Questionnaire/interview: various measures of smoking, socioeconomic status, analgesics use, and BMI. SES was an independent risk factor for kidney cancer among women. Cases and controls did not differ in BMI, education, age, region, and smoking status, and analgesics use
Disease assessment | Histologically (95%) or sonographically (5%) confirmed
Dosemeci et al. (1999)
Related References | Chow et al. (1994)
Geographic Location | Minnesota (USA)
Population Characteristics
Cases: selection and ascertainment | [underlined: Cases]: 438 (273 men, 165 women) [underlined: Case eligibility criteria]: Newly diagnosed white cases RCC 1988 to 1990 from state cancer registry; deceased cases excluded [underlined: Participation rate]: 87% cases, 86% controls; Occupational analysis with complete personal interviews: 64% cases; 97% controls
Controls: selection and ascertainment | [underlined: Referents]: 687 (462 men, 225 women) [underlined: Referent eligibility criteria]: Randomly selected (random digit dialing) (ages 20 to 64) or systematic selection from health care financing agency (ages 65 to 85 yr old) white controls [underlined: Matching criteria]: Age and sex stratified
Study Design and Analytical Methods | Population-based: Logistic regression controlling for age, smoking, hypertension status, use of diuretic or anti-hypertension drugs, BMI; Risk for ever-exposed reported separately for men and women
Exposure Data and Information Assessment
Exposure: levels and co-exposures | NR Exposure prevalence to TCE among controls was 10%
Exposure assessment | In-person interview with questionnaire for usual and most recent occupation, employment duration and duration for industries with specific exposure; Exposure assigned using JEM which linked occupation/industry code to exposure to chemicals (TCE and other chlorinated hydrocarbons). Interviewer blinded to case/control status and proxy interviews excluded from analysis
Assessment of potential confounders | Questionnaire/interview: demographic and ethnic variables, residential history, smoking habits, medical history, and drug use
Disease assessment | Histologically confirmed

RCC = renal-cell cancer; NR = not reported; BMI = body mass index; GST = glutathione-S-transferase; IQR = interquartile range; ppm = parts per million; TCE = trichloroethylene; ICD = International Classification of Diseases; TWA = time-weighted average; JTEM = job-task exposure matrix; CAREX = CARcinogen EXposure (Canada); JEM = job exposure matrix; SES = socioeconomic status; PPE = personal protective equipment; NAS = National Academy of Science.

Table D-3 Study Descriptions and Methodologies: Case-control Studies of Trichloroethylene Exposure and NHL and Related Subtypes

| Study Description and Methodology
Christensen et al. (2013)
Related References | Siemiatycki (1991)
Geographic Location | Montreal, Canada
Population Characteristics
Cases: selection and ascertainment | [underlined: Cases]: 215 NHL [underlined: Case eligibility criteria]: Male Canadian citizens, ages 35–70, incident cases 1979–1985 identified from 18 major hospitals [underlined: Participation rate]: 82% total cancer cases (also used as cancer controls), 72% total population controls (used for analysis of 11 cancer sites)
Controls: selection and ascertainment | [underlined: Referents]: 2,341 cancer controls, 533 population controls [underlined: Referent eligibility criteria]: Population controls randomly selected from electoral records; cancer controls - no more than 20% of one cancer, excluded lung and contiguous sites for the index cancer; Specific cancers not reported [underlined: Matching criteria]: Age, sex
Study Design and Analytical Methods | Hospital and population-based: Unconditional logistic regression using each type of control and pooled (weighted) controls controlling for age, ethnicity, SES, interview type (self or proxy); Risk calculated for any and substantial exposure. Exposures occurring 5 years before diagnosis were excluded
Exposure Data and Information Assessment
Exposure: levels and co-exposures | Levels NR Exposure prevalence to TCE very rare; ≤2% of cancer controls or population controls had substantial exposure and 3% had any exposure Occupations considered to have the highest exposure were mechanics and repairmen, metal machining occupations, electrical and electronics and metal shaping and formulation
Exposure assessment | In-person interviews (with subject or proxy) obtaining detailed information on lifetime occupational history, PPE, and duration in 13 specific occupations/industries and seven jobs with specific exposures; Proxy interviews were done for 12% of population controls and 21.9% of cases Expert assessment (team) translated jobs into potential exposure for close to 300 substances and rated the confidence, frequency, and intensity for each exposure. Assessor blinded to case-control status. Substantial exposure based on duration, frequency, confidence, and concentration
Assessment of potential confounders | Questionnaire/interviews: age, SES, ethnicity, interview type (self or proxy), and lifestyle factors (such as smoking, alcohol consumption)
Disease assessment | Histologically confirmed
Cocco et al. (2013)
Related References | Includes populations reported by Cocco et al. (2010); Miligi et al. (2006); Orsi et al. (2010); Purdue et al. (2011a)
Geographic Location | Multiple centers Europe, U.S. SEER regions
Population Characteristics
Cases: selection and ascertainment | [underlined: Cases]: 3,788 [underlined: Study eligibility criteria]: Study selected had (1) complete occupational history for all study participants, (2) expert exposure assessment to TCE, (3) incident NHL cases, and (4) histological information available for each case
Controls: selection and ascertainment | Referents: 4,279 Matching criteria: Age and sex (frequency or individually) except MIS, selected to represent age and sex distribution in general population Participation rate: see individual studies
Study Design and Analytical Methods | Pooled analysis of four case-control studies (EPILYMPH, NCI-SEER, ENGELA, MIS): Risks calculated for ever, probability, intensity, frequency, and duration of exposure, and intensity, duration, and frequency among high probability subjects and all subjects using unexposed as reference group and calculating linear trend test. Unconditional logistic regression was used for NHL and NHL subtypes. Polytomous regression analysis was used for NHL adjusting for age, gender, and study. Fisher statistics using Bonferroni correction were conducted to test chance probability of trends for 4 exposure metrics. Sensitivity analysis also conducted; excluded subjects exposed to benzene.
Exposure Data and Information Assessment
Exposure: levels and co-exposures | 9% of subjects ever exposed to TCE and 1% had high probability of exposure No assessment of exposure to other solvents but benzene not shown to be a confounder
Exposure assessment | Expert assessment of questionnaire data, workplace inspection, industrial hygiene report and experience used to assign scores of intensity (4-point scale related to OSHA PEL), frequency (4-point scale on work time in contact with agent), duration, and probability of exposure (harmonized using a priori JEM). The objective was to harmonize the exposure assessment from the four studies
Assessment of potential confounders | NR in pooled analysis
Disease assessment | NHL incidence: InterLymph Consortium classification
Cocco et al. (2010)
Related References | Besson et al. (2006) (Same EPILYMPH study population—association of alcohol and smoking on NHL risk) Included in pooled InterLymph analysis: Cocco et al. (2013)
Geographic Location | Multiple centers in Europe (Czech Republic, France, German, Ireland, Spain)
Population Characteristics
Cases: selection and ascertainment | [underlined: Cases]: 2,348 lymphoma (analysis for histologic subtypes of B-NHL including multiple myeloma) [underlined: Case eligibility criteria]: Consecutive adult lymphoma at participating centers 1998–2004 [underlined: Participation rate]: Cases 88%; population controls 52%; hospital controls 81%
Controls: selection and ascertainment | Referents: 2,462 Referent eligibility criteria: Germany & Italy: Randomly selected from population; Others: Hospital controls (diagnoses other than cancer, infectious and immunodeficiency diseases) Matching criteria: Age (5 yr), sex, residence
Study Design and Analytical Methods | Multi-center population and hospital-based (EPILYMPH Study): Unconditional logistic regression adjusting for age, education, and center using unexposed to any solvent as the reference group and calculated for ever exposed, combined confidence, intensity and frequency, and cumulative exposure (among subject with exposure assessed as having high degree of confidence) for histologic subtypes of NHL; Bonferroni correction for multiple comparisons
Exposure Data and Information Assessment
Exposure: levels and co-exposures | NR TCE exposure prevalence is low: For B-cell lymphoma, 5% among controls with high confidence of exposure, 2% had high cumulative exposure Approximately one third of chlorinated aliphatic solvent-exposed workers had concurrent exposure to benzene, toluene, or xylene
Exposure assessment | In-person interviews with structured questionnaires: Detailed lifetime occupational history for jobs held more than 1 year; Detailed questionnaire on tasks, processes, and PPE for exposures of a priori concern Expert review of questionnaire and assessment of 43 agents according to confidence, intensity, and frequency; Cumulative exposure scores were calculated based on intensity, duration, and frequency
Assessment of potential confounders | Questionnaire/interview on social and demographic variables, lifestyle, health history
Disease assessment | 2001 WHO Classification, 20% centrally reviewed by pathologist, B-NHL and major subtypes and Hodgkin lymphoma including multiple myeloma
Deng et al. (2013)/Wang et al. (2009b)
Related References | Morton et al. (2003); Zhang et al. (2004)
Geographic Location | Connecticut (USA)
Population Characteristics
Cases: selection and ascertainment | [underlined: Cases]: 601 NHL (inc. DLBCL, FL, CLL/small lymphocytic-lymphoma); 518 for genotype analysis [underlined: Case eligibility criteria]: Women 21–24 years old without history of other cancer (except non-melanoma skin cancer) and residents of Connecticut [underlined: Participation rate]: Cases 72%; Controls - RDD 69%, Health care 47%
Controls: selection and ascertainment | [underlined: Referents]: 717; 597 for genotype analysis [underlined: Referent eligibility criteria]: Selected via RDD (<65) or Medicare/Medicaid service files (≥65) in Connecticut [underlined: Matching criteria]: Age (5 yr frequency)
Study Design and Analytical Methods | Population-cancer registry-based: Unconditional logistic regression adjusting for age, family history of LHC (Wang only), alcohol consumption, race was used to calculate risks by ever, average (intensity and/or probability). Smoking, medical history, income, education levels and LHC history (Deng only) were not included in final models because they did not change the risk estimates. Polytomous logistic regression was used to evaluate using tertiles of cumulative exposure and histological subtype of NHL. Trends using continuous exposures; Deng reported risk estimates for ever vs. never stratified by immune gene polymorphisms
Exposure Data and Information Assessment
Exposure: levels and co-exposures | NR TCE exposure prevalence among controls was 11% for ever-exposed and 1.8% for medium/high exposure
Exposure assessment | Interviews using structured questionnaire on detailed lifetime occupational history on job titles, companies, and activities (jobs 1 yr or longer); Jobs were linked to a JEM, which assigned probability and intensity index of exposure to solvents for each occupation/industry. Individual assigned to exposure categories that combined duration with probability and intensity to estimate ever exposure, cumulative intensity, cumulative probability for each job, and the average intensity, average probability exposure across jobs. Exposure assessment was blinded to case/control status
Assessment of potential confounders | Age, family history of LHC, alcohol consumption, race (considered smoking, education, income, family history of immune disease)
Disease assessment | Histologically confirmed by study pathologists using 2001 WHO (REAL) classification ICD-O-2, M-9590-9642, 9690-9701, 9740-9750
Gold et al. (2011)
Related References | Chatterjee et al. (2004)
Geographic Location | Seattle, WA and Detroit, MI SEER sites
Population Characteristics
Cases: selection and ascertainment | [underlined: Cases]: 181 MM [underlined: Case eligibility criteria]: M+F alive at time of study, 35–74 years old, resident in SEER area and diagnosed between 2000 and 2002 [underlined: Participation rate]: 60% eligible cases alive at study date; 71% of contacted cases, 52% eligible (living) controls
Controls: selection and ascertainment | [underlined: Referents]: 481 (used for study of NHL; see Chatterjee et al. (2004)) [underlined: Referent eligibility criteria]: Randomly selected via random digit dialing (<65 yr) or Medicare files (>65 yr) from two SEER regions, 35–74 yr old with no previous HIV infection, multiple myeloma, or plasmacytoma [underlined: Matching criteria]: Age, sex, residence
Study Design and Analytical Methods | Population-based: Unconditional logistic regression, adjusted for age, sex, race, education, residence (SEER site) used to calculate risks for exposure categories—ever, exposure duration and cumulative exposure (unlagged and 10-yr lagged) for TCE and other chlorinated solvents. Sensitivity analysis considering low-exposed jobs as unexposed
Exposure Data and Information Assessment
Exposure: levels and co-exposures | Exposure prevalence of TCE among controls was 29% for ever-exposed and 14% in highest cumulative exposure category Highest cumulative exposure category >7,794 ppm Separate analyses for methylene chloride, tetrachloroethylene, 1,1,1-trichloroethane, chloroform and carbon tetrachloride (not clear if co-exposures)
Exposure assessment | In-person interview with subjects using questionnaires on work history (>1 yr from 1,941 cases, 1,946 controls); Job-specific questionnaires (tasks and work environment) for 20 solvent-related occupations for jobs held for at least 2 years Exposure metrics (probability, frequency, and intensity) were assigned by experts using questionnaire data and calendar-specific JEM for industries related to solvent exposure based on extensive literature review. Cumulative exposure was calculated as sum of the intensity, frequency, and duration of all exposed jobs with a probability of exposure >2 for each solvent Reviewer blind to case-control status
Assessment of potential confounders | NR
Disease assessment | SEER cancer registry (data from hospitals, physicians, laboratories, death certificates); ICD-O 2/3
Costantini et al. (2008)
Related References | Costantini et al. (2001); same population base as Miligi et al. (2006)
Geographic Location | 11 centers, Italy
Population Characteristics
Cases: selection and ascertainment | [underlined: Cases]: MM (6 centers): 263 cases; CLL: NR (7 centers), 2,737 total lymphohematopoietic (11 centers) [underlined: Case eligibility criteria]: All LH cancers (M+F) in 11 centers, 20–74 years of age 1991–1993 [underlined: Participation rate]: 83% MM cases, 76% controls; CLL NR
Controls: selection and ascertainment | [underlined: Referents:] MM: 1,100 (6 centers); CLL: NR (7 centers); total: 1,799 (11 centers) [underlined: Referent eligibility criteria]: Random sample of population registers [underlined: Matching criteria]: Age (5 yr), sex, region
Study Design and Analytical Methods | Population-based: Multiple logistic regression models controlling for age, sex, education, region; Analyses for exposure intensity (very low/low and medium/high) and duration (< and >15 years) using individuals without exposure to any of the listed chemicals as the referent group
Exposure Data and Information Assessment
Exposure: levels and co-exposures | Study regions chosen because of large presence of manufacturing industries using solvents or they were agricultural areas TCE prevalence among controls was 2.5% for medium/high and 3.5% for low/very low exposure
Exposure assessment | In-person interviews (subject or proxy) using job/industry specific questionnaires; Expert assessment (ranked) by regional industrial hygienists of job information on the probability (3 levels) and intensity (4-point scale) of exposure to solvents. Experts blinded to case-control status
Assessment of potential confounders | Interviews: Education, relevant lifestyle factors (such as smoking), residential history, extra occupational history, medical history (including X-rays, medications, diseases, and reproductive history) Characteristics (demographics and ever smoking) were similar among cases and controls
Disease assessment | Hospitals ICD-9 MM 203, CLL 204.1
Persson and Fredrikson (1999)
Related References | Pooled analysis of two studies Persson et al. (1989); Persson et al. (1993)
Geographic Location | Regional, Sweden
Population Characteristics
Cases: selection and ascertainment | [underlined: Cases]: 199 NHL, 106 (1989) + 93 (1993) [underlined: Case eligibility criteria]: NHL in 2 hospital registries 1989 study: 1964–1986; 1993 study: 1975–1984. 20–80 years old, resident in hospital catchment area, Swedish-born [underlined: Participation rate]: 1989: cases 96%; 1993: cases 90%, controls NR
Controls: selection and ascertainment | [underlined: Referents]: 479 population controls [underlined: Referent eligibility criteria]: population registry, 20–80 years old, resident in same catchment area as cases, Swedish-born; Unclear which years cases were recruited [underlined: Matching criteria]: No matching specified; eligibility criteria required same age range, similar residence, and citizenship
Study Design and Analytical Methods | Population-based: Mantel-Haenszel OR stratified by age and sex with 5-yr lag. Logistic regression if OR > 1.5 on separate analyses by exposures and occupations with at least 10 cases
Exposure Data and Information Assessment
Exposure: levels and co-exposures | NR TCE exposure prevalence among referents ~7%
Exposure assessment | Mailed questionnaire on occupational and leisure exposures, medical data. Self-reported exposure by rank category; Minimum 1 yr of exposure and exposure window of 5 to 45 yr before disease diagnosis; Not clear if interviewers were blinded to case-control status
Assessment of potential confounders | Smoking, medication, X-rays, pets assessed by questionnaire and evaluated in separate analyses. Unclear whether case and controls varied on demographic variables
Disease assessment | Cancer registry; 1989 study: not histologically confirmed; 1993 study: 2 histologically confirmed with 4% misclassification rate cf. clinical diagnosis ICD code NR
Nordström et al. (1998)
Related References | None
Geographic Location | Sweden
Population Characteristics
Cases: selection and ascertainment | [underlined: Cases]: 111 HCL [underlined: Case eligibility criteria]: Men identified from Swedish Cancer Registry 1987–1992 [underlined: Participation rate:] cases 91%; controls 83%
Controls: selection and ascertainment | [underlined: Referents]: 400 [underlined: Referent eligibility criteria]: National Population Registry [underlined: Matching criteria]: Age, sex, county
Study Design and Analytical Methods | Population-based: TCE: Logistic regression controlling for age; matching dissolved in analysis. Total solvents: multivariate analysis, controlling for exposure to herbicides, fungicides, impregnating agents, all exhausts for ever-exposure and univariate exposure, controlling for age and duration of exposure
Exposure Data and Information Assessment
Exposure: levels and co-exposures | Level: NR TCE exposure prevalence among controls 7%
Exposure assessment | Mailed questionnaire on complete working history, information on leisure activity and protective equipment. Ever exposed—at least 1 working day and induction of at least 1 yr.; Reviewer of questionnaire data blinded to case-control status. Proxy answers for 3 cases and 5 controls
Assessment of potential confounders | Smoking not a risk factor for HCL. No information on other lifestyle habits
Disease assessment | NCI classification, 20% and doubtful diagnosis reviewed by 3 pathologists; histological subtypes
Hardell et al. (1994)
Related References | Hardell et al. (1981)
Geographic Location | Umeå region, Sweden
Population Characteristics
Cases: selection and ascertainment | [underlined: Cases]: 105 NHL [underlined: Case eligibility criteria]: Men 25–85 yr old, diagnosed at hospital pathology dept. 1974–1978 [underlined: Participation rate]: NR
Controls: selection and ascertainment | [underlined: Referents]: 355 NHL [underlined: Referent eligibility criteria]: National Population Registry, National Registry for Causes of Death [underlined: Matching criteria]: Age, sex, place of residence, vital status; deceased subjects also matched by year of death
Study Design and Analytical Methods | Population-based: TCE-specific analysis: Mantel-Haenszel stratified analysis by age and vital status. Organic solvents class analysis: Multivariate logistic regression controlling for phenoxyacetic acids, chlorophenols, DDT, asbestos, for ever-exposed, and univariate analysis for subtype and stage of NHL
Exposure Data and Information Assessment
Exposure: levels and co-exposures | NR Prevalence of TCE exposure among controls was 1%
Exposure assessment | Mailed questionnaire to subjects and next of kin: self-reported complete working history, information on leisure activity and protective equipment; Low grade exposure—<1 wk continuous or 1 mo; high-grade greater than that; Reviewer of questionnaire data (not clear that reviewer was an expert in exposure assessment) blinded to case-control status
Assessment of potential confounders | NR
Disease assessment | Histologically confirmed; reexamined Rappaport classification

NHL = non-Hodgkin lymphoma; SES = socioeconomic status; NR = not reported; TCE = trichloroethylene; PPE = personal protective equipment; SEER = Surveillance, Epidemiology and End Results Program; MIS = Multicentre Italian Study; NCI = National Cancer Institute; OSHA = Occupational Safety and Health Administration; PEL = permissible exposure limit; WHO = World Health Organization; DLBCL = diffuse large B-cell lymphoma; FL = follicular lymphoma; CLL = chronic lymphocytic lymphoma; RDD = random digit dialing; LHC = lymphohematopoietic cancers; REAL = Revised European-American Lymphoma classification; MM = multiple myeloma; M = males; F = females; HIV = human immunodeficiency virus; ppm = parts per million; OR = odds ratio; HCL = hairy-cell leukemia.

## D.2 Assessment of Potential Biases and Other Characteristics

Each primary study was systematically evaluated for its ability to inform the cancer hazard identification using similar questions and guidelines outlined in the protocol (see https://ntp.niehs.nih.gov/NTP/roc/thirteenth/Protocols/TCE_Protocol12-31-13_508.pdf). Studies were evaluated for elements of study quality (potential for biases), study sensitivity, the ability to evaluate exposure-response relationships, and the potential for confounding (see Section 3.3.2). The guidelines describe the ideal methods and design for each study element. Two reviewers evaluated study quality in concert with input from technical advisors and from a public webinar(https://ntp.niehs.nih.gov/go/711176).

The study quality elements for each individual study that contribute to its ability to inform the cancer hazard evaluation are evaluated and summarized in Table D-4 (cohort and nested case-control studies), Table D-6 (kidney and liver cancer case-control studies) and Table D-8 (NHL case-control studies). These elements include the following: (1) the potential for selection and attrition bias (unlikely, possible, or probable), (2) the quality of the exposure and disease assessment (good, adequate, limited to adequate, and limited) and the (3) likelihood of and concern for exposure or disease misclassification, and whether such misclassification is considered differential or nondifferential. The general terms used for defining the potential for selection or information bias (exposure and disease misclassification) are as follows:

- Unlikely/minimal: Information from study designs and methodologies indicate that they are close to the ideal study characteristics and the potential for bias is unlikely or minimal. (See below for a description of the ideal characteristics for each specific study element.)
- Possible: Study designs or methodologies are close to but less than ideal, recognizing that in observational studies, there is almost always some methodological or informational limitation and thus some potential for certain types of bias.
- Probable: Study designs or methodologies suggest that the potential for a specific type of bias is likely.

In some cases, there is insufficient information to evaluate the level of concern. If adequate information is available, each type of bias is also characterized as to whether it is differential or non-differential. Differential (systematic) biases in the selection of study participants or information assessment are related to both exposure and disease status and have the potential to bias findings in one direction or another, whereas non-differential (random) biases, which are not related to both exposure and disease, tend to reduce the precision of the risk estimates and often bias the findings toward the null. For example, occupational cohort studies may have limited exposure data across exposure groups, increasing the potential for non-differential exposure misclassification, and may also have the potential for a healthy worker (hire or survival) effect, a type of selection bias that tends to bias findings away from finding an effect (if present) in studies where the comparison group comes from the general population.

The presence of a potential bias in a study does not necessarily mean that the findings of the study should be disregarded. For example, the effect of confounding may only account for a small percentage of the magnitude of the risk estimate. Therefore, an important step in the process of evaluating biases is to determine the probable impact of the described biases on study results—that is, the magnitude of distortion and the direction in which each bias is likely to affect the outcome of interest (if known). The impact of the potential bias or confounding on the study findings is discussed in the cancer hazard assessment (see Sections 4.1, 5.1, and 6.1).

### D.2.1 Selection Bias

Selection or attrition bias was considered unlikely if cohorts or cases and controls represented the same underlying population, there was little or no evidence of a healthy worker hire or survival effect, cases and controls were selected by similar criteria that were not related to trichloroethylene exposure, participation was high and not related to exposure or disease status, and loss to follow-up was low (preferably <5%) and similar in both groups.

### D.2.2 Quality of Exposure Assessment and Misclassification of Exposure

Exposure assessment: A ranking of good was given to studies having many of the following elements: industrial hygiene or biomonitoring data, individual detailed job-task exposure matrices, job or task descriptions, knowledge of the exposure setting, consideration of frequency, confidence and intensity, expert assessment, and/or calendar period-specific exposure data. It should be noted, for example, that not all job-exposure or job-task exposure matrices are of equal quality; some are based only on generic occupational or industrial categories or codes, rather than information specific for the plant or industry under investigation, and this may result in substantial misclassification of exposure.

The assessment of exposure misclassification is complex and involves multiple factors such as the likelihood that subjects were ever exposed and misclassification of exposure level, and thus labels such as unlikely, possible, or probable, do not adequately capture the complexity of exposure misclassification; thus, his study element is evaluated qualitatively rather than by category.

### D.2.3 Quality of Case Ascertainment and Disease Misclassification

Case ascertainment: A ranking of good was given to studies where multiple or verified sources were used to identify vital status and/or cases/deaths and ascertainment of cases/deaths was complete or close to complete.

Disease misclassification, for each endpoint of concern, is ranked as unlikely, possible, or probable, based on the sensitivity and specificity of the disease diagnosis, i.e., whether cases were histologically confirmed and whether the system of disease classification was based on newer ICD classifications. The potential for bias in case or death misclassification is typically nondifferential, but can also be differential, i.e., differ by exposure status.

### D.2.4 Study Sensitivity and Exposure-response Relationships

The study sensitivity and exposure-response elements evaluated and summarized in Table D-5 (cohort and nested case-control studies), Table D-7 (kidney and liver cancer case-control studies) and Table D-9 (NHL case-control studies). A study’s sensitivity is defined as the ability to detect an effect of exposure, which is principally a function of study size (specifically, the numbers of trichloroethylene-exposed subjects in cohort studies or the numbers of trichloroethylene-exposed controls in case-control studies), the length of follow-up and levels of exposure to trichloroethylene. A ranking of good was given to studies having many of the following elements: larger numbers of exposed subjects or cases, adequate length of follow-up, high levels of exposure, long exposure duration, large groups or subgroups with a range of exposures from low/medium to high to permit the evaluation of exposure-response relationships and little concern about exposure misclassification. Factual information on these elements is also presented in these tables. Studies less than ideal were assigned rankings of adequate or limited. The adequacy of data (range of exposure) and methods used to evaluate exposure-response relationships were also evaluated.

### D.2.5 Overall Ranking of Studies

In general, studies given the most weight in the cancer hazard evaluation had the following characteristics:

- little evidence of the potential for selection bias
- adequate to good exposure assessment with little evidence for exposure misclassification
- incidence studies, histologically confirmed case or use of more recent classification codes
- adequate sensitivity (e.g., sufficient power, length of follow-up and adequate levels of exposure) to detect an effect of exposure
- potential confounding is considered minimal
- appropriate methods for evaluating exposure-response relationships

The ranking of study sensitivity considered multiple factors. For example, very low (or uncertain) exposure levels or duration and/or a high probability of exposure misclassification may result in the study being inadequate to evaluate cancer risk despite adequate study size, or a lack of other biases or evidence of potential confounding. Conversely, high exposure levels may partly compensate for smaller study sizes in some studies.

Based on the overall evaluation, studies were broadly grouped according to their ability to inform the cancer hazard evaluation based on the above characteristics, as follows:

- high utility: most elements were ranked as having little concern for biases or misclassification or the quality of the element was ranked as good to adequate
- moderate utility: most elements were ranked as having some concern bias or information misclassification, or the quality of the element was ranked as limited
- low to moderate utility: similar to moderate but lower study sensitivity and somewhat greater concerns for exposure or disease misclassification
- low utility: considerable concerns about exposure misclassification or systematic biases, and low study sensitivity

Not all elements may equally affect the overall ability of a given study to inform the evaluation. The quality of the exposure assessment and potential for exposure misclassification was given considerable weight in ranking the studies. In addition, studies with high probability of systematic biases were rated low. The impact of identified biases, in terms of both direction and magnitude, and potential for confounding, is evaluated in the cancer hazard assessment in the light of the study findings (Sections 4, 5, and 6). For example, the potential for selection or participation bias, or confounding does not always negate a positive association, if the observed risk estimate is high.

Table D-4 Cohort and Nested Case-control Studies of Trichloroethylene Exposure: Summary of Study Quality

Study and Number of TCE-exposed Subjects | Selection Bias and Completeness of Follow-up | Quality of Exposure Assessment and Misclassification of Exposure | Quality of Case Ascertainment and Misclassification of Diagnosis
Nordic Studies
Vlaanderen et al. (2013) Cancer registry-based (Nordic Occupational Cohort); Nested case-control analysis 76,130 kidney cancer cases (41% F); 380,650 controls (41% F); 23,896 liver cancer cases (38% F), 119,480 controls (38% F) 1960–90 to 2003–05 Mortality | Unlikely Adequate methods (census, cancer registry, population registries) for identifying cohort; Controls matched to cases by age, sex, country Loss to follow-up: Not reported; assume complete because of linkage with registry data | Limited: Quantitative, calendar-year specific, country specific, generic JEM; Exposure was assigned based on limited occupation information on specific jobs from census data and assumed no changes in jobs between censuses. The JEM had poor sensitivity and did not account for job tasks, heterogeneity within jobs and changes over time Use of population-wide occupational exposure database may lack precision for individual participants Exposure misclassification (with respect to whether workers were ever exposed) is a concern, and likely to be considerable, because of the population-wide occupational exposure database, and limited occupational information for individual workers. The probability of exposure may be higher among subjects in the highest exposed groups. Misclassification of exposure intensity is also a concern | Case ascertainment: Adequate Linkage via cancer registry Misclassification of diagnosis: Possible for NHL, unlikely for kidney and liver RCC (histologically confirmed), liver and MM; Diagnosis of NHL based on broad ICD-7 classification that includes several diseases and does not differentiate subtypes
Hansen et al. (2013) Pooled Nordic cohort incidence analysis; 5,553 workers (3,776 men, 1,777 women) Axelson et al. (1994), Anttila et al. (1995), Hansen et al. (2001) | Unlikely Adequate methods to select cohort members. All workers with ≥1 urine TCA or air TCE measurement included in cohort. No evidence of HWE Loss to follow-up: Minimal; (<1%). | Adequate to good: Biomonitoring at the individual level (urine-TCA); Few data on individual industries or jobs of workers, cumulative exposure, and exposure duration; Diverse TCE-using industries included The U-TCA exposure assessment is expected to have high sensitivity, but specificity may be a concern if workers were exposed to other chlorinated solvents that are metabolized to TCA. In addition, because few measurements (2 to 3) were available for most subjects and many subjects (55% of Swedish study) had only 1 measurement, individuals classified as unexposed could have been exposed to TCE and U-TCA and U-TCA exposure misclassification related to intensity level may occur | Case ascertainment: Adequate Cases identified in cancer registries via ID linkage; only 0.1% of the cohort was lost to follow-up Misclassification of diagnosis: Possible for NHL, unlikely for kidney and liver Histologically confirmed in Swedish study; Diagnosis of NHL based on broad ICD-7 classification that includes several diseases and does not differentiate subtypes
Raaschou-Nielsen et al. (2003) Danish TCE blue-collar worker cohort; 40,049 workers approx. 70% men) Record linkage incidence study | Possible Cohort and comparison group differ with respect to socioeconomic status. Cohort included all “blue-collar” workers whereas reference population (Danish population) included both blue- and white-collar workers, which could lead to an under- or overestimate of expected cases for cancer sites that are associated with SES. Differences in SES may explain significant increase in all-cancer incidence (M and F) and of smoking-related cancers. Loss to follow-up: Minimal; authors report follow-up as being virtually complete | Limited: Employment as a blue-collar worker in a TCE-using company used as a surrogate for potential TCE exposure and size of company used as surrogate for estimated percentage of workers exposed to TCE. Limited characterization of exposure: Urine TCA and air TCE data for some workers but not used in exposure assessment Exposure misclassification (non-differential): is a concern. Only 19%–81% (41% overall) with estimated exposure to TCE (working in the same room that TCE was used); Employment duration before 1964 was not considered, which could attenuate exposure-duration relationships | Case ascertainment: Adequate Cases identified via ID linkage with cancer registry Misclassification of diagnosis: Possible for NHL, unlikely for kidney and liver Diagnosis of NHL based on broad ICD-7 classification includes several diseases and does not differentiate subtypes
Rocket engine testing or aircraft manufacturing workers
Lipworth et al. (2011) Burbank, CA (USA) aircraft manufacturing workers cohort; 5,443 (approx. 80% male) Mortality Study | Possible Adequate methods to select cohort: All workers with minimum of 1 year employment. Some evidence for HWE based on 9% decrease in all-cause and all-cancer mortality than CA and U.S. population Loss to follow-up: Minimal; 1.7% total cohort | Limited to adequate: Qualitative JEM for occupational job groups based on plant data; Workers classified by ever exposure, type of exposure (routine or intermittent) and duration of potential exposure. No quantitative exposure assessment or ranking of relative intensity of exposure Exposure misclassification is a concern (non-differential) for all analyses | Case ascertainment: Adequate Multiple sources used to determine vital status Misclassification of diagnosis: Possible (non-differential) for some tumor sites NDI using ICD at the time of diagnosis; possible concern for diagnosis of NHL Potential for missing cases that do not result in death for cancers with long survival (kidney and NHL), which would decrease precision
Radican et al. (2008) (mortality update); Blair et al. (1998) (incidence) Utah (USA) aircraft maintenance workers cohort; 7,204 (6,153 men, 1,051 women) Mortality and incidence study | Unlikely Adequate methods to select cohort: All workers potentially exposed to TCE included in exposed cohort. Little evidence for HWE Loss to follow-up: Not reported | Adequate to good: Semi-quantitative calendar year specific JEM constructed from detailed occupational information used to develop exposure scores for each job based on intensity, frequency, and duration of exposure. Each worker classified by cumulative exposure score and pattern of exposure; however, exposure records that specific subjects were missing, and information was based on position descriptions. Some limited air monitoring by job/task but not used in exposure assessment Exposure misclassification (with respect to whether workers were ever exposed) is a concern (non-differential). Misclassification regarding intensity level would most likely attenuate any exposure-response relationships | Case ascertainment: Adequate Use of state vital records and NDI for vital status (missing data NR) Misclassification of diagnosis: Possible (non-differential) for some tumor sites in mortality study NDI using ICDA-8 or 9, ICD-10. Underlying and contributing causes of death; possible concern for diagnosis of NHL; SEER (Utah) registry used for incident cases (1973–1999) so possible concern about earlier ICD classifications of NHL Potential for missing cases that do not result in death for cancers with long survival (kidney and NHL), which would decrease precision
Boice et al. (2006) Los Angeles (USA) rocket engine testing workers cohort; 1,111 men Mortality study Overlap with Zhao et al. (2005) cohort | Possible for external analyses Adequate methods to select cohort; all workers with adequate employment data included in cohort. Evidence of HWE based on 13% (significant decrease in all-cause mortality among test stand mechanics with any exposure to TCE) Loss to follow-up: Minimal; 3.1% missing vital status | Limited to adequate: Qualitative assessment of TCE exposure using test stand mechanics as a surrogate of exposure, exposure-based duration of employment using TCE, walk-through surveys and dates that TCE was used and duration of exposure from engine flush. No assessment of exposure intensity The probability of being exposed to TCE is greatest in analyses by test engine flush; however, exposure misclassification is still possible | Case ascertainment: Adequate Use of state vital records and NDI for vital status Misclassification of diagnosis: Possible (non-differential) for some tumor sites Death certificate using ICD at the time of diagnosis; possible concern for diagnosis of NHL Potential for missing cases that do not result in death for cancers with long survival (kidney and NHL), which would decrease precision.
Zhao et al. (2005) Los Angeles (USA) aerospace workers cohort Mortality; 6,044 men Incidence; 5,049 men | Unlikely Adequate methods to select cohort; all workers with potential exposure to TCE included in cohort Loss to follow-up: Minimal; (<0.1%) | Adequate to good: Semi-quantitative JEM (relative intensity), which was calendar-year specific, constructed using job titles and detailed description of job tasks. Each worker’s exposure classified by cumulative relative intensity scores to TCE and co-exposures, by calendar period. No quantitative exposure measurements Exposure misclassification is not a concern, especially among individuals with the highest cumulative exposure. Exposure misclassification between levels of cumulative exposure would most likely attenuate any exposure | Case ascertainment: Adequate NDI for cause of death (missing data NR) and multiple cancer registries used for diagnosis (missing data NR) Misclassification of diagnosis: Unlikely for incidence Incidence: ICD-O (extension of ICD-10). Deaths: ICD-9 and 10; Underlying and contributing causes of death
Morgan et al. (1998) Arizona (USA) aircraft manufacturing workers cohort; 4,733 (2,555 men, 2,178 women) Mortality study | Possible for external analysis Adequate methods to select cohort (all workers employed for specific dates) but evidence of HWE based on 15% significant decrease in all-cause mortality for TCE-exposed subcohort Loss to follow up: Minimal; appears to be 0.1% (excluded due to “missing information” but not clear if applies to vital status or other data) | Adequate: Semi-quantitative expert assessment, using JEM by job title and based on location of jobs in proximity to degreaser area, used to estimate exposure category scores. Exposure assessment is limited with respect to calendar year, confidence, frequency, or probability of exposure and information on tasks. Limited quantitative exposure measurements available during most of period TCE used (not reported or used in exposure assessment) The probability of being exposed to TCE is greatest among workers in the “high” and “peak” exposure categories. Exposure misclassification (with respect to whether workers were ever exposed) is more of a concern (non-differential) in the med/low exposure categories | Case ascertainment: Adequate Use of SSA, NDI, or state vital records Potential for missing cases that do not result in death for cancers with long survival (kidney and NHL), which would decrease precision Misclassification of diagnosis: Possible (non-differential) for some tumor sites Death certificate using ICD at the time of diagnosis (7 to 9); possible concern for diagnosis of NHL
Other industries: Cohort and nested case-control studies
Silver et al. (2014) New York State (USA) electronics manufacturing workers cohort; 24,037 men, 10,457 women (total cohort) Mortality study | Unknown for internal analysis used for TCE-exposed subcohort Strong evidence for healthy worker effect in total cohort; not clear if there is a healthy worker survival effect | Limited: Exposure assessment based on work history and dept.-year JEM, cumulative exposure assigned based on potential exposure to TCE (based on dept. use and board categories of position) and duration of TCE. No information on job tasks or exposure condition or levels of use. Exposure intensity could vary within a dept. and over time. Position title could not be used to compare exposure across dept. (except for classifying admin. staff as unexposed). Company records and work history incomplete, especially for time periods before 1974. Incomplete and contradictory work history records Exposure misclassification (with respect to whether workers were ever exposed) is a concern (non-differential) | Case ascertainment: Adequate Use of appropriate methods (State vital records or NDI) to ascertain vital status Young cohort (17% deaths) and potential for missing cases of cancers with long survival (especially kidney and NHL), which would decrease precision Misclassification of diagnosis: Possible (non-differential) for some tumor sites Death certificate using ICD code at time of death used; possible concern for diagnosis of NHL
Bahr et al. (2011) Kentucky (USA) uranium enrichment workers cohort; 5,535 men Mortality study | Probable Difficult to evaluate because of limited information. Selection of workers based on complete work histories; however, information about other eligibility criteria (e.g., age of workers, enrollment, number of subjects excluded due to missing data) were not provided. Evidence of HWE, based on ~20% to 30% decrease in all-cause mortality in TCE-exposed groups. Evidence of healthy worker survival effect Loss to follow-up: Not reported | Limited: Generic qualitative JEM based on work history but little data provided on ranking of probability of TCE exposure. No quantitative exposure measurements Exposure misclassification (non-differential) is a concern and likely to be substantial | Case ascertainment: Unknown Source and completeness of vital status and cause of death data NR Misclassification of diagnosis: Possible (non-differential) for some tumor sites Death certificate using ICD code at time of death used; possible concern for diagnosis of NHL Potential for missing cases of cancers with long survival (kidney and NHL), which would decrease precision
Yiin et al. (2009) Tennessee (USA) Uranium enrichment workers Nested case-control mortality study; 47,941 men and women 114 cases of multiple myeloma (ICD 203) | Possible Cohort selection based on employee roster for all workers employed in gaseous diffusion plant prior to 1985 (plant closing date) and employed >30 days; cases and controls selected based on availability of uranium dose data (appears complete) Loss to follow-up: NR | Limited to adequate: Individual cumulative exposure score for TCE assigned based on modified JEM that estimated levels for exposure activities by decade. Inadequate information to link monitoring data to workers and work history data missing information on building/work location. Limited information available on assessment Exposure misclassification (non-differential) is a concern | Misclassification of diagnosis of cases: Possible (non-differential) Cases of multiple myeloma (underlying and contributory causes of death, ICD 203) identified from death certificates (no other details reported)
Ritz (1999) Ohio (USA) uranium processing workers cohort; 2,972 men Mortality study | Possible Selection of workers based on all workers with data on chemical exposure and monitored for radiation exposure included in cohort, but 35% total cohort excluded due to absence of radiation records. Some evidence of HWE based on ~15% statistically significant decrease in all- cause mortality. Also, a possible bias if radiation exposure associated with TCE exposure Loss to follow up: Not reported | Limited to adequate: Semi-quantitative JEM for individual workers based on verified job title and department using company industrial hygienists and workers but does not appear to be calendar-period specific. Exposure categorized by 2 levels (light and moderate) and 2 categories of duration. No quantitative exposure measurements Exposure misclassification (with respect to whether workers were ever exposed) is a concern (non-differential). Most of the workers in this study had low levels of exposure | Case ascertainment: Adequate Use of appropriate methods (SSA or NDI Records) to ascertain vital status Misclassification of diagnosis: Possible (non-differential) for some tumor sites Death certificate (NDI) using ICDA-8 (external analysis) and ICD-9 (internal analysis); possible concern for diagnosis of NHL Potential for missing cases that do not result in death for cancers with long survival (kidney and NHL) which would decrease precision
Henschler et al. (1995) German cardboard manufacturing cohort; 169 men Incidence & mortality study of kidney cancer | Probable Selection of cohort may be based on cluster of renal cancers, which would bias towards an overestimate of the risk estimate. Comparison group from different countries from exposed cohort (if a bias, the direction would most likely be towards underestimating the risk estimate from using possibly inflated expected rates); Evidence for a HWE based on statistically significant 30% decrease in all cancer mortality Loss to follow-up: Minimal; 8% (refusal, ill-health, or untraced) suggesting most cases and deaths were identified | Limited: Exposure assigned based on job location in the plant and descriptions of plant conditions (walk-through and interview) for ever exposure only. Level and duration of exposure not characterized Although the exposure assessment was of limited quality (based on workspace), exposure to TCE occurred in an open system. Thus, exposure misclassification is not a concern for most workers, although exposure duration and intensity are likely to vary among workers. It is not clear if the unexposed workers included in the internal analysis could have had some exposure to TCE (no details are provided) | Case ascertainment: Limited Multiple methods used to identify deaths and cases such as hospital/medical records, rather than central death records or cancer registry. Different methods may have been used to assign cause of death or cases for exposed cohort (physicians and records and abdominal sonogram) than the general population in external analysis, which could potentially bias external (but not internal) analyses towards an overestimate of the risk estimate Misclassification of diagnosis: Unlikely for incidence, possible for deaths (but only 2 deaths reported) Deaths classified from medical records or physicians using ICD-9; different sources may vary in reliability. Histological confirmation of renal-cell cancer from incident cases (the only tumors that were reported)
Greenland et al. (1994) Massachusetts (USA) electrical manufacturing workers nested case-control study 15 deaths NHL, 12 kidney cancer, 9 liver cancer (men) | Probable Selection is not adequate because the case control study only included analysis of deaths for pensioned workers with job history for 7 selected chemicals and death benefit claims for specific time period. Cases were cancer deaths for specific sites. Controls (not matched to the cases) included any deaths “unrelated” to these exposures. No information on the size of the underlying cohort (males 21–90 years old employed before 1984 Loss to follow-up: Cohort selection based on deceased employees (known to pension fund) and appears that death certificate data were available for all cohort members | Limited: Qualitative JEM constructed based on job title and interviews and combined with work history used to classify workers as ever/never exposure. Doesn’t appear to be calendar specific; No quantitative exposure measurements Exposure misclassification (non-differential) is a concern and likely to be substantial. Exposure duration and intensity are likely to vary among workers classified as ever exposed | Misclassification of diagnosis: Unlikely for kidney and liver, possible for NHL Death certificate diagnoses verified using hospital records for subset of deaths Potential for missing cases that do not result in death for cancers with long survival (kidney and NHL) which would decrease precision
Wilcosky et al. (1984) Ohio (USA) rubber manufacturing workers nested case-control study; 6,678 (men) 9 cases of NHL (lymphosarcoma, ICD 200) | Unlikely Original cohort deaths (1,793) ascertained among life insurance benefit recipients (McMichael et al. 1974) so workers leaving early were excluded from analysis; however, only 2 deaths occurred in this latter group Loss to follow-up: Complete work histories available in 1964 (start of follow-up) | Inadequate: Qualitative assessment for ever work in area of authorized use of 1 or more of 25 chemicals based on solvent products that were authorized for use and is not known whether they were actually used. Individual work histories (department, dates, and job title) used to assign exposure Exposure misclassification (non-differential) is a serious concern and likely to be substantial | Misclassification of diagnosis of cases: Possible (non-differential) for some cancer sites Death certificate using ICD-8; possible concern for NHL. Potential for missing cases of cancers with long survival (kidney and NHL), which would decrease precision
Drinking Water Study
Bove et al. (2014) Cohort study (drinking water contamination) Camp Lejeune, NC and Camp Pendleton, CA (USA) 154,932 (Lejeune) 154,969 (Pendleton) Mortality Study | Unlikely Adequate methods for selecting cohort Cohort: All active service personnel eligible Loss to follow-up: Minimal; <2% | Limited: Reconstruction of exposure is based on historical sampling of two water supply systems in defined regions. Estimate of cumulative exposure based on duration at residence and modeled TCE concentration levels from the water supply system associated with the residence. No data on individual consumption; May have had errors in assignment of residential location Exposure misclassification (with respect to whether residents were ever exposed) is a concern) although to a lesser degree among individuals with higher estimated cumulative exposure. Exposure misclassification regarding cumulative exposure would most likely attenuate any exposure-response relationship | Case-ascertainment: Adequate Multiple sources used to determine vital status including the NDI Potential for missing cases of cancers with long survival (kidney and NHL), which would decrease precision Misclassification of diagnosis: possible for some tumor sites. Death certificate; underlying and contributing causes; ICD NR; possible concern for NHL

TCE = trichloroethylene; F = females; JEM = job exposure matrix; NHL = non-Hodgkin lymphoma; RCC = renal-cell cancer; MM = multiple myeloma; ICD = International Classification of Diseases; TCA = trichloroacetic acid; HWE = healthy worker effect; U-TCA = urine trichloroacetic acid; SES = socioeconomic status; M = male; NDI = National Death Index; NR = not reported; ICDA = International Classification of Diseases-Adjusted; SEER = Surveillance, Epidemiology and End Results Program (National Cancer Institute); SSA = Social Security Administration.

Table D-5 Cohort Studies: Study Sensitivity and Exposure-response Analyses

Study Summary (Study Sensitivity) | Study Size/Length of Follow-up | Reported or Estimated Exposure Levels or Duration | Exposure-response Analyses: Dose Metrics/Range Lagging Analyses
Nordic studies
Vlaanderen et al. (2013) Cancer registry-based, Nordic countries, nested case-control study Limited Large number of exposed cases and controls; however, exposure levels were very low | Large cohort: number of exposed cases: 4,145 kidney, 1,610 liver, 3,607 NHL, 1,583 multiple myeloma Follow-up: up to 45 years | Levels not reported. Estimated median exposure (unit-yr)^b^ for the cumulative exposure categories: 1st tertile: 0.04 (for liver, kidney, NHL, MM) 2nd tertile: 0.25 (liver), 0.13 (kidney), 0.12 (NHL), 0.13 (MM) 3rd tertile: 0.77 (liver), 0.72 (kidney), 0.72 (NHL), 0.74 (MM) Estimated cumulative levels of exposure based on occupational group (not individual job data) High exposure was assigned to shoe and leather industry workers, mechanics, laundry workers. Laundry workers may not be a good population to evaluate exposure to TCE Estimated exposure group^a^ for highest cumulative exposure: assumed low (uncertain because calculation includes prevalence) | Cumulative exposure (categorical and continuous models) (units-yr^b^) Range not reported; tertiles of estimated cumulative exposure only used to evaluate for exposure-response relationship Lagging, 0, 1, 5, 10 yr
Hansen et al. (2013) Pooled Nordic cohort incidence analysis Limited for high exposure effects Large numbers of exposed cases that were ever exposed to TCE but few cases with high exposure (especially liver or NHL); Most of the cohort was exposed to low levels for short time periods. | Medium size cohort: 5,553 workers; ~1,000 cancer cases Number of exposed cases: 32 kidney 36 liver, 38 NHL ever exposed; 9 kidney, 3 liver, 4 NHL in highest exposure group 49% total workers with >30 years of follow-up | Low exposure levels and short exposure duration Estimated TCE ambient levels: 4 ppm (median, Finland), 12 ppm (median, Denmark); >80% of Swedish study with <20 ppm Only ~20% of subjects had U-TCA levels >50 mg/L (equivalent to ~20 ppm) Median duration of employment (yr): 5.5 (Sweden) and 6.3 (Denmark), NR for Finland Estimated exposure group^a^ for highest U-TCA exposure group (20 ppm): moderate | Average U-TCA (mg/L, 4 levels) Range: Appears adequate based on U-TCA in exposure groups Lagging: 0, 10, 20 yr
Raaschou-Nielsen et al. (2003) Danish TCE blue-collar worker cohort Record linkage incidence study Adequate in subcohort of higher exposed subjects Large number of exposed cases for NHL and kidney cancer in both cohort and subcohort analysis; fewer deaths from liver cancer | Large cohort: >40,000 workers, ~14,000 subcohort considered to have higher exposure; >3,000 cancer cases; 76 RCC, 25 liver, 96 NHL Follow-up to approx. 30 years but cohort is relatively young; 56% were 38 to 57 years old at end of follow-up; 29% of subjects were older than 57 years of age | Low exposure levels after 1980 Median exposures to TCE (ppm) [NAS (2006)] 1960–1969: 49 1970–1979: 20 1980–1989: ~4 Only 21% of workers began employment before 1970 (highest levels). Only 42% of the cohort was considered to be exposed to TCE Estimated exposure group^a^ for high exposure group (since 1970): moderate | Exposure duration (yr), year of first employment (crude surrogate for level), company size (surrogate for probability of exposure), lag time. Analysis on presumed higher exposed workers Range: Appears to be wide based on exposure changes over time. Lagging 0–9, 10–20, >20 yr
Rocket engine or aircraft manufacturing workers
Lipworth et al. (2011) Burbank, CA (USA) aircraft manufacturing workers cohort Mortality study Limited Adequate numbers of exposed cases but exposure duration may be relatively short; few exposed cases worked longer than 5 years. No information or analysis by exposure intensity | Medium size cohort: 5,443; ~1,000 cancer deaths; Exposed deaths: 16 kidney, 24 liver, over 50 NHL Follow-up: Average 32 years | No information on reported levels Exposure duration most likely short for unknown portion of the workers; Cohort includes workers employed since 1960, but TCE exposure ceased in 1966. Enrollment of cohort started in 1960, so maximum possible exposure duration was 6 years. 12% of the cohort with potential exposure to TCE Estimated exposure group^a^ for longest duration: low (includes workers with high and low exposure) | Duration of exposure (yr) Range: limited for duration, highest category 5 years Lagging: no analysis
Radican et al. (2008) (mortality update); Blair et al. (1998) (incidence) Utah (USA) aircraft maintenance workers cohort Mortality and incidence study Limited for subgroup analysis Adequate number of exposed deaths but few deaths or cases among highest exposed group (especially for kidney and liver cancer) | Medium size cohort: 7,204; 729 cancer deaths; 528 cancer cases. Exposed deaths/cases (men): kidney: 16 deaths/13 cases; NHL: 37 deaths/21 cases; liver: 28 deaths/12 cases). Few cases or deaths (≥5) for kidney & liver in highest exposure category Follow-up: Average length of follow-up not reported, but extended follow-up approx. 44 years after latest date of first employment (1956–2000) | Cherrie et al. (2001) estimated long-term exposure as 50 ppm and short term up to 600 ppm TCE. The NAS (2006) concluded the cohort had a modest number of highly exposed (~100 ppm) but most were exposed to low TCE concentrations (~10 ppm). Other estimates for cumulative exposure are up to 38 ppm-yr from degreasing and up to 15 ppm-yr from benchwork. Intensity would be high^c^ Estimated exposure group^a^ for highest cumulative exposure: moderate | Cumulative exposure (unit-yr) and exposure pattern (peak and intermittent exposure) Range. Appears adequate (categories of exposure ranged up to 25 units-year)
Boice et al. (2006) Los Angeles (USA) rocket engine testing workers cohort Mortality study Limited Few exposed deaths but presumably high exposure. | Small cohort: 1,111 workers; 121 cancer deaths; Exposed deaths: kidney: 7 deaths Follow-up: 88% of test mechanics followed for over 20 years | Approx. 58% exposed to TCE during engine flushing/cleaning (high exposure); approx. 42% exposed to TCE during utility cleaning (lower exposure) | Exposure duration (yr) Range: Unknown, only two exposure duration categories Lagging: no analysis
Zhao et al. (2005) Los Angeles (USA) aerospace workers cohort Mortality and incidence study Limited Small numbers of cases for subgroup analysis for kidney; however, strengths are analysis of risks for high exposed workers and exposure-response relationships | Medium size cohort: 6,107; Exposed deaths/cases: Kidney: 17 deaths/16 cases; NHL: 60 deaths/45 cases Follow-up: Average 29 yr | Workers with job titles indicating technical or mechanical work on rocket engines were presumed to have high hydrazine rocket fuel exposure and high TCE exposure, which was used in cleaning rocket engines and parts. 80% of workers employed before 1970 when exposure levels were high. Intensity estimated to be >200 ppm for 1970 and 400 to 600 ppm for intensity. Cumulative exposure estimated to range up to 38 ppm-yr^c^. Estimated exposure group^a^ for cumulative exposure: moderate | Cumulative exposure score (ranked categories) lagged and unlagged. Range: Adequate Lagging: 0, 20 yr
Morgan et al. (1998) Arizona (USA) aircraft manufacturing workers cohort Mortality study Limited statistical power in overall and subgroup analysis; Some workers with potential for exposure to high levels but number not known | Median size cohort: 4,733; 270 cancer deaths. Exposed deaths: kidney: 8, liver: 6, NHL: 3 Follow-up: not reported | High exposure jobs were considered to be >50 ppm TCE. Unclear on the number of workers in high exposed jobs Estimated exposure group^a^ for highest exposure group (peak/cumulative): moderate | Cumulative exposure score ranked (two levels), peak exposure Range: Not known, but only analyzed low vs. high Lagging: no analysis
Other cohorts
Silver et al. (2014) New York State (USA) electronics manufacturing workers cohort Mortality study Limited Exposure prevalence in total cohort low, # exposed deaths and exposure levels NR. Analysis by 1 cumulative exposure score | Medium size exposed cohort: 3,113 ever exposed to TCE Follow-up: Average 26 years, but young cohort with only 17% deaths in total cohort at end of follow-up | Level of exposure NR. Only 13.9% of male hourly workers exposed to TCE | Cumulative exposure score (1 category) Range: Not known Lagging: 10 yr
Bahr et al. (2011) Kentucky (USA) uranium enrichment workers cohort Mortality study Unclear Inadequate information to evaluate | Medium size cohort: 5,335 men; 32 NHL deaths Follow-up: Information not reported; up to 50 years for some workers, but may be more limited for others | No information on exposure levels or nature of work. Exposure scores and categories not clear | Exposure score and category (ranked) Range: not known Lagging: no analysis
Yiin et al. (2009) Tennessee (USA) uranium enrichment workers nested case-control study Limited Number of exposed deaths and exposure levels unknown | Number exposed to TCE unknown Follow-up: NR, minimum of 13 years, analysis lagged 15 years | Exposure levels or duration not reported. Mean cumulative exposure in cases 183.8 ± 668.2 for cases and 113.4 ± 558.3 for controls. Units not reported | Average cumulative exposure score (1 category) Range: Wide range of estimated cumulative exposure, No analyses by exposure category. Lagging: 0, 5, 50, 20 yr
Ritz (1999) Ohio (USA) uranium processing workers cohort Mortality study Limited Few exposed deaths | Medium size cohort: 2,971; 328 deaths; Exposed deaths: TCE light: 6 deaths, TCE moderate: 2 deaths; Analysis not specific for kidney or NHL Adequate: Average 31 years | 94% workers have low exposure, only 6% of cohort had moderate exposure and no workers had heavy exposure 54% were employed for >5 years | Exposure level (ranked); exposure duration (yr, 2 categories) Range: limited, most exposed to light work Lagging: 0, 15 yr
Henschler et al. (1995) German cardboard manufacturing cohort Renal cancer incidence and mortality study Adequate for very high exposure effects Few numbers of exposed cases but very high exposure levels | Small cohort: 169; 7 RCC deaths Follow-up: >30 years for both exposed and unexposed | Estimated to be very high from inhalation and dermal due to degreasing under open conditions Estimated peak exposures (during machine cleaning were >2,000 ppm) and sustained long-term exposure exceeding 100 ppm (Cherrie et al. 2001) Long exposure periods (17.8 months) Estimated exposure group^a^ for ever exposure: high to very high (although highest exposure group is not reported, data suggest all workers are highly exposed | Ever exposure Range not reported Lagging: no analysis
Greenland et al. (1994) Massachusetts (USA) electrical manufacturing workers nested case-control study Limited Inadequate to evaluate effects from moderate or high exposure | Small studies: 15 deaths NHL, kidney cancer: 12, liver cancer: 9 (men) Follow-up time for cohort: Short 1969–1984 | Fewer than 10% of jobs had potential for TCE exposure, most of which were from indirect exposure | Ever vs. never exposed Range: not applicable Lagging: no analysis
Wilcosky et al. (1984) Ohio (USA) rubber manufacturing workers nested case-control study Limited Unclear if workers were exposed to TCE | Small studies: 14 deaths from lymphosarcoma + reticulosarcoma 9 observed cases of lymphosarcoma + reticulosarcoma in case-control study Follow-up: 10 years | No quantitative exposure assessment or industrial hygiene measurements available; Exposure based on authorized use | Ever vs. never exposed Range: not applicable Lagging: no analysis
Drinking water study
Bove et al. (2014) Cohort studies using an ecological exposure (drinking water contamination) Mortality Unclear Adequate number of cases in cohort, number in subgroups not reported; unclear how to compare with occupational studies due to differences in exposure route | Large cohort: 154,932 (Camp Lejeune); 1,008 cancer deaths. Kidney: 42, liver: 58, NHL: 51; 11–15 for 3 cancers in high-exposure groups Follow-up ranged from 23 to 30 yr; however, probably insufficient because it was a young cohort | Estimated mean levels (μg/L): TCE: 358.7 Overall cumulative exposure (μg/L-months) for TCE, mean 6,369.3 (approx. 0.17 ppm-months), median 5,289 (approx. 0.14 ppm-months), 20% were exposed to levels between 7,700 and 39,745 μg/L-months (0.20–1.06 ppm-months) Potential daily exposure from TCE-contaminated water system up to 3.6 mg/day (showering and drinking water), which could be equivalent to 0.07 ppm/day and (25 ppm-yr) Estimated exposure group^a:^ for cumulative exposure: low (could be moderate, but because of uncertainty about different route, is rated as low | TCE drinking water levels (μg/L-month) Range: adequate Lagging: 10 yr

NHL = non-Hodgkin lymphoma; MM = multiple myeloma; TCE = trichloroethylene; ppm = parts per million; U-TCA = urine trichloroacetic acid; RCC = renal-cell cancer; NR = not reported; NOCCA = Nordic Occupational Cancer; JEM = job exposure matrix.

^a^ Estimated exposure groups across studies for forest plot of kidney cancer and highest exposure group reported in the study (Figure 4-2). This information is only provided for studies reporting a risk estimate for highest exposure and kidney cancer.

^b^ NOCCA-JEM estimates exposure as ppm-yr but author reported as units per year because of uncertainty in the estimates (personal communication with authors).

^c^ Personal communication from technical advisor.

Table D-6 Case-control Studies of Trichloroethylene and Kidney or Liver Cancer: Study Quality

Study | Selection Bias Participation Rates | TCE Exposure Assessment: Quality and Misclassification | Misclassification of Disease
Studies in specific areas with knowledge of local industries.
Moore et al. (2010) Hospital-based, Central and Eastern Europe 1,097 cases RCC, 1,476 controls 1999–2003 | Possible (direction unclear) Hospital controls excluded smoking-related diseases Participation bias: Unknown: NR | Good: Structured, special job-specific questionnaire (job titles, tasks, working conditions) and expert assessment (with knowledge of plants in area) of intensity, frequency, and confidence; Assessment re-evaluated at a later time period with 83% agreement for TCE in 1 country and 100% in 2 countries Exposure misclassification with respect to whether workers were ever exposed to TCE is not a concern among workers (~50%) with high confidence assessment (especially among workers with higher or longer exposure) but is more a concern for analysis of all workers | Unlikely RCC cases histologically confirmed
Charbotel et al. (2006); Charbotel et al. (2009) Population-based, France 86 cases RCC, 326 controls 1993–2003 | Unlikely Cases and controls (matched on area of residence, sex, and age) were randomly selected from same practitioners (excluding patients with kidney or bladder cancer, or chronic kidney disease) Participation rate similar among cases and controls | Good: Semi-quantitative estimates of TCE exposure based on detailed questionnaire, JTEM, and exposure monitoring data (air and urine) of industries in the area; Temporal trends were considered Exposure misclassification (with respect to whether workers were ever exposed) is not a concern especially among individuals in the highest exposure categories (e.g., cumulative, cumulative + peaks). Study was conducted in a localized area with screw-cutting industry. Exposure prevalence and intensity was high, which increases the probability of exposure among the exposed group | Unlikely RCC cases histologically confirmed
Brüning et al. (2003) Hospital-based, Germany 134 cases RCC, 401 controls 1992–2000 | Possible Prevalent cases from different hospital departments (presumably most from the same hospital) than residual controls. Cases and control matched by age and gender Participation rate high among cases but not reported for controls | Limited: Exposure assessed via 3 methods: Self-reported exposure, including narcotic symptoms using subjects (cases and controls) and/or proxies (cases only); CAREX database (expert assessment of occupation groups using TCE) and agent specific (solvents as a group); British JEM; British JEM and CAREX are broad and not country or calendar-year specific. No information was provided on whether the interviewers were blinded to disease status but may not have been blinded The potential for recall bias (differential, over- or under-estimate of the risk estimate) is usually a concern for self-reported exposure. Self-reported exposure can also be associated with non-differential misclassification; however, it is less likely in this study because exposure to TCE was probably high among at least some (symptomatic) workers, and common knowledge. It seems reasonable that most of the workers with self-reported exposure had high exposure. Exposure misclassification (non-differential) is a concern for subjects classified by the CAREX and JEM assessment. Exposure prevalence varied greatly depending on the methods (80% for CAREX versus 18% for self-reported) | Unlikely RCC cases histologically confirmed
Vamvakas et al. (1998) Hospital-based, Germany 58 cases RCC, 84 controls 1987–2002 | Probable (differential) Differences in case and control selection. Cases were selected from a hospital in a highly industrial area with small industries from 1987 to 1993. Unmatched controls selected from different hospitals in adjacent geographical region and at a later time period (time of case-interview) than prevalent cases. If potential bias (differential, overestimate of the risk estimate) could occur if TCE exposure prevalence was lower in these areas and time periods. Cases were older than controls. Study done during period in which legal proceedings were in progress Participation rate: 87% cases and 75% controls | Adequate: Self-reported TCE exposure (duration, use of TCE) and self-reported narcotic symptoms (frequency, severity); Physician interview with subject (case and controls) or proxy (cases only) not blinded to case status; Expert assignment to exposure categories based on integration of exposure duration and symptoms. The study population was located in a geographical area with similar industries with widespread exposure to TCE with details on the exposure conditions Potential for recall and interviewer bias (differential, overestimate of risk estimate), especially for reporting symptoms due to a legal investigation; However, estimated exposure levels were very high in this study, which may mitigate this concern | Unlikely RCC cases histologically confirmed
Other studies
Christensen et al. (2013) Hospital and population-based, Canada 177 cases RCC, 48 liver cancer cases; 533 population controls, 2,299 cancer controls 1975–1985 | Unlikely for population controls Cases and cancer controls selected from same hospital and controls randomly from same underlying population using similar inclusion criteria Insufficient data regarding the tissue sites of cancer controls, but <20% of any given cancer site used Participation rates were 82% for cancer cases (both cancer cases and controls) and 72% for population controls | Adequate to good: Detailed interview and expert assessment; duration, frequency, intensity, and confidence assessed; Proxy interviews conducted with 12% to 14% of subjects The use of a population-wide occupational database may decrease the probability of exposure and the precision of exposure estimates for individuals. Although expert assessment is detailed and systematic, exposure misclassification (non-differential) is still possible | Unlikely RCC, liver cases histologically confirmed
Pesch et al. (2000b) Population-based, Germany 935 cases RCC, 4,298 controls 1991–1995 | Unlikely Cases and controls selected from same population using the same inclusion criteria Participation rates high for cases and controls (88% cases, 71% controls) | Adequate: Questionnaire and expert assessment using JEM and JTEM which ranked probability and intensity to a given agent but few details on job tasks; Self-reported exposure also used; The JTEM is considered to be a better assessment than JEM. The British JEM may not reflect differences in occupational exposures across studies Exposure misclassification (non-differential) is a concern because of the lower probability of exposure and limited JEM. The level of concern is greater for subjects classified by JEM than individuals classified by JTEM. Exposure misclassification is probably the highest among individual in the lower exposure categories for both matrices. Exposure misclassification regarding exposure group (e.g., low, medium, high) would most likely attenuate any exposure-response relationships | Unlikely Most RCC cases histologically confirmed; some sonographically confirmed
Dosemeci et al. (1999) Population-based, Minnesota (USA) 438 cases RCC, 687 controls 1988–1999 | Unlikely Cases identified via state cancer registry and controls randomly selected from the same underlying population using similar inclusion criteria Participation rate was lower among cases (64%) than controls (97%) but no information to suspect that participation was related to exposure and thus the lower participation rate would most likely reduce precision | Limited: JEM assigned by expert but based on broad occupational and industry codes; Only considered current and usual jobs and duration of employment only assessed; Duration by calendar period not considered Exposure misclassification (non-differential) for ever-exposure to TCE is a concern because of the limited JEM and lower probability of exposure | Unlikely RCC cases histologically confirmed

TCE = trichloroethylene; RCC = renal-cell cancer; NR = not reported; JTEM = job-task exposure matrix; CAREX = CARcinogen EXposure (Canada); JEM = job exposure matrix.

Table D-7 Kidney Case-control Studies: Study Sensitivity and Exposure Response Analyses

Study Summary | Study Size/Exposure Prevalence | Reported or Estimated Exposure Levels or Duration | Exposure Response Analyses: Dose Metrics/Range Lagging
Studies in specific areas with knowledge of local industries
Moore et al. (2010) Hospital-based, Central and Eastern Europe 1999–2003 Adequate Adequate cases and controls with high confidence of exposure; Ability to evaluate effects of high exposure is increased by stratifying on probability and exposure intensity or duration | Large study: 1,097 RCC cases/1,476 controls Exposure prevalence: 5.8% (N = 48) cases and 3.4% (N = 40) controls for any exposure and ~2%–4% (N = 17–31) cases and 1%–2% controls (N = 10–21) for high exposure categories | No information on actual exposure Estimated TCE intensity in JEM were coded into 3 categories: 0 to <5 ppm, 5 to 50 ppm, and >50 ppm (2.5, 25, and 75 ppm midpoints) Duration (years): 1.35 (6.3–26.3 for controls) 19.5 (5.8–31) for cases Estimated exposure group for individuals with highest average exposure: moderate to high | Ever, cumulative (ppm-yr), average-intensity (ppm), duration (hours and years); Separate analyses conducted for all and high confidence exposure assessments (>40% workers probably or definitely exposed jobs) Range: Appears to be adequate based on estimated interquartile range and differences in exposure intensity among jobs; however, only two exposure groups for each metric Lagging: 0, 20 yr
Charbotel et al. (2006); Charbotel et al. (2009) Population-based, France 1993–2003 Adequate to good Adequate number of subjects exposed to high levels of TCE. May not have adequate statistical power in subgroup analysis but good range in exposure intensity | Small study: 86 RCC cases; 326 referents Exposure prevalence: 43% (N = 37) cases, 35% (N = 110) controls for ever exposed, and 19% (N = 16) cases, and 11.7% (N = 37) among highest exposure group | High intensity of exposure (duration NR); Among controls the median exposure for low, medium, and high categories = 60,252 and 630 ppm, respectively; Among cases, median exposure = 30, 300, and 885 ppm, respectively Estimated TCE intensities (ppm) for specific jobs • 15–18 for open cold degreasing • 120 for jobs near open hot degreasing machines • up to 300 for work directly above tank • 300–600 for emptying, cleaning, and refilling degreasers Cumulative exposure categories: low 1–150 ppm-yr, medium 155–335 ppm-yr and >335 ppm-yr Estimated exposure group^a^ for highest cumulative exposure: very high | Ever exposed, cumulative exposure (ranked), and combined cumulative and peak exposure, trend analysis Range: good (see previous column) Lagging: no analysis
Brüning et al. (2003) Hospital-based, Germany 1992–2000 Adequate to good Adequate number of subjects exposed to high levels of TCE | Small/medium study: 134 RCC cases/401 controls Exposure prevalence: 18.7% (N = 25) cases, 9.5% (N = 38) using self-assessment 87% cases, 79% controls using CAREX (less confidence) | Very high exposure and long exposures Estimated to be 400–600 ppm during peak (hot dipping) and >100 ppm overall (Cherrie et al. 2001) Approx. 50% cases >10 years’ exposure Estimated exposure group^a^ for workers with daily narcotic symptoms: very high | Jobs using TCE (CAREX), exposure to solvent (JEM) Self-assessed: exposure + narcotic symptoms, duration (yr) and time since first and last exposure Range: not known, but may be shallow due to exposure from open conditions Lagging 5–9, 10–19, 20 yr
Vamvakas et al. (1998) Hospital-based, Germany 1987–2002 Adequate Limited number of subjects but exposed to high levels of TCE | Small study: 58 RCC cases/84 controls Exposure prevalence: 33% (N = 19) cases; 6% (N = 5) controls | Very high exposure and long exposures Estimated to be 400 to 600 ppm during peak (hot dipping) and >100 ppm overall (Cherrie et al. 2001) Mean duration of exposure among cases was 16 years and 7 years among controls Estimated exposure group^a^ for highest rank exposure category: very high | Ever/never and exposure category (ranked, integration of exposure time and symptoms) Range: not known, but may be shallow due to exposure from open conditions Lagging: no analysis
Other studies
Christensen et al. (2013) Hospital and population-based, Canada 1975–1985 Limited Few exposed cases and controls with substantial exposure | Moderate size: 177 RCC cases/ 1,999 cancer controls, 533 population controls Small size: 48 liver cases, 1,834 liver cancer controls and 533 population controls Exposure prevalence: <3% (N = 15 population controls; 63 cancer cases, and 5 RCC cases, 1 liver cancer) for any exposure and controls and <2 (N = 9 population controls, N = 2 RCC, 1 liver cancer) for substantial exposure | Levels and duration not reported Occupations considered to have the highest exposure were mechanics and repairmen, metal machining occupations, electrical and electronics and metal shaping and formulation Estimated exposure group for individuals with substantial exposure: assumed low (unclear because category includes confidence of exposure) | Any and substantial (integration of probability, frequency, concentration, and duration) Range: not applicable Lagging: no analysis
Pesch et al. (2000b) Population-based, 5 German regions 1991–1995 Limited Few exposed cases and controls, most of which were likely exposed to low levels of TCE | Large study size: 935 (570 men & 375 women) cases/4,298 controls Prevalence of substantial TCE exposure was low among male cases and varied by type of JEM: 10% (N = 55) males German JEM 3.9% (N = 15) (JTEM). Prevalence was <2% (N < 5) in females. Exposed controls NR | No information on the types of job that were considered to be exposed to TCE or on estimated exposure levels Includes the Arnsberg and other regions; NAS (2006) estimated that most subjects had minimal contact with TCE averaging concentration of 10 ppm or less Estimated exposure group for individuals with substantial exposure: assumed low (unclear because category includes probability of exposure) | Exposure index (ranked; integration of probability, duration, and intensity) for two JEM and JTEM; Reported separately for men and women Range: Not applicable Lagging: no analysis
Dosemeci et al. (1999) Population-based, Minnesota, (USA) 1988–1999 Limited to adequate Adequate numbers of exposed cases and controls to evaluate ever versus never exposure; No evaluation of exposure level | Moderate size: 438 (273 men 165 women) cases; 687 (462 men, 225 women) controls Exposure prevalence: 13% cases (N = 55); 10% controls (N = ~69) | No information on level duration or jobs considered to have TCE exposure | Ever-exposed reported separately for men and women Range: not applicable Lagging: no analysis

RCC = renal-cell cancer; N = number; TCE =trichloroethylene; JEM = job exposure matrix; ppm = parts per million; NR = not reported; CAREX = CARcinogen EXposure (Canada); NAS = National Academy of Science; JTEM = job-task exposure matrix.

^a^ Estimated exposure groups across studies for forest plot of kidney cancer and highest exposure group reported in the study (Figure 4-2). This information is only provided for studies reporting a risk estimate for highest exposure and kidney cancer.

Table D-8 Case-control Studies of Trichloroethylene and NHL and Related Subtypes: Summary of Study Quality

Study and Number of TCE-exposed Cases/Controls | Selection/Participation Bias | Quality of TCE Exposure Assessment and Exposure Misclassification | Misclassification of Disease
NHL
Christensen et al. (2013) Hospital and population-based, Canada 215 cases NHL, 533 controls | Unlikely Cases and cancer controls selected from same hospital and controls randomly from same underlying population using similar inclusion criteria Participation rates were 82% for cancer cases (both cancer cases and controls) and 72% for population controls | Adequate to good: Detailed occupational information, expert assessment by team of experts; semi-quantitative rating of duration, frequency, intensity, and confidence assessed; Not clear if calendar-year specific The probability of exposure is less certain in population-based studies. Although expert assessment is detailed and systematic, exposure misclassification (non-differential) is still possible | Possible Histologically confirmed but older classification (ICD-9)
Cocco et al. (2013) and studies included in the analysis: ENGELA (Orsi et al. 2010) MIS(Miligi et al. 2006) EPILYMPH (Cocco et al. 2010) NCI-SEER (Purdue et al. 2011a) 3,788 cases NHL + subtypes (DLBCL, FL, CLL), 4279 controls MM evaluated in Cocco et al. (2010) | Unlikely Adequate methods to select cases and controls in all studies; consecutive incident cases and matched controls in 3 studies or selected to represent age and gender in the MIS study Population controls: EPILYMPH, NCI-SEER, MIS Hospital controls: EPILYMPH and ENGELA Participation rates in the individual studies ranged from 76% to >90% among cases, 73% to 81% among hospital controls, and 52% to 73% for population controls. There are no concerns of differential bias in the pooled analysis although lower rates may decrease precision | Good: Detailed questionnaire and occupational data; expert assessment by team of experts, semi-quantitative rating of exposure using multiple scales (intensity, frequency, duration, probability); Calendar-year specific; Exposure assessment from the four studies was harmonized NCI-SEER analysis also assessed average exposure, average weekly, and average exposure intensity for each subject Exposure misclassification (with respect to whether workers were ever exposed) is not a concern among individuals classified as having high probability of exposure or with the higher level of exposure (frequency, duration, or intensity) but is possible (non-differential) among individuals in the lower exposure categories. Exposure misclassification regarding intensity level (e.g., low, medium, high) may be more of a concern and would most likely attenuate any exposure-response relationships | Unlikely Histologically confirmed; a subset re-reviewed in some studies; Classification harmonized using the WHO InterLymph consortium classification
Deng et al. (2013), Wang et al. (2009b) Population-based Connecticut (USA) 601 NHL+subtypes cases, 7,171 controls | Unlikely Cases and matched controls selected from the same underlying population using similar inclusion criteria; Cases selected from cancer registry Participation rates: Cases 72%; Controls: RDD 69%, health care 47%. Low rates may decrease precision | Limited to adequate: Occupational data on job titles and companies, generic JEM based on semi-quantitative rating of occupations (rather than tasks); Not calendar-year specific Overall, exposure misclassification (non-differential) is a concern among individuals classified as ever exposed. The likelihood of exposure is increased among workers in the higher probability or higher intensity categories | Unlikely Cases reviewed by pathologists; 2001 WHO (REAL) classification
Persson and Fredrikson (1999) Population-based (pooled study) Sweden 199 cases NHL, 479 controls | Unlikely Cases and matched controls selected from the same underlying population using similar inclusion criteria Controls drawn for other studies and unclear which years controls were recruited Participation rate: 90% among cases but NR for controls | Limited: Self-reported ranked exposures (~19 occupational exposures); Not clear if interviewers were blinded to case-control status Exposure misclassification is a concern and likely to be substantial. Direction of potential of bias is unknown since self-reported exposures can vary between cases and control; however, considerable non-differential misclassification for cases and controls is also likely | Possible 2nd study histologically confirmed but not 1st study (not histologically confirmed); ICD coding NR
Nordström et al. (1998) Population-based Sweden 121 cases HCL, 484 controls | Unlikely Cases and matched controls selected from the same underlying population using similar inclusion criteria; Cancer selected from cancer registry Participation rates: cases 91%; controls 83% | Limited: Complete occupational history and self-reported exposure (primarily job titles, not tasks or working conditions); Exposure assigned based on self-report/occupation, qualitative; Minimal requirements for ever exposure based on very low exposure Exposure misclassification is a concern and likely to be substantial | Possible Subset of cases re-reviewed: NCI classification
Hardell et al. (1994) Population-based Sweden 105 cases NHL, 355 controls | Unlikely Cases and matched controls selected from the same underlying population using similar inclusion criteria; Cases selected from hospital dept Participation rates: unknown | Limited: Complete occupational history (primarily job titles, not tasks or working conditions) and self-reported exposure; Exposure assigned based on self-report/occupation, qualitative; Minimal requirements for ever exposure based on very low exposure Exposure misclassification is a concern and likely to be substantial | Possible Cases histologically confirmed by subtype, stage, and site but older Rappaport classification
Multiple Myeloma
Gold et al. (2011) Seattle, WA and Detroit, MI (USA) SEER registry 181 cases MM, 481 controls | Unlikely Cases and matched controls selected from the same underlying population using similar inclusion criteria; Cases selected from cancer registry Participation rates: cases 71% and controls 52% | Good: Detailed occupational information, JTEM specific for 6 solvents assigned by experts; quantitative rating of exposure intensity and assignment of cumulative exposure (based on exposure measurement reported in the literature); (Same exposure assessment as Purdue et al. (2011a) for NHL) Exposure misclassification is not a concern, especially among individuals with the highest cumulative exposure. Exposure misclassification between levels of cumulative exposure would most likely attenuate any exposure-response | Unlikely Most SEER registry cases histologically confirmed; ICD –O-2 or 3)
Costantini et al. (2008) Population-based, Italy (MIS) 263 cases MM, 1,100 controls; cases CLL NR; (total LH cases 2,737, 1,799 controls) | Unlikely Cases and matched controls selected from the same underlying population using similar inclusion criteria Participation rates were moderately high: 83% cases, 76% controls | Adequate: Job/industry specific questionnaire, regional experts, semi-quantitative rating of exposure using two exposure scales; calendar-year specific; Individuals classified by 2 exposure levels and 2 duration levels; Intensity was primarily based on control measures used to limit exposure Although individuals with low probability of exposure were excluded from the study, exposure misclassification (with respect to whether individuals were ever exposed) is possible (random, non-differential), especially among individuals in the low exposure group | Possible Cancer diagnosis from local hospital reclassified using the NCI classification; Pathologists verified subset of cases; NHL and CLL classified based on biological properties

NHL = non-Hodgkin lymphoma; TCE = trichloroethylene; ICD = International Classification of Diseases; MIS = Multicentre Italian Study; NCI = National Cancer Institute; SEER = Surveillance, Epidemiology and End Results Program; DLBCL = diffuse large B-cell lymphoma; FL = follicular lymphoma; CLL = chronic lymphocytic lymphoma; MM = multiple myeloma; WHO = World Health Organization; RDD = random-digit dialing; JEM = job exposure matrix; REAL = Revised European-American Lymphoma classification; NR = not reported; HCL = hairy-cell leukemia; JTEM = job-task exposure matrix; LH = lymphohematopoietic.

Table D-9 NHL Case-control Studies: Study Sensitivity and Exposure Response Analysis

Study Summary (Study Sensitivity) | Study Size/Exposure Prevalence | Reported or Estimated Exposure Levels or Duration | Exposure Response Analyses: Dose Metrics/Range Lagging
NHL
Christensen et al. (2013) Hospital and population-based, Canada Limited Small numbers of exposed cases and controls | Moderate size: 215 NHL cases/23,141 cancer controls, 533 population controls Exposure prevalence: <3% (N = 15 population controls; 65 cancer cases, and 7 NHL) for any exposure and controls and <2% (N = 9 population controls, N = 30 cancer controls, N = 2 NHL) for substantial exposure | Levels and duration not reported Occupations considered to have the highest exposure were mechanics and repairmen, metal machining occupations, electrical and electronics and metal shaping and formulation | Any and substantial Range: NA Lagging: no analysis
Cocco et al. (2013) and studies included in the pooled analysis: ENGELA (Orsi et al. 2010) MIS (Miligi et al. 2006) EPILYMPH (Cocco et al. 2010) NCI-SEER (Purdue et al. 2011a) Adequate Adequate number of cases and controls all NHL but not all NHL subtypes; Estimated levels suggest levels relatively high for the highest exposed workers | Very large study: 3,788 cases/4,279 controls Exposure prevalence in total population: 9% (N = 711) ever exposed, 1% (N = 88) definite exposed Exposure prevalence among highest exposure intensity category: <1.5% (N = 57 controls, 48 cases) for total population; <10 cases or controls among those with high probability of exposure | Levels not reported: levels estimated for analysis: Highest exposure intensity category >75 ppm Estimated levels NCI-SEER: levels not reported; levels estimated for analysis Highest cumulative exposure category: >234,000 ppm-hr (prevalence: 0.7% controls, 2.5% cases) Highest average intensity exposure category: >99 ppm (prevalence: 2.3% controls, 3.4% cases) MIS Study regions chosen because of large presence of manufacturing industries using solvents or they were agricultural areas | Probability, intensity (ppm), frequency (% work time), duration (yr) among all subjects and high probability subjects Additional metrics in individual studies Cumulative exposure (ranked): EPILYMPH, NCI-SEER (ppm-hr) Average weekly ppm-hr/week): NCI-SEER Sensitivity by latency, interviewing variable, & unemployment – NCI-SEER Range: Adequate range based on estimates of intensity, duration, and frequency of exposure Lagging: no analysis, although NCI-SEER conducted 5- and 15-yr lagged analysis
Deng et al. (2013), Wang et al. (2009b) Population-based Connecticut, (USA) (Women) Limited Few numbers of exposed cases and controls; Limited ability to detect an effect because there are no workers with high exposure and high probability of exposure | Large study: 601 NHL/717 controls Exposure prevalence: 11% controls (N = 79) and 13% (N = 77) for ever exposed; <2% (N = 8 controls and 13 cases) for medium high exposure; and (N = 31) controls and 5.7% (N = 34) cases for medium high probability; 0 cases and controls with high probability and medium and high intensity | No information on reported or estimated level. | Exposure intensity (ranked), exposure probability Range: No information Lagging: no analysis
Gold et al. (2011) Seattle, WA and Detroit, MI (USA) SEER registry 181 cases MM, 481 controls Adequate Adequate number of cases in control in subgroup analysis, including the highest exposure group | Medium size study: 181 MM cases, 481 controls Exposure prevalence: 29% (N = 138) controls and 37% (N = 66) cases for ever-exposed and 7.1 (N = 34) controls and 13% (N = 24) in highest cumulative exposure category | Exposure levels not reported. Levels estimated for analysis: Highest cumulative exposure category >7,794–57,000 ppm | Exposure duration (yr) and cumulative exposure (ppm-hr) Range: adequate (estimated) range of exposures Lagging: 0, 10 yr
Costantini et al. (2008) Population-based, Italy Limited statistical power Few exposed cases and controls | Medium size study: 263 cases MM, 1,100 controls; cases CLL NR TCE prevalence among controls was ~2.5% (N = 5 cases and 27 controls for medium/high and 3.5% (N = 9 cases and 28 controls) for low/very low exposure | Study regions chosen because of large presence of manufacturing industries using solvents or they were agricultural areas | Intensity and duration of exposure. Range: No information Lagging: no analysis
Persson and Fredrikson (1999) Population-based (pooled study) Sweden Limited Relatively small number of exposed cases with possibly low levels of exposure | Medium size study: 199 cases NHL, 479 controls TCE exposure prevalence among referents ~7% (16 cases/32 controls) | No information on reported or estimated levels or duration of exposure reported; Authors state quantitative information available but merged intensity categories Minimum of 1-year exposure duration | Ever/never exposure only. Range: Not applicable
Nordström et al. (1998) Population-based Sweden Limited Relatively few exposed cases and controls with possibly low levels of exposure | Small study: 121 cases NHL, 484 controls TCE exposure prevalence among referents ~7% (9 cases and 26 controls) | No information on reported or estimated levels or duration of exposure; Minimum requirement for being classified as exposed was 1 day | Ever/never only Range: Not applicable Lagging: No analysis
Hardell et al. (1994) Population-based Sweden Limited Few cases and controls with possibly low levels of exposure | Small study: 105 cases and 355 controls Prevalence of TCE exposure among controls was 1% (4 cases/4 controls) | No information on exposure levels or duration; Minimal criteria for being considered exposed is low: <1 week continuous exposure or <1 month total exposure was considered low grade, and more than that was considered high grade | Ever/never only Range: Not applicable Lagging: No analysis

NHL = non-Hodgkin lymphoma; N = number; NA = not applicable; MIS = Multicentre Italian Study; NCI = National Cancer Institute; SEER = Surveillance, Epidemiology and End Results Program; ppm = parts per million; MM = multiple myeloma; CLL = chronic lymphocytic lymphoma; NR = not reported; TCE = trichloroethylene.

Table D-10 Studies Included in Three Meta-analyses by Cancer Site

Studies Included | Kidney | | | Liver | | NHL
Studies Included | Scott and Jinot (2011) ^a^ | Karami et al. (2012) ^b^ | Kelsh et al. (2010) ^c^ | Scott and Jinot (2011) ^a^ | Alexander et al. (2007) ^d^ | Scott and Jinot (2011) ^a^ | Karami et al. (2013) ^b^
Cohort and nested case-control studies
Anttila et al. (1995) | X | X | X | X | X | X | X
Axelson et al. (1994) | X | X | X | X | X | X | X
Bahr et al. (2011) | | | | | | | X
Blair et al. (1998) | | | X | | X
Boice et al. (1999) | X | | X | X | X | X
Boice et al. (2006) | | X | X | X | X | X | X
Greenland et al. (1994) | X | X | | X | X | X
Hansen et al. (2001) | X | X | X | X | X | X | X
Lipworth et al. (2011) | | X | | | | | X
Morgan et al. (1998) | X | X | X | X | X | X | X
Raaschou-Nielsen et al. (2003) | X | X | X | X | X | X | X
Radican et al. (2008) | X | X | X | X | | X | X
Ritz (1999) | | X | | | X | | X
Zhao et al. (2005) | X | | | X | | X
Case-control studies
Asal et al. (1988) | | X
Brüning et al. (2003) | X | X | X
Charbotel et al. (2006) | X | X | X
Cocco et al. (2010) | | | | | | X | X
Dosemeci et al. (1999) | X | X | X
Hardell et al. (1994) | | | | | | X | X
Harrington et al. (1989) | | X
Henschler et al. (1995) | | X | X
Kato et al. (2005) | | | | | | | X
Moore et al. (2010) | X | X
Miligi et al. (2006) | | | | | | X | X
Nordström et al. (1998) | | | | | | X | X
Persson and Fredrikson (1999) | | | | | | X | X
Pesch et al. (2000b) | X | X | X
Purdue et al. (2011a) | | | | | | X | X
Siemiatycki (1991) | X | X | X | | | X | X
Vamvakas et al. (1998) | | X | X
Wang et al. (2009b) | | | | | | X | X

^a^ See also EPA (2011a).

^b^ Karami et al. (2013); Karami et al. (2012): Studies classified as TCE-exposed only; chlorinated solvent studies not included.

^c^ Kelsh et al. (2010): Group I studies (classified as having adequate exposure data to identify workers with TCE exposure) only; Group II studies (limited exposure data) excluded.

^d^ Alexander et al. (2007): Group 1 studies, TCE-exposed subgroup (classified as having adequate exposure data to identify subgroup of workers with TCE exposure) only; Group II studies (limited exposure data) excluded.