# Appendix C Genetic Toxicology

The tables on the following pages contain data discussed in the section “Genotoxicity and Related Effects” for trichloroethylene (Section 2).

Data are reported for in vitro studies of trichloroethylene, including mutagenicity in bacteria (Table C-1) and genotoxicity studies in non-mammalian eukaryotes (Table C-2) and mammalian cells (Table C-3). Studies on DNA and protein binding related to trichloroethylene exposure are included in Table C-4. In vivo studies of cytogenetic effects after trichloroethylene exposure in rodents are presented in Table C-5; studies of cytogenetic effects in peripheral blood lymphocytes from trichloroethylene-exposed workers are provided in Table C-6. The chemical purity of the test samples of trichloroethylene used in the studies is included here if available, or it is noted if the sample is of unknown purity/contained stabilizers or pure/did not contain stabilizers.

Table C-1 In Vitro Mutagenicity Studies of Trichloroethylene in Bacteria

Test System/Endpoint | LEC/HIC^a^ | Without Activation | With Activation | Purity, Methods and Comments^b^ | References
S. typhimurium TA100 | 14,650 | − | − | Stabilizers (not epoxides), no DMSO Plate incorporation assay | Henschler et al. (1977)
S. typhimurium TA100, TA1535 | 160 (vapor) 2,800 (vapor) | − − | (+) − | No stabilizers, no DMSO Desiccator assay; rat and mouse S9 For TA100, increased revertants but not doubled; effect greater with mouse S9 | Simmon et al. (1977)
S. typhimurium TA98, TA100 | 525 (vapor) | − all strains | − all strains | Stabilizers, no DMSO Study conducted in sealed desiccator vials | Waskell (1978)
S. typhimurium TA100, TA1535 | 160 (vapor) 526 (vapor) | − both strains; both methods | (+) TA100 − TA1535 | No stabilizers, ≥99.5% purity, no DMSO Two methods: plate incorporation in desiccator and preincubation; rat S9 Increased revertants but not doubled; effect only for plate incorporation in desiccator | Baden et al. (1979)
S. typhimurium TA100 | 420 (8% vapor), 16 hr | − plate incorporation | − plate incorporation + preincubation | No stabilizers; purity 99.5%, DMSO used as solvent Two methods: plate incorporation in desiccator and preincubation; mouse S9 Revertants doubled for preincubation assay | Bartsch et al. (1979)
S. typhimurium TA1535 | | (+) | | No stabilizers; purity 99.5%, no DMSO Plate incorporation | Kringstad et al. (1981)
S. typhimurium TA100 | 18 (vapor) | − | + | No stabilizers (epoxide-free), no DMSO | Crebelli et al. (1982)
S. typhimurium TA1535, TA100 | 50 (vapor) | H: − both strains L: (+) both strains | H: − both strains L: (+) both strains | No stabilizers, purity 99.98% (L) and 99.5% (H); tested high (H, Trichlor 136) and low (L, Trichlor 119) stabilized samples, no DMSO TA100 ± S9 positive only at top dose and 3% survival | Shimada et al. (1985)
S. typhimurium TA98, TA100, TA1535, TA1537, TA97 | 167 | − all strains | − all strains | No stabilizers; purity >99%, DMSO used as solvent Preincubation assay | Mortelmans et al. (1986)
S. typhimurium TA1535, TA100, TA1537, TA98 | Not reported | + TA1535, TA100 − TA1537, TA98 | + TA1535, TA100 − TA1537, TA98 | Purity not specified (97%–99%), no DMSO Desiccator (vapor) assay | Milman et al. (1988)
S. typhimurium TA98, TA100 | 1,050 (vapor) | | − | No stabilizers, purity >99.9%, DMSO used as solvent Desiccator (vapor) assay; S9 from rat and hamster | McGregor et al. (1989)
S. typhimurium TA98, TA100 | 1,050 (vapor) | − | − | No epoxybutane and epichlorohydrin, oxirane stabilized, purity >99.9%, DMSO used as solvent Preincubation assay | McGregor et al. (1989)
S. typhimurium TA1535, TA100, TA98 | 33 (vapor) 130 (vapor) 65 (vapor) | + TA1535 + TA100 − TA98 | + TA1535 + TA100 − TA98 | Stabilizers (epoxybutane and epichlorohydrin and oxirane), DMSO used as solvent Desiccator (vapor) assay | McGregor et al. (1989)
S. typhimurium BAL13 | 190 (vapor) | − | − | No stabilizers, purity 99%, DMSO used as solvent Forward mutation assay (ara test) | Roldan-Arjona et al. (1991)
S. typhimurium YG7108 | 3,000 μg/plate | + | | Purity ≥99.5%, DMSO used as solvent CYP E1 metabolically competent strain microcolony assay/revertants | Emmert et al. (2006)
Escherichia coli K12, reverse mutation arg^+^ | 434 | − | + | Purity unknown; analytical grade, no DMSO Reverse mutation (arg^+^) | Greim et al. (1975)
Escherichia coli PQ37 | 13,140 | − | − | Purity unknown, use of DMSO unknown SOS chromotest | von der Hude et al. (1988)
Escherichia coli PQ37 | 7,325 | − | − | No stabilizers, purity unknown, use of DMSO unknown SOS chromotest | Mersch-Sundermann et al. (1989)

Sources: EPA (2011a), IARC (2014); primary papers were reviewed for additional details on purity of test substance and solvent used.

+ = positive; (+) = weak positive; − = negative.

^a^ Treatment concentrations are μg/mL unless noted otherwise.

^b^ Presence of DMSO in test sample is indicated when noted by authors.

Table C-2 In Vitro Genotoxicity Studies of Trichloroethylene in Non-mammalian Eukaryotes

Test System/ Endpoint | LEC/HIC | Without Activation | | With Activation | Purity, Methods, and Comments^a^ | References
Gene mutation
S. cerevisiae D7 | 1,300 | − | | + | No stabilizers, solvent corn oil, no DMSO Reverse mutation | Bronzetti et al. (1978)
S. cerevisiae D7 | 1,970 | | | + | Purity unknown, contained 0.01% thymol as stabilizer, no DMSO Reverse mutation, log phase | Callen et al. (1980)
S. cerevisiae D7 | 725 | − | | (+) | Purity unknown, analytical grade, no DMSO Reverse mutation, log phase and stationary | Koch et al. (1988)
A. nidulans haploid strain 35 | 100 ppm (quiescent) 13 ppm (growing) | − + | | | No stabilizers, purity unknown, no DMSO Forward mutation, desiccator (vapor) | Crebelli et al. (1985)
Schizosaccharomyces pombe P1 | 3,280 (quiescent) 13,140 (growing) | − − | | − − | Measured forward mutation Tested both technical grade and pure (without stabilizers), DMSO (≤2%) used as solvent Negative for both sample purities and growth conditions | Rossi et al. (1983)
Gene conversion
Saccharomyces cerevisiae | Strain D7: 1,970 Strain D4: 2,900 | | | + − | Purity unknown, contained 0.01% thymol as stabilizer, no DMSO Log-phase cultures CYP content 5-fold greater in D7 than D4 Strain D7 had high cytotoxicity at 2,900 μg/mL | Callen et al. (1980)
S. cerevisiae D7 | 2,900 | − | | − | Purity unknown, analytical grade, no DMSO Stationary and log phase cultures Production of phototropic colonies | Koch et al. (1988)
S. cerevisiae D7 | 2,600 | − | | + | No stabilizers, solvent corn oil, no DMSO | Bronzetti et al. (1978)
Recombination and mitotic crossover
S. cerevisiae D7 | 1,970 | | | + | Purity unknown, contained 0.01% thymol as stabilizer, no DMSO | Callen et al. (1980)
Aspergillus nidulans yA2/+ strain 35/17 | 3,660 (quiescent) 90 (growing) | − − | | | No stabilizers, purity unknown, no DMSO Gene crossover; tested quiescent and growing cells Desiccator (vapor) | Crebelli et al. (1985)
Mitotic aneuploidy
S. cerevisiae D61.M | 725 | | + | + | Purity unknown, analytical grade, no DMSO Loss of dominant color homolog | Koch et al. (1988)

* p < 0.05, **p < 0.01, ***p < 0.001.

Sources: EPA (2011a), IARC (2014); primary papers were reviewed for additional details on purity of test substance and solvent used.

LEC/HIC = lowest effective concentration/highest ineffective concentration (treatment concentration μg/mL unless otherwise noted).

^a^ Presence of DMSO in test sample is indicated when noted by authors.

Table C-3 In Vitro Studies of Genotoxicity and Related Effects of Trichloroethylene in Mammalian (Including Human) Cells

Endpoint Test System | LEC/HIC | Without Activation | With Activation | Purity, Methods, and Comments^a^ | References
Gene mutation
Mouse lymphoma L5178Y tk locus | 146 μg/mL | − | + | Purity ≥99%, no stabilizers, DMSO used as solvent | Caspary et al. (1988)
Human lymphoblastoid TK6 cells | 600 μg/mL | − | − | Purity ≥99%, no stabilizers, DMSO used as solvent | Caspary et al. (1988)
Micronucleus induction
Chinese hamster ovary-K_1_ cells | 150 [0.8–1.4 ppm] | + | | Purity 99%, no DMSO Dose-dependent significant increase | Wang et al. (2001)
Rat primary kidney cells | 16.5 | + | | Purity unknown, reagent grade, solvent EtOH (0.3%) no DMSO Dose-dependent significant increase | Robbiano et al. (2004)
Human primary kidney cells | 16.5 | + | | Purity unknown, reagent grade, solvent EtOH (0.3%), no DMSO Dose-dependent significant increase | Robbiano et al. (2004)
Human hepatoma HepG2 cells | 0.5 mM [65.7 μg/mL] | + | | Purity ≥99.5%, DMSO (1%) used as solvent | Hu et al. (2008)
Human lymphocytes | 6 mM | − | | Purity unknown, DMSO (0.3%) used as solvent Cytokinesis-block assay | Kumar et al. (2009)
Chromosomal aberrations
Chinese hamster lung cells | 1,000 μg/mL | − | − | Purity unknown, use of DMSO not known | Sofuni et al. (1985)
Chinese hamster ovary cells | 14,900 μg/mL | − | − | No stabilizers, use of DMSO not known but probable | Galloway et al. (1987)
Human lymphocytes | 6 mM | − | | Purity unknown, DMSO (0.3%) used as solvent | Kumar et al. (2009)
Sister chromatid exchange
Chinese hamster ovary cells | 9 | | − | Purity unknown, no DMSO 1 hr (vapor) Limitations: short exposure time, few doses, no positive control | White et al. (1979)
Chinese hamster ovary cells | +S9: 401 μg/mL −S9: 700 μg/mL | (+) | + | Purity ≥99%, use of DMSO not known but probable | Galloway et al. (1987)
Human lymphocytes | 178 μg/mL | + | | No stabilizers, use of DMSO unknown | Gu et al. (1981)
DNA strand breaks
Human hepatoma HepG2 cells | 0.5 mM [65.7 g/mL] | + | | Purity ≥99.5%, DMSO (1%) used as solvent Comet assay | Hu et al. (2008)
Rat primary kidney cells | 16.5 | + | | Purity unknown (reagent grade), Solvent EtOH (0.3%), no DMSO Comet assay Dose-dependent significant increase | Robbiano et al. (2004)
Human primary kidney cells | 16.5 | + | | Purity unknown (reagent grade), Solvent EtOH (0.3%), no DMSO Comet assay Dose-dependent significant increase | Robbiano et al. (2004)
UDS (DNA repair)
Rat hepatocytes, phenobarbital-induced | 368 | + | | Purity unknown, no DMSO | Costa and Ivanetich (1984)
Rat primary hepatocytes | 130 (vapor) | − without stabilizers − with stabilizers | | Tested samples with and without stabilizers, no DMSO Cytotoxic | Shimada et al. (1985)
Rat primary hepatocytes | 56.77 (without stabilizer) 1,445 (with or without stabilizer) | + without stabilizers − vapor phase testing | | No stabilizers, purity unknown, no DMSO, standard test Tested vapor phase for samples both with and without stabilizers | Williams et al. (1989)
B6C3F_1_ mouse primary hepatocytes | NR | + | | Stabilizers; purity unknown, no DMSO | Milman et al. (1988)
Rat primary hepatocytes | NR | − | | Stabilizers; purity unknown, no DMSO | Milman et al. (1988)
Human lymphocytes | 2.5 μl/mL | (+) | | No stabilizers; purity 97%–99%, DMSO (1%) used as solvent | Perocco and Prodi (1981)
Cell transformation
RLV/Fischer rat F1706 embryo cells | 144 | + | | Purity 99.9%, no DMSO | Price et al. (1978)
Syrian hamster embryo cells | 25 | (+) | | Purity unknown, DMSO used as solvent | Amacher and Zelljadt (1983)
BALB/C-3T3 mouse cells | 250 | (+) | | Purity not specified (97%–99%), no DMSO | Tu et al. (1985)

* p < 0.05, **p < 0.01, ***p < 0.001.

Sources: EPA (2011a), IARC (2014); primary papers were reviewed for additional details on purity of test substance and solvent used.

LEC/HIC = lowest effective concentration/highest ineffective concentration (concentration in μg/mL unless otherwise noted); NR = not reported; + = positive; (+) = weak positive; − = negative.

^a^ Presence of DMSO in test sample is indicated when noted by authors.

Table C-4 Studies of DNA and Protein Binding of Trichloroethylene in Mammalian Cells or Rodents

Endpoint/ Test System | LED/HID | Without Activation | With Activation | Purity, Methods, and Comments^a^ | References
In vitro
Covalent binding Calf thymus DNA | 131 | | + | No stabilizers, purity unknown, no DMSO | DiRenzo et al. (1982)
Covalent binding Calf thymus DNA | 340 | − | + | No stabilizers, purity >99%, no DMSO | Bergman (1983)
Covalent binding Calf thymus DNA | 13 | | + | No stabilizers, purity >99%, no DMSO | Miller and Guengerich (1983)
Covalent binding Rat hepatocyte DNA | 13 | + | | No stabilizers, purity >99%, no DMSO | Miller and Guengerich (1983)
Covalent binding Mouse hepatocyte DNA | 13 | + | | No stabilizers, purity >99%, no DMSO | Miller and Guengerich (1983)
Covalent binding Calf thymus DNA | 3.2 | | + | Purity 98.9%, no DMSO Mediated by phenobarbitone-induced microsomal and/or cytosolic fractions from rat and mouse organs (mainly liver; also kidney, lung, stomach) | Mazzullo et al. (1992)
Covalent binding DNA Salmon sperm DNA | 270 | − | + | No stabilizers, purity >99%, no DMSO | Banerjee and Van Duuren (1978)
Protein binding Liver, lung, stomach, kidney microsomes Sprague-Dawley, Osborne-Mendel, and Fischer 344 rats (M & F) | | + | | No stabilizers, purity >99%, no DMSO Sprague-Dawley-rats had higher binding levels than Osborne-Mendel and Fischer 344 rats Binding was greater for males than females in Osborne-Mendel rats but not other strains | Banerjee and Van Duuren (1978)
Protein binding Liver, lung, stomach, kidney microsomes B6C3F_1_ mouse | | + | | No stabilizers, purity >99%, no DMSO Liver, lung stomach, kidney Binding was greater in mouse than rat (all strains) in same study Binding was greater in male than female mice | Banerjee and Van Duuren (1978)
Protein binding Liver and lung microsomes Osborne-Mendel rat | | + | | No stabilizers, purity >99%, no DMSO Binding to TCE oxide | Miller and Guengerich (1983)
Protein binding Liver microsomes B6C3F_1_ mouse | | + | | No stabilizers, purity >99%, no DMSO Binding to TCE oxide | Miller and Guengerich (1983)
Protein binding Insulin and adrenocorticotropic hormone Rabbit | | + | | No stabilizers, purity unknown, no DMSO Binding to TCE oxide | Cai and Guengerich (2001)
Protein binding Liver microsomes Human | | + | | No stabilizers, purity >99%, no DMSO Binding to TCE oxide | Miller and Guengerich (1983)
In vivo
Protein binding Liver Kidney B6C3F_1_ mouse (male) | 10 ppm 600 ppm | + + | | Purity >99.9%, no DMSO Amine stabilized inh. 6 hr (10 or 600 ppm) Measured reactive metabolite Mouse greater binding than rat in same study, for both doses and tissues | Stott et al. (1982)
Protein binding Liver, kidney Osborne-Mendel rat (male) | 600 ppm | − | | Purity >99.9%, no DMSO Amine stabilized inh. 6 hr (10 or 600 ppm) Measured reactive metabolite | Stott et al. (1982)
Covalent binding Liver DNA B6C3F_1_ mouse (male) | 1,200 | ? | | Purity >99.9%, no DMSO Amine stabilized p.o. × 1 | Stott et al. (1982)
Covalent binding Liver, kidney, lung, stomach DNA BALB/c mouse (male) | 0.76 | (+) | | Purity 98.9%, no DMSO i.p. × 1 | Mazzullo et al. (1992)
Covalent binding Liver, kidney, lung, stomach DNA Wistar rat (male) | 0.76 | (+) | | Purity 98.9%, no DMSO i.p. × 1 | Mazzullo et al. (1992)
Covalent binding Spleen, lung, kidney, pancreas, testis, brain DNA NMRI mouse | 67 | − | | No stabilizers, purity >99%, solvent peanut oil, no DMSO i.p. × 5 Metabolic incorporation of ^14^C into nucleotides was observed; findings for liver inconclusive | Bergman (1983)
Covalent binding Spleen, lung, liver, kidney, pancreas, testis, brain RNA NMRI mouse | 67 | − | | No stabilizers, purity >99%, solvent peanut oil, no DMSO i.p. × 5 Metabolic incorporation of ^14^C into nucleotides observed | Bergman (1983)

Sources: EPA (2011a), IARC (2014); primary papers were reviewed for additional details on purity of test substance and solvent used; studies considered to be inconclusive are not included here.

Exposure in vitro, μg/mL, unless otherwise indicated; in vivo, doses in ppm; p.o. = orally; i.p. = intraperitoneal injection in mg/kg body weight; inh. = inhalation; + = positive, (+) = weak positive; − = negative; ? = inconclusive.

^a^ Presence of DMSO in test sample is indicated when noted by authors.

Table C-5 In Vivo Studies of Genotoxicity of Trichloroethylene in Rodents

Test System/ Endpoint | LED/HID | Results | Purity, Methods, and Comments | Reference
Gene mutation
NMRI-Hans/BGA mouse (male) Dominant lethal | 3,400 | − | No stabilizers, purity 99.5%, no DMSO inh. 24 hr × 1 | Slacik-Erben et al. (1980)
Lac Z transgenic mouse (male and female) Lung, liver, spleen, kidney, testicular germ cells | 3,144 | − | No stabilizers, purity >99%, no DMSO inh. 6 hr/d × 6 d No base changes or small deletions | Douglas et al. (1999)
Micronucleus induction
Mouse Bone-marrow erythrocytes | 750 | + | No stabilizers, use of DMSO unknown p.o. in gum arabic × 2 | Duprat and Gradiski (1980)
B6C3F_1_ mouse (male) Bone-marrow erythrocytes | 2,500 | − | No stabilizers, purity not reported, no DMSO i.p. in corn oil × 3 | Shelby et al. (1993)
C57BL/6J mouse (male) Bone marrow erythrocytes | 9,800 | − | No stabilizers, purity >99%, no DMSO inh. 6 hr × 1 | Kligerman et al. (1994)
CD-1 mouse (male) Bone-marrow erythrocytes | 460 | + | Purity not reported, no DMSO i.p. in corn oil × 1 Correlated with urinary TCOH | Hrelia et al. (1994)
C57B1/6J mouse (male) Spermatocytes | 565 | − | No stabilizers, purity ≥99%, no DMSO inh. 6 hr/d × 5 d Spermatids examined | Allen et al. (1994)
C57BL/6J mouse (male) Splenocytes | 9,800 | − | No stabilizers, purity >99%, no DMSO inh. 6 hr × 1 | Kligerman et al. (1994)
Sprague-Dawley CD rat (male) Bone-marrow erythrocytes | 5 | + | No stabilizers, purity >99%, no DMSO inh. 6 hr × 1 Dose-related increases from 5 to 5,000 ppm; findings confirmed in repeated study of high dose | Kligerman et al. (1994)
Sprague-Dawley CD rat (male) Bone-marrow erythrocytes | 960 | − | No stabilizers, purity >99%, no DMSO inh. 6 hr × 4 Authors note concurrent controls were unusually high | Kligerman et al. (1994)
Sprague-Dawley CD rat (male) Bone marrow erythrocytes | 5,000 | − | Purity 99.97%, no DMSO inh. 6 hr × 1 | Wilmer et al. (2014)
Sprague-Dawley CD rat (male) Peripheral blood lymphocytes | 8,800 | − | No stabilizers, purity >99%, no DMSO inh. 6 hr × 1 | Kligerman et al. (1994)
Sprague-Dawley CD rat (male) Peripheral blood lymphocytes | 960 | − | No stabilizers, purity >99%, no DMSO inh. 6 hr × 4 | Kligerman et al. (1994)
Sprague-Dawley CD rat (male) Kidney cells | 3,591 | + | Purity unknown, reagent grade, no DMSO p.o. in EtOH × 1 | Robbiano et al. (2004)
Chromosomal aberrations
C57BL/6J mouse (male) Splenocytes | 9,800 | − | No stabilizers, purity >99%, no DMSO inh. 6 hr × 1 | Kligerman et al. (1994)
Sprague-Dawley CD rat (male) Peripheral blood lymphocytes | 8,800 | − | No stabilizers, purity >99%, no DMSO inh. 6 hr × 1 | Kligerman et al. (1994)
Sprague-Dawley CD rat (male) Peripheral blood lymphocytes | 960 | − | No stabilizers, purity >99%, no DMSO inh. 6 hr × 4 | Kligerman et al. (1994)
CD-1 mouse Bone-marrow cells | 1,000 | − | Purity unknown, use of DMSO unknown p.o. × 1 | Loprieno and Abbondandolo (1980)
Sister chromatid exchange
C57BL/6J mouse (male) Splenocytes | 9,800 | − | No stabilizers, purity >99%, no DMSO inh. 6 hr × 1 | Kligerman et al. (1994)
Sprague-Dawley CD rat (male) Peripheral blood lymphocytes | 8,800 | − | No stabilizers, purity >99%, no DMSO inh. 6 hr × 1 | Kligerman et al. (1994)
Sprague-Dawley CD rat (male) Peripheral blood lymphocytes | 960 | − | No stabilizers, purity >99%, no DMSO inh. 6 hr × 4 | Kligerman et al. (1994)
DNA single-strand breaks
B6C3F_1_ mouse (male) Liver | 2,000 | − | No stabilizers, purity unknown, use of DMSO unknown i.p. × 1 | Parchman and Magee (1982)
NMRI mouse (male) Kidney, liver, lung | 790 1,300 | + (kidney, liver) − (lung) | No stabilizers, purity 99.5%, no DMSO Alkaline unwinding i.p. in Tween-80 × 1 | Walles (1986)
B6C3F_1_ mouse (male) Liver | 1,500 | + | Purity >99%, no DMSO DNA single strand breaks Alkaline unwinding p.o. in Tween-80 (1%) × 1 | Nelson and Bull (1988)
Mouse spot test in (DNA alternations) embryos from treated dams | 350 | − | No stabilizers, purity 99.5%, no DMSO i.p. × 1 | Fahrig (1977)
Sprague-Dawley rat (male) Liver | 3,000 | + | Purity >99%, no DMSO Alkaline unwinding p.o. in Tween-80 (1%) × 1 | Nelson and Bull (1988)
Sprague-Dawley CD rat (male) Kidney | 3,591 | + | Purity reagent grade, no DMSO Comet assay p.o. in EtOH | Robbiano et al. (2004)
Sprague-Dawley CD rat (male) Kidney | 2,000 ppm [~10,800 mg/kg/day^a^] | − | Purity 99.5%, no DMSO Comet assay inh. 6 hr × 5 | Clay (2008)
UDS (DNA repair)
Fischer 344 rat (male) Primary hepatocytes | 1,000 | − | Purity unknown, no DMSO p.o. corn oil or water × 1 | Mirsalis et al. (1989)
B6C3F_1_ mouse (male and female) Primary hepatocytes | 1,000 | − | Purity unknown, no DMSO p.o. corn oil or water × 1 | Mirsalis et al. (1989)
CD-1 mouse (male) Primary hepatocytes | 1,000 | − | No stabilizers, no DMSO p.o. in corn oil × 1 | Doolittle et al. (1987)

Sources: EPA (2011a), IARC (2014); if additional detail was needed, primary paper was reviewed.

LED = lowest effective dose; HID = highest ineffective dose.

Exposure: i.p. = intraperitoneal injection, p.o. = oral, both in mg/kg body weight, inh. = inhalation, doses in ppm.

^a^ Estimated 10,800 mg/kg/day based on the following assumptions: inhalation rate for rats = 73 cm^3^/min; body weight (white rat) = 113 g and assuming 100% assumption. (10,748 mg/m^3^ × 73 cm^3^/min × 1 m^3^/1,000,000 cm^3^ × 1,440 min/day)/0.0113 kg = ~10,800 (USEPA 2006). Absorption would most likely be lower at 2,000 ppm, resulting in a lower mg/kg/day dose.

Table C-6 Cytogenetic Studies in Peripheral Blood Lymphocytes from Trichloroethylene-exposed Workers

Reference | Population | Exposure Group | Findings | Comments
Rasmussen et al. (1988) Denmark | 15 metal degreaser workers exposed to TCE >20 hr/wk 669 controls from population-based study and survey of parents with offspring with stable chromosomal abnormalities in same geographical location | Exposed Controls Exposed Controls Exposed Controls | CA: breaks 1.90 (1.22–2.84) 0.85 (0.66–1.08)*** CA: other 1.35 (0.79–2.16)*** 0.15 (0.08–0.27) CA: hyperdiploid 0.79 (0.38–1.46)* 0.24 (0.15–0.38) | 15 workers identified from a total of 116 workers Control population may not be comparable to workers although the large size may reduce any potential selection bias Other chromosomal aberrations include translocations, deletions, and inversions
Seiji et al. (1990) Japan | 38 TCE-exposed (22 M, 16 W) 7 ppm 51 controls (26 M, 25 W) matched on age, sex, smoking habits, and geographical location | Men Exposed smoker (8) Control smokers (7) Exposed non-smokers (14) Control non-smokers (19) Women Exposed non-smokers (16) Control non-smokers (25) | SCE 7.06 ± 1.38** 5.10 ± 1.16 6.46 ± 1.25 5.78 ± 1.64 6.15 ± 1.34 6.25 ± 1.42 | Workers TCE synthesis and degreasers TCE exposure levels (ppm) were higher in women (3–32 ppm) than men (2–10 ppm); duration was shorter in women (~70 months) than men (120 months) No independent effect of smoking
Nagaya et al. (1989) Japan | 22 TCE-exposed workers (~30 ppm) 22 workers without exposure to solvents and matched on age, and sex, and smoking habits | Exposed Controls | SCE 7.7 ± 1.3 8.0 ± 1.4 | Employment duration 0.7–34 years, mean 9.7 years Estimated exposure 30 ppm, based on urinary total trichloro compounds, but large range in exposure levels
Gu et al. (1981) (Cited from IARC 2014) | 6 TCE-exposed workers 9 controls | Exposed Controls | SCE 9.045 ± 4.898 7.910 ± 2.890 | Exposure assessed by measurement of TCE and metabolite (U-TCA) in blood

* p < 0.05, χ^2^-test (Rasmussen et al. 1988); **p < 0.01 (t-test compared with concurrent male controls for Seiji et al. (1990)); ***p < 0.001, χ^2^-test (Rasmussen et al. 1988).

CA = chromosomal aberrations; SCE = sister chromatid exchange; TCE = trichloroethylene; U-TCA = urinary trichloroacetic acid.