# Appendix B ADME Tables

Table B-1 In Vitro Kinetics of Oxidative Metabolism of Trichloroethylene

System | N | K_m_ (μM) | V_max_ (nmol TCE/min/mg Protein) | 1,000 × V_max_/K_m_ | Reference
Human
Hepatocytes | 6 | 210 ± 159^a^ | 1.5 ± 1.2^b^ | [13.7 ± 12.8] | Lipscomb et al. (1998a)
Liver microsomes | 10 9 4 23 | 16.7 ± 2.45^c^ 30.9 ± 3.3^d^ 51.1 ± 3.77^e^ 28.3 ± 12.9^f^ | 1.25 ± 0.81^c^ 1.44 ± 0.46^d^ 2.77 ± 0.58^e^ 1.59 ± 0.84^f^ | [74.1 ± 44.1] [47.0 ± 16.0] [54.9 ± 14.1] [60.2 ± 32.9] | Lipscomb et al. (1997)
Liver microsomes | 7 | 24.6 | 1.44 | 58.5 | Lipscomb et al. (1998b)
Liver microsomes (high affinity) | 3 3 | 12 ± 3 26 ± 17 | 0.52 ± 0.17 (males) 0.33 ± 0.15 (females) | 48.0 ± 23.1 15.3 ± 10.1 | Elfarra et al. (1998)
Liver microsomes (low affinity) | 3 3 | 93 ± 26 160 ± 162 | 0.93 ± 0.17 (males) 0.72 ± 0.60 (females) | 10.7 ± 3.9 6.8 ± 5.6 | Elfarra et al. (1998)
Rat
Liver microsomes | 5 | 55.5^g^ | 4.83 | 87.0 | Lipscomb et al. (1998b)
Liver microsomes (high affinity) | 5 3 | 72 ± 82 42 ± 21 | 0.96 ± 0.65 (males) 2.91 ± 0.71 (females) | 23.8 ± 20.6 80.0 ± 33.9 | Elfarra et al. (1998)
Liver microsomes (low affinity) | 5 3 | 482 ± 104 111 ± 27 | 2.48 ± 0.97 (males) 4.31 ± 0.31 (females) | 5.3 ± 2.2 40.1 ± 7.1 | Elfarra et al. (1998)
Kidney microsomes | 3 | 940^h^ | 0.154 | [0.164] | Cummings et al. (2001)
Mouse
Liver microsomes | 5 | 35.4^g^ | 5.43 | 153.4 | Lipscomb et al. (1998b)
Liver microsomes | 5 3 | 378 ± 414 161 ± 29 | 8.6 ± 4.5 (males) 26.1 ± 7.29 (females) | 42.0 ± 28.5 162.8 ± 36.7 | Elfarra et al. (1998)

Values in brackets were calculated by NTP.

^a^ Converted from ppm trichloroethylene in headspace.

^b^ Converted from nmol/h/10^6^ hepatocytes.

^c^ Low K_m_ (12–20) group.

^d^ Mid K_m_ (26–37) group.

^e^ High K_m_ (>46) group.

^f^ Combined across all K_m_ groups.

^g^ K_m_ value for 0–5,000 μM TCE concentration.

^h^ Mean of values calculated by Lineweaver-Burk and Eadie-Hofstee analysis.

Table B-2 In Vitro Kinetics of Chloral Hydrate and Dichloroacetic Acid Biotransformation

Metabolic Step | System | K_m_ (μM) | V_max_ (nmol/min/mg Protein) | 1,000 × V_max_/K_m_
CH to TCOH | Human Rat Mouse high affinity low affinity | 1,340 520 190 120 510 | 34.7 24.3 11.3 6.3 6.1 | 25.9 46.7 59.5 52.5 12.0
CH to TCA | Human Rat Mouse | 23,900 16,400 3,500 | 65.2 4.0 10.6 | 2.7 0.24 3.0
DCA to glyoxylate | Human Rat Mouse | 71 280 350 | 0.37 11.6 13.1 | 5.2 41.4 37.4

Sources: Adapted from EPA (2011a), Lash et al. (2000a).

CH = chloral hydrate; DCA = dichloroacetic acid; TCA = trichloroacetic acid; TCOH = trichloroethanol.

Table B-3 Rates of DCVG Formation from Trichloroethylene Conjugation^a^

System | Male | Female | Reference
Human
Hepatocytes (0.9 mM, pooled) | 11 ± 3^b^ | | Lash et al. (1999a)
Liver cytosol (1 mM, individual samples) | 156 ± 16 | 174 ± 13 | Lash et al. (1999a)
Liver cytosol (1 mM, pooled) | 420^b^ | | Lash et al. (1999a)
Liver cytosol (2 mM, pooled) | 346^b^ | | Lash et al. (1999a)
Liver cytosol (1.9 mM) | 0.011^c^ | | Green et al. (1997)
Liver microsomes (1 mM, individual samples) | 108 ± 24 | 83 ± 11 | Lash et al. (1999a)
Liver microsomes (1 mM, pooled) | 146^b^ | | Lash et al. (1999a)
Kidney cytosol (2 mM, pooled) | 42^b^ | | Lash et al. (1999a)
Kidney microsomes (1 mM, pooled) | 320^b^ | | Lash et al. (1999a)
Rat
Hepatocytes (2 mM) | 9.7 ± 0.29* | 2.67 ± 0.69 | Lash et al. (1998)
Liver cytosol (2 mM) | 7.3 ± 2.8 | 4.86 ± 0.14 | Lash et al. (1998)
Liver cytosol (1.9 mM) | 0.097^c^ | | Green (1997)
Liver cytosol (4 mM) | nd | | Dekant et al. (1990)
Liver microsomes (2 mM) | 10.3 ± 2.8 | 7.24 ± 0.24 | Lash et al. (1998)
Liver microsomes (4 mM) | 0.12 | | Dekant et al. (1990)
Kidney cortical cells (2 mM) | 0.48 ± 0.02 | 0.65 ± 0.15 | Lash et al. (1998)
Kidney cytosol (2 mM) | 0.45 ± 0.22 | 0.32 ± 0.02 | Lash et al. (1998)
Kidney microsomes (2 mM) | nd | 0.61 ± 0.06 | Lash et al. (1998)
Mouse
Liver cytosol (2 mM) | 24.5 ± 2.4 | 21.7 ± 0.9 | Lash et al. (1998)
Liver cytosol (1.9 mM) | 0.15^c^ | | Green (1997)
Liver microsomes (2 mM) | 40.0 ± 3.1* | 25.6 ± 0.8 | Lash et al. (1998)
Kidney cytosol (2 mM) | 5.6 ± 0.24* | 3.7 ± 0.48 | Lash et al. (1998)
Kidney microsomes (2 mM) | 5.47 ± 1.41* | 16.7 ± 4.7 | Lash et al. (1998)

* p < 0.05 (compared to corresponding tissue sample in females).

Source: Adapted from EPA (2011a).

nd = not detected.

^a^ Units are nmol/hr/mg protein or 10^6^ cells.

^b^ Pooled samples include preparations derived from both sexes.

^c^ Converted from pmol/min/mg protein.

Table B-4 Kinetics of In Vitro Glutathione Conjugation of Trichloroethylene

System | K_m_ (μM TCE) | V_max_ (nmol DCVG/min/mg Protein or 10^6^ Cells) | 1,000 × V_max_/K_m_
Human
Hepatocytes | 37 ~ 106 | 0.16 ~ 0.26 | 2.4 ~ 4.5
Liver cytosol: high affinity | 22.7 | 4.27 | 190
Liver cytosol: low affinity | 333 | 8.77 | 26.3
Liver microsomes: high affinity | 29.4 | 1.42 | 48.3
Liver microsomes: low affinity | 250 | 3.1 | 12.4
Kidney proximal tubular cells: high affinity | 580 | 0.11 | 0.19
Kidney proximal tubular cells: low affinity | 29,400 | 1.35 | 0.046
Kidney cytosol | 26.3 | 0.81 | 31
Kidney microsomes | 167 | 6.29 | 38
Rat
Kidney proximal tubular cells: high affinity | 460 | 0.47 | 1.0
Kidney proximal tubular cells: low affinity | 2,910 | 0.65 | 0.22

Sources: Cummings and Lash (2000), Cummings et al. (2000), Lash et al. (1999a), EPA (2011a).

Table B-5 β-Lyase Activity from Human, Rat, and Mouse Kidney Cytosol

System | Substrate | K_m_ (mM TCE) | V_max_ (nmol TCE/min/mg Protein) | Reference
Human
Male | TCVC | 2.53 ± 0.09 | 0.49 ± 0.07 | Green et al. (1990)
Female | TCVC | 2.67 ± 2.11 | 0.64 ± 0.54 | Green et al. (1990)
F344 Rat
Male | BTC | 1.66 ± 0.19 | 74.8 ± 6.5 | Lash et al. (1986)
Male | CTFC | 1.78 ± 0.17 | 11.6 ± 1.6 | Lash et al. (1986)
Male | DCVC | 1.36 ± 0.05 | 38.3 ± 1.4 | Lash et al. (1986)
Male | DCVC | 0.26 | 2.2 | Stevens et al. (1989)
Male | TCVC | 0.68 ± 0.06 | 4.00 ± 0.11 | Green et al. (1990)
Female | TCVC | 1.26 ± 0.21 | 3.64 ± 0.41 | Green et al. (1990)
B6C3F_1_ Mouse
Male | TCVC | 5.69 ± 2.22 | 1.15 ± 0.31 | Green et al. (1990)
Female | TCVC | 4.43 ± 1.42 | 1.66 ± 0.27 | Green et al. (1990)

Sources: Adapted from Lash et al. (2000a).

BTC = S-(2-benzothiazolyl)-L-cysteine; CTFC = S-(2-chloro-1,1,2-trifluoroethyl)-L-cysteine; DCVC = S-dichlorovinyl-L-cysteine; TCVC = S-(1,2,2-trichlorovinyl)-L-cysteine.

Table B-6 Comparison of Hepatic In Vitro Oxidation and Glutathione Conjugation of Trichloroethylene in Human Hepatocytes and Liver Subcellular Fractions^a^

System | Pathway | K_m_ (μM in Blood) | V_max_ (nmol TCE/min/g Tissue | V_max_/K_m_ (mL/min/g Tissue)
Hepatocytes | Oxidation Conjugation | 22.1–198 16–47 | 10–68.4 16–25 | 0.087–1.12 0.55–1.0
Microsomes (option 1)^b^ | Oxidation Conjugation | 2.66–11.1 5.9 | 6.1–111 45 | 1.71–28.2 7.6
Microsomes (option 2)^b^ | Oxidation Conjugation | 71–297 157 | 6.1–111 45 | 0.064–1.06 0.29
Cytosol (option 1)^c^ | Oxidation Conjugation | na 4.5 | na 380 | na 84
Cytosol (option 2)^c^ | Oxidation Conjugation | na 22.7 | na 380 | na 16.7

Sources: Adapted from EPA (2011a).

na = not applicable.

^a^ When biphasic metabolism was reported, only the high affinity pathway is shown.

^b^ K_m_ values for microsomal protein calculated using different conversion assumptions: option 1 assumes K_m_ in medium is equal to K_m_ in tissue and converts to K_m_ in blood by using a liver:blood partition coefficient of 5; option 2 converts K_m_ in medium to K_m_ in air using the measured microsomal protein:air partition coefficient of 1.78, then converts to K_m_ in blood using blood:air partition coefficient of 9.5.

^c^ K_m_ values for cytosolic protein calculated using different conversion assumptions: option 1 assumes K_m_ in medium is equal to K_m_ in tissue and converts K_m_ in blood by using a liver:blood partition coefficient of 5; option 2 assumes K_m_ in medium is equal to K_m_ in blood, thus no conversion was necessary.