# Appendix A Literature Search Strategy

The data sources, search terms, and search strategies that were used to identify literature for the draft monograph on trichloroethylene are described in the “Trichloroethylene Protocol” (https://ntp.niehs.nih.gov/ntp/roc/thirteenth/protocols/tce_protocol12-31-13_508.pdf).

Figure A-1

Literature Search Strategy and Review