# 6 Overall Cancer Evaluation – Synthesis of Human, Animal, and Mechanistic Data

This section synthesizes the information from toxicological, mechanistic, and human epidemiological studies, and applies the RoC listing criteria to that body of knowledge to reach a preliminary listing recommendation. The evidence for urinary bladder cancer, which is the only tumor site that has been adequately studied in humans, is discussed in Section 6.1 and the available data for other tumor sites associated with exposure to ortho-toluidine are briefly discussed in Section 6.2.

## 6.1 Urinary Bladder Cancer

Evidence that ortho-toluidine is a known human bladder carcinogen comes from human cancer studies finding increased risks of urinary bladder cancer in humans, in concert with studies showing that it causes cancer in experimental animals, including site concordance at the same tissue site in rats and studies demonstrating the biological plausibility of mechanisms of its carcinogenicity in humans.

### 6.1.1 Human Cancer Studies

There is credible evidence of an association between increased urinary bladder cancer risk and exposure to ortho-toluidine based on consistent findings across studies, the presence of statistically significant, positive exposure-response relationships with cumulative rank exposure and duration, and large magnitudes of effect across studies. Potential confounding by occupational co-exposures can reasonably be ruled out in the studies of rubber chemical workers. Although there is limited information on cigarette smoking, potential confounding from smoking can reasonably be ruled out in the NIOSH cohort, and it is unlikely to explain the large risk estimates found in the smaller studies. Finally, the finding of increased urinary bladder cancer risk in different cohorts with different exposure conditions and different co-exposures lends strong support to the conclusion that ortho-toluidine is the common causal risk factor (see Section 3).

### 6.1.2 Studies of Cancer in Experimental Animals

There is site concordance for urinary bladder cancer; ortho-toluidine causes urinary bladder neoplasms in both female and male rats although the evidence is stronger in females. The urinary bladder cancer findings in female rats are considered to be robust because of the relatively high tumor incidences, the rarity of the tumor in this species, and the shorter time to first observed tumor in the high-dose females than in the low-dose females (NCI 1979). Although the incidences of urinary bladder cancer are lower in male rats and not statistically significantly increased, they are considered to be exposure related because they are very rare, and were observed in all three carcinogenicity studies The observation of a significantly increased incidence of transitional-cell hyperplasia of the urinary bladder in male rats after 13 or 26 weeks of exposure in subchronic exposure study (NTP 1996) (see Section 4) supports this conclusion.

### 6.1.3 Mechanistic Evidence

Although the mechanisms of carcinogenicity of ortho-toluidine are not completely understood, the available evidence suggests that they are complex and involve several key modes of action, including metabolic activation that results in binding of reactive metabolites to DNA and proteins, mutagenicity, oxidative DNA damage, chromosomal damage, and cytotoxicity. The key metabolic activation steps and genotoxic effects occur in both experimental animals and humans. ortho-Toluidine is an aromatic amine, and some chemicals in this class are known human bladder carcinogens: 4-aminobiphenyl, benzidine, and 2-naphthylamine. In addition, ortho-toluidine has a similar toxicological profile as another aromatic amine, 4,4′-methylenebis(2-chloroaniline), which is classified as carcinogenic to humans based on strong mechanistic data involving metabolic activation similar to that proposed for ortho-toluidine.

#### 6.1.3.1 Metabolic Activation Leading to Formation of Hemoglobin and DNA Adducts

Metabolism of monocyclic aromatic amines, including ortho-toluidine, involves many competing activating and deactivating pathways including N-acetylation, N-oxidation and hydroxylation, and ring oxidation (C-hydroxylation). Cytochrome P450-mediated N-hydroxylation to the N-hydroxy derivative (N-hydroxy-ortho-toluidine), a proximate carcinogenic metabolite, occurs in the liver. N-hydroxy-ortho-toluidine is transported to the urinary bladder and can be bioactivated via conjugation by sulfation and/or acetylation by cytosolic NATs or SULTs. The postulated (based on comparison with other aromatic amines) conjugated form, N-acetoxy-ortho-toluidine, is a reactive ester that forms electrophilic arylnitrenium ions that can bind DNA.

Studies of other aromatic amines that cause urinary bladder cancer have shown that during the transport of the N-hydroxy-arylamines to the urinary bladder, bioreactive metabolites (nitroso form) can form and bind to hemoglobin in the blood (Skipper and Tannenbaum 1994). Thus, hemoglobin adducts may reflect the amount of amine that an individual takes up from the environment, converts to its proximate carcinogenic form (i.e., N-hydroxy-toluene for ortho-toluidine), and exports into blood.

Evidence suggesting that this pathway is relevant to humans comes from numerous studies that detected hemoglobin adducts in ortho-toluidine-exposed humans (following both occupational and nonoccupational exposures), consistent with studies in experimental animals. Hemoglobin adducts are thought to be formed from the ortho-toluidine metabolite, ortho-nitrosotoluene, which also causes urinary bladder cancer in rats (Hecht et al. 1982).

#### 6.1.3.2 Metabolic Activation Leading to Oxidative DNA Damage

Other activation pathways for aromatic amines include peroxidase-catalyzed reactions that form quinone imines from non-conjugated phenolic metabolites. The urinary bladder, a primary target for carcinogenic aromatic amines, contains high peroxidase activity. Semiquinone/quinone redox cycling of unconjugated phenolic metabolites in the transitional epithelium can produce reactive oxygen species (ROS), oxidative cellular damage and compensatory cell proliferation. Support for this mechanism comes from studies of (1) ortho-toluidine (via its metabolites) induced oxidative DNA damage in cultured cells (HL-60), DNA or DNA fragments from key genes (c-Ha-ras oncogene and the p53 tumor-suppressor gene) thought to be involved in carcinogenesis (Ohkuma et al. 1999; Watanabe et al. 2010) and (2) ortho-toluidine induced DNA damage (strand breaks) in cultured human urinary bladder cells and urinary bladder cells from rats and mice exposed to ortho-toluidine.

#### 6.1.3.3 Genetic and Related Effects

Overall, the extensive data on genetic and related effects of ortho-toluidine indicate that it can cause DNA and chromosomal damage and induce mutations. Although ortho-toluidine is a weak mutagen in bacteria, it causes mutations in human lymphocytes and cell transformation in rodent cells in vitro, and two ortho-toluidine metabolites (N-hydroxy-ortho-toluidine and ortho-nitrosotoluene) are potent mutagens in bacteria with mammalian metabolic activation. DNA adducts have been detected in liver (similar to other aromatic amines) and nasal (but not urinary bladder) tissue from exposed rats. ortho-Toluidine-releasing DNA adducts have been reported in human urinary bladder tumors and in normal human urinary bladder tissue (presumably as a result of background environmental exposure albeit covalent binding was not demonstrated (see Section 5.). Exposure to o-toluidine also caused DNA damage in other tissues in addition to the urinary bladder including bladder, kidney, colon, and stomach in exposed rats, and liver, lung, stomach, and brain in exposed mice.

There is evidence that ortho-toluidine also causes large-scale chromosome damage in yeast and mammalian cells (e.g., deletions, insertions, translocations, and/or aneuploidy). Exposure to aromatic amines has been shown to induce chromosomal instability in genetically stable urinary bladder cancer cells. Chromosomal instability is associated with aneuploidy and loss of heterozygosity. Aneuploidy is a common feature of bladder cancer in humans and loss of heterozygosity is an important mechanism for inactivation of tumor-suppressor genes.

## 6.2 Other Tumor Sites

In addition to urinary bladder neoplasms, exposure to ortho-toluidine also caused increases in the incidence of (malignant or combined malignant and benign) tumors in the blood vessels of male and female mice, liver of female mice, subcutaneous tissue in male and female rats, and connective tissue and mesothelium in male rats (see Section 4). It also caused benign tumors of the mammary gland in rats of both sexes. Few mechanistic data are available for most of these tumor sites; and no compelling information was found to disregard the relevance to humans. In the liver, metabolic activation to reactive metabolites is a key step in aromatic amine-induced liver neoplasms; N-acetylation is an activating reaction in the liver. NAT enzyme activity for other aromatic amines in rat liver cytosol was about an order of magnitude lower than in mouse liver cytosol and may explain the greater susceptibility to liver cancer in mice (Lower and Bryan 1973). ortho-Toluidine caused single-strand breaks in exposed mice, suggesting that DNA damage might play a role in ortho-toluidine carcinogenicity. In addition, hemoglobin adducts have been reported in exposed mice, suggesting the role of reactive (hydroxylated) metabolites.

Several studies also examined the unique splenotoxic effects of ortho-toluidine and related compounds, and the evidence suggests that splenic tumors in rats result from a secondary response at cytotoxic doses associated with erythrocyte damage, vascular congestion, hemosiderin deposition, iron overload, hemorrhage, hyperplasia, and fibrosis. No mechanistic data were found for tumors at other sites.

## 6.3 NTP’s Listing Recommendation

ortho-Toluidine is known to be a human carcinogen based on sufficient evidence from studies in humans in concert with (1) sufficient evidence from cancer studies in animals, including site concordance for cancer in female and male rats and (2) mechanistic data demonstrating biological plausibility in humans.