# 5 Mechanistic Data and Other Relevant Effects

The purpose of this section is to review data that identify or elucidate potential mechanisms of action for the carcinogenic effects discussed in Sections 3 and 4. These data include but are not necessarily limited to: (1) genetic and related effects, (2) relevant toxicological effects (effects that may be associated with carcinogenicity or are a key feature of a proposed carcinogenic mechanism), (3) mechanistic considerations, and (4) carcinogenic effects of metabolites and analogues.

## 5.1 Genetic and Related Effects

The genetic and related effects of ortho-toluidine have been extensively investigated and reviewed (Danford 1991; IARC 2000; 2010e). Many of the data came from two international collaborative studies of short-term tests for carcinogens (Ashby et al. 1985; de Serres and Ashby 1981). The first of these studies included 42 coded chemicals and the second included 10 uncoded chemicals; ortho-toluidine was included in both studies. Some important features of these studies included the following: (1) more than 35 assays were used to represent all available types of short-term tests claimed to have potential as carcinogen prescreens, (2) multiple laboratories participated in the studies; (3) chemicals were prepared in pure form and dispatched to the participating laboratories from the same batch; (4) a common S9 preparation was provided but its use was optional; (5) all participating investigators were required to submit protocols prior to the beginning of the studies but no attempt was made to standardize protocols; (6) standard defined criteria were used to evaluate assay performance; and (7) data reporting was limited because of the number of chemicals involved.

Overall, the data show that ortho-toluidine has a wide range of genetic effects; however, there is substantial variation in results between different laboratories as well as minor variations in protocols. Data are presented for bacterial systems (Section 5.1.1), non-mammalian eukaryotes (Section 5.1.2), in vitro mammalian systems (Section 5.1.3), in vivo studies (Section 5.1.4), and genotoxicity studies of ortho-toluidine metabolites (Section 5.1.4.3). Results for genetic and related effects are synthesized in Section 5.1.5. All tables for this section, with the exception of the overall summary table, are provided in Appendix F.

### 5.1.1 Bacterial Systems

ortho-Toluidine has a mutagenicity profile similar to other arylamines, with weakly positive results in bacteria and requiring specific assay conditions to demonstrate positive effects. ortho-Toluidine has been tested for reverse and forward mutations (using plate incorporation, preincubation, and fluctuation protocols) and prophage induction in Salmonella typhimurium; reverse mutations, differential toxicity, growth inhibition, and prophage induction in Escherichia coli; and DNA damage (rec assay) in Bacillus subtilis. Results from these studies are summarized in Appendix F, Table F-1.

ortho-Toluidine did not cause mutations in S. typhimurium or E. coli without metabolic activation. There were a few positive reverse mutation studies in S. typhimurium strains TA100, TA98, and TA1538 with metabolic activation only and, in most cases, with modifications to the standard protocol. These modifications included use of the fluctuation protocol (one study each with TA100 and TA1538), use of higher concentrations of S9 (30% rat or hamster, three studies with TA100 and one with TA98), and/or specific preparations of S9 (phenobarbitol-induced rat S9, or phenobarbitone + β-naphthoflavone, one study each with TA98 and TA1538). Some negative findings were also found using the more sensitive fluctuation protocol in Salmonella strains TA98, 1535, and 1537. No clear differences were observed in studies using strains that detect base-pair mutations compared with strains detecting frameshift mutations. One forward mutation study in S. typhimurium strain BA13 was positive (arabinose resistance) with 30% rat S9 but negative with 10% rat S9. Two forward mutation studies (8-azaguanine resistance) in strain TM677 were negative. A host-mediated assay also reported that urine from ortho-toluidine-treated rats induced reverse mutations in TA98 but not in TA100.

The mutagenicity profile for ortho-toluidine in the Ames test is consistent with findings from studies on other arylamines. These studies suggest that the low mutagenic activity of arylamines in the Ames test might be explained by deficiencies in metabolizing enzymes (e.g., sulfotransferases and acetyltransferases) in Salmonella. One study found that the introduction of cDNA encoding hamster acetyltransferase in S. typhimurium TA1538 markedly enhanced the mutagenicity of arylamines in that test system (Kato and Yamazoe 1994). Similarly, Oda et al. (1999; 1995) reported increased sensitivity to aromatic amines in Salmonella tester strains over-expressing bacterial O-acetyltransferase (O-AT) or human N-acetyltransferases (NATs) compared with parent or O-AT deficient strains. This system is based on the induction of the umuC gene as part of the general SOS response to DNA damage. It is also possible that the type of damage induced by these carcinogens might include large-scale changes in genome structure (e.g., deletions, insertions, or translocations) that are not detected by the Salmonella tester strains. Other possibilities include a lack of sufficient quantities of the particular enzymes (with or without added S9 mix) required to activate certain carcinogens, or reactive intermediates might not be able to cross the cell wall. The specific conditions required in most of the positive Salmonella assays with ortho-toluidine, and results for other genetic toxicity assays support these possibilities.

Reverse mutations were reported with metabolic activation in only one of five studies with E. coli, and growth inhibition was reported with metabolic activation in two of six DNA-repair-deficient E. coli strains. Differential toxicity was reported without metabolic activation in one study with E. coli strains with different capacities for recombinational repair (pol A^+^ and pol A^-^). The positive result was not confirmed in repeat studies in two different laboratories using the same protocol, or in another study that used the liquid suspension protocol. DNA damage was reported in one study with rec strains of B. subtilis, with and without metabolic activation.

Several studies investigated the co-mutagenic activity of norharman and ortho-toluidine (Appendix F, Table F-2). Norharman is found in cigarette smoke, coffee, alcoholic beverages, cooked meat and fish (formed as a pyrolysis product of tryptophan), and human urine (Gupta et al. 1989; Hada et al. 2001; Mori et al. 1996; Nishigaki et al. 2007; Oda et al. 2006). Norharman is non-mutagenic when administered alone but is co-mutagenic when administered with non-mutagenic or weakly mutagenic aromatic amines in the presence of S9. Norharman reacts with ortho-toluidine in the presence of S9 mix to form two mutagenic compounds (amino-3´-methylphenylnorharman and its hydroxyamino derivative). These compounds may be further activated by acetyltransferases (NATs). Oda et al. (2006) identified CYP1A1, CYP1A2, NAT1, and NAT2 as the activating enzymes.

### 5.1.2 Non-mammalian Eukaryote Systems

Studies in non-mammalian systems support the conclusion that ortho-toluidine is mutagenic under certain assay conditions (Appendix F, Table F-3). In contrast to studies in bacteria and fungi, 5 of 6 somatic mutation studies in Drosophila were positive. Exposure to ortho-toluidine did not cause mutations or genetic crossing-over (based on one study each in Aspergillus). Some positive studies in yeast (Saccharomyces cerevisiae) were reported for mutations, gene conversion, deletions, and aneuploidy with or without S9; however, most of the mutation and gene conversion studies were negative. Two studies of interchromosomal recombination in yeast were negative. Although many of the positive studies used an optimized yeast P448/P450 assay that eliminated the need for exogenous metabolic activation. Two studies that used the optimized yeast system reported a negative result (gene conversion). Conflicting findings were found for differential toxicity (based on only 2 studies).

### 5.1.3 Mammalian In Vitro Studies

Studies clearly show that ortho-toluidine induces a variety of genotoxic effects in human and rodent cells in vitro (Appendix F, Table F-4). Most of the in vitro genetic toxicology assays with ortho-toluidine were conducted as part of the second international collaborative study (Ashby et al. 1985) and were reviewed by Danford (1991) and IARC (2010e).

The available genotoxicity studies in human cells demonstrate that ortho-toluidine causes different types of genetic damage (including DNA and chromosomal damage) in various types of human cells. Genetic effects in human cells included DNA damage, unscheduled DNA synthesis (UDS), gene mutation, sister chromatid exchange (SCE), and micronucleus formation. Exogenous metabolic activation was required for UDS but not for SCE or micronucleus formation. All studies gave clear positive results with the exception of one inconclusive study for SCE. The inconclusive study showed a slight dose-related increase in SCE but did not reach a doubling of the control value and used a short incubation time (1 hour).

In general, similar types of genetic effects that were observed in human cells were also reported to occur in mammalian cells; however, for some types of damage, results were less consistent. The studies in non-human cells were conducted in a greater variety of cell types compared with the human cells. DNA damage was reported in rat hepatocytes, rat urinary bladder mucosa cells, and Chinese hamster ovary cells (CHO). DNA damage in both human and rat urinary bladder mucosal cells are of particular interest because the urinary bladder is a target site for carcinogenic effects in rats and humans (see Sections 3 and 4). The data also indicate that ortho-toluidine causes cytogenetic damage (SCE, chromosomal aberrations, micronuclei, or aneuploidy) in rodent cells; however, results were less consistent for SCE. There was no apparent requirement for S9 metabolic activation for cytogenetic effects, with the possible exception of chromosomal aberrations. In some studies, metabolic activation appeared to reduce SCE levels. The negative results for SCE, micronucleus, and chromosomal aberrations occurred when short treatment times were used (1 hour). The positive studies used treatment times of at least 2 hours.

Gene mutation studies in rodent cells were positive in over one half of the studies reviewed; however, the required conditions were unclear. Chinese hamster V79 cells and mouse L5178Y cells were the most frequently used but there were no apparent patterns related to locus, S9 presence or concentration, dose, or treatment time. UDS was positive in only one of eight studies in rat or hamster hepatocytes. The one positive study used a relatively high dose compared with the negative studies. One study that investigated effects on the mitotic spindle in Chinese hamster lung cells was negative.

In addition, ortho-toluidine consistently induced cell transformation in rodent cells (Appendix F, Table F-5). Cell transformation assays measure morphological transformation as an early event in the in vitro neoplastic process and allow for a broader assessment of carcinogenic potential including both genotoxic and non-genotoxic events (Maire et al. 2012; Pant et al. 2012).

### 5.1.4 In Vivo Studies

The genotoxic effects of ortho-toluidine have been investigated in more than a dozen studies. Endpoints evaluated include DNA adducts, DNA damage, single-strand breaks, clastogenic effects, altered sperm morphology, and DNA synthesis inhibition. The data indicate that ortho-toluidine forms DNA adducts and damages DNA and chromosomes, although certain types of genetic damage were only observed in some tissues.

#### 5.1.4.1 DNA Adducts

DNA adducts of ortho-toluidine can be synthesized by reacting the N-acetoxyarylamine derivative of ortho-toluidine with nucleosides (2′-deoxyguanosine or 2′-deoxyadenosine) or with calf thymus DNA (Jones and Sabbioni 2003; Marques et al. 1997; Marques et al. 1996). The dG-C8 adduct, which has been associated with point mutations and activation of the c-H-ras oncogene, was the most common; however, dC, dA, and dT adducts also were detected when incubated with calf thymus DNA.

Some studies indicate that ortho-toluidine forms DNA adducts in rats in vivo in liver and nasal mucosa (Appendix F, Table F-6). (Brock et al. 1990; Duan et al. 2008). DNA adducts were detected in rat liver, which is consistent with findings with studies of aromatic amines although they were not detected in the urinary bladder from rats. The mechanistic implications of DNA adducts and DNA damage are discussed in Sections 5.2.1 and 5.2.2.

Böhm et al. (2011) reported ortho-toluidine-releasing DNA adducts in 11 urinary bladder tumor samples (urothelial carcinomas) taken from 12 cancer patients and in 13 urinary bladder epithelial samples and 10 bladder submucosal tissue samples taken from 46 sudden death victims at autopsy (Appendix F, Table F-7), which were measured after acid hydrolysis. This method was not validated with synthesized DNA adducts to confirm that covalently bonded ortho-toluidine would be released. Although acid hydrolysis has not been validated for ortho-toluidine, it has been used for releasing DNA adducts of tobacco-specific nitrosamines and for all species of adducts, including phosphotriesters (Haglund et al. 2002; Lao et al. 2007a; 2007b). (The releasing DNA adducts for 1-(N-methyl-N-nitrosamino)-4-(3-pyridyl)-4-oxobutane [NNK] were later shown to be covalently bound (Haglund et al. 2002).) The major limitation of the study is that it is does not provide definite evidence of covalent DNA binding. DNA-releasing adduct levels in bladder tumors were significantly higher than in non-cancerous bladder tissue but did not differ between smokers and non-smokers.

#### 5.1.4.2 Other Genotoxic Effects

Genotoxic effects were reported in two of the target organs where carcinogenic effects occurred (liver in mice and urinary bladder in rats and mice). In addition, ortho-toluidine induced DNA strand breaks in the kidney, colon, and stomach in rats, and lung, stomach, and brain in mice (Appendix F, Table F-8). Micronucleus (MN) formation was detected in peripheral blood of rats and erythrocytes of Pleurodeles waltl, an amphibian, but not in mouse bone marrow or rat liver. No increase in chromosomal aberrations was observed in mice administered ortho-toluidine by intraperitoneal injection; this was the only study that evaluated chromosomal aberrations. One sperm morphology study was negative, and a second study was inconclusive. The latter study showed a statistically significant increase in abnormal sperm, but it did not meet all the criteria for a positive finding. DNA synthesis was inhibited in mouse testes but not mouse kidney.

#### 5.1.4.3 Genotoxic Effects of ortho-Toluidine Metabolites

N-Oxidized metabolites of ortho-toluidine were mutagenic in Salmonella while other metabolites were not mutagenic (Appendix F, Table F-9). Mutagenic activity of these metabolites is consistent with N-hydroxylation as a required step for metabolic activation (see Section 5.2.1). S. typhimurium tester strains TA98, TA100, TA1535, and TA1538 were used (Gupta et al. 1987; Hecht et al. 1979). No mutagenic activity was observed in TA1538. N-Hydroxy-ortho-toluidine and ortho-nitrosotoluene showed marked dose-related mutagenic activity toward TA100 and TA1535 with S9. When assayed without S9, these metabolites were non-mutagenic when tested to toxicity. N-Acetyl-N-hydroxy-ortho-toluidine showed slight mutagenic activity in TA1535 without S9 at 10 μM/plate and a marginal mutagenic response in TA98 with S9 at 5 to 10 μM/plate. Other studies showed that anthranilic acid was not mutagenic in S. typhimurium TA98, TA100, TA1535, TA1537, or TA1538 with or without metabolic activation when tested by plate incorporation or preincubation methods at maximum nontoxic concentrations (1,000 to 5,000 µg/plate) (Chung et al. 1981) or in TA102 at concentrations up to 250 µg/plate with or without rat S9 (Gadupudi and Chung 2011).

N-Hydroxy-ortho-toluidine and ortho-nitrosotoluene were potent frameshift mutagens in S. typhimurium TA98 in the presence of the co-mutagen norharman and S9 (Gupta et al. 1989). Other ortho-toluidine metabolites tested (see list from Appendix F, Table F-9) were not mutagenic even in the presence of norharman and S9. The meta- and para-toluidines and their nitroso or hydroxylamino metabolites were not mutagenic with or without norharman or S9. These data provide further evidence that N-oxidation is required for metabolic activation and that the ortho-toluidine is more mutagenic than the meta or para isomers.

In addition to the reverse mutation assays in Salmonella discussed above, several other genotoxicity studies with the ortho-toluidine metabolite anthranilic acid also were negative. McFee et al. (1989) reported that anthranilic acid did not induce chromosomal aberrations or micronuclei in male B6C3F_1_ mice but did have a positive effect on SCE in two of three trials. It did not induce DNA strand breaks in the pSP-72 plasmid at concentrations up to 400 μM (Gadupudi and Chung 2011), and it did not induce micronuclei in rodent V79, CHL, or CHO cells or in human peripheral blood lymphocytes, liver, or TK6 cells at doses up to 10 mM (Fowler et al. 2012). DNA strand breaks were not increased in mouse lymphoma cells (L5178Y/TK) with or without metabolic activation, but mutations at the TK locus were increased without metabolic activation (Garberg et al. 1988). Umeda et al. (1989) reported that anthranilic acid did not increase transformation frequency in X-ray-irradiated BALB/3T3 cells, but 3-hydroxyanthranilic acid (a metabolite of anthranilic acid) had a weak, though statistically significant, activity.

### 5.1.5 Synthesis of Results

Overall, the large database of genetic and related effects indicates that ortho-toluidine can bind to DNA, cause DNA and chromosomal damage, and induce mutations. For some genetic endpoints, positive findings were only observed when certain protocols were used or were limited to specific cell or tissue types. Genetic damage was observed in some tissues or cells that are target sites for carcinogenicity in experimental animals or humans.

Most of the data were reported in two international collaborative studies published in the early to mid-1980s. Only a few genetic toxicology studies were published since that time. A limitation of the database is there are no studies in humans with known exposure to ortho-toluidine; however, there are studies in human cells and human tissues. Studies in bacteria, mammalian cells, exposed animals, or cells from humans were considered to be the most informative. The overall assessment of the genetic effects of ortho-toluidine is summarized in Table 5-1. Findings were considered to be positive in the table if a consistent pattern was observed across studies, i.e., any conflicting findings across a specific endpoint could be explained by conditions of the assays, such as protocol, tissue or cell type, species, or metabolic activation.

Table 5-1 Genetic and Related Effects of ortho-Toluidine

Effect | Bacteria | In Vitro | | In Vivo
Effect | Bacteria | Rodents | Humans | Rodents
DNA adducts^a^ | NT | NT | NT | + ^a^
Mutation | (+) ^b^ | (−) | + | NT
DNA damage/strand breaks | NT | + | + | + ^c^
SCE | NT | + | ± | +
Chromosomal aberrations | NT | + | NT | − ^d^
Micronucleus | NT | ± | + | + ^e^
Aneuploidy | NT | + ^f^ | NT | NT
Inhibition of cellular communication | NT | + | NT | NT
Differential toxicity | − | NT | NT | NT
Cell transformation | NT | + | NT | NT
Inhibition of DNA synthesis | NT | NT | NT | ± ^g^
Unscheduled DNA synthesis | NT | − | + | NT

− = negative; + = positive; (+) = weakly positive; ± = inconclusive; (−) = mostly negative; NT = not tested.

^a^ Adducts detected in calf thymus DNA.

^b^ Positive in some tissues: male rat liver and nasal mucosa; negative in male rat urinary bladder and white blood cells and female rat liver. A few positive studies with modified protocols primarily using different metabolic activation systems, comutagenic activity with norharman, and some N-oxidized metabolites were mutagenic; overall assessment weakly mutagenic.

^c^ Positive in several tissues: rat: urinary bladder, kidney, colon, and stomach; mouse: liver, lung, urinary bladder, stomach, and brain.

^d^ Only one study reviewed.

^e^ Positive in some tissues of some species: rat reticulocytes and newt erythrocytes; negative in mouse bone marrow and rat liver.

^f^ Positive in some tissues/species: hamster lung V79 cells and liver fibroblasts, negative in rat liver epithelial cells.

^g^ Positive in mouse testes, negative in mouse kidney.

Evidence that ortho-toluidine can bind DNA comes from findings of adducts in liver and nasal mucosa of rats exposed to ortho-toluidine. ortho-Toluidine is considered to be weakly mutagenic. Although ortho-toluidine was not mutagenic in most bacteria studies, a few reverse mutation studies in Salmonella were positive under certain conditions (fluctuation protocol, high concentrations of rat or hamster S9, and/or certain preparations of induced S9), and one forward mutation study was positive with 30% hamster S9. This is consistent with findings observed for other aromatic amines. ortho-Toluidine was co-mutagenic with norharman and some oxidative metabolites of ortho-toluidine also were mutagenic in bacteria. It was also mutagenic in human lymphoblast cell lines (TK6 and AHH-1); however, findings were mixed in mammalian cells, which did not seem to be explained by exogenous metabolic activation. These conclusions are supported by the studies in non-mammalian eukaryotes; ortho-toluidine was clearly mutagenic in Drosophila and weakly mutagenic in yeast (see Appendix F, Table F-3).

DNA damage was reported in both in vitro and in vivo mammalian systems. Other cytogenetic effects (SCE, chromosomal aberrations, or micronuclei) were consistently induced in mammalian cells when incubation times of 2 hours or more were used. Clastogenic affects also were observed in vivo but not in all tissues examined. There is evidence that ortho-toluidine causes large-scale chromosome damage in yeast and mammalian cells (e.g., deletions, insertions, translocations, and/or aneuploidy) and oxidative damage to DNA. The only study that examined chromosomal aberrations (mouse bone marrow) was negative. Micronucleus formation was observed in rat reticulocytes but not in rat liver or mouse bone marrow. Aneuploidy also occurred in mammalian cells. Most cell transformation studies in several mammalian cell types were positive.

Genetic damage was observed in cells or tissue of some of the target sites (liver in mice and urinary bladder in rats) for carcinogenicity in experimental animals and humans (urinary bladder). DNA adducts were observed in liver but not urinary bladder tissue of rats exposed to ortho-toluidine. DNA damage was observed in both human and rat urinary mucosal cells, and in urinary bladder tissues of rats and liver tissue of mice exposed to ortho-toluidine.

## 5.2 Mechanistic Considerations

Aromatic amines include many chemicals that are carcinogenic, mutagenic, and/or are hemotoxicants (Benigni and Passerini 2002). In general, the same metabolic schemes, same kind of genotoxic lesions, and similar tissue specificity have been described for many aromatic amines and support a common mode of action for this chemical class (IARC 2010d). Recent investigations indicate that the biochemical mechanisms of action for the monocyclic compounds may be more complex than for the more extensively studied multi-ring aromatic amines (Skipper et al. 2010); however, data specific for ortho-toluidine are limited. Several aromatic amines are known human bladder carcinogens (benzidine, 4-aminobiphenyl, and 2-napthylamine) or are listed as reasonably anticipated to be a human carcinogen based in part on increased incidences of bladder tumors in animals (2-acetylaminofluorene and 4-chloro-ortho-toluidine). IARC has classified ortho-toluidine as a Group 1 carcinogen based on sufficient evidence of carcinogenicity in humans (IARC 2010e) IARC (2010b) classified another bicyclic aromatic amine, 4,4´-methylenebis(2-chloroaniline) (MOCA or MBOCA), as a Group 1 carcinogen based on inadequate evidence in humans and sufficient evidence in experimental animals for its carcinogenicity supported by a common mode of action for monocyclic aromatic amines (which include ortho-toluidine) and evidence of genotoxicity and adducts in urothelial cells or lymphocytes from workers with known occupational exposure to MOCA.

No criteria have yet been identified that can separate genotoxic from non-genotoxic, or carcinogenic from non-carcinogenic monocyclic aromatic amines (IARC 2010d). However, quantitative structure-activity relationship (QSAR) models suggest that carcinogenic potency and carcinogenic activity of aromatic amines are described by different molecular properties (Benigni et al. 2000; Benigni and Passerini 2002; Franke et al. 2010; Franke et al. 2001). The QSARs for carcinogenicity were similar to those for mutagenicity in Salmonella and suggested that similar mechanisms were responsible for the mutagenic and carcinogenic activity of aromatic amines. Thus, results from the QSAR models are consistent with the importance of metabolic activation in aromatic amine carcinogenicity and mutagenicity. Electronic properties (measures of chemical reactivity or the ability to undergo metabolic transformation) and steric characteristics were the most important factors related to carcinogenic activity, while hydrophobicity (log P) was the most important factor for carcinogenic potency. Carcinogenic potency increased with increasing hydrophobicity (particularly for monocyclic amines) and increasing energy of the highest occupied molecular orbital (EHOMO). EHOMO is a parameter for oxidation reactions and indicates the propensity of the toxic amines to form N-hydroxylamines. Hydrophobicity is a primary determinant of absorption, distribution, and the interaction of xenobiotics with metabolizing enzymes.

The epidemiology data (see Section 3) identified the urinary bladder as a target for ortho-toluidine-induced cancer in humans. Carcinogenicity studies in experimental animals indicate that the urinary bladder, liver, mesenchymal tissue in the spleen and other visceral organs, the mesothelial lining of the testis and epididymis (tunica vaginalis), subcutaneous tissue, mammary gland, and blood vessels are target sites for ortho-toluidine (see Section 4). The data suggest the following: (1) multiple mechanisms are involved, (2) mechanisms may vary with target tissue, and (3) aromatic amines generally must be mutagenic and cytotoxic to induce a carcinogenic effect. Although the mechanisms of carcinogenicity in the various target tissues are not completely understood, the following sections discuss possible mechanisms of carcinogenicity for the target tissues.

### 5.2.1 Urinary Bladder Tumors

Proposed mechanisms associated with urinary bladder carcinogenesis by aromatic amines include metabolic activation, direct and indirect genotoxic effects, and non-genotoxic mechanisms (e.g., cytotoxicity and sustained cell proliferation) (Skipper et al. 2010). Polymorphic expression of some of the metabolizing enzymes has been linked to aromatic amine exposure and urinary bladder cancer risk in humans. Genotoxic effects have been reported for ortho-toluidine and some of its metabolites (reviewed in Section 5.1) and cytotoxicity and cell proliferation are known to be important promoting factors in aromatic amine-induced carcinogenicity (Bitsch et al. 1999; IARC 2010d; Neumann 1986; 2007; Poirier et al. 1995; Woo and Lai 2004).

A comprehensive model of the possible mode of carcinogenic action of ortho-toluidine in the human and rodent urinary bladder was recently developed by (English et al. 2012). The proposed key events based on data from ortho-toluidine and other aromatic amines are illustrated in Figure 5-1 and include the following: (1) initial bioactivation by hepatic P450 enzymes to N-hydroxy-ortho-toluidine, (2) further bioactivation in the urinary bladder transitional epithelium via NAT1 yielding N-acetoxy-ortho-toluidine that hydrolyzes to nitrenium ions that can bind to DNA, (3) semiquinone/quinone redox cycling of unconjugated phenolic metabolites in the transitional epithelium producing reactive oxygen species (ROS), oxidative cellular damage and compensatory cell proliferation, (4) mutations from direct or indirect DNA damage to urinary bladder epithelial cells, and (5) development of urinary bladder tumors. N-hydroxy-arylamines also can be further metabolized to reactive N-sulfonyloxy-arylamines or N-hydroxyarylamine N-glucuronides in the liver and these metabolites also may contribute to the genotoxicity and cytotoxicity of ortho-toluidine (English et al. 2012; Sabbioni and Sepai 1995). These key events, supporting data, and data weaknesses for the proposed mechanisms are discussed in the following sections.

Figure 5-1

Proposed Key Events in the Mode of Action of ortho-Toluidine-induced Urinary Bladder Cancer

Source: English et al. (2012); Kadlubar and Badawi (1995).

#### 5.2.1.1 Metabolic Activation

It is known that aromatic amines require metabolic activation to exert toxic effects (IARC 2010a). Although not completely understood, activation steps include both phase-I oxidation and phase-II conjugation (primarily acetylation or sulfation) reactions (Skipper et al. 2010; Woo and Lai 2004). The first step involves N-hydroxylation (N-oxidation) or N-acetylation in the liver to form an aryl-N-hydroxylamine or an N-acetylated (arylamide) derivative. N-Acetylation is usually considered a detoxification pathway; however, arylamides can undergo further metabolic activation in the liver to form reactive and toxic metabolites (Delclos and Kadlubar 1997; Woo and Lai 2004). Studies in experimental animals indicate that N-acetylation of aromatic amines is a detoxification step for urinary bladder carcinogenesis while N-hydroxylation is an obligatory step for carcinogenic activity (Freudenthal et al. 1999; Windmill et al. 1997).

Following N-oxidation or N-acetylation in the liver, further activation can occur through N,O-transacetylation, O-acetylation, or O-sulfation to form acyloxy-arylamines or sulfonyloxy-arylamines (English et al. 2012; Hein 1988a; 1988b; Windmill et al. 1997; Woo and Lai 2004). These reactions are catalyzed by cytosolic N-acetyltransferases (NAT1 and NAT2 in humans) and cytosolic sulfotransferases. Acyloxy-arylamines and sulfonyloxy-arylamines are highly reactive esters that can form electrophilic arylamidonium or arylnitrenium ions via heterolysis of the ester bond. Aryl-N-hydroxylamines may be further oxidized to nitroso derivatives in the blood. Nitroso metabolites form hemoglobin adducts and generate methemoglobin (see Appendix F, Table F-10) (English et al. 2012; Eyer 1983). However, the N-acetoxy derivative of ortho-toluidine so far has been identified only as a postulated metabolite based on studies with other aromatic amines. In addition, Hein et al. (1993) showed that the N-acetylation of ortho-toluidine by human NAT1 and NAT2 was consistently lower than for most other arylamines, including para-toluidine, 4-aminobiphenyl, 2-aminofluorene, 2-naphthylamine, and para-aminobenzoic acid. Zhang et al. (2006) also reported that ortho-toluidine binding to NAT1 was lower than that of 4-aminobiphenyl and para-aminobenzoic acid, which is because of steric hindrance by the methyl group. Both studies showed better activity for NAT2 than NAT1.

The phase-II activation steps are in competition with glucuronide or glutathione conjugation (Woo and Lai 2004). Glucuronide formation usually is a detoxification pathway, but these metabolites may be cleaved nonenzymatically in the mildly acidic pH of the urinary bladder (typically found in humans and dogs) or enzymatically by β-glucuronidase and further activated to arylnitrenium ions that can covalently bind to urothelial DNA (English et al. 2012; Freudenthal et al. 1999; Woo and Lai 2004; Yu et al. 2002). The N-hydroxy metabolites of aromatic amines also may enter the urinary- bladder lumen in the unconjugated form and, thus, would immediately be available for reabsorption into the bladder mucosa and binding to urothelial DNA (Kadlubar et al. 1991). There also is some evidence in dogs and humans that the N-glucuronide of the parent amine may reach the bladder. In this case, hydrolysis in the urine would release the free parent compound where it may be N-hydroxylated (activated) directly by the bladder epithelium (Freudenthal et al. 1999). Thus, N-hydroxy-ortho-toluidine conjugates are formed in the liver, and based on hypothesis developed from metabolism of other aromatic amines, are proposed to enter the blood, and to be transported to the bladder where they form reactive nitrenium ions that can react with DNA in the transitional epithelium (English et al. 2012; Kadlubar and Badawi 1995; Riedel et al. 2006).

In general, glutathione conjugation is a detoxification reaction. Although glutathione conjugates have been described for other aromatic amines (Delclos and Kadlubar 1997; Skipper et al. 2010; Woo and Lai 2004), no glutathione conjugates were identified in metabolism studies with ortho-toluidine (see Section 2).

Further evidence of the importance of N-oxidation of ortho-toluidine as a metabolic activation step for bladder carcinogenicity was shown in a comparative carcinogenicity study of ortho-toluidine hydrochloride and ortho-nitrosotoluene in male F344 rats (Hecht et al. 1982). Test compounds were administered in feed for 72 weeks and all animals were killed at 93 weeks. Rats treated with the N-oxidized metabolite (ortho-nitrosotoluene) developed significantly more urinary bladder tumors (16/30) than rats treated with ortho-toluidine (4/30).

#### 5.2.1.2 Hemoglobin Adducts

The finding of hemoglobin adducts in humans provides indirect evidence for the relevance of the N-oxidation metabolic pathway in humans. ortho-Toluidine-releasing hemoglobin or albumin adducts have been reported in in vitro studies (Stettler et al. (1992), see Appendix F, Table F-8), in vivo studies of exposed rats and mice (Birner and Neumann (1988); Cheever et al. (1992); DeBord et al. (1992); Stettler et al. (1992), see Appendix F, Table F-8), and in several studies in humans, including workers with a known excess of urinary bladder cancer, non-occupationally exposed populations from various countries (see Table 1-4) and in patients treated with the local anesthetic prilocaine (which is metabolized to ortho-toluidine) (Gaber et al. 2007). (See Section 1 for additional information on ortho-toluidine hemoglobin adducts in human studies.) Hemoglobin adducts are formed from the reaction of hydroxy-ortho-toluidine metabolites with hemoglobin and most of the studies measured adducts released from the hemoglobin via base hydrolysis. Although the possibility that hydroxyl metabolites formed from ring oxidation cannot be ruled out, the hemoglobin adducts are believed to be formed from the N-hydroxy metabolites. An in vitro study of a related aromatic amine (3,4-dichloroaniline) reported that its N-hydroxy metabolite with hemoglobin was an order of magnitude greater that its ring-hydroxylated metabolite (Cheever et al. 1992). Studies of other aromatic amines that cause urinary bladder cancer have shown that N-hydroxy-amines may be further oxidized to nitroso derivatives in the blood, generating methemoglobin and forming hemoglobin adducts (Skipper and Tannenbaum 1994). Birner and Neumann (1988) reported a positive correlation between hemoglobin-binding index and methemoglobin formation for six monocyclic amines that were studied (ortho-toluidine was not tested). Hemoglobin adducts are considered as biological markers of aromatic amine bioactivation to their ultimate carcinogenic metabolites and have been associated with bladder cancer risk in a population-based study (Gan et al. 2004). One study also reported a correlation between hemoglobin adducts and DNA adducts of 4-aminobiphenyl in exfoliated urothelial cells (Talaska et al. 1991).

#### 5.2.1.3 Polymorphisms in Metabolizing Enzymes

Polymorphic expression of some of the metabolizing enzymes has been linked to aromatic amine exposure and urinary bladder cancer risk in humans. Polymorphisms have been described for human NAT1 and NAT2 (Kadlubar and Badawi 1995; Talaska 2003; Yu et al. 2002). The human population can be divided into slow, intermediate, and fast acetylator phenotypes based on polymorphic expression of NAT2. Since N-acetylation in the liver is a detoxifying pathway for the urinary bladder, slow acetylators would be expected to detoxify aromatic amines less efficiently. Epidemiological data indicate that slow acetylators are more susceptible to aromatic amine-induced bladder cancer. In addition, the human urinary bladder has appreciable NAT1 activity and can catalyze O-acetylation of N-hydroxylamines to electrophilic N-acetoxy derivatives. There is some evidence that cigarette smokers that carry the high-activity NAT1 allele, especially when combined with the NAT2 slow acetylation genotype, are more likely to develop bladder cancer.

#### 5.2.1.4 Sex and Species Considerations

Urinary bladder neoplasms were significantly increased in rats but not in mice (see Section 4); however, mice are less sensitive for developing urinary bladder cancer than rats (Frith et al. 1994). Although both male and female rats developed urinary bladder tumors, the lower incidence in male rats (which was not statistically significant but considered to be treatment related because of their rarity) compared with female rats might be related to sex-specific patterns of metabolic activation and detoxification (English et al. 2012). No metabolic studies have been conducted in female rats (see Section 2.2); however, English et al. (2012) reported that GSTM1 (a phase-II enzyme involved in arylamine detoxification) is more abundant in male mouse liver compared with females. If a similar pattern is true for rats, this would be consistent with a lower tumor incidence in male rats. There also is some evidence that women have a higher capacity for arylamine activation than men (Castelao et al. 2001). In addition, Richter et al. (2001) reported that levels of hemoglobin adducts of toluidine isomers tended to be lower in boys than in girls.

#### 5.2.1.5 Genetic Damage

Genotoxic effects of ortho-toluidine that are potentially relevant to bladder cancer have been reported; they include demonstration that ortho-toluidine can bind DNA and damage DNA and chromosomes (see Section 5.1 and Appendix F).

Some N-oxidized metabolites of ortho-toluidine are mutagenic with exogenous metabolic activation (see Section 5.1.5) and are carcinogenic (see Section 5.2.1.4). Thus, the N-oxidized derivatives of arylamines or arylamides are considered the proximate carcinogenic forms (Hein 1988a; Kato and Yamazoe 1994). Studies using calf thymus DNA or in exposed rats have demonstrated that ortho-Toluidine can form DNA adducts (Duan et al. 2008; Marques et al. 1996) and ortho-toluidine releasing DNA were detected in the urinary bladder tumor and tissue from humans (Böhm et al. 2011); however, because of methodological limitations, covalent binding was not confirmed. No DNA adducts were detected in the urinary bladder of exposed rats (Duan et al. 2008). Thus, evidence for DNA adduct formation in the urinary bladder tissue is less clear. Evidence that ortho-toluidine causes DNA damage in the urinary bladder includes DNA strands breaks detected in human cells in vitro and in rats and mice in vivo.

Evidence for the relationships between DNA adduct formation, mutagenicity, and carcinogenicity comes from studies of other aromatic amines. A study in dogs reported that the extent and relative persistence of total DNA binding of several bicyclic and polycyclic aromatic amines (4-aminobiphenyl, 2-acetylaminofluorene, 1-naphthylamine, 2-naphthylamine, 4-nitrobiphenyl, benzidine, and N-acetylbenzidine) correlated with the compounds’ carcinogenic potency in the urinary bladder (Beland et al. 1983). The adduct profiles were very similar to those obtained when the N-hydroxy metabolites of these compounds were reacted with DNA in vitro. Further studies in S. typhimurium showed that the C8-deoxyguanosine adduct was correlated with frameshift reversions and could be important for tumor initiation.

Although several studies have suggested that aromatic amines cause urinary bladder cancer by forming DNA adducts and inducing mutations, there is evidence that gross chromosome alterations may also be involved. A correlation between formation of DNA adducts and induction of chromosomal aberrations has been demonstrated in the liver of mice exposed to the aromatic amine benzidine (Talaska et al. 1987). Cytotoxic levels of 4-aminobiphenyl caused chromosomal instability (CIN, i.e., selective loss of chromosomes 4 and 6) in urinary bladder and liver cells; the specific chromosome lost varied according to cell type (Saletta et al. 2007). CIN not only results in aneuploidy but also is associated with loss of heterozygosity, an important mechanism for inactivation of tumor suppressor genes. Thus, aromatic amines may affect tumorigenesis by inducing CIN. These data are consistent with previous studies of bladder cancer in humans that show complex patterns of aneuploidy (Höglund et al. 2001; Phillips and Richardson 2006; Sandberg 2002) and provide further evidence that exposure to specific carcinogens can select for tumor cells with distinct forms of genetic instability (Bardelli et al. 2001; Breivik and Gaudernack 1999).

The genetic toxicology data for ortho-toluidine (see Section 5.1) are consistent with this hypothesis. Although ortho-toluidine is a weak mutagen, it induced aneuploidy, DNA strand breaks, chromosomal damage, and cell transformation in mammalian cells. It also caused DNA damage or strand breaks in the liver and kidney of exposed mice, SCE in bone marrow of exposed hamsters and mice, and micronuclei in peripheral blood cells of exposed rats.

#### 5.2.1.6 Oxidative DNA Damage

Oxidative DNA damage may be more important for the mutagenic and carcinogenic effects of monocyclic compounds compared with the bicyclic and polycyclic aromatic amines (Kawanishi et al. 2002; Ohkuma et al. 1999). DNA adducts can result in tumor initiation while oxidative products of DNA bases can be highly mutagenic and are involved in tumor initiation and promotion (Kawanishi et al. 2002). Many organic carcinogens, including aromatic nitro and amino compounds, induce oxidative DNA damage through generation of copper or iron-catalyzed reactive oxygen species (ROS) (Murata and Kawanishi 2011).

Two metabolites of ortho-toluidine (4-amino-3-methylphenol (also called 4-amino-meta-cresol) and ortho-nitrosotoluene) caused oxidative DNA damage in DNA fragments from human c-Ha-ras and p53 genes and induced 8-oxodG lesions in calf thymus DNA (Ohkuma et al. 1999). The presence of both NADH and Cu(II) was required for ortho-nitrosotoluene, but Cu(II) alone was sufficient for 4-amino-3-methylphenol. Oxidative lesions (8-oxodG) in calf thymus DNA increased with dose for both metabolites (Figure 5-2). ortho-Nitrosotoluene also caused oxidative damage in human leukemia (HL-60) cells (Watanabe et al. 2010). Two distinct mechanisms of Cu(II)-mediated DNA damage were proposed. 4-Amino-3-methylphenol is autooxidized to form the aminomethylphenoxyl radical while NADH reduces ortho-nitrosotoluene to the ortho-toluolhydronitroxide radical in the presence or absence of Cu(II). These radicals react with oxygen to form superoxide ion and hydrogen peroxide. Cu(II) is reduced by superoxide ion to Cu(I), and the interaction of Cu(I) and hydrogen peroxide generates ROS that are capable of damaging DNA. This is the same mechanism proposed by. Superoxide dismutase (SOD), catalase, and the Cu(I) chelator, bathocuproine, reduced the amount of DNA damage. 8-OxodG is known to cause GC to TA transversions (Ohkuma et al. 1999; Shibutani et al. 1991). The mutation spectrum for the p53 gene in human urinary bladder carcinomas and bladder tumor cell lines has shown that GC to TA transversions are relatively common (Williamson et al. 1994).

Figure 5-2

Formation of 8-oxodG Lesions in Calf Thymus DNA Treated with Metabolites of ortho-Toluidine in the Presence of Cu(II)

4-AMP = 4-amino-3-methylphenol; o-NT = o-nitrosotoluene.

Source: Ohkuma et al. (1999).

#### 5.2.1.7 Semiquinone/Quinone Redox Cycling, Cytotoxicity, and Cellular Proliferation

The cytochrome P450-mediated N-hydroxylation pathway is not the only phase-I oxidative metabolic pathway for aromatic amines. Direct ring oxidation of aromatic amines produces aminophenols that generally are regarded as detoxification products because they are usually conjugated with sulfate or glucuronic acid and excreted (English et al. 2012; Skipper et al. 2010). If the aminophenols are not conjugated, they can undergo peroxidase-catalyzed oxidation to form quinone imines (Figure 5-1). Although peroxidase activity in the liver is low compared with monooxygenase activity, other tissues, including the urinary bladder, contain high levels of peroxidase.

Concentrations of one of the phenolic metabolites of ortho-toluidine (N-acetyl-4-amino-meta-cresol) in rat urine were correlated with urinary bladder-cell proliferation (UNEP 2004). These data support the assertion that toxicity to the urinary bladder epithelium may be associated with reactive oxygen species generated by the redox cycling of N-acetyl-4-amino-meta-cresol and its quinone imine counterpart, or with direct damage mediated by the electrophilic quinone imine itself. The induction of reactive oxygen species can lead to oxidative damage to DNA.

Several studies have reported cytotoxic and proliferative effects in the urinary bladder following subacute, subchronic, and chronic exposure of rats and mice to ortho-toluidine. Ekman and Strömbeck (1947; 1949) reported that the tumorigenic action of azo compounds was likely due to metabolism to toluidines because albino rats fed a diet containing ortho-toluidine or meta-toluidine developed epithelial changes in the bladder mucosa that were similar to those observed in rats fed tumorigenic azo compounds. These changes included keratosis, metaplasia, early epithelial proliferation, and a tendency to incipient papillomatosis. Both meta- and ortho-toluidine are metabolites of 2,3′-azotoluene and urinary bladder tumors occurred only when the metabolic products of 2,3′-azotoluene were in direct contact with the bladder mucosa (Strömbeck 1946).

The incidence of proliferative nonneoplastic lesions in the urinary bladder was significantly increased in rats or occurred only in dosed animals in two NTP carcinogenicity studies of ortho-toluidine (NCI 1979; NTP 1996). Neoplastic effects and preneoplastic effects (hyperplasia of transitional-cell epithelium) observed in the urinary bladder were reviewed in Section 4. A dose-related progression from hyperplasia of transitional-cell epithelium to transitional-cell carcinoma in the urinary bladder was observed, particularly in female rats. This lesion was reversible because complete regression occurred in the stop-exposure group (NTP 1996).

### 5.2.2 Other Tumors

Very few mechanistic data for other tumor sites were identified. Reactive N-oxidized metabolites or ortho-toluidine reach the blood as evidenced by hemoglobin adducts detected in exposed humans and experimental animals, and at least one study reported micronucleus formation in peripheral blood of rats (see Sections 5.1.4, 5.2.1, 5.2.2). Limited information is available on mechanisms for liver tumors and splenic tumors (see below). In addition to ortho-toluidine, other aromatic amines often induce liver neoplasms in rodents.

Liver tumors were significantly increased in female mice exposed to ortho-toluidine but not in male or female rats (see Section 4); however, placental glutathione S-transferase (PGST)-positive foci (a preneoplastic lesion) were significantly increased in male rats in a subchronic study (NTP 1996). Metabolic activation to reactive metabolites is a key step in aromatic amine-induced liver neoplasms, differences in metabolism may contribute to interspecies differences in susceptibility; N-acetylation is an activating reaction in the liver. Liver tumors in rodents exposed to aromatic amines likely result from N-hydroxy-N-acetylarylamine metabolites, which are formed from N-acetylation of N-hydroxy metabolites in the liver. The relative capability of NAT enzyme systems from liver cytosol of various mammalian species to acetylate the amine function of three carcinogenic aromatic amines (2-aminofluorene, 4-aminobiphenyl, and 2-aminonaphthalene) was highest in hamster followed by guinea pig, but enzyme activity in mouse liver cytosol was about an order of magnitude higher than rat liver cytosol (Lower and Bryan 1973). The comparatively greater acetylating activity in mouse liver could explain the greater susceptibility of mice to liver tumors with exposure to ortho-toluidine.

Exposure to ortho-toluidine caused DNA strand breaks in liver tissue from exposed mice, suggesting a role for genotoxicity. However, data on interactions of ortho-toluidine with DNA are limited. DNA binding alone does not necessarily explain the differences in carcinogenic potency observed among various aromatic amines or tissue-specific responses because biological events (e.g., promotion, DNA repair, DNA adduct persistence, cytotoxicity) in addition to macromolecular binding influence the expression of carcinogenic potential (Brock et al. 1990).

The spleen is a specific tumor target for ortho-toluidine based on evidence from studies in rats (see Section 4) (NCI 1979). Splenic fibrosarcomas are rare in rats, occurring in about 0.4% (4/1,003) of males and 0% (0/1,000) of females in historical controls in dietary studies (http://www.ntp.niehs.nih.gov/ntp/research/database_searches/historical_controls/path/r_orlfd.txt). The morphologic similarity of splenic fibrosis and capsule hyperplasia to the sarcomas suggested that these lesions were preneoplastic and that the treatment-related splenic lesions appeared to be precursors to the neoplastic process (NCI 1979; Short et al. 1983). There is limited mechanistic data that is specific for ortho-toluidine-induced splenic tumors; however, data on aromatic amines suggest that the carcinogenic effects of ortho-toluidine in the spleen are associated with oxidative stress and erythrocyte toxicity (Ciccoli et al. 1999; Khan et al. 1997). Two metabolites of ortho-toluidine, 4-amino-3-methylphenol and ortho-nitrosotoluene, have been shown to cause oxidative damage in DNA (see Section 5.2.1), although no direct evidence of oxidative damage to the spleen was identified. Exposure to ortho-toluidine results in an increased incidence of several nonneoplastic effects in the spleen of rats that are consistent with a proposed mode-of-action involving toxic effects resulting from damaged red blood cells reaching the spleen. Histopathologic effects (fibrosis and mesothelial capsule hyperplasia) consistent with enhanced erythrocyte toxicity were reported by Short et al. (1983), and both NTP carcinogenicity studies (NCI 1979; NTP 1996) also reported nonneoplastic effects in the spleen of rats (congestion, hematopoietic cell proliferation, hemosiderin pigmentation, capsule fibrosis, capsule-lymphatic angiectasis).

## 5.3 Structural Comparison Studies

Several lines of evidence point to a role for the methyl group in the ortho-position in the carcinogenicity of ortho-toluidine. Rats administered single oral doses of ortho-, meta-, or para-toluidine excreted higher concentrations of unchanged ortho-toluidine (21% to 36%) compared with 2.5% for the meta- or para- isomers (Cheever et al. 1980). Thus, the higher concentration of unmetabolized ortho-toluidine in urine might partially explain why only the ortho-isomer caused urinary bladder tumors in rats.

Hecht et al. (1979) investigated the structure-mutagenicity relationships among several monocyclic (including aniline and ortho-toluidine) and bicyclic aromatic amines and their N-oxidized derivatives and reported that the derivatives having a methyl group ortho to the amine group were generally more mutagenic in the Ames test. QSAR models suggest that substitution at the ortho-position also was an important factor that affected carcinogenic potency. Steric bulk at the ortho-position decreased potency by preventing enzymatic access to the nitrogen and formation of the reactive intermediate; however, substitution of chloro-, methyl- (e.g., ortho-toluidine), or methoxy- groups at this position enhanced potency (Benigni et al. 2000; Benigni and Passerini 2002; Franke et al. 2010; Franke et al. 2001).

The genotoxic effects of many aromatic amines are likely initiated by DNA adducts (Beyerbach et al. 1996). N-Hydroxy-arylamines (N-oxidation products of aromatic amines form hemoglobin, albumin, and DNA adducts (Cheever et al. 1992; Sabbioni 1992; Sabbioni and Sepai 1995). The dG-C8 adduct, which has been associated with point mutations and activation of the c-H-ras proto-oncogene, is the most common (Beland and Kadlubar 1985; Beland et al. 1997; Marques et al. 1997; Marques et al. 1996). Other sites of DNA adducts include the N^2^ and O^6^ atoms of guanine and the C8 and N^6^ atoms of adenine (Branco et al. 1999; Delclos and Kadlubar 1997; Jones and Sabbioni 2003). Several studies reported that ortho-toluidine formed adducts with nucleosides, nucleotides, and DNA in vitro and that the three-dimensional conformation of various single-ring arylamine (methyl-, ethyl-, and dimethylaniline) adducts affected their ability to induce mutations (Beland et al. 1997; Beyerbach et al. 1996; Jones and Sabbioni 2003; Marques et al. 1997; Marques et al. 1996). Adducts that contained alkyl groups ortho- to the amine function (e.g., ortho-toluidine and 2,6-dimethylaniline) tended to be more mutagenic than their meta- or para-substituted analogues. Spectroscopic and theoretical data indicated that conformational differences among these adducts depended on the location of the alkyl group. The increased biological activity was attributed in part to the greater propensity of ortho-alkylated adducts to adopt a higher percentage of low-energy syn conformers that increased with the substitution pattern in the order para < meta < ortho < ortho, para < ortho, meta (Marques et al. 1996). The syn conformation enables an arylamine adduct to be inserted into the DNA helix.