# 4 Studies of Cancer in Experimental Animals

ortho-Toluidine has been listed as reasonably anticipated to be a human carcinogen in the Report on Carcinogens (RoC) since 1983 based on sufficient evidence of carcinogenicity in experimental animals. This section reviews and assesses carcinogenicity studies in experimental animals exposed to ortho-toluidine. The steps in the cancer evaluation process are (1) identifying new studies published since, or not included in the original listing in 1983 (hereafter referred to as “new” studies) (Section 4.1), (2) assessing the quality of all studies (Section 4.2), (3) synthesizing the findings across studies (Section 4.3), and (4) reaching a preliminary conclusion on the level of evidence of carcinogenicity of ortho-toluidine from these studies (Section 4.4).

## 4.1 Identification and Overview of the Studies

The studies that formed the basis for the 1983 listing of ortho-toluidine in the RoC include (1) two feed studies in different strains of rats, one in male CD rats (Weisburger et al. 1978) and the other in male and female F344 rats (NCI 1979), and (2) two feed studies in different strains (Albino CD-1 [HaM/ICR] and B6C3F_1_) of male and female mice (NCI 1979; Weisburger et al. 1978) (see Table 4-1 for a brief overview of these studies). All of these feeding studies were two-year carcinogenicity studies that used two different exposure groups in addition to untreated controls. Rats and mice were exposed in the diet for two years in the NCI studies and for 18 months in the studies reported by Weisburger and colleagues (see Table 4-1).

Table 4-1 Overview of Studies of Exposure to ortho-Toluidine in Experimental Animals

Route of Exposure | Species (Sex) | Exposure/Observation Duration | Reference
Studies included in the 1983 evaluation^a^
Feed | F344 rat (male and female) | 101–104 wk | NCI (1979)
Feed | CD rat (male) | 18 mo/24 mo | Weisburger et al. (1978)
Feed | B6C3F_1_ mouse (male and female) | 101–104 wk | NCI (1979)
Feed | Albino CD-1 (HaM/ICR) mouse (male and female)] | 18 mo/24 mo | Weisburger et al. (1978)
Studies published after (or not included) in the 1983 evaluation^b^
Feed | F344 rat (male) | 73 wk/93 wk | Hecht et al. (1982)
Feed | F344 rat (male) | 13 wk/26 wk | NTP (1996)
Feed | Dog (female)^c^ | 9 yr | Pliss (2004)
Subcutaneous | Syrian golden hamster (male) | 52 wk/87 wk | Hecht et al. (1983)
Subcutaneous | Rat (male and female)^c^ | 2 yr | Pliss (2004)
Subcutaneous | CC_57_BR mice (male and female) | 2 yr | Pliss (2004)
Per os | Genetically altered fish | 4 wk | Anders et al. (1991)

^a^ All studies for the 1983 evaluation tested ortho-toluidine at two dose levels.

^b^ All studies listed below tested ortho-toluidine at only one dose level.

^c^ Strain or breed not specified.

Cancer studies in experimental animals published since the review (or not included in the review) were identified by searching databases, comprehensive reviews, and citations from studies retrieved from the literature searches as described in Appendix A. Five publications published after the 1983 evaluation met the inclusion/exclusion criteria requiring that included studies evaluated exposure specifically to ortho-toluidine and either (1) report neoplastic lesions, or non-neoplastic or preneoplastic lesions relevant to carcinogenicity, or (2) are subchronic studies that provide information on dose selection (see Appendix A). These publications reported on seven studies including (1) three feed studies, two in male rats (Hecht et al. 1982; NCI 1979), and one in dogs (Pliss 2004), (2) three parenteral studies, all by subcutaneous injection, in rats (Pliss 2004), mice (Pliss 2004), and hamsters (Hecht et al. 1983), (3) and one tumor initiation study in genetically altered fish (Anders et al. 1991). An additional feed study (Takayama et al. 1989) in rats was identified in the literature search but was excluded from the review because exposure was to a mixture of 39 chemicals including ortho-toluidine hydrochloride.

All of the studies in rodents published since 1983 evaluated exposed animals to only one dose of ortho-toluidine. In the feeding study reported by Hecht et al. (1983) female rats were exposed to ortho-toluidine in the diet for 73 weeks and held for a total of 93 weeks. NTP (1996) reported on short-term exposure experiments using three different conditions: 13-week continuous exposure, 13-week exposure and held for a total of 26 weeks, and 26-week continuous exposure (NTP 1996). Five dogs (between 2 and 3 years) were exposed to ortho-toluidine, first in the food and later by gavage, for up to 9 years in the study reported by Pliss (2004); however, there were no untreated controls and two dogs died of non-cancer related deaths within three years of the study onset.

The subcutaneous studies in mice and rats were two-year carcinogenicity studies with animals receiving weekly subcutaneous injections for the entire study duration (Pliss 2004). The study in hamsters was shorter; the animals were injected weekly for 52 weeks and observed up to 87 weeks (Hecht et al. 1983).

The study by Anders et al. (1991) reported on melanomas (external evaluation) in genetically modified fish dosed for 4 months.

## 4.2 Quality Assessment of Studies

The eleven studies, including the seven published after 1983 and four studies included in the previous evaluation, were systematically evaluated in a two-step process. The first step was to evaluate whether the level of detail reported for key elements of study design, experimental procedures, and carcinogenesis endpoints was adequate for evaluating its quality and interpreting its results. The reporting quality of key elements for 2 of the 11 studies was considered to be inadequate for cancer evaluation: the study in mice exposed to ortho-toluidine by subcutaneous injection (Pliss 2004) and the tumor initiation study in genetically altered fish (Anders et al. 1991).

The second step was to evaluate the nine remaining studies, which were adequately reported, for concerns for study quality, using a priori criteria, which might negatively impact the ability to assess carcinogenicity. Key factors considered in the quality assessment include characterization of the chemistry of the substance, dosing regimen, exposure and observation period, number of animals per exposure group, monitoring of animal health, and assessment for neoplasm endpoints. Details of each study assessment and quality criteria are reported in Appendix E.

Eight of the remaining nine studies—the four feed studies in rats (Hecht et al. 1982; NCI 1979; NTP 1996; Weisburger et al. 1978), two feed studies in mice (NCI 1979; Weisburger et al. 1978), two subcutaneous studies, one in hamsters (Hecht et al. 1983) and one in rats (Pliss 2004)—were considered to have adequate quality to inform the carcinogenicity assessment. The feeding studies in rats and mice were considered to be more informative (e.g., had minimal concerns for most study quality elements) (Hecht et al. 1982; NTP 1996) than the two subcutaneous studies in rodents (Hecht et al. 1983; Pliss 2004). One of the feeding studies in rats, the NTP feed study in male rats, was a subchronic study, which by virtue of its design (e.g., short exposure and duration period) would usually not be considered able to detect tumors, due to the long latency period usually required for tumor development. Despite such limitations, preneoplastic and neoplastic findings were reported, and the study was included in the cancer assessment. One of the remaining nine studies, a feeding study in dogs, was considered to be inadequate to inform the cancer evaluation, primarily because no untreated control group of dogs was tested and there were also concerns about other study elements as described in Appendix E.

Overall, the studies in rodents provide an adequate database for evaluating the carcinogenicity of ortho-toluidine. Although some limitations in study design or reporting were observed in some studies, most of the limitations would bias towards not finding an effect (type-I error) and would not necessarily bias towards finding a “false” positive effect (type-II error).

## 4.3 Assessment of Neoplastic Findings

The studies in rats and mice previously evaluated for the 1983 listing of ortho-toluidine in the RoC provided sufficient evidence for its carcinogenicity based on tumors of the connective tissue (sarcoma) in the spleen and other organs in both sexes of rats, urinary bladder in female rats, mesothelium and subcutaneous tissue in male rats, blood vessels in both sexes of mice, and liver in female mice. This section integrates the findings across the new (two feeding studies in male F344 rats and two subcutaneous studies), and earlier studies (two feeding studies each in rats and mice). Findings from the four feeding studies in rats are reported in Table 4-2 (urinary bladder neoplasms), Table 4-3 (sarcoma), and Table 4-4 (other neoplasms); the two feeding studies in mice are reported in Table 4-5, and the two subcutaneous injection studies in rodents in Table 4-6. All studies are discussed below.

Table 4-2 Studies of Dietary Exposure to ortho-Toluidine in Rats: Urinary Bladder Hyperplasia and Neoplasm Incidence

Reference Strain, Sex Study Duration | Exposure, ppm (# Rats) | Hyperplasia | Papilloma | Carcinoma | Carcinoma or Papilloma (Combined) | Comments
Weisburger et al. (1978) CD [Sprague-Dawley], Male 18 mo exposed (24 mo total) | 0 (111)^a^ 0 (25)^b^ 8,000–4,000 (25)^c^ 16,000–8,000 (25)^c^ | – | – | 5/111 (4.5) 0/16^d^ 3/23 (13) 4/24 (22) | – | o-Toluidine HCl (97%–99% pure). Survival similar between concurrent controls and exposed groups (16/25, 23/25, 24/25). Food consumption not reported for individual animals.
NCI (1979) F344, Male 101–104 wk | 0 (20) 3,000 (50) 6,000 (50) Trend^e^ | 0/20 9/50 (18) 7/44 (16) NR | – | 0/20 3/50 (6) 0/44 (0) p > 0.05 | 0/20 3/50 (6) 1/44 (2) p > 0.05 | Technical grade (>99% pure, with one contaminant <1%). Body weights of both sexes of exposed rats lower than controls and dose-related. Dose-related trends in mortality observed in both sexes; steep increases in mortality occurred after 70 wk in high-dose males, 75 wk in low-dose males, 80 wk in high-dose females and 90 wk in low-dose females. Food consumption not reported for individual animals.
NCI (1979) F344, Female 101–104 wk | 0 (20) 3,000 (50) 6,000 (50) Trend^e^ | 0/20 21/45 (47)*** 13/47 (28)** NR | – | 0/20 9/45 (20)* 22/47 (47)*** p < 0.001 | 0/20 10/45 (22)* 22/47 (47)*** p < 0.001
Hecht et al. (1982) F344, Male 72-wk exposure (93 wk total) | 0 (30) 4,000^f^ (30) | – | 0/27 3/30 | 0/27 1/30 | – | o-Toluidine HCl (purified, but purity not reported). Survival at week 22 was 18/30 for controls and 6/30 for exposed. Body weight of exposed reported as “somewhat lower than control group.”
NTP (1996) F344, Male | | | | | | o-Toluidine HCl (100% pure). Survival 100% in all groups. Mean body weights were 82%–89% lower in exposed groups than control group.
13-wk interim sacrifice | 0 (10) 5,000^h^ (20) | 0/10 10/20** | – | – | – | o-Toluidine HCl (100% pure). Survival 100% in all groups. Mean body weights were 82%–89% lower in exposed groups than control group.
13-wk stop exposure^g^ | 0 (10), 5,000^h^ (20) | 0/10 0/20 | – | – | – | o-Toluidine HCl (100% pure). Survival 100% in all groups. Mean body weights were 82%–89% lower in exposed groups than control group.
26-wk continuous exposure | 0 (10) 5,000^h^ (20) | 0/10 17/18** | – | – | – | o-Toluidine HCl (100% pure). Survival 100% in all groups. Mean body weights were 82%–89% lower in exposed groups than control group.

* p ≤ 0.05, **p ≤ 0.01, ***p ≤ 0.001 (compared with concurrent controls by Fisher’s exact test).

^a^ Pooled controls, controls from all compounds tested in study.

^b^ Concurrent controls.

^c^ Body weights in exposed groups <10% of concurrent control weights by 12 wk; doses reduced for remaining 60 wk. Low dose reduced from 8,000 to 4,000 mg/kg food, and high dose reduced from 16,000 to 8,000 mg/kg food.

^d^ Six cases of subcutaneous fibroma or fibrosarcoma occurred along with transitional-cell carcinoma of the male rat urinary bladder.

^e^ Trend calculated using Cochran-Armitage trend test.

^f^ Mean Daily Dose: 62 mg/rat; Total dose of o-toluidine HCl: 31.3 g/rat; Average exposure of o-toluidine HCl per body weight per day of animals not reported.

^g^ Rats exposed for 13 wk and observed for another 13 wk.

^h^ Exposure (mg/kg/d) = 301 for 13-wk interim sacrifice, 304 for 13-wk stop exposure, and 285 for 26-wk continuous exposure.

Table 4-3 Studies of Dietary Exposure to ortho-Toluidine in Rats: Sarcomas

Reference Strain, Sex Study Duration | Exposure, ppm (# Rats) | Multiple Tissues (Multiple Types) | Multiple Tissues (Specific Types) | Spleen (Multiple Types) | Spleen (Specific Types) | Comments^a^
Weisburger et al. (1978) CD (Sprague-Dawley), male 18 mo exposed (24 mo total) | 0 (111)^b^ 0 (25)^c^ 8,000–4,000 (25)^d^ 16,000–8,000 (25)^d^ | Not reported | Not reported | Not reported | Not reported | –
NCI (1979) F344, male 101–104 wk | 0 (20) 3,000 (50) 6,000 (50) Trend^e^ 0 (20) 3,000 (50) 6,000 (50) Trend^e^ | 0/20 15/50 (30)** 37/49 76)*** p < 0.001 | Fibrosarcoma 0/20 8/50 20/49*** p < 0.001 Sarcoma NOS 0/20 3/50 (6) 11/49 (22)* p = 0.003 | 0/20 8/49 (16) 4/42 (10) p > 0.05 | Fibroma 0/20 10/49 (20)* 2/42 (5) p > 0.05 | Multiple types of poorly differentiated sarcoma primarily include sarcoma, NOS (not otherwise specified), fibrosarcoma, angiosarcoma, or osteosarcoma in multiple organs or spleen
NCI (1979) F344, female 101–104 wk | 0 (20) 3,000 (50) 6,000 (50) Trend^e^ | 0/20 3/50 (6) 21/49 (43)*** p < 0.001 | Osteosarcoma 0/20 0/50 18/49 (37)** p < 0.001 | 0/20 9/49 (18)* 2/49 (24)** p = 0.018 | Angiosarcoma 0/20 7/49 (14) 9/49 (18)* p = 0.045 | Multiple types: sarcoma, NOS, angiosarcoma or osteosarcoma
Hecht et al. (1982) F344, male 72 wk exp. (93 wk total) | 0 (30) 4,000 (30)^f^ | – | Peritoneal cavity: sarcoma 0/27 9/30 (30)** | – | Fibroma 0/27 10/30 (33)*** | –
NTP (1996) F344, male 13-wk interim sacrifice; 13-wk stop exposure^g^; 26-wk continuous exposure | 0 (10) 5,000 (20) | None observed under any conditions | None observed under any conditions | None observed under any conditions | None observed under any conditions | –

* p ≤ 0.05, **p ≤ 0.01, ***p ≤ 0.001 (compared with concurrent controls by Fisher’s exact test).

^a^ See Table 4-2 for information on purity, survival, body weight, or feed consumption.

^b^ Pooled controls, controls from all compounds tested in study.

^c^ Concurrent controls.

^d^ Body weights in exposed groups <10% of concurrent control weights by 12 wk; doses reduced for remaining 60 wk. Low dose reduced from 8,000 to 4,000 mg/kg food, and the high dose reduced from 16,000 to 8,000 mg/kg food.

^e^ Trend calculated using the Cochran-Armitage trend test.

^f^ Mean daily dose: 62 mg/rat; Total dose of o-toluidine HCl: 31.3 g/rat; average exposure of o-toluidine HCl per body weight per day of animals not reported.

^g^ Rats exposed for 13 weeks and observed for another 13 weeks.

Table 4-4 Studies of Dietary Exposure to ortho-Toluidine in Rats: Mesothelium, Subcutaneous Tissue and Mammary Gland Neoplasm Incidence (%)

Reference Strain, Sex Study Duration | Exposure, ppm (# Rats) | Mesothelium: Various Body Cavities Mesothelioma | | Subcutaneous Tissue Fibroma, Fibrosarcoma | Mammary Gland Fibroadenoma Adenocarcinoma | Comments
Weisburger et al. (1978) CD [Sprague-Dawley], male 18-mo exposed (24 mo total) | 0 (111)^a^ 0 (25)^b^ 8,000–4,000 (25)^c^ 16,000–8,000 (25)^c^ | – | – | Fibroma and fibrosarcoma 18/111 (16) 0/16 18/23 (78) [***] 21/24 (88) [***] | – | See Table 4-2 for information on purity, survival, and feed consumption
NCI (1979) F344, male 101–104 wk | 0 (20) 3,000 (50) 6,000 (50) Trend^d^ | Tunica vaginalis 0/20 10/50 (20) ^[^*^]^ 17/50 (34)*** 6/49 (12) NR | Multiple organ^e^ 0/20 9/49 (18)* p > 0.05 | Fibroma^f^ 0/20 28/50(56)*** 27/49(55)*** p = 0.001 | Fibroadenoma 0/20 7/50 (14) 1/49 (2) p > 0.05 | See Table 4-2 for information on purity, survival, body weight, and feed consumption
NCI (1979) F344, female 101–104 wk | 0 (20) 3,000 (50) 6,000 (50) Trend^d^ | – | – | Fibroma 0/20 4/50 (8) 2/49 (4) p > 0.05 | Fibroadenoma 6/20 20/50 (40) 35/49 (71)** p < 0.001 | See Table 4-2 for information on purity, survival, body weight, and feed consumption
Hecht et al. (1982) F344, male 72 wk exp. (93 wk total) | 0 (30) 4,000 (30)^g^ 0 (30) 4,000^g^ | Peritoneal^h^ 2/27 (7) 5/30 (17) | – | Fibroma 1/27 (3) 25/30 (83)*** | Fibroadenoma 0/27 11/30 (37)*** Adenocarcinoma^i^ 0/27 2/30 (7) | See Table 4-2 for information on purity, survival, body weight, and feed consumption
NTP (1996) F344, male 13-wk stop exposure^j^ | 0 (10) 5,000 (20)^j^ | Epididymis 0/10 2/20 (10)^k^ No tumors in 13-wk interim sacrifice or 26-wk continuous exposure studies | – | – | – | See Table 4-2 for information on purity, survival, body weight, and feed consumption 2/20 mesothelial hyperplasia of the epididymis in stop-exposure study

* p ≤ 0.05, **p ≤ 0.01, ***p ≤ 0.001 (compared with concurrent controls by Fisher’s exact test).

[ ] = Statistical significance calculated by NTP using Fisher’s exact test.

^a^ Pooled controls, controls from all compounds tested in study.

^b^ Concurrent controls.

^c^ Body weights in exposed groups <10% of concurrent control weights by 12 wk; doses reduced for remaining 60 wk. Low dose reduced from 8,000 to 4,000 mg/kg food, and the high dose reduced from 16,000 to 8,000 mg/kg food.

^d^ Trend calculated using the Cochran-Armitage trend test.

^e^ Mesothelioma included malignant mesothelioma and mesothelioma NOS in tunica vaginalis and in other organs in the abdominal cavity.

^f^ Malignant subcutaneous tumors including osteosarcoma, myxosarcoma, fibrosarcoma, sarcoma NOS were also observed in exposed males.

^g^ Mean daily dose: 62 mg/rat; Total dose of o-toluidine HCl: 31.3 g/rat; average exposure of o-toluidine HCl per body weight per day of animals not reported.

^h^ Located in muscular wall and organs of abdominal cavity.

^i^ Fibroadenoma and adenocarcinoma combined – Control: 0/27, 4,000: 13/30 (43) ^[^***^]^.

^j^ Rats exposed for 13 weeks and held for another 13 weeks.

^k^ Exposure = [304 mg/kg/d].

Table 4-5 Summary of Dietary ortho-Toluidine Hydrochloride Studies in Mice: Neoplasm Incidence (%)

Reference Strain; Sex Study Duration | Doses: ppm, (# Animals) | Blood Vessels Hemangiosarcoma or Hemangioma | | Liver Hepatocellular Adenoma or Carcinoma | | Comments
Weisburger et al. (1978) Albino CD-1 (HaM/ICR; male 18 mo exp/24 mo total | 0 (99)^a^ 0 (25)^b^ 16,000–8,000 (25)^c^ 32,000–16,000 (25)^c^ | – | Combined 5/99 (5) 0/14 (0) 5/14 (36)* 9/11 (82)* | – | | ortho-Toluidine hydrochloride (97%–99% pure) Survival was similar between concurrent controls and exposed groups (Males: 14/25, 14/25, 11/25; Females: 15/25, 18/25, 21/25). Body weights decreased by >10% of concurrent control weights at 12 wk.
Weisburger et al. (1978) Albino CD-1 (HaM/ICR); female 18 mo exp/24 mo total | 0 (102)^a^ 0 (25)^b^ 16,000–8,000 (25)^c^ 32,000–16,000 (25)^c^ | – | Combined 9/102 (8.8) 0/15 (0) 5/18 (28)* 9/21 (43)* | –
NCI (1979) B6C3F_1_; male 2 yr (101–104 wk) | 0 (20) 1,000 (50) 3,000 (50) Trend^d^ | Hemangio-sarcoma 1/19 (5) 1/50 (2) 10/50 (20) p = 0.004 | Combined Neoplasms^e^ 1/19 (5%)^f^ 2/50 (4%) 12/50 (24%) p = 0.002 | Carcinoma 4/19 (21) 16/50 (32) 11/50 (22) p > 0.05 | Combined 5/19 (26) 19/50 (38) 14/50 (28) p > 0.05 | o-Toluidine hydrochloride (Technical grade, >99% pure, one contaminant <1%) No significant dose-related trends were found for mortality. Body weights were lower in exposed mice of both sexes and were dose related. Food consumption not reported for individual animals.
NCI (1979) B6C3F_1_; female 2 yr (101–104 wks) | 0 (20) 1,000 (50) 3,000 (50) Trend^d^ | – | Combined 1/20 (5) 1/49 (2) 3/50 (6) p > 0.05 | Carcinoma 0/20 2/49 (4) 7/15 (14) p = 0.015 | Combined 0/20 (0)^g^ 4/49 (8) 13/50 (26)** p = 0.001

* p ≤ 0.05, **p ≤ 0.01, ***p ≤ 0.001 (compared with concurrent controls by Fisher’s exact test).

^a^ Pooled controls, controls from all compounds tested in study.

^b^ Concurrent controls.

^c^ Body weights in exposed groups decreased to <10% of concurrent control weights by 12 wk; doses reduced for remaining 60 wk. Low dose was reduced from 16,000 to 8,000 mg/kg food, and the high dose from 32,000 to 16,000 mg/kg food.

^d^ Trend calculated using Cochran-Armitage trend test.

^e^ Neoplasms of the blood vessels were predominantly located in either the periuterine or periepididymal fat in the abdominal viscera.

^f^ Incidence in historical control male mice is 4% for hemangiosarcoma and 5% for hemangiosarcoma and hemangioma combined; the probability (in 50 animals) is <0.001 for obtaining 10 or more hemangiosarcoma and 12 or more combined neoplasms.

^g^ Incidence of hepatocellular neoplasms in historical control female mice is 4.3% (range 0% to 11%).

Table 4-6 Summary of Neoplasm Incidence in Subcutaneously Injected ortho-Toluidine Studies in Rats and Hamsters

Reference Species (Strain; Sex Study Duration | Exposure Interval and Period Dose (# of Animals) | Neoplasm Incidence (%) or Findings | Comments
Pliss (2004) Rat (strain/source not reported); Male and female Up to 2 yr | 1 d/wk, 18–24 mo [underlined: mg/injection] 0 (25 Male/25 Female) 30 (25 Male/25 Female) Total maximum dose/animal: 3.25 g [estimated dose at study start: 300–375 mg/kg bw] | [underlined: Combined neoplasm^a,b^] 4/38 (10.5) 12/30 (40)** Individual neoplasms not reported. | o-Toluidine (99.7% pure, with 0.2% p-toluidine) Survival of exposed rats (30/50) at time of first neoplasm (19.6 mo) in exposed rats was lower than controls (38/50) at time of first neoplasm (23 mo). Neoplasm incidences were not reported by sex or by tissue type.
Hecht et al. (1983) Hamster (Syrian Golden); Male 87 wk | 1 d/wk, 52 wk [underlined: mmol [mg]/kg/wk] 0 (15) 1.9 [203] (15) Total maximum dose/animal: 99 mmol/kg [10.6 g/kg bw] | No statistically significant increase in neoplasm incidence in exposed hamsters compared with controls. Neoplasm incidence data not reported. | o-Toluidine pure as analyzed by TLC and gas chromatography; details not provided. Mean survival time (wk) in exposed hamsters (males 61.3) and females 57.8) were lower than controls (males 75.5, females 68.7).

* p ≤ 0.05, **p ≤ 0.01, ***p ≤ 0.001 (compared with concurrent controls by Fisher’s exact test).

bw = body weight.

^a^ Neoplasms in control rats included 2 mammary fibroadenomas, 2 leucoses.

^b^ Neoplasms in exposed rats included: 4 mammary fibroadenomas, 2 sarcomas and fibromas at the injection site, and 1 hepatic sarcoma, 1 renal plasmocytoma, 1 testicular lymphohemangioma, and 3 leucoses.

### 4.3.1 Feed Studies: Rats

The new feeding studies also support the conclusions of the original listing that dietary exposure to ortho-toluidine causes neoplasms of the urinary bladder, connective tissue, subcutaneous tissue, mammary gland, and mesothelium in rats. These conclusions are based on studies that are considered to be of adequate quality to inform a cancer evaluation and thus increase the confidence in the conclusions. Strengths of the studies were lifetime exposure to doses approaching toxicity and performance of complete histopathological examination of all major organs. The Hecht study, which is a “new” study, was conducted in the same strain of male rats as one of the original studies (the NCI study) and, in general, confirmed the findings of the NCI study. The other “new” feeding study, the NTP subchronic study, was informative for the evaluation of neoplasms of the mesothelium. The new studies also provide some support that ortho-toluidine causes urinary bladder neoplasms and mammary tumors in male rats in addition to females. Some types of neoplasms were observed in both male and female rats (urinary bladder, connective tissue, mammary gland), whereas other neoplasms may be sex specific (subcutaneous tissue and mesothelium). Some types of neoplasms may be strain specific (connective tissue, mesothelium, and mammary gland), although differences in study design (e.g., shorter exposure and observation period in the CD rat study compared with the F344 rat study) may also account for the differences in findings. Details on the findings of these tumor sites that support these conclusions are discussed below.

Urinary bladder cancer is a potential target site in human cancer studies. The collective data from the four feeding studies in experimental animals provide strong evidence that ortho-toluidine exposure causes urinary bladder neoplasms in female rats (a conclusion of the 1983 evaluation), with weaker evidence observed for male rats (Table 4-2) (conclusion supported by the new studies). In female F344 rats, dietary exposure to ortho-toluidine caused a dose-related statistically significant increased incidence of urinary bladder cancer (transitional-cell carcinoma) in both exposure groups with the incidence reaching 47% in the high-exposure group. This was considered to be a robust finding because spontaneous urinary bladder neoplasms in rats are rare; no carcinomas were observed in 989 female F344 rats from 20 feed studies (NIH-07 diet, which includes data up to 1999). In addition, the time to first observed tumor was shorter in high-dose females (65 weeks) compared with low-dose females (103 weeks). In male rats, dietary exposure to ortho-toluidine induced low incidences of urinary bladder neoplasms (statistically non-significant) in two strains of rats. Similar to females, spontaneous urinary bladder neoplasms are rare in both male F344 and CD rats: (1) 3 neoplasms (carcinoma or papilloma) and 1 carcinoma were observed in 991 rats from 20 studies using NIH-07 diet of F344 rats, and (2) 6 urothelial (transitional-cell) papilloma or carcinoma were observed in 30 studies of Charles River Crl:CD rats published between 1989 and 2002. The results in the chronic studies in rats are supported by the findings of a statistically significant increased incidence of transitional-cell hyperplasia of the urinary bladder in F344 male rats in the NTP subchronic study (13-week interim study and 26-week exposure study). NCI noted that there appeared to be a dose-related progression, especially in female rats, from transitional-cell hyperplasia to transitional-cell carcinoma of the urinary bladder.

Increased incidences of sarcoma in the spleen and other tissue sites were observed in rats of both sexes (NCI 1979) and in male rats in two different studies (Hecht et al. 1982; NCI 1979) (see Table 4-3). In the NCI study, ortho-toluidine exposure caused significant dose-related increased incidences of (1) multiple types of sarcoma (fibrosarcoma, angiosarcoma, osteosarcoma, and sarcoma NOS [not otherwise specified]) in the spleen and other abdominal organs in rats of both sexes, (2) specific sarcomas in multiple organs (fibrosarcoma in males, and osteosarcoma in females), and (3) multiple types of sarcoma and angiosarcoma in the spleen of females. The NCI (1979) noted that the histologic appearance of each type of sarcoma was similar regardless of the organs involved; they were of mesenchymal origin, closely related, and poorly differentiated. There was also a high incidence of invasion into adjacent organs and soft tissues and/or metastasis to other sites, suggesting that they were highly malignant. In the Hecht study, statistically significant increased incidences of sarcoma in the peritoneum and fibroma (benign neoplasm) in the spleen occurred in male F344 rats. Sarcoma in the spleen is a rare tumor in F344 rats; the historical control data for untreated rats from NTP oral studies using NIH-07 diet (which was also the diet used in the Hecht study) ranged from 0% to 0.4% (based on 1,003 tumors) for males and 0% to 0.1% in females depending on the specific type of sarcoma (https://ntp.niehs.nih.gov/go/15482).

Increased incidences of mesothelioma (tunica vaginalis or abdominal cavity and organs) were observed in males in all three studies of F344 rats but were only statistically significant in the NCI chronic study (see Table 4-4). In the NCI chronic study, the incidence of mesothelioma (multiple organs/tunica vaginalis) was higher (34%) in the low-dose exposure group than the high-dose exposure group (18%) and most of the mesotheliomas were located in the tunica vaginalis. The historical control rate for mesothelioma for the study laboratory in the NCI study was reported to be 0.4% (1/285). A small, but not statistically significant, excess of malignant mesothelioma (located in the peritoneal cavity) was observed in the exposed male F344 rats (16.6%) compared with the controls (7.4%) in the Hecht study, and thus the finding in this study is weaker than in the NCI study. The NTP subchronic study provides supporting evidence that dietary exposure to ortho-toluidine causes mesothelioma; malignant mesothelioma and mesothelial hyperplasia of the epididymides occurred in male rats exposed in the diet for only 13 weeks and held for an additional 13 weeks (stop-exposure). Although the findings were not statistically significant they are considered to be of biological significance because of the short exposure and observation duration (NTP 1996).

Fibroma or fibrosarcoma of the subcutaneous tissues was observed in all three chronic feed studies (Hecht et al. 1982; NCI 1979; Weisburger et al. 1978) including two different strains of male rats (CD and F344). In male CD rats, statistically significant increased incidences of fibroma or fibrosarcoma were observed in both the low- and high-dose groups, but no further pathological information or stratification of incidence by type of neoplasm was provided (Weisburger et al. 1978). Increased incidences of fibroma were observed in male F344 rats in both the low- and high-dose groups in the NCI study; in addition to fibroma, a few osteosarcoma, myxosarcoma, fibrosarcoma, and unspecified sarcoma were also observed. The Hecht study reported a high incidence (83%) of fibromas occurring in the skin (presumably the subcutaneous tissue of the skin) in male F344 rats at the only dose tested.

Statistically significant increased incidences of fibroadenoma of the mammary gland were found in male F344 rats in the Hecht et al. (1982) study and in high-dose female F344 rats in the NCI (1979) study; a non-statistically significant excess of fibroadenoma was found in the low-exposure group males in the NCI (1979) chronic study. Fibroma and fibroadenoma of the mammary gland are benign, well-localized neoplasms with few mitotic figures. Some fibromas may actually be part of a fibroadenoma of mammary gland because the histological section reviewed contains only the fibrous components. In the Hecht study, two adenocarcinomas of the mammary gland were also observed. Occasionally, adenocarcinoma has been observed arising from within a fibroadenoma or there is a chemically induced increase suggesting that fibroadenoma sometimes progresses to adenocarcinoma (Boorman et al. 1990); however, no information on histogenesis was reported in the Hecht study. Mammary gland adenocarcinoma is rare in the male rat in F344 rats NTP studies (2/1,004 or 0.2% according to historical control data for NTP studies using the NIH-07 diet), which is the same strain used in the Hecht study.

### 4.3.2 Feed Studies: Mice

No new studies with adequate design and reporting were identified in mice, and the conclusions, based on the two feed studies in two different strains of mice (NCI (1979), B6C3F_1_ strain; Weisburger et al. (1978), Albino CD-1 (HaM/ICR) strain) are the same as the 1983 evaluation. These studies were considered to be informative for cancer evaluation because they exposed animals to doses approaching toxicity for close to their lifetime and conducted complete histopathological examination on all major organs. Neoplasms of the blood vessels (hemangioma and hemangiosarcoma combined) were observed in both studies and liver cancer was observed in one study (Table 4-5). In the NCI study, a significant dose-related trend was observed in male but not female B6C3F_1_ mice; most of the neoplasms observed in both the low and high doses were malignant neoplasms (hemangiosarcoma). Although the increases in incidences of the blood vessel neoplasms in male B6C3F_1_ mice were not statistically significant, they were considered exposure related because they were outside the historical control range (hemangioma and hemangiosarcoma combined). The increased incidences of blood vessel neoplasms in male and female Albino CD-1 (HaM/ICR) mice were statistically significant in both the low- and high-dose groups; these doses were much higher than the dose used in the NCI study. Statistically significant dose-related increases in liver neoplasms (hepatocellular carcinoma and adenoma combined) were also observed in ortho-toluidine exposed B6C3F_1_ females but not in Albino CD-1 (HaM/ICR) females; most of the neoplasms observed were carcinomas. This finding is consistent with other aromatic amines, as they often induce liver neoplasms in rodent studies.

### 4.3.3 Subcutaneous Injection Studies in Rodents

No evidence of carcinogenicity was observed in studies of rats and hamsters administered ortho-toluidine by subcutaneous injection; however, the data are inadequate to conclude whether these negative findings are due to study design issues, species differences or route of exposure (see Table 4-6). No increases in specific neoplasm incidences were found in any of the studies. The incidence of all neoplasms in rats was reported to be statistically higher than in unexposed controls, but these findings have little biological meaning. As discussed in Section 4.1, these studies were considered to have limited ability to inform a cancer evaluation, and most of the limitations (e.g., less than lifetime exposure and observation duration, smaller numbers of animals, and uncertainty about whether necropsies were completed on all major organs) would decrease the sensitivity for detecting a neoplastic response.

## 4.4 NTP’s Level of Evidence Recommendation

There is significant evidence for the carcinogenicity of ortho-toluidine from studies in experimental animals based on increased incidences of malignant or combined benign and malignant tumors in rats and mice at multiple tissue sites. Dietary exposure to o-toluidine caused tumors of the urinary bladder and connective tissue (sarcoma) in rats of both sexes, subcutaneous tissue and mesothelium in male rats, blood vessels in male and female mice, and liver in female mice. Statistically significant increased incidences of benign tumors of the mammary gland (fibroadenoma) in male (Hecht et al. 1982) and female (NCI 1979) rats were also reported, which support the findings of sufficient evidence of the carcinogenicity of ortho-toluidine from studies in experimental animals.