# 3 Human Cancer Studies

## Introduction

Human exposure to ortho-toluidine occurs mainly among industrial populations, where it is used primarily in the rubber chemical industry, as an intermediate in the manufacture of pesticides and of a variety of dyes and pigments, and in pharmaceuticals manufacturing (see Section 1, “Human Exposure”). Although exposure to ortho-toluidine can also occur via tobacco smoke, the environment, and consumer products, all of the available human studies have been conducted among occupationally exposed populations.

The human cancer studies section describes and evaluates the available epidemiological data on exposure to ortho-toluidine and cancer, reaching a level of evidence conclusion according to the approach outlined in the “Protocol: Evaluation of Human Cancer Studies on Exposure to ortho-Toluidine for the Report on Carcinogens” (hereafter referred to as “Protocol,” available at https://ntp.niehs.nih.gov/NTP/roc/thirteenth/Protocols/ortho-ToluidineProtocol_508.pdf). The steps in the cancer evaluation process, listed below, are captured in the following subsections or appendices.

1. Selection of the relevant literature included in the cancer evaluation (Section 3.1 and Appendix A, [underlined: and in the Protocol]).
2. Description of the study design, methodologies, and characteristics of the individual studies and identification of the tumor sites of interest (Section 3.2, Table 3-1 and Appendix D).
  Table 3-1 Human Cancer Studies of Potential Exposure to ortho-Toluidine
  Primary Reference | Name of Study | Exposure Assessment | Cancer Endpoints
  Cohort studies
  Case and Pearson (1954), Case et al. (1954) ^a^ | U.K. dye workers | Exposure assigned based on company rolls of magenta manufacturing workers | Mortality (SMR): Urinary bladder cancer
  Pira et al. (2010), Piolatto et al. (1991), Rubino et al. (1982) | Italian dye workers | Individual exposure assessment based on work history in departments producing ortho-toluidine, fuchsin, or safranine T dyes | Mortality (SMR): Urinary bladder cancer
  Ott and Langner (1983) | U.S. dye workers | Individual exposure assigned by work history in one or both of departments producing bromindigo and thioindigo dyes | Mortality (SMR): All causes, all cancers, digestive, respiratory, urinary bladder cancers
  Stasik (1988) | 4-COT production workers | Employment in department producing or processing 4-chloro-ortho-toluidine | Mortality (SMR): All causes, stomach, urogenital, brain cancers Incidence (SIR): Urinary bladder cancer
  Carreón et al. (2014; 2010), Hanley et al. (2012), Ward et al. (1991; 1996), Prince et al. (2000) | NIOSH (U.S.A.) rubber chemical workers | Individual exposure classified as definitely, probably (2 categories), and probably not exposed to ortho-toluidine, and by cumulative exposure based on work history and occupational hygiene data | Incidence (SIR, SRR, HR): Urinary Bladder cancer Mortality (SMR): All causes, all cancers, 8 specific sites (Prince et al. 2000)
  Sorahan (2008), Sorahan et al. (2000), Sorahan and Pope (1993) | U.K. rubber chemical workers | Individual exposure assigned by history and 3 levels of duration of employment in department producing “Sopanox” rubber chemical agent | Incidence (SIR, SRR): Urinary bladder cancer Mortality (SMR): All causes, all cancers and >30 specific cancers (Sorahan et al. 2000) Combined incidence and mortality (RR): Urinary bladder cancer
  Population- or hospital-based case-control studies
  Richardson et al. (2007) | Canadian case-control study | Job-exposure matrix based on self-reported occupational questionnaire and NIOSH NOES Survey data | Incidence (OR): Urinary bladder cancer
  Castro-Jiménez and Orozco-Vargas (2011) | Colombian case-control study | Parental exposure to hydrocarbons including ortho-toluidine | Incidence (OR): Childhood acute lymphoblastic leukemia
  4-COT = 4-chloro-ortho-toluidine; HR = hazard ratio; JEM = job-exposure matrix; NIOSH = National Institute for Occupational Safety and Health; NOES = National Occupational Exposure Survey (1983–1986); OR = odds ratio; RR = relative risk; SIR = standardized incidence ratio; SMR = standardized mortality ratio; SRR = standardized rate ratio.
  ^a^ Although ortho-toluidine was not specifically mentioned in the study by Case and Pearson, exposure among magenta manufacturing workers is likely based on knowledge of the industrial process. In the U.K., the process for manufacturing magenta, resulting mainly in the production of magenta III (new fuchsin), involved condensation of ortho-toluidine and formaldehyde in the presence of ortho-nitrotoluene (Howe 1977).
3. Assessment of study quality (Section 3.3, Table 3-2; Appendix D, Table D-3 and Table D-4).
  Table 3-2 Co-exposures and Potential for Confounding
  Study | Co-exposures^a^ | Exposure Assessment and Levels and Methods to Evaluate Potential for Confounding | Potential for Confounding
  U.K. dye workers cohort Case et al. (1954); Case and Pearson (1954) | High probability: Magenta Potential exposure^b^ [ortho-Nitrotoluene], [formaldehyde] | No exposure assessment at the individual level. Levels of potential co-exposures relative to ortho-toluidine cannot be evaluated. Excluded workers with exposure to auramine, benzidine, α-naphthylamine, or β-naphthylamine. | Exposure to other known human urinary bladder carcinogens unlikely; exposure to animal or human carcinogens probable. Magenta production is a known human bladder carcinogen per IARC; however, any effects from magenta cannot be separated from its co-exposures (of which ortho-toluidine is a major suspect); studies of magenta in experimental animals are inadequate.
  Italian dye workers cohort Piolatto et al. (1991); Pira et al. (2010); Rubino et al. (1982)^c^ | High probability: o-Toluidine and 4,4´-methylene bis(2-methylaniline) production: [ortho-Nitrotoluene]; [4,4´-methylene-bis(2-methylaniline)] Fuchsin and safranine T production: Aniline, [ortho-aminoazotoluene], 2,5-diaminotoluene, fuchsin, safranine T | No exposure assessment at the individual level. Levels of o-nitrotoluene and 4,4´-methylene-bis(2-methylaniline) are predicted to be similar to that of ortho-toluidine.^d^ Exposure to other chemicals probably lower. Excluded workers with exposure to benzidine, α-naphthylamine, or β-naphthylamine. | Exposure to other known human urinary bladder carcinogens unlikely; exposure to animal urinary bladder carcinogens possible, exposure to animal carcinogens probable. See comment for Case and Pearson for magenta (e.g., fuchsin) production.
  U.S. dye workers cohort Ott and Langner (1983) | Potential exposure: [Nitrobenzene]; [4-chloro-ortho-toluidine]; 4-chloro-acetyl-o-toluidine; thioindigo dyes; 1,2-dihydroacenaphthylene; 2-aminobenzoic acid | No exposure assessment at the individual level. Odor of nitrobenzene reported. Excluded individuals with high exposure to arsenicals, vinyl chloride, or asbestos. | Exposure to animal carcinogens or suspect human urinary bladder carcinogen (4-chloro-ortho-toluidine) probable for some workers in cohort. (Note: This refers to the potential for confounding that remains after workers exposed to vinyl chloride or asbestos were excluded).
  4-COT production workers cohort (Germany) Stasik (1988) | High probability: [4-Chloro-ortho-toluidine] Potential exposure: 6-Chloro-ortho-toluidine; N-acetyl-ortho-toluidine | No exposure assessment at the individual level. Authors state exposure to 4-chloro-ortho-toluidine was predominant. | High probability of potential confounding from exposure to a suspected human bladder carcinogen (4-chloro-o-toluidine). Study methods do not allow for attributing any observed effects to ortho-toluidine.
  NIOSH (U.S.) rubber chemical workers cohort Carreón et al. (2010); Hanley et al. (2012); Ward et al. (1991); Ward et al. (1996) | High probability: [Aniline] Potential exposure: [4-Aminobiphenyl] (trace) | Air sampling of co-exposure available for ortho-toluidine exposure groups but not at the individual level; biomonitoring data (urine and ortho-toluidine-Hb adducts) available on subgroup of workers but not used in risk calculations. Definitely exposed jobs: Aniline: Breathing zone GM: slightly lower than ortho-toluidine; urine and aniline-Hb adducts lower than ortho-toluidine. Nitrobenzene: Breathing zone GM: ~2.5 lower than ortho-toluidine; non-detectable in most samples. 4-Aminobiphenyl: observed in air at trace levels; 4-ABP-Hb adducts found at similar (low) levels in ortho-toluidine and unexposed workers. Other co-exposures: levels NR, but evidence from process descriptions Hanley et al. (2012) suggest low or minimal potential exposure. Internal analyses (probability, duration, and cumulative exposure to ortho-toluidine only). | No evidence that exposure to 4-aminobiphenyl (a known human bladder carcinogen) was a potential confounder in this study; exposure to other animal carcinogens possible.
  U.K. rubber chemicals workers cohort Sorahan (2008); Sorahan et al. (2000); Sorahan and Pope (1993) | High probability: “Sopanox” (1-tolylbiguanidine) Potential exposure^e^: [Aniline]; MBT; PBN | Quantitative cumulative exposure assessment to MBT; duration of employment in aniline- and PBN-exposed departments. Analysis of bladder cancers among ortho-toluidine exposed workers adjusted for exposure to MBT and PBN in internal analysis. | Exposure to other known human bladder carcinogens unlikely; methods to evaluate potential confounding adequate.
  Canadian case-control study Richardson et al. (2007) | Other potential co-exposures among cases associated with ortho-toluidine exposure not reported. | No adjustment of case-control analysis for other occupational co-exposures was conducted. | Co-exposure to other carcinogens possible; inadequate data to evaluate potential confounding from co-exposures.
  See also Table D-4.
  GM = geometric mean; MBN = 2-mercaptobenzothiazole; ND = non-detectable; PBN = phenyl-β-naphthylamine.
  ^a^ Co-exposures include those where there is a reasonable potential for exposures, does not include co-exposure to very low or trace levels unless that chemical is a known human bladder carcinogens; blue font ([bold italic type] = known or potential human urinary bladder carcinogens, orange font [bold type] = animal urinary bladder carcinogen; green font [italic type] = animal or human carcinogen, not urinary bladder.
  ^b^ Based on knowledge of manufacturing process (see Section 1). According to Howe (1977), U.K. magenta manufacture mainly resulted in Magenta III, produced by condensing ortho-toluidine with formaldehyde in the presence of ortho-nitrotoluene.
  ^c^ According to the authors (Rubino et al. 1982), ortho-toluidine and 4,4´-methylene-bis (2-methylaniline) were made in one department and New Fuchsin (new magenta or Magenta III) was produced in a second by heating ortho-toluidine, 4,4´-methylene-bis (2-methylaniline) with ortho-nitrotoluene; workers in the second department also made safranine T by oxidizing ortho-toluidine and 2,5-diaminotoluene in the presence of aniline, with ortho-aminoazotoluene as an intermediate of the reaction (see Section 1). Workers in the ortho-toluidine-exposed subcohort worked in one or other of these departments.
  ^d^ Based on knowledge of manufacturing process (see Section 1).
  ^e^ Some workers may have been exposed to these chemicals via working in other departments.
4. Cancer assessment (Section 3.4): (a) evaluation of the cancer findings from the individual studies (Table 3-3) and (b) synthesis of the evidence for human carcinogenicity across studies.
  Table 3-3 Urinary Bladder Cancer among ortho-Toluidine-exposed Workers
  Reference | Study Name Design/ Population Exposure Assessment | | Exposure Group (N) | External Analysis: SMR or SIR (95% CI); # Obs Deaths or Cases | Internal Analysis: OR SRR, HR or RR (95%CI); # Obs Cases | Interpretation
  Carreón et al. (2014) incidence analysis and Carreón et al. (2010) mortality analysis United States | U.S. (NIOSH) rubber chemical workers (1,786) Historical cohort cancer mortality and incidence study of urinary bladder cancer Exposure assessment-based work history (jobs and dept.), industrial hygienist surveys, and expert assessment | | [underlined: Exposure probability] Probably not (562) Probably [1]^b^ (155) Probably [2]^c^ (195) Definitely^d^ (900) [underlined: Definitely exposed] Employment duration (yr) <5 5–9 ≥10 p_trend_ Time since first exposure (yr) <10 10–19 20–30 >30 p_trend_ [underlined: Cumulative rank (unit-days)] Quartile model 10 yr. lag^e^ <11,000 11,000 to <27,000 27,000 to <48,000 48,000+ p_trend_ Continuous: Log-square^f^ 3,652.5 18,262.5 36,525 | [underlined: Incidence (SIR)^a^] 0.59 (0.07–2.12); <5 2.47 (0.67–6.33); <5 4.21 (1.15–10.8); <5 3.90 (2.57–5.68); 27 1.98 (0.80–4.08); <10 4.52 (0.93–13.2); <5 6.24 (3.63–9.99); 17 1.74 (0.04–9.68); <5 3.41 (0.93–8.72); <5 4.75 (2.17–9.02); 9 3.97 (2.11–6.79); 13 1.32 (0.61–2.51); 9 3.37 (1.62–6.20); 10 5.44 (2.49–10.3); 9 6.13 (2.80–11.6); 9 | [underlined: Incidence (SRR)] 1.00 2.50 (0.42–14.8) 4.85 (0.81–29.0) 4.28 (1.02–18.0) 1.00 2.56 (0.60–10.9) 4.50 (1.74–11.6) <0.0001 1.00 7.09 (0.76–66.2) 13.4 (1.59–11.3)) 8.61 (1.11–67.0) 0.001 1.00 3.05 (1.13–8.22) 6.37 (2.30–17.7) 7.34 (2.44–22.1) <0.001 [underlined: HR] 1.88 (1.48–2.42) 4.11 (2.39–7.23) 7.39 (3.42–16.4) | High risk estimates in incidence study Evidence of exposure-response relationship with duration and level of exposure. Potential co-exposures unlikely to explain increase in risk Potential confounding by smoking unlikely: estimated increase in SIR due to smoking = 1.08 based on 5% sample of smoking data, compared with national rates Overall quality of evidence: high
  Sorahan (2008) United Kingdom | U.K. rubber chemical workers (2,160) Historical cohort cancer mortality and incidence study of urinary bladder cancer Exposure assessment based on detailed job history and expert assessment | | o-Toluidine-exposed subcohort (53) [underlined: Employment duration (yr)] Ref 0.1–4.9 ≥5 p_trend_ (continuous) | SIR = 5.56 (1.51–14.22); 4 SMR = 11.16 (2.30–32.61); 3 | Combined incidence and mortality [underlined: Adjusted RR^d^] 1.00 3.72 (1.21–11.4); NR 3.38 (0.67–17.0); NR p < 0.05 | High risk estimates Evidence of exposure response with duration of employment (exposure categories treated as continuous measure) Significantly elevated risk after adjustment for co-exposures Overall quality of evidence adequate to high
  Pira et al. (2010) Italy | Italian dye workers (906) Historical cohort mortality study Exposure assessment based on work history and expert assessment | | Fuchsin, safranine T, or ortho-toluidine mfr. (47) | SMR = 22.5 (8.3–49.0); 6 | NR | Confounding by co-exposures unlikely but cannot be ruled out High risk estimate but based on small numbers Overall quality of evidence: adequate
  Ott and Langner (1983) United States | U.S. dye workers (275) Historical cohort mortality study Exposure based on working in a production area associated with exposure to o-toluidine, but extent of exposure is unclear and misclassification likely | | Bromindigo or thioindigo mfr. (117) | [underlined: Deaths] 0 observed deaths (Expected not reported; 1.2 expected in total cohort) | NR | No excess mortality Limited power to detect effect due to potential exposure misclassification and low statistical power Overall quality of evidence: limited
  Case and Pearson (1954) United Kingdom | U.K. dye workers (4,622) Historical cohort mortality study of urinary bladder cancer Exposure inferred via manufacturing process | | Magenta production (85) | SMR = [23.0 (5.87–62.8)]; 3 | NR | High risk estimate but based on small numbers Indirect but plausible evidence of exposure to ortho-toluidine No clear evidence of carcinogenicity of co-exposures Overall quality of evidence: limited
  Richardson et al. (2007) Canada | | Canadian case-control study Cancer registry-based study of urinary bladder cancer: 1,062 cases, 805 controls, 7 cancer controls Exposure assessment based on JEM (NIOSH survey); concerns about quality of JEM) | Ever exposed (39) [underlined: Probability of exposure] Low (NR) Medium (NR) High (NR) p_trend_ | – | [underlined: Adjusted OR^h^] 1.01 (0.71–1.44); 39 1.49 (0.89–2.52); NR 0.46 (0.20–1.07); NR 1.10 (0.62–1.94); NR 0.79 | No excess risk or exposure response relationship Limited ability to detect an effect because of potential for exposure misclassification and rarity of exposure specific to ortho-toluidine in study. Overall quality of evidence: limited
  Numbers in [ ] calculated by RoC.
  SMR = standardized mortality ratio; SIR = standardized incidence ratio; SRR = standardized rate ratio; OR = odds ratio; NR = Not reported; JEM = job exposure matrix.
  ^a^ SIR based on rates for New York State excluding New York City.
  ^b^ [1] Low and irregularly/occasionally.
  ^c^ [2] Low and regularly.
  ^d^ Moderate/high.
  ^e^ Similar findings reported for unlagged and 20-yr lagged models and in Cox regression models using quartile or quintile categories of category rank exposure lagged for 10 yr.
  ^f^ Cox regression model; cases matched to cases with risk sets on gender, race and attained age, birth yr. was not a confounder; HR reported for 1, 5, 10 yr at Rank 10 (corresponding unit-days reported in table); similar exposure-response found (albeit lower magnitudes) for log-linear model.
  ^g^ Adjusted for exposure to MBT, PBN, aniline, age, and calendar period; trend calculated by treating 4 exposure categories as a continuous measure.
  ^h^ Matched for age and additionally adjusted for ethnicity, years of smoking, alcohol consumption, and questionnaire respondent. (Other variables considered in the analysis were marital status, education, and other measures of smoking status. Reference group was 0 exposure group.
5. Preliminary recommendation for the level of evidence of carcinogenicity (sufficient, limited, or inadequate) of ortho-toluidine from human studies (Section 3.5).

## 3.1 Selection of the Relevant Literature

Details of the procedures used to identify and select the primary studies and supporting literature for the human cancer evaluation are detailed in Appendix A and in the Protocol. The primary epidemiological studies considered for the cancer evaluation had to meet the following criteria: (1) was a peer-reviewed, primary research study on potential exposure to ortho-toluidine, (2) provided exposure-specific analyses for ortho-toluidine or evidence that potential exposure to ortho-toluidine was highly likely based on author’s report or inferred using relevant knowledge of industrial processes, and (3) provided risk estimates for carcinogenesis endpoints or information needed to calculate risk estimates. Studies identified that met these criteria included six occupational historical cohort studies of cancer, and two population-based case-control studies (urinary bladder cancer and childhood acute lymphoblastic leukemia).

Studies excluded from the review were one case-control study of renal-cell cancer among paperboard printing workers (Sinks et al. 1992) that did not provide qualitative or quantitative evidence of potential exposure (although pigments containing ortho-toluidine and other chemicals were reportedly used in the past) and several case-series of urinary bladder cancer, primarily among dyestuff manufacturers, that did not report or permit the calculation of risk estimates for potential exposure to ortho-toluidine (Conso and Pontal (1982); Genin et al. (1978); Khlebnikova et al. (1970); Oettel et al. (1968); Uebelin and Pletscher (1954); for a historical review of earlier case series, see e.g., Michaels (1988)). In general, no exposure data were reported in these studies, with the exception of the study of ortho-toluidine manufacturing workers in the former USSR by Khlebnikova et al. (1970), who reported ambient concentrations ranging from 0.5 to 28.6 mg/m^3^ of ortho-toluidine and dermal exposure (see IARC 2010e).

## 3.2 Overview of the Selected Epidemiological Studies and Identification of Cancer Endpoints

This section provides an overview of the study population characteristics and methodologies of the individual studies included in the review (see Table 3-1) and identifies the primary cancer endpoint(s) of interest. For each of the reviewed studies, detailed data on study design, methods, and findings were systematically extracted from relevant publications, as described in the study Protocol, into Table D-1 and Table D-2 in Appendix D and in Section 3.4. Background exposure information for some of these epidemiological studies is available in Appendix C.

Six occupational historical cohort studies of cancer among ortho-toluidine-exposed workers were identified: three cohort mortality studies were conducted among workers in the dyestuffs industry, two incidence/mortality studies in the rubber chemicals industry, and one incidence study in a plant manufacturing 4-chloro-ortho-toluidine (4-COT) (Table 3-1). Each of the studies conducted external or internal analyses on urinary bladder cancer risk, and four of the studies reported on some or all other cancer sites.

Two standardized cohort mortality studies of dyestuff workers were conducted among male workers manufacturing magenta: a study in the United Kingdom, hereinafter referred to as the U.K. dye workers study (Case and Pearson 1954) and a second study in Italy hereinafter referred to as the Italian dye workers study (Pira et al. 2010) (see Table 3-1). In the U.K. study, exposure to ortho-toluidine was inferred based on knowledge of the industrial process in the United Kingdom during that time period. Findings of the Italian dye workers study were reported in an initial mortality analysis to 1976 (Rubino et al. 1982) and in two follow-up studies to 1989 (Piolatto et al. 1991) and to 2003 (Pira et al. 2010). Exposure was assessed via individual work history. A third standardized mortality study was conducted among male workers engaged in the manufacture of thio- and bromindigo dyes in the United States (Ott and Langner 1983), hereinafter referred to as the U.S. dye workers study. Exposure to ortho-toluidine occurred only during the manufacture of thioindigo dyes and there was limited quantitative data documenting ortho-toluidine exposure.

A standardized urinary bladder cancer incidence analysis among male workers in Germany engaged in the manufacture of the azo dye and chlordimeform pesticide intermediate 4-COT, in which ortho-toluidine is used as a precursor, has been reported by Stasik (1988) (hereafter referred to as the 4-COT production workers study).

Two standardized mortality and incidence studies in the rubber chemical industry, in the United States (conducted by NIOSH, hereinafter referred to as NIOSH rubber chemical workers) and United Kingdom (hereinafter referred to as the U.K. rubber chemical workers) were identified. Findings from the NIOSH rubber chemical workers were reported in a series of publications involving two different exposure assessments. An analysis of urinary bladder cases identified in the New York State Cancer Registry (Ward et al. 1991) and mortality (Prince et al. 2000) was conducted among male and female workers with a follow-up from 1973 through 1988, which assigned workers to categories of probability of exposure to ortho-toluidine based on employment in a department where ortho-toluidine was used. Air monitoring and biological monitoring of a subset of workers for ortho-toluidine and co-exposures were also conducted (Ward et al. 1991; 1996). An updated, detailed exposure survey of ambient levels of ortho-toluidine and co-exposures was subsequently conducted by Hanley et al. (2012). Urinary bladder cancer cases and deaths identified in the 1991 analysis were subsequently re-analyzed by Carreón et al. (2010), using the updated work histories and occupational hygiene data reported by Hanley et al. (2012). Carreón et al. (2014) reported on a reanalysis of this cohort, which (1) updated the follow-up until 2007, using incident urinary bladder cases identified in six State cancer registries, and (2) expanded the cohort to include workers hired from 1946 to 2006. Importantly, this study refined the exposure classification using department-job combinations and by approximately exposure ranks (Hanley et al. 2012). The (1991, 2010, 2014) incidence analyses included internal analyses of duration of employment and time since first employment and the 2014 update incorporated internal analyses of cumulative exposure to ortho-toluidine for the first time. Incidence data from the most recent updated and expanded study are reported in this review (2014 incident cases and mortality data from the 2010 study) unless data from earlier reports were considered relevant to the assessment.

The United Kingdom study evaluated standardized cancer mortality and incidence among male rubber chemical manufacturing workers. Findings of an initial follow-up to 1986 were reported by Sorahan and Pope (1993), follow-ups to 1992 (incidence) and 1996 (mortality) by Sorahan et al. (2000), and follow-up to 2005 by Sorahan (2008). Analysis by duration of employment was conducted for this cohort but no quantitative data on ortho-toluidine exposure were reported.

Two case-control studies were identified: a population-based Canadian cancer registry study of male urinary bladder cancer in which job-exposure matrices of exposure to a range of occupational agents were applied (Richardson et al. 2007) (hereafter referred to as the Canadian case-control study) and a hospital-based case-control study in Colombia of childhood acute lymphoblastic leukemia (ALL) in association with parental exposure to a range of hydrocarbons, again using a job-exposure matrix (hereafter referred to as the Colombian case-control study) (Castro-Jiménez and Orozco-Vargas 2011).

The available database is only adequate to evaluate urinary bladder cancer. Urinary bladder cancer has been the primary focus of concern in human studies, driven in part by early case reports of increased numbers of these cancers among workers in the dyestuffs industry, in ortho-toluidine or 4-COT manufacturing, and in other amine manufacturing processes in which ortho-toluidine is used as an intermediate (see Section 3.1). Reporting is limited or absent for the majority of other tumor sites among the available cohort studies. The available case-control studies on exposure to ortho-toluidine reported on only one other tumor site, childhood ALL, in the Colombian case-control study (Castro-Jiménez and Orozco-Vargas (2011); see Appendix D, Table D-2) in addition to the Canadian case-control study of urinary bladder cancer by Richardson et al. (2007). A statistically significant increase in ALL was observed among children whose parents were both estimated to have had potential occupational exposure to ortho-toluidine; however, potential confounding by one of a number of other hydrocarbons that were associated with an increase in ALL risk could not be ruled out. The available database on this cancer endpoint is inadequate to evaluate the relationship between exposure to ortho-toluidine and childhood ALL.

## 3.3 Assessment of the Quality of the Individual Studies

Each primary study was assessed for its ability to inform hazard identification including the potential for biases and the adequacy of the “ability to detect an effect” and analytical methods, following the approach outlined in the Protocol for evaluating human cancer studies on exposure to ortho-toluidine. Details on the assessment of study quality are presented in Appendix D and in Table D-3 and details on the description of the study elements are in Appendix D, Table D-1 [underlined: and] Table D-2. Section 3.3.1 reports on the assessment of biases and other factors of study quality, Section 3.3.2 focuses on the assessment of potential confounding, and Section 3.3.3 integrates these assessments, reaching decisions on the utility of the individual studies to inform cancer identification.

### 3.3.1 Assessment of Potential Bias, Analytical Methods, and Other Study Quality Characteristics

#### 3.3.1.1 Selection and Attrition Bias

Selection bias is not generally a major concern in cohort studies, with the exception of the potential for a healthy worker effect in studies using external (non-occupational) comparison groups (e.g., standardized mortality and incidence studies). Both the healthy worker hire effect and healthy worker survival effect tend to bias towards the null, so that positive associations are unlikely to be biased upward. The potential for a healthy worker hire effect can be indirectly assessed based on observed differences between all-cause and all-cancer mortality or incidence rates; no strong evidence of a healthy worker hire effect was identified in any of the cohort studies. No analyses were done in the studies to determine whether there was a healthy worker survival effect.

Overall, selection bias was not a major concern (i.e., potential for bias is not probable) in any of the studies with the exception of the 4-COT production worker study (Stasik 1988) (see Appendix D, Table D-3). The potential for a healthy worker effect was considered to be unlikely or minimal for analyses using internal controls in the two rubber chemical workers studies (Carreón et al. 2014; Sorahan 2008) and possible in the three dye worker cohort studies (Case and Pearson 1954; Ott and Langner 1983; Pira et al. 2010). The 4-COT production workers study (Stasik 1988) was initiated based on the findings of two urinary bladder cancer incident cases that were identified as a result of an earlier mortality study, and there is potential (probable) for a systematic bias, most likely towards finding a positive effect in this subcohort. The potential for selection bias in the Canadian case-control study (Richardson et al. 2007) was considered to be possible based on the use of cancer cases as controls and a low participation rate (60%). It is difficult to predict whether using cancer cases as the referent group would bias the risk estimate towards the null because it is not known whether ortho-toluidine is a risk factor for other types of cancers.

Attrition bias was assessed via loss to follow-up in the cohort studies. Where reported, loss to follow-up was generally low and the potential for this type of bias was considered unlikely/minimal (Carreón et al. 2014; Ott and Langner 1983; Sorahan 2008) or possible (Pira et al. 2010). Information on follow-up was not available in two studies (U.K. dye workers and 4-COT production workers). Although loss to follow-up was higher (12%) in the Italian dye workers study (for the total cohort, but unknown for ortho-toluidine-exposed workers), there is no a priori reason to suspect that loss to follow-up would be related to exposure or disease status, and thus any potential bias would most likely be towards the null (Pira et al. 2010).

#### 3.3.1.2 Information Bias: Exposure Endpoints

The adequacy of the characterization of exposure to ortho-toluidine and potential for misclassification was assessed based on quality of information provided to document exposure to ortho-toluidine at the individual level. Studies considered to have good or adequate exposure characterization were the two rubber chemical cohort studies and the Italian dye worker study. The most detailed and best-documented characterization of exposure was conducted in the NIOSH rubber chemical cohort (Carreón et al. 2014) because of the extensive ambient exposure measurements and biomonitoring data for a sample of workers, and the use of expert judgment, which included a review of records, plant walkthroughs, and interviews with company personnel (Hanley et al. 2012). The updated exposure assessment permitted the classification or reclassification of workers’ exposure according to probability of exposure, duration, and cumulative exposure (as unit-days, using rank and continuous measures). (See Appendix C, Table C-1 and Section 1, Figure 1-4 and Figure 1-5 for more information on ortho-toluidine exposure levels among the different types of workers.)

Exposure assessment was based on individual work histories specific process information provided by the authors and expert judgment in the U.K. rubber chemical (Sorahan 2008) and Italian dye worker (Pira et al. 2010) studies (see Appendix B); although no quantitative exposure data were provided There is a higher potential for non-differential misclassification of exposure in these studies compared with the Carreón et al. (2014) study, but overall the exposure assessment was considered to be adequate to inform the evaluation of carcinogenicity.

The potential for misclassification of exposure was more of a concern in the U.K. and U.S. dye workers studies, 4-COT-production workers study, and the Canadian case-control study. In the U.K. dye worker study (Case and Pearson 1954), exposure to ortho-toluidine was inferred via knowledge of magenta manufacturing in the United Kingdom during the study time period. Although there was some limited ambient air and urine data in the 1940s indicating the presence of ortho-toluidine exposure in the U.S. dye worker study (Ott and Langner 1983), the potential for exposure misclassification was considered to be probable in this study because exposed workers (those producing thioindigo dyes) were grouped together with workers without potential exposure to ortho-toluidine (those producing bromindigo dyes). In addition, there were four alternative manufacturing processes, and ortho-toluidine might not have been used in all processes (see Appendix C). It also seems likely that not all 4-COT production and process workers were exposed to ortho-toluidine (Stasik 1988). In the Canadian case-control study (Richardson et al. 2007), exposure to ortho-toluidine was assessed via self-reported occupational history and a job-exposure matrix (JEM). However, the quality of the JEM was limited because it was based on a U.S.-walk-through exposure survey (the NIOSH National Occupational Exposure Survey) in one calendar year and did not include information on specific jobs. In addition, it is not clear if there are differences in ortho-toluidine industries between Canada and the United States. Misclassification of exposure was considered to be probable in this study because of potential recall bias from using self-reported information and the unclear relevance of the JEM.

#### 3.3.1.3 Information Bias: Disease Endpoints

The assessment of the potential for misclassification of urinary bladder cancer deaths or incident cases was based on the accuracy and completeness of ascertainment of vital status and diagnosis. Mortality data are typically less informative than incidence data for long survival cancers such as urinary bladder cancer, and the use of underlying cause of death from death certificates may underestimate cases of bladder cancer among deceased cohort members. In addition, cancer registries provide potentially greater diagnostic precision compared with death certificates; however, any cases that are not registered or occur outside of the state/region or time period covered may be missed. A strength of the updated NIOSH study (Carreón et al. 2014) was the expansion of the identification of cancer cases from the New York cancer registry (used by Ward et al. (1991)) to five additional cancer registries, together with increasing the follow-up time from 1988 through 2007.

Non-differential misclassification of cases, tending to bias the findings toward the null, was considered unlikely or minimal in the studies reporting cancer incidence (the two rubber chemical worker cohorts and the Canadian case-control study), but possible in the NIOSH and U.K. rubber chemical mortality analyses and the Italian and U.S. dye workers studies reporting mortality data. In the 4-COT production workers and U.K. dye workers studies, methods used to ascertain urinary bladder cancer cases (4-COT production workers) or deaths (U.K. dye workers) might have differed between the cohort and reference group, leading to the potential for a systematic (differential) misclassification of disease.

#### 3.3.1.4 Ability to Detect an Effect and Adequacy of Analytical Methods

Factors influencing a study’s ability to detect an effect include statistical power, levels, duration, level or range of exposure to ortho-toluidine, and length of follow-up in cohort studies. The statistical power (based on a one-sided test) to detect a twofold increased risk of urinary bladder cancer was limited in all the cohort studies except the NIOSH study (Carreón et al. 2014). In the Canadian case-control study, exposure to ortho-toluidine was rare (approximately 3.6% of cases; exposure prevalence not reported among controls) in the Canadian study, which limits its ability to detect an effect. All the cohort studies had adequate length of follow-up which, based on U.S. and European data on the latency of urinary bladder cancer, is considered to be 20 years. With respect to level, range, and duration of exposure, the ability to detect an effect was considered to be good for the NIOSH rubber chemical workers (Carreón et al. 2014), adequate for the cohorts of U.K. rubber chemical workers (Sorahan 2008), Italian dye workers (Pira et al. 2010), and U.K. dye workers (Case and Pearson 1954), and limited for the Canadian case-control study and cohort studies of U.S. dye workers (Ott and Langner 1983), and 4-COT production workers (Stasik 1988). In addition, no information on actual exposure levels was provided. The Canadian case-control study is population- rather than occupation-based, and it is not clear how many of the participants who were assigned exposure to ortho-toluidine, particularly those in the “low” or “medium” exposure groups, would have had levels of exposure comparable to those typically experienced by the occupationally exposed workers in the cohort studies.

The adequacy of analytical methods was assessed based on whether the analyses included internal analyses, evaluated exposure-response relationships or time since first exposure, or adjusted for (or considered) potential confounding. Exposure-response relationships were evaluated in three studies: the two rubber chemical worker studies (Carreón et al. 2014; Sorahan 2008) and the Canadian case-control study (Richardson et al. 2007). Only two studies had formal statistical methods to evaluate confounding. The U.K. rubber chemical workers cohort study (Sorahan 2008) adjusted for occupational co-exposures but not for occupational risk factors for urinary bladder cancer, whereas the case-control study adjusted for some non-occupational risk factors but not occupational co-exposures. Although the NIOSH rubber chemical workers cohort study (Carreón et al. 2014) did not adjust for co-exposures in its analysis, it included extensive internal analyses, which help to mitigate potential confounding, and collected other information to evaluate potential confounding (see Sections 3.3.2 and 3.3.3). The U.K. rubber chemical workers study also conducted internal analyses. The three dye worker cohort studies excluded individuals with co-exposure to some known human bladder carcinogens (Case and Pearson 1954; Pira et al. 2010) or, in the U.S. study, to the known human carcinogens vinyl chloride and asbestos (Ott and Langner 1983). Although the Canadian case-control study conducted exposure-responses analyses, there is a high probability of misclassification to each of the exposure categories, and no information was provided in the number of cases and control for each exposure category. A strength of the study is that it controlled for cigarette smoking; however, no information on co-exposures was reported and no analyses controlling for any other occupational co-exposures were conducted. Analyses of the studies on dye workers (all three studies) and the 4-COT production workers were limited to external analyses with no consideration of exposure categories or accounting for potential confounders.

### 3.3.2 Assessment of Potential Confounding by Occupational Co-exposures to Known or Suspect Carcinogens

Workers in both the dyestuffs industry and rubber chemical manufacturing industry may be exposed to a number of other chemicals, some of which may cause urinary bladder cancer or other cancers. In general, most studies did not assess exposure to potential confounders at the individual level or consider them in analytical models; however, in some cases the relative level of exposure to other chemicals compared with exposure to ortho-toluidine can be predicted from knowledge of the industrial process. The approach and conclusions of the evaluation of whether confounding from co-exposures is a concern in each study are captured in the table below and include the following steps:

1. A list of chemicals in each study of potential concern (e.g., reasonable potential of worker exposure) is compiled, together with the identification of co-exposures that may cause urinary bladder cancer (blue and orange font) or other cancers (green font) is co. (Table 3-3; see Appendix D, Table D-4 for background information regarding the potential carcinogenicity of the various co-exposures.)
2. Methods for assessing exposure to other chemicals or estimates of exposure compared to ortho-toluidine are evaluated (Table 3-2).
3. Analytical methods to consider or adjust for exposure to co-exposures are evaluated (Table 3-2).
4. An overall assessment of the potential for confounding is conducted.

The U.S., U.K., and Italian dye workers were potentially exposed to several suspected or known animal carcinogens, one of which, ortho-aminoazotoluene, causes urinary bladder cancer in animals. The U.K. and Italian dye workers were involved in magenta production, which is classified as carcinogenic to humans (IARC 2012); ortho-toluidine is one of the suspected co-exposures. Exposure data are lacking in each of the dye workers cohorts, however, and there is limited or no available evidence for the human carcinogenicity of the individual agents used in the dye production processes.

The German 4-COT production workers were exposed to 4-chloro-ortho-toluidine, for which there is some evidence of urinary bladder carcinogenicity in humans. The author noted that exposure to 4-COT was the predominant exposure, and it is not possible to separate potential effects of ortho-toluidine from those of 4-COT. It is also not clear whether workers in the U.S. dye workers study would also have been exposed to this substance as an intermediate in the thioindigo dye manufacturing processes.

With respect to potential confounding by co-exposures in the NIOSH cohort of rubber chemical workers, Hb adducts of 4-aminobiphenyl (the only known human bladder carcinogen with potential exposure in this population) were detected at very low levels and were similar in ortho-toluidine-exposed and unexposed workers (Ward et al. 1996), and ambient exposures were very low and intermittent (Hanley et al. 2012; Ward et al. 1991), which argues against 4-aminobiphenyl being a potential confounder. Workers were exposed to aniline, which is an animal carcinogen; however, exposure levels relative to ortho-toluidine were low. Nitrobenzene levels were mostly non-detectable (Hanley et al. 2012). The U.K. rubber chemical workers were likely to be exposed to several other chemicals if they worked in other departments, including aniline, phenyl-β-naphthylamine (PBN), and 2-mercaptobenzothiazole (MBT), but evidence of carcinogenicity in humans of these substances is limited or inadequate for evaluation. In addition, internal analyses were conducted in which risk estimates for urinary bladder cancer incidence were adjusted for these co-exposures.

In the Canadian case-control study of bladder cancer, it is not clear whether individual observed cases were exposed to other chemicals; no adjustments were made in the analysis for multiple chemical exposures.

### 3.3.3 Assessment of Potential Confounding by Other Risk Factors

In addition to the healthy worker effect and industrial co-exposures discussed above, exposed workers may differ from the comparison group with respect to demographic, lifestyle, or other risk factors. With the exception of smoking, there are few known non-occupational risk factors for urinary bladder cancer other than radiation and some chemotherapy drugs, and these would be unlikely to be related to ortho-toluidine exposure. There is strong evidence to suggest that smoking is an independent risk factor for urinary bladder cancer. In addition, ortho-toluidine has been detected in tobacco smoke (IARC 2010e). The NIOSH study (Carreón et al. 2014; Ward et al. 1991; Ward et al. 1996) was the only cohort study to examine the effect of smoking on urinary bladder cancer risk, first by assessing smoking status among an approximately 12% sample of workers and measuring ortho-toluidine, aniline, or 4-aminobiphenyl in urine and hemoglobin (Hb) adducts in a sample of smokers and nonsmokers (Ward et al. 1996). No differences were observed between smokers and non-smokers for ortho-toluidine in urine or ortho-toluidine Hb adducts. Secondly, the effect of the difference in smoking status among a subset of workers in comparison with the U.S. population on expected urinary bladder cancer risk was calculated, using an indirect adjustment method (using the method of Axelson and Steenland 1988) and incorporating a Monte Carlo sensitivity analysis to examine potential bias. The difference in smoking status between workers and the U.S. population was estimated to increase the risk of urinary bladder cancer incidence by 8%. (Carreón et al. 2014). The U.K. rubber chemical worker study reported a SMR for lung cancer for the overall cohort, which provides some indirect information on evaluating potential confounding from cigarette smoking. In the case-control study, analyses were adjusted for smoking, alcohol consumption, and demographic variables. In the Canadian case-control study, ethnicity, marital status, education, questionnaire respondent, alcohol, and smoking variables were considered by backwards stepwise conditional logistic regression.

### 3.3.4 Summary of the Utility of the Studies to Inform the Cancer Evaluation

Based on the methodological evaluation of the adequacy of study design, adequacy of exposure and disease assessment of cancer incidence or mortality, and ability to detect an effect of ortho-toluidine on urinary bladder cancer risk, the NIOSH and U.K. rubber chemical worker cancer incidence studies and the Italian dye workers cohort mortality study are considered to be of high or moderate utility to inform the cancer evaluation. The NIOSH cohort is considered to be the most informative study because it provides the best exposure assessment of ortho-toluidine and co-exposures. Exposure was not as well characterized (by e.g., ambient air monitoring or biomonitoring) in the U.K. rubber chemical and Italian dye workers studies; however, detailed job histories were available, and thus we can reasonably conclude that each worker was exposed to ortho-toluidine, although the levels of exposure are unknown. Strengths of the U.K. rubber chemical study are analysis by duration of employment and internal adjustment of potential confounding. The Italian dye workers study is of moderate but more limited utility due to the possibility of potential confounding, the smaller numbers of exposed workers, and higher overall number of workers lost to follow-up.

The cohort studies of U.K. and U.S. dye workers and the Canadian case-control study are of more limited utility because of the potential for misclassification of exposure and confounding by co-exposures. The U.S. dye workers study only has sufficient statistical power to detect a large effect. In addition, only 23% of the dye workers had more than 5 years of employment and ortho-toluidine was used to make only one of the two types of dyes included in the potentially exposed group. Although the Canadian case-control study used a job-exposure matrix to assess exposure at the individual level, there is still potential for misclassification due to the limited quality of the exposure assessment and data are inadequate to evaluate potential confounding from occupational co-exposures in this study. In addition, exposure to ortho-toluidine (approximately 3.6% of cases, exposure prevalence not reported in controls) was rare among the study participants, which limits its ability to inform the cancer evaluation.

In the German 4-COT production worker study, it is not possible to reliably distinguish the potential effect of ortho-toluidine from that of 4-COT, a suspect human bladder carcinogen, and there is a risk of positive selection bias in this cohort; therefore, the study was considered to be methodologically inadequate for inclusion in the synthesis.

## 3.4 Cancer Assessment: Urinary Bladder Cancer

This section summarizes and interprets the findings from the individual studies and synthesizes the evidence for urinary bladder cancer across the body of studies. Five cohort studies and one case-control study were considered adequate for inclusion in the evaluation of the level of evidence of carcinogenicity of ortho-toluidine from studies in humans. As noted in Section 3.3.4 (“Summary of the utility of the studies to inform the cancer evaluation”), based on the methodological strengths and limitations of these studies, the two (U.K. and NIOSH) rubber chemical cohorts of bladder cancer incidence and mortality and, to a lesser extent, the Italian dye workers cohort mortality study are considered the most informative for the evaluation of the overall findings, while the U.K. and U.S. dye workers cohort studies and the Canadian case-control study are of more limited utility. When both incidence and mortality data were available for the same study, incidence was considered to be more informative for evaluating urinary bladder cancer risk.

The key question for evaluating the level of evidence across the body of studies is whether any observed associations between ortho-toluidine exposure and urinary bladder cancer could be explained by chance, bias, or confounding by co-exposures or other risk factors. Several of the guidelines developed by Austin Bradford Hill (1965) are relevant to the evaluation of the level of evidence for human carcinogenicity, including the magnitude (strength) and consistency of any observed associations across studies; evidence for exposure-response relationships and associations with appropriate latency; and the degree to which chance, bias, and confounding could plausibly explain observed associations. Observed associations from methodologically limited studies or negative findings from such studies are given less weight in the overall evaluation than findings from methodologically strong studies.

### 3.4.1 Individual Studies

The findings for the six studies evaluating urinary bladder cancer and exposure to ortho-toluidine are summarized in Table 3-3 below. The interpretation of the studies, including the conclusions of the findings, whether they can be explained by confounding, and the overall quality of the evidence, is presented in the “Interpretation” column.

#### 3.4.1.1 Studies of Rubber Chemical Workers

In the expanded and updated analysis of the NIOSH rubber chemical workers (Carreón et al. 2010), a statistically significant increased SIR was found among definitely exposed workers (SIR = 3.90; 95% CI = 2.57 to 5.68, 27 cases; SRR (vs. probably not exposed workers) = 4.28; 95% CI = 1.02 to 18.0). These data confirm the finding of a statistically significant risk of bladder cancer among exposed workers reported in both publications of the original cohort, which used two different exposure assessments (Carreón et al. 2010; Ward et al. 1991). The magnitude of the risk estimate among workers reclassified as having definitely (moderate to high) exposure in the 2014 study was somewhat lower than the previous reports, but the estimate was more precise.

There was strong evidence for a positive association between urinary bladder cancer risk and both cumulative rank exposure and exposure duration; risk estimates among the highest or longest exposed workers ranged between approximately five- and ninefold in most analyses. Among definitely exposed workers, the risk of urinary bladder cancer increased with longer duration of exposure in both external (SIR) or internal incidence analyses (using directly standardized rates, SRR, and <5 years duration as a referent group) and longer time since first exposure (SRR using <10 years as the referent group); statistically significant exposure response-relationships were observed in internal analyses (p_trend_ < 0.001 for each analysis) (Carreón et al. 2010). Among all cohort members, urinary bladder cancer risk also increased with increasing quartiles of cumulative rank exposure in both external (SIR) and internal analyses (SRR, using the lowest exposure groups as the referent groups) and in unlagged, 10-year lagged, and 20-year lagged models for both types of analyses. Statistically significant, positive exposure-response relationships were observed in the unlagged (p_trend_ < 0.001), 10-year lagged (p_trend_ < 0.001) and 20-year lagged (p_trend_ = 0.037) SRR analyses, albeit the 10-year lagged model was considered to have the best fit. In Cox regression analyses (10-year lagged, using the lowest exposure group as the referent group), cumulative rank exposure was significantly related to urinary bladder cancer risk in categorical models (quartile, quintile, decile, based on exposure distribution of cases) and continuous models (log-linear, log square). (Table 3-3 reports findings for several of these analyses.) Mortality analyses were not reported in the 2014 update, and analyses reported in the 2010 study were uninformative because of the small number of exposed cases; there was only one exposed case among definitely exposed workers (SMR = 1.96, 95% CI = 0.05 to 11.05, 1 exposed death).

It is unlikely that the increased risk of urinary bladder cancer in the NIOSH cohort could be explained by selection and information biases or confounding. There is no clear evidence of selection, ascertainment, or attrition bias (see Section 3.2, Table 3-2), and the high magnitude of the observed risk estimate mitigates against a risk of these types of biases. Based on detailed industrial hygiene data, biomonitoring data, individual work histories, and extensive use of records to reclassify exposure, there is documented evidence of substantial exposure to ortho-toluidine in the NIOSH cohort among workers in the “definitely exposed” category. It is unlikely that co-exposure to known or suspected carcinogenic substances or other risk factors could explain the observed associations between exposure to ortho-toluidine and urinary bladder cancer risk in the NIOSH cohort study. As noted, 4-aminobiphenyl (4-ABP) is the only co-exposure that has been clearly established as a urinary bladder carcinogen in humans; however, exposure to 4-ABP was very low (<1 ppm) (Hanley et al. 2012; Viet et al. 2009; Ward 1997; Ward et al. 1996), intermittent (1972 and 1985) (Ward et al. 1994; Ward 1997), and not correlated with ortho-toluidine exposure (as assessed by hemoglobin adducts (Ward et al. 1996). Although workers were also exposed to aniline, it is unlikely that aniline can explain the association between ortho-toluidine and urinary bladder cancer. The available epidemiological studies have not found an association between aniline exposure and urinary bladder cancer (Case and Pearson 1954; IARC 1987; Sorahan 2008; USEPA 1994). Although aniline is an animal carcinogen (Group 3), it has not caused urinary bladder cancer in animals and it is considered a less potent animal carcinogen than ortho-toluidine (see Section 5, “Other Relevant Data”). Nitrobenzene, considered a Group 2B carcinogen by IARC is not associated with urinary bladder cancer in animals and, as noted, was mostly non-detectable in the plant (Hanley et al. 2012).

Smoking is also unlikely to explain the excess risk of urinary bladder cancer. As noted in Section 3.3.2, smokers and non-smokers had similar levels of ortho-toluidine that were not related to their occupational exposure status, and, when compared with national rates, smoking prevalence differences were estimated to potentially increase urinary bladder cancer risk in this cohort by only 8%, compared with the approximately three- and fourfold overall observed increases in association with ortho-toluidine exposure in external analysis and internal analyses respectively (Carreón et al. 2014). The indirect smoking adjusted SIR for the entire cohort was close to three-fold (SIR = 2.67, 95% Monte-Carlo limits for bias = 1.87 to 3.75).

Overall, the finding of an increased risk of urinary bladder cancer remained robust (1) using different methods to analyze exposure-response relationships, (2) adjusting for smoking, and (3) using sensitivity analyses, primarily related to different methods of case ascertainment in the different cancer registries.

Statistically significant increased risks of urinary bladder cancer incidence (SIR = 5.56; 95% CI = 1.51 to 14.22, N = 4) and mortality (SMR = 11.2, 95% CI = 2.30 to 32.61; 3 deaths) were observed in the U.K. rubber chemical cohort study. The major limitations of this study are the small number of exposed cases and the lack of quantitative information on exposure levels; however, neither of these limitations would create a false positive. Internal analyses showed a significant positive trend (continuous measure, p < 0.05) for cumulative duration of employment in the ortho-toluidine department, after simultaneous adjustment for co-exposure to aniline, MBT and PBN (Table 3-3). Similar to the NIOSH study, there was no evidence of a potential for selection bias, and the potential for nondifferential exposure misclassification, is mitigated by the use of individual work histories to assign person-years at risk.

The U.K. rubber workers were also potentially exposed to 2-mercaptobenzothiazole (MBT), phenyl-β-naphthylamine (PBN) and aniline, if they rotated to other departments of the plant where these chemicals were used, which approximately 74% of the ortho-toluidine-exposed workers did (Sorahan et al. 2000). Confounding by these exposures is considered to be unlikely. MBT and PBN have not been clearly associated with urinary bladder cancer in other epidemiological studies (Collins et al. 1999; Veys 1996), although they were associated with increased risks of urinary bladder cancer incidence in the U.K. rubber chemical cohort in an unadjusted (SRR) analysis. However, the relative risks were strongly attenuated and no longer statistically significant after simultaneous adjustment for co-exposure to ortho-toluidine, aniline, and either MBT or PBN in internal analyses by duration of employment. Although there was no information on cigarette smoking in this study, there was no excess risk of lung cancer among workers in the overall (not restricted to ortho-toluidine exposed workers) cohort (SMR = 0.91, 95% CI = 0.75 to 109; 120 deaths), suggesting that smoking habits among workers were not substantially different than the general population (reference group).

#### 3.4.1.2 Other Studies: Dye Workers and Case-control Study

A large excess mortality was found in both studies of dye workers involved in magenta manufacturing: the Italian study (SMR = 22.5; 8.3 to 49.0, N = 6) and the U.K. study ([SMR = 23.0; 95% CI = 5.87 to 62.8], N = 3); however, exposure to ortho-toluidine in the U.K. study is inferred via industrial process and not definitely established. The use of individual work histories to assign person-years at risk helps mitigate the potential for misclassification of exposure in the Italian cohort. Workers in the Italian dye workers cohort who made ortho-toluidine were likely exposed at similar levels to ortho-nitrotoluene and 4,4´-methylene-bis (2-methylaniline), both of which are listed as reasonably anticipated to be human carcinogens (NTP 2011a; 2011b) based on sufficient evidence of carcinogenicity from studies in experimental animals; however, these chemicals did not cause cancer of the urinary bladder, although site concordance between animals and humans is not always observed. Workers who made fuchsin or safranine T were possibly exposed to the intermediate ortho-aminoazotoluene, for which there is some evidence of bladder tumors in animal studies. Three urinary bladder cancer deaths were reported among workers in the section making ortho-toluidine and two among workers in the dyemaking section (the location of the most recent death was not reported), with no overlap in exposure, according to the authors, suggesting that ortho-toluidine was the only common exposure. Effect modification cannot completely be ruled out, however, since co-exposures are mostly other aromatic amines that share common metabolic activation pathways.

In contrast to these studies, no association was found among U.S. dye workers who were involved in thioindigo manufacturing processes (Ott and Langner 1983); however, the study had low statistical power to detect an effect; only 8 cancer deaths (from all cancers) were expected in the subcohort, only 1.2 cases of urinary cancer were expected in the entire cohort of dye workers, and approximately 77% of workers had short-term employment (of 4 years or less). Thus, this study only had statistical power to detect large risk estimates. In addition, it is not known how many of the 117 workers were potentially exposed to ortho-toluidine because the subcohort also included workers who manufactured bromindigo dyes, who presumably were not exposed to ortho-toluidine. In summary, no firm conclusions can be drawn from the absence of observed urinary bladder cancer deaths in this cohort.

No association between ortho-toluidine and urinary bladder cancer was observed in the Canadian case-control study. However, the study had limited ability to detect an effect because of a limited exposure assessment and rarity of exposure to ortho-toluidine in this study population.

### 3.4.2 Synthesis of Evidence across the Body of Studies

Overall, there is credible evidence of an association between increased urinary bladder cancer risk and exposure to ortho-toluidine based on consistent findings across studies, the presence of exposure-response relationships (with cumulative rank exposure and employment duration) and large magnitudes of effect across studies.

An increased risk of urinary bladder cancer (incidence or mortality) was consistently observed in all four studies with adequate latency that used statistical or other methods capable of detecting an association (Carreón et al. 2014; Case and Pearson 1954; Pira et al. 2010; Sorahan 2008) (see Figure 3-1). Both rubber chemical cohort studies (NIOSH and U.K.) of urinary bladder cancer incidence reported high and statistically significant increased SIRs of similar magnitude (approximately four- to fivefold) among exposed workers. Urinary bladder cancer mortality findings also point to an increase in urinary bladder cancer risk, although they vary across studies. In the rubber chemical cohorts, a 11-fold significantly elevated mortality risk was observed in the U.K. study; the NIOSH study was inadequate to evaluate mortality because only two deaths were observed in the entire cohort (Prince et al. 2000). These findings are supported by large and statistically significant increases (approximately 22-fold) in urinary bladder cancer mortality observed in two cohorts of magenta dye makers (U.K. and Italian) exposed to ortho-toluidine, both of which had a long follow-up period; both of these studies, as noted, have methodological limitations. Two studies did not find an excess of urinary bladder cancer among ortho-toluidine-exposed workers; however, the statistical power to detect an effect was low in the U.S. dye workers study (Ott and Langner 1983), and misclassification of exposure is a serious concern in both the U.S. dye workers cohort and the Canadian case-control study (Richardson et al. 2007).

Figure 3-1

Risk Estimates for Urinary Bladder Cancer

Risk estimates and 95% confidence intervals for urinary bladder cancer for five of the six studies that were considered in the assessment. SIR reported for the NIOSH and U.K. rubber-chemical cohorts, SMR for the Italian and U.K. dye workers cohort, and OR for the Canadian case-control study. No deaths were observed in the U.S. dye-worker study (Ott and Langner 1983). Solid circles = cohort studies, clear circle = case-control study.

Risks of urinary bladder cancer increased with increasing cumulative exposure level, duration, or time since first exposure to ortho-toluidine, which strengthens the arguments for causality. Among NIOSH rubber chemical workers definitely exposed to ortho-toluidine, statistically significant, positive exposure-response relationships (p_trends_ ranged from 0.037 to <0.001) for cumulative exposure rank and urinary bladder incidence were observed in both lagged and unlagged analyses with risks ranging from approximately seven- to eightfold in the highest exposure category for each specific analysis (compared to the lowest exposure category) (Carreón et al. 2014). Risks also increased with exposure duration in both of the rubber chemical cohorts (p_trend_ < 0.001 for Carreón et al. (2014), and p_trend_ < 0.005 for Sorahan (2008)). and with time since first exposure in the NIOSH study (p_trend_ < 0.001). (Employment duration was used as a surrogate of exposure in the UK study (Sorahan 2008).)

Limitations of the database are the limited number of methodologically adequate studies, and imprecise risk estimates in many studies because of the small number of urinary bladder cancer deaths or cases. In the updated NIOSH study, the number of exposed cases increased from 13 to 37, which resulted in more precise risk estimates. The findings of increased risks reported in the original report of this cohort (Ward et al. 1991), which have been reconfirmed and strengthened in both the 2010 reanalysis and the 2014 update (Carreón et al. 2014; Carreón et al. 2010), increases the confidence in the body of literature. Finally, the large magnitudes of the risk estimates across studies also reduce concerns that the strong associations between ortho-toluidine exposure and increased urinary bladder cancer risk are due to chance.

The next key question is whether the excess risk of urinary bladder cancer observed in these cohort studies can be attributed to exposure to ortho-toluidine or other factors. The NIOSH study provides strong evidence that the exposed cases/deaths were actually exposed to ortho-toluidine, and based on the authors’ documentation and knowledge of the industrial processes, it is reasonable to assume that most, if not all, of the exposed cases or deaths in the other informative studies were exposed to ortho-toluidine (Pira et al. 2010; Sorahan 2008). In addition, the large magnitude of the risk estimates helps rule out bias due to exposure misclassification.

Another limitation is the lack of formal methods to evaluate confounding from exposure to smoking or other occupational carcinogens in many of the studies. Smoking can reasonably be ruled out in the NIOSH study, in which information was only available for a subset of workers. The large magnitude of risk estimates also provides high confidence for ruling out smoking across studies.

The most challenging issue is potential confounding from other occupational co-exposures. In the most informative study, the NIOSH cohort of rubber chemical workers, there is substantial evidence that ortho-toluidine is the most plausible agent causally related to the observed increase in urinary bladder cancer risk among workers considered to be definitely or probably exposed to ortho-toluidine (see above), and these conclusions are supported by the study of U.K. rubber chemical workers. Potential confounding by aniline, the principal common co-exposure in these two studies, can be reasonably ruled out because aniline has not been shown to cause urinary bladder cancer in experimental animals or humans in other epidemiologic studies (Case and Pearson 1954; IARC 1987; Sorahan 2008; USEPA 1994). Also, in the NIOSH cohort, workers were exposed to approximately three times higher levels of ortho-toluidine (which is a more potent animal carcinogen) than aniline, according to biomonitoring data reported by Ward et al. (1996). Potential confounding from occupational co-exposures is of greater concern for the two cohorts manufacturing magenta dyes (see above). Magenta manufacturing has been classified by IARC as a known to be carcinogenic to humans based largely on these two studies; however, IARC was unable to identify the specific chemical exposures, which include ortho-toluidine, responsible for the increased risk of urinary bladder cancer. In addition, urinary bladder cancer deaths were observed in both subgroups of workers in the Italian dye workers cohort study who were exposed to different process chemicals except for ortho-toluidine, strongly suggesting that ortho-toluidine is the common causal agent. Finally, the finding of urinary bladder cancer among rubber chemical workers who are not exposed to many of the chemicals found in the dye workers studies argues that ortho-toluidine contributes to the excess urinary bladder cancer among dye workers. In addition, there is no independent evidence that the other co-exposures cause urinary bladder cancer in humans, although some are animal carcinogens. The possibility of effect modification may exist and may help explain the observed large risk estimates, however.

Overall, the finding of increased urinary bladder cancer risk in separate cohorts with different exposure conditions and co-exposures lends strong support to the conclusion that ortho-toluidine is the common causal risk factor.

## 3.5 NTP’s Level of Evidence Recommendation

There is sufficient evidence of carcinogenicity from studies in humans based on epidemiological studies finding a causal association between increased risk of urinary bladder cancer and exposure to ortho-toluidine that is unlikely to be explained by chance, bias, or confounding. An increased risk of urinary bladder cancer was observed across studies of workers with different occupations and in different geographical locations. In addition, risks of urinary bladder cancer increased with increasing level and duration of exposure.