# 2 Disposition and Toxicokinetics

The available data on the absorption, distribution, and excretion of ortho-toluidine in humans and experimental animals are summarized in Section 2.1, and metabolism is discussed in Section 2.2. Toxicokinetic data for ortho-toluidine were limited and are briefly reviewed in Section 2.1.1. Mechanistic implications of the processes of absorption, distribution, metabolism, and excretion are discussed further in Section 5.

## 2.1 Absorption, Distribution, and Excretion

### 2.1.1 Experimental Animals

ortho-Toluidine is well absorbed following oral exposure based on studies in male rats (IARC 2000; 2010e). Absorption data for female rats, other species, or other routes of exposure were not available. Once absorbed, ortho-toluidine is rapidly distributed, metabolized, and excreted (Brock et al. 1990; Cheever et al. 1980; Son et al. 1980). Distribution data were available from rats exposed by subcutaneous (s.c.) injection or oral gavage. These studies show general agreement regarding tissues with the highest concentrations. In male F344 rats exposed to 50 or 400 mg/kg ortho-[methyl-^14^C]toluidine (2 animals/dose) by s.c. injection, radioactivity was detected in the liver, kidney, lung, spleen, colon, and urinary bladder 48 hours later (Son et al. 1980). The highest concentrations occurred in the liver; however, compared with the increase in dose, disproportionate increases of ^14^C occurred in all tissues examined. These data imply saturation of some metabolic pathway(s) at the higher dose. Brock et al. (1990) reported more extensive tissue distribution data in male Crl:CD^®^ BR rats 72 hours after receiving a single 500 mg/kg oral dose of radiolabeled ortho-[ring-U-^14^C]toluidine (Figure 2-1). The dose was selected as an approximate equivalent of the dietary level that produced tumors in the long-term carcinogenicity studies (see Section 4). The highest concentrations were found in whole blood, spleen, kidneys, and liver. Peak blood levels of undifferentiated radioactivity were reached at 24 hours, and the half-life for plasma elimination ranged from about 12 to 15 hours. The kinetic studies are of limited use in that it is unknown what percentage of the radioactivity in plasma is due to parent [^14^C]-ortho-toluidine, as opposed to metabolites. The major tumor sites in animals administered ortho-toluidine in feed (see Section 4) were the urinary bladder, spleen, and abdominal organs and connective tissue in rats and liver and blood vessels in mice. The urinary bladder also is the tumor site of interest in humans (see Section 3). Most of these tissues were among those with the highest accumulation of radioactivity in both distribution studies in rats.

Figure 2-1

Tissue Distribution of Orally Administered ortho-Toluidine in Male Rats

Source: Brock et al. (1990) (mean ± SD from four rats; samples collected at 72 h).

The primary route of excretion in rats was the urine regardless of exposure route. Following a single subcutaneous dose of either 50 or 400 mg/kg, 74% to 83% was excreted in the urine within 48 hours (Son et al. 1980) while more than 92% of administered radiation from an oral dose of 50 mg/kg was excreted in the urine within 24 hours (Cheever et al. 1980). Subcutaneous administration forces 100% absorption of the dose. The observation that urinary excretion is about the same for both routes implies near 100% absorption of the oral dose. The saturation of metabolic pathways is not as apparent in the urinary excretion data. Excretion via the lungs and feces were approximately 1% and 3%, respectively (Son et al. 1980). The amount of unmetabolized compound detected in the urine ranged from about 3.6% to 5.1% in male F344 rats administered 0.82 mmol/kg (about 88 mg/kg) (Kulkarni et al. 1983) or 400 mg/kg ortho-toluidine by s.c. injection (Son et al. 1980). The amount of unchanged toluidine excreted in rat urine also depended on the dose and isomer administered (Cheever et al. 1980). Male Sprague-Dawley rats administered a single oral dose (500 mg/kg) of meta- or para-toluidine excreted only 2.5% of the dose as the parent compound compared with 21% for ortho-toluidine, even though there were no major differences in the primary metabolic pathways (ring hydroxylation followed by sulfate or glucuronide conjugation) (see Section 2.2). Rats administered a lower oral dose of ortho-toluidine (50 mg/kg) excreted 36% of the dose unchanged.

### 2.1.2 Humans

The primary routes of exposure to ortho-toluidine in humans are the respiratory tract and skin (IARC 2000). Evidence that ortho-toluidine is absorbed following inhalation exposure comes from studies that measured ortho-toluidine in urine and/or as hemoglobin adducts in occupationally exposed workers (Jones et al. 2005; Korinth et al. 2007; Lüersen et al. 2006; Ward et al. 1996). Studies in different populations of rubber industry workers reported that ortho-toluidine concentrations in workplace air correlated significantly with concentrations in the urine (Brown et al. 1995). A series of studies of ortho-toluidine exposed and non-exposed workers in the rubber chemicals industry reported that exposed workers had approximately 25 times higher post-shift urinary levels of ortho-toluidine compared with non-exposed workers and that the post-shift urinary exposure levels among exposed workers were sixfold higher than the pre-shift levels (Stettler et al. 1992). Pre-shift urinary levels of exposed workers were also higher than those of non-exposed workers suggesting that ortho-toluidine is not completely eliminated from the bodies of the exposed workers between work shifts (Brown et al. 1995; Stettler et al. 1992). ortho-Toluidine has been detected in the urine of non-smoking individuals with no known occupational exposure to ortho-toluidine, which implies exposure and absorption from contaminated food and water or from consumer or medical products (see Section 1).

Several in vitro studies reported that ortho-toluidine (either as neat compound or in a solution with phosphate buffer and 5% ethanol) was readily absorbed through excised human skin mounted on diffusion cells (Lüersen et al. 2006; Wellner et al. 2008). About 15% of the applied dose penetrated over 7 hours and 50% penetrated within 24 hours (Lüersen et al. 2006). Dermal absorption of ortho-toluidine was shown to be significant in studies of rubber industry workers (Korinth et al. 2008; Korinth et al. 2007). These studies monitored workplace air concentrations of ortho-toluidine, measured internal exposure based on either hemoglobin adducts or urinary excretion, and documented skin conditions of the workers. These studies demonstrated that the relative internal exposure depended more on the skin condition of the workers than on the concentrations of ortho-toluidine in the air. Internal exposure was significantly higher in workers with skin lesions (burns, erythema, or eczema) compared with workers with healthy skin. Furthermore, frequent use of skin barrier creams was shown to enhance dermal absorption of ortho-toluidine. Korinth et al. (2008) confirmed that skin barrier creams actually enhanced dermal absorption of ortho-toluidine in vitro using diffusion cells and excised human skin. The highest mean enhancement factors (based on maximum fluxes from the same skin donor in the same experimental series for untreated and treated skin) ranged from 6.2 to 12.3.

No tissue distribution studies were identified for humans.

## 2.2 Metabolism

Few studies have investigated ortho-toluidine metabolism in experimental animals or humans or have identified the specific cytochromes P450 involved. This section provides a brief review of the metabolism of aromatic amines and ortho-toluidine. Metabolism studies in experimental animals and humans are reviewed in Sections 2.2.1 and 2.2.2, respectively, and metabolic enzymes are discussed in Section 2.2.3.

### 2.2.1 Experimental Animals

Metabolism studies that were identified were in male rats exposed to ortho-toluidine by oral or subcutaneous injection (Kulkarni et al. 1983; Son et al. 1980); however, the studies by subcutaneous injection used higher doses and more sensitive methodologies. Son et al. (1980) used solvent extraction and chromatography on several absorbants to isolate metabolites. Nonextractable conjugated metabolites were hydrolyzed enzymatically and the aglycones were isolated by chromatography. GC/MS was used to identify the aglycones. The major metabolic pathways of ortho-toluidine in rats were N-acetylation and hydroxylation at the 4 position (para to the amine group), followed by glucuronide or sulfate conjugation. Glucuronidation, acetylation, and oxidation are competing metabolic reactions in most species (Freudenthal et al. 1999). Sulfate and glucuronide-conjugated urinary metabolites comprised about half of the administered dose (Table 2-1). The ratio of sulfates to glucuronides was approximately 6:1. Minor metabolic pathways included hydroxylation at the 6 position (ortho to the amine group), oxidation of the methyl group, and oxidation of the amine group. A double acid conjugate of 4-amino-meta-cresol (thought to be the N-glucuronide of 4-amino-meta-cresyl sulfate) was identified but the amount was not reported. A subsequent study by Kulkarni et al. (1983) identified N-hydroxy-ortho-toluidine in rat urine using HPLC with an electrochemical detector. They noted that this metabolite might play a role in urinary bladder carcinogenicity (see Section 5.2.1). In the oral administration study (Cheever et al. 1980), unmetabolized ortho-toluidine and 4-amino-meta-cresol were detected, suggesting that ring hydroxylation was a major metabolic pathway in rats.

Table 2-1 Metabolites of ortho-Toluidine Detected in Rat Urine

Metabolite | Relative Amount (% of Dose)^a^
Ether-extractable metabolites
ortho-Toluidine Anthranilic acid N-Acetyl-anthranilic acid N-Acetyl-ortho-toluidine N-Acetyl-ortho-aminobenzyl alcohol N-Acetyl-4-amino-meta-cresol 4-Amino-meta-cresol ortho-Azoxytoluene ortho-Nitrosotoluene N-Hydroxy-ortho-toluidine | 3.6^b^–5.1 0.3 0.3 0.2 0.3 0.3 0.06 0.2 ≤0.1 0.1^b^
Acid-conjugated metabolites
4-Amino-cresyl sulfate N-Acetyl-4-amino-meta-cresyl sulfate 2-Amino-meta-cresyl sulfate 4-Amino-meta-cresyl glucuronide N-Acetyl-4-amino-meta-cresyl glucuronide N-Acetyl-ortho-aminobenzyl glucuronide Unidentified conjugated metabolites | 27.8 8.5 2.1 2.6 2.8 1.3 5.9

Sources: Kulkarni et al. (1983); Son et al. (1980).

^a^ Measured 24 hours after a single s.c. dose of 400 mg/kg unless otherwise noted.

^b^ Measured 6 hours after a single s.c. dose of 0.82 mmol/kg [~88 mg/kg].

In addition to the metabolites listed in Table 2-1, Gupta et al. (1987) predicted the existence of several metabolites based on data from other aromatic amines. These included N-acetoxy-ortho-toluidine (formed by acetylation of N-hydroxy-ortho-toluidine), N-acetyl-N-hydroxy-ortho-toluidine (formed by oxidation of N-acetyl-ortho-toluidine), N-acetoxy-N-acetyl-ortho-toluidine (formed by acetylation of N-acetyl-N-hydroxy-ortho-toluidine), 2-hydroxy-6-methyl-acetanilide (formed by acetylation of 2-amino-meta-cresol), and ortho-azotoluene (formed through a reaction of ortho-toluidine with ortho-nitrosotoluene). N-acetoxy-ortho-toluidine could undergo non-enzymatic breakdown to form several reactive electrophilic species (i.e., nitrenium ions, nitrene, and free radicals) that could bind to macromolecules. Another pathway involves oxidation of unconjugated phenolic metabolites to form reactive quinone imines (English et al. 2012; Skipper et al. 2010). Metabolic pathways of ortho-toluidine are shown in Figure 2-2.

Figure 2-2

Metabolism of ortho-Toluidine in Rats

Brackets indicate postulated proximate or reactive metabolites based on data from other aromatic amines.

Sources: English et al. (2012); IARC (2000); Skipper et al. (2010); Son et al. (1980).

Toxicity studies of various aromatic amines in rats, mice, guinea pigs, rabbits, dogs, and monkeys show significant species differences in sensitivity to the carcinogenic effects of these chemicals (Freudenthal et al. 1999). The differences in species responses were related to differences in metabolism, particularly the ability of each species to N-acetylate aromatic amines, which is considered to be a detoxification step for urinary bladder cancer but an activating step for liver cancer. The mechanistic implications of these species differences in metabolism are discussed in Sections 5.2.1 and 5.2.2.

### 2.2.2 Humans

No studies of ortho-toluidine metabolism in humans were identified; however, metabolic pathways are expected to be similar to those reported in experimental animals based on studies of other aromatic amines and knowledge of the key metabolizing enzymes.

Ward et al. (1996) monitored aromatic amine exposure in workers at a chemical plant and reported that base hydrolysis was used to convert N-acetyl-ortho-toluidine to the parent compound prior to analysis, thus, indicating that N-acetylation of ortho-toluidine occurred in humans. Lewalter and Korallus (1985) noted that acetylation is a common metabolic pathway for aromatic amines but that only free, nonacetylated aromatic amines could lead to formation of hemoglobin (protein) adducts. Based on data for other aromatic amines, an oxidized metabolite (nitroso form) can come in contact and bind to hemoglobin in the blood (Skipper et al. 2010; Skipper and Tannenbaum 1994). Several studies have detected ortho-toluidine hemoglobin adducts in humans (Bryant et al. 1988; Korinth et al. 2007; Richter and Branner 2002; Richter et al. 2001; Seyler et al. 2010; Ward et al. 1996). The presence of hemoglobin adducts can be used as a biomarker of aromatic amine bioactivation to their ultimate carcinogenic form (Richter and Branner 2002; Skipper and Tannenbaum 1994). Methemoglobin is one of the principal acute effects observed in humans exposed to ortho-toluidine (English et al. 2012). The probable metabolic pathway leading to methemoglobinemia is metabolism of ortho-toluidine by hepatic cytochrome P450 enzymes to N-hydroxy-ortho-toluidine. Further oxidation of the N-hydroxy metabolite to nitrosotoluene occurs in the blood, thus generating methemoglobin.

ortho-Toluidine also is a metabolite of the commonly used local anesthetic prilocaine (Gaber et al. 2007). Gaber et al. (2007) also reported that ortho-toluidine-releasing hemoglobin adducts were increased up to 360-fold above background after prilocaine treatment. Prilocaine also is a well-known methemoglobin inducer (Gaber et al. 2007; Hjelm 1965; Lindenblatt et al. 2004). The amide bond in prilocaine is hydrolytically metabolized by human carboxylesterases (CES1A or CES2) in vitro to release ortho-toluidine (Higuchi et al. 2013).

### 2.2.3 Metabolic Enzymes

Cytochromes P450 (possibly CYP1A2 and CYP1A1) are responsible for N-hydroxylation of aromatic amines (Delclos and Kadlubar 1997; Windmill et al. 1997). Mammalian peroxidases also can catalyze oxidative metabolism of aromatic amines (Delclos and Kadlubar 1997; English et al. 2012). o-Toluidine increased cytochrome P450 content as well as the enzymatic activities, ethoxyresorufin-O-deethylase and ethoxycoumarin-O-deethylase, associated with CYP1A1, CYP1A2, and CYP2E1 (Leslie et al. 1988). In humans, CYP1A2 is expressed constitutively in the liver but not in other tissues, while CYP1A1 is predominantly expressed in extrahepatic tissues. Some studies in rats and humans suggest that CYP1A2 does not play a significant role in the metabolic activation of this compound (Gaber et al. 2007; IARC 2010e) but they were not definitive. Some data suggest that the ring-hydroxylation of ortho-toluidine is catalyzed by CYP2E1 (Díaz Gómez et al. 2006).

Jodynis-Liebert and Matuszewska (1999) studied the effects of toluidines and dinitrotoluenes on caffeine metabolism in rats and showed that ortho-, meta-, and para-toluidine induced CYP1A2 in the liver. CYP1A2-catalyzed N-hydroxylation is known to lead to bioactivation of many carcinogenic aromatic amines. Other studies have shown that recombinant human cytochromes P450 (CYP2A6, CYP2E1, CYP1A1, CYP2B6, CYP2D6, or CYP3A4) can metabolize the aromatic amines 2,6-dimethylaniline and ortho-anisidine and might play a role in their bioactivation (Gan et al. 2001; Stiborová et al. 2005). Most of these P450s are expressed in the liver; however, CYP1A1 primarily is expressed in extrahepatic tissues, while 2E1, 2B6, 3A4, and 2D6 also have extensive extrahepatic activity. CYP1A1, 2D6 and 2E1 mRNA expression has been reported in human urinary bladder tissue and 1A1 also is expressed in human urinary bladder malignancies (Brauers et al. 2000).

In addition to P450-mediated N-hydroxylation, mammalian peroxidases (e.g., prostaglandin H synthase or myeloperoxidase) can metabolize ring-hydroxylated metabolites of aromatic amines to reactive quinone imines (Skipper et al. 2010). Phase II metabolic steps include N-acetylation, O-acetylation, N,O-transacetylation, O-sulfation, and glucuronidation (Woo and Lai 2004). Cytosolic arylamine N-acetyltransferases (NATs) catalyze N-acetylation, O-acetylation, and N,O-transacetylation reactions. Two mammalian cytosolic NATs have been identified in a variety of species, while three have been identified in mice (Delclos and Kadlubar 1997). Both of the NAT isozymes (NAT1 and NAT2) in humans are polymorphic and have different substrate specificities. NAT1 is expressed in most human tissues while NAT2 is predominantly expressed in liver, small intestine, and colon (Hein 2009). O-Sulfation reactions are catalyzed by cytosolic sulfotransferases (SULTs) (Windmill et al. 1997) and glucuronidation is catalyzed by UDP-glucuronosyltransferases in the endoplasmic reticulum (Woo and Lai 2004).

## 2.3 Synthesis

ortho-Toluidine can be absorbed after exposure in the air, on the skin, or through the gastrointestinal tract. Its distribution and excretion have been studied primarily in rodents where ortho-toluidine was detectable in blood, spleen, liver, kidneys, urinary bladder, and other tissues; excretion was mainly in the urine for all exposure routes with much smaller amounts eliminated through the lungs and in the feces.

ortho-Toluidine metabolism has only been investigated in male rats, thus, specific information on species and/or sex differences were not available. However, metabolism and toxicity data for various aromatic amines indicate that metabolic differences are important for species differences in toxicity. Cytochromes P450-mediated oxidation and acetylation, and glucuronide/sulfate conjugation reactions are the primary metabolic steps in all mammalian species studied. N-Hydroxylation has been identified as a key bioactivation step. The majority of the administered dose of ortho-toluidine is excreted as metabolites. More than half of a subcutaneous dose in rats was recovered in the urine as sulfate or glucuronide conjugates with smaller amounts of the parent molecule or acetylated metabolites.

Studies in the rat indicate that nitrosotoluene is formed from N-hydroxy-ortho-toluidine (Figure 2-2). Further metabolism of this molecule may lead to formation of reactive metabolites such as nitrenium ions, nitrene, and free radicals. Although no specific metabolism studies were available, there is indirect evidence based on formation of hemoglobin adducts and methemoglobin that nitrosotoluene is a metabolite of ortho-toluidine in humans. N-hydroxy-ortho-toluidine would be a likely intermediate in the formation of nitrosotoluene.