# 1 Properties and Human Exposure

ortho-Toluidine is a high-production-volume chemical (a classification based on imports exceeding 1 million pounds/year) used in the manufacture of rubber chemicals, of herbicide intermediates, of dye intermediates, and of the local anesthetic prilocaine. This section describes the chemical and physical properties of ortho-toluidine (Section 1.1); its uses and production (Section 1.2); exposure to ortho-toluidine and biomarkers for exposure (Section 1.3); exposure in the workplace (Section 1.4); potential exposure from other sources such as cigarette smoking, medical and consumer products, and food (Section 1.5); and potential for environmental exposure (Section 1.6). Section 1.7 synthesizes and summarizes the information in Sections 1.1 to 1.6. U.S. regulations and guidelines that potentially limit exposure to ortho-toluidine are in Appendix B. (Note: Links provided in the text connect directly to each table as it is discussed, and a link is provided at the end of each table to return to the text citing the table.)

## 1.1 Chemical Identification and Properties

ortho-Toluidine (Figure 1-1) is a synthetic chemical that exists at room temperature as a light-yellow liquid that darkens rapidly on exposure to air and light. It is described as having an aromatic odor (IPCS 1998). ortho-Toluidine may be classified as a monocyclic aromatic amine, arylamine, or alkylaniline (IARC 2010e; Skipper et al. 2010; Yu et al. 2002). It is soluble in water and dilute acids; and miscible with ethanol, diethyl ether, and carbon tetrachloride (NLM 2011). Toxicological studies of ortho-toluidine using its hydrochloride salt (ortho-toluidine hydrochloride) are considered relevant for the cancer evaluation of ortho-toluidine because the use of the salt is unlikely to alter the observed health effects of the parent chemical (IPCS 1998). In addition, the reaction of ortho-toluidine with stomach acid will yield the hydrochloride salt as the test article (English et al. 2012). ortho-Toluidine hydrochloride is the solid salt form of ortho-toluidine that exists at room temperature as a green or white crystalline solid that is slightly soluble in water (University of Akron 2012a). Table 1-1 contains some chemical identification information for ortho-toluidine and ortho-toluidine hydrochloride.

Figure 1-1

Chemical Structure of ortho-Toluidine

Table 1-1 Chemical Identification of ortho-Toluidine and ortho-Toluidine Hydrochloride

Characteristic | Information (ortho-Toluidine) | Information (ortho-Toluidine Hydrochloride)
Chemical Abstracts index name | ortho-toluidine | ortho-toluidine hydrochloride
CAS Registry number | 95-53-4 | 636-21-5
Molecular formula | C_7_H_9_N | C_7_H_9_N•HCl
Synonyms | 1-amino-2-methylbenzene, 2-aminotoluene, o-methylaniline | 2-toluidine hydrochloride, o-aminotoluene hydrochloride, methylaniline

Sources: IPCS (1998); NTP (1996).

Some physical and chemical properties for ortho-toluidine and ortho-toluidine hydrochloride are listed in Table 1-2.

Table 1-2 Physical and Chemical Properties of ortho-Toluidine and ortho-Toluidine Hydrochloride

Property | Information (ortho-Toluidine) | Information (ortho-Toluidine Hydrochloride)
Molecular weight | 107.2^a^ | 143.6^c^
Melting point | < −15°C^a^ | 215°C^d^
Boiling point | 198°C–201°C^a^ | 242.2°C^d^
Vapor pressure (mm Hg) | 0.33 at 25°C^a^ | 0.293 at 25°C^e^
Equilibrium concentration (ppm) | 434^h^ | 385^h^
Vapor density (air = 1) | 3.69^a^ | –
Density | 0.998 g/cm^3^ at 20°C^a^ | 1.288 g/cm^3^ at 20°C^f^
Solubility water (25°C) most organic solvents | 16.6 g/L^e^ | 8.29 g/L^e^
Octanol/water partition coefficient (log K_ow_) | 1.32^b^ | 1.62^e^
Critical temperature | 717°K^b^ | –
Henry’s law constant | 1.98 × 10^-6^ atm-m^3^/mol at 25°C^b^ | 2.10 × 10^-6^ atm-m^3^/mol at 25°C^e^
Conversion factors (ortho-toluidine, ortho-toluidine hydrochloride in air) parts per million (ppm) to µg/m^3^ µg/m^3^ to parts per million (ppm) | µg/m^3^ = 4,384.5 × (ppm)^g^ ppm = 2.281 × 10^-4^ × (µg/m^3^)^g^ | µg/m^3^ = 5,873.2 × (ppm)^g^ ppm = 1.703 × 10^-4^ × (µg/m^3^)^g^

^a^ University of Akron (2012b).

^b^ NLM (2011).

^c^ NTP (1996).

^d^ NLM (2005).

^e^ NLM (2012a).

^f^ University of Akron (2012a).

^g^ Smarte.org (2008).

^h^ Equilibrium concentration = (vapor pressure (mm Hg) × 1,000,000)/760.

## 1.2 Uses and Production

Although o-toluidine is no longer produced in the United States, it is still considered to be a high-production-volume chemical based on its importation into the United States in quantities of 1 million pounds or more per year (see table below). In the past it was produced in the United States in large amounts; in the early 1970s, production exceeded 454,000 kg (1 million pounds) (NLM 2005). In 2011, o-toluidine was reported to be manufactured by at least 15 companies worldwide, including at least 3 in the United States (SRI Consulting 2012); however, in 2014, no U.S. producers of ortho-toluidine were identified. Reported recent and historical volumes of U.S. production, imports, and exports of o-toluidine are listed in the Table 1-3.

Table 1-3 Production Data for ortho-Toluidine

Category | Years Covered | Quantity in Pounds^a^
Chemical Data Reporting Rule^b^ | 2012 | 60.0 million
U.S. imports (recent) | 2013 | [52.7 million] (reported as 26.3 million kg)
U.S. imports (historical) | 1989 | [10.1 million] (reported as 4.6 million kg)
U.S. exports (recent) | 2013 | [3.1 million] (reported as 1.4 million kg)
U.S. exports (historical) | 1989 | [5.1 million] (reported as 2.3 million kg)

Sources: USEPA (2012a), SRI Consulting (2012), USITC (2012).

^a^ From 1/2012, 3/2012, 7/2012 Internet searches; data subject to change.

^b^ Formerly called the Inventory Update Rule.

ortho-Toluidine (either directly or as an intermediate) is currently used to make dyes, rubber chemicals, herbicides, and prilocaine; however, the major uses of ortho-toluidine in the United States have changed over time (see Figure 1-2). Major uses of ortho-toluidine in the past, i.e., in the early to mid-20th century, that have not continued to the present or have greatly diminished in the United States are uses in manufacture of large quantities of dyes (1910s to 1980s) and in manufacture of 4-chloro-ortho-toluidine (4-COT, an intermediate in the production of the acaricide, chlordimeform, and additionally as a dye intermediate) (1930s to 1970s) (Baptista 2012; IARC 2010c; Morris and Travis 1992). The dye industry in the United States began to decline in the 1970s when the 1974 oil crisis greatly increased costs of raw materials, and by 1977 to 1982 four of the largest dye makers had exited the business (Baptista 2012; Morris and Travis 1992). Production of ortho-toluidine-based dye and pigment intermediates is still reported by several companies in the United States, however.

Figure 1-2

Timeline for Continuing (Current) and Past Uses of ortho-Toluidine in the United States

Information obtained from the U.S. Environmental Protection Agency’s (EPA) Toxics Release Inventory (TRI) and Chemical Data Reporting (CDR) Rule indicates that ortho-toluidine continues to be used in the rubber chemicals, herbicide intermediates, and dye intermediates sectors as of 2010 (USEPA 2012b). Based on TRI data, two of the top five ortho-toluidine air emitters (see Section 1.6.1) reported production of rubber chemicals, and two other companies included herbicide intermediates among their products; the remaining company in the top five emitters reported production of toluidines. Inspection of data on ortho-toluidine manufacture or importation reported to EPA under the CDR Rule (formerly the Inventory Update Rule or IUR) identified one additional company that produced rubber chemicals and another that produced herbicide intermediates.

The largest current use of ortho-toluidine has been reported to be in production of 6-ethyl-ortho-toluidine as a herbicide intermediate, which is used to manufacture the widely used herbicides metolachlor and acetochlor (Bowers 2011). The potential for exposure to ortho-toluidine as part of this production would exist only during production of 6-ethyl-ortho-toluidine as the intermediate; that production is indicated in Figure 1-2 as “herbicide precursors.” Metolachlor was produced in the United States for more than 20 years from the late 1970s to the late 1990s (Bernard 2012), but no information on the source of the 6-ethyl-ortho-toluidine used during that period was identified. No export information on 6-ethyl-ortho-toluidine was identified. All current production of metolachlor has been reported to occur outside the United States (Bernard 2012), but no specific information on U.S. production of acetochlor was identified. No herbicides other than metolachlor and acetochlor whose intermediates are prepared from ortho-toluidine were identified.

Another important use for ortho-toluidine is as an intermediate for synthesis of rubber chemicals (e.g., the accelerant di-ortho-tolyl-guanidine or the antioxidant di-tolyl-phenyl-para-phenylenediamine) and pharmaceuticals (e.g., prilocaine) (Hanley et al. 2012; IARC 2012; UNEP 2004). No uses of ortho-toluidine in the rubber chemicals manufacturing industry other than as intermediates to synthesize accelerants and antioxidants were identified. The largest release of ortho-toluidine to the air (68% of the total) reported to TRI in 2010 was by a company in the rubber industry (USEPA 2012b).

ortho-Toluidine can also be used in the manufacture of more than 90 dyes and pigments (e.g., acid-fast dyestuffs, azo pigment dyes, triarylmethane dyes, sulfur dyes, and indigo compounds) with acetoacet-ortho-toluidine, 3-hydroxy-2-naphthoyl-ortho-toluidine, 2-toluidine-5-sulfonic acid, and ortho-aminoazotoluene as four major intermediates (Bowers 2011). A search for producers of these intermediates identified three companies that reported use or storage of ortho-toluidine on site and included 2-toluidine-5-sulfonic acid or acetoacet-ortho-toluidine among their products (USEPA 2013a; 2013b). In the clinical laboratory, ortho-toluidine is also used as an ingredient in a reagent for glucose analysis, and for tissue staining (IARC 2012).

## 1.3 Exposure to ortho-Toluidine

Evidence for exposure to ortho-toluidine comes from biological monitoring data demonstrating worldwide exposure to ortho-toluidine in both occupationally and non-occupationally exposed individuals and in both smokers and non-smokers. Methods for biological indices for exposure to ortho-toluidine include measurement of ortho-toluidine and its N-acetyl-metabolites in urine and ortho-toluidine hemoglobin adducts in blood (Brown et al. 1995; Ward et al. 1996). Urinary levels provide an assessment of recent exposure, whereas assessment of hemoglobin adducts likely reflects cumulative dose to ortho-toluidine because of the 120-day half-life of human red blood cells. Table 1-4 reports studies measuring urine and hemoglobin adducts among occupationally and non-occupationally exposed people in the United States and other countries. (No analyses of ortho-toluidine in blood, serum, or urine specimens from the National Health and Nutrition Examination Survey (NHANES) have been identified.) The highest exposures were found for people exposed in the workplace (see Section 1.4), although low levels were reported among workers at a German chemical factory. In addition to the studies in Table 1-4, other studies detected ortho-toluidine in breast milk (DeBruin et al. (1999), as cited in IARC (2012)) and it was release from urinary bladder tissue or tumors after acid hydroloysis (Böhm et al. 2011). Potential for exposure from non-occupational sources includes cigarette smoking, medical and consumer products, food (see Section 1.5), and the environment (see Section 1.6).

Table 1-4 ortho-Toluidine in Urine and Hb Adducts in Different Populations

Population | Urine or Hb Adduct Levels (#): Mean (Range) Smokers | Urine or Hb Adduct Levels (#): Mean (Range) Non-smokers | Reference
o-Toluidine: Urine (μg/24 hr unless otherwise specified)
Volunteers, U.S.A. | 6.3 ± 3.7 (16) | 4.1 ± 3.2 (12) | el-Bayoumy et al. (1986)
Volunteers, Germany | 0.204 ± 0.059 (10) | 0.105 ± 0.026 (9) | Riedel et al. (2006)
Volunteers, Germany | 0.13 (0.03–173) (145) | 0.1 (0.03–34.25) (856) | Kütting et al. (2009)
Volunteers, Europe | 0.179 ± 0.491 (1159) | 0.064 ± 0.128 (399) | Lindner et al. (2011)
Chemical factory, Germany | 0.6 ± 1.0 μg/L (22) | 0.4 ± 1.1 μg/L (21) | Riffelmann et al. (1995)
Rubber factory, Germany | 14.5 μg/L (mean) (36) | 38.6 μg/L (mean) (15) | Korinth et al. (2007) ^a^
NIOSH rubber chemical cohort, U.S.A.^b^ | Exposed (post-shift) 132 ± 153 μg/L (15) Nonexposed (post-shift) 2.8 ± 1.2 µg/L (9) | Exposed (post-shift) 80 ± 94 μg/L (27) Nonexposed (post-shift) 2.8 ± 1.6 µg/L (16) | Ward et al. (1996) (see also Brown et al. (1995), Stettler et al. (1992))
Rubber chemical workers, U.S.A. | Exposed (post-shift)^c^ 104 ± 111 μg/L (46) Unexposed (post-shift)^c^ 2.7 ± 1.4 µg/L (31) | | Teass et al. (1993)
o-Toluidine: Hb adducts^d^ (pg/g Hb)
Volunteers, U.S.A. | 100 ± 30 (12) | 34 ± 10 (10) | Stillwell et al. (1987)
Volunteers, Italy | 290–329 (means) (61) | 188 (mean) (19) | Bryant et al. (1988)
Pregnant women, Germany | 289 ± 25 pg/g Hb (27) | 237 ± 65 (73) | Branner et al. (1998)
Children, Germany | – | 487–632 (220) | Richter et al. (2001)
Patients, 24 hr post prilocaine administration, Germany | 21,350 ± 15,000 (8) | 22,330 ± 12,080 (17) | Gaber et al. (2007)
Rubber factory, Germany | 1,900^d^ (mean) (36) | 2,900^d^ (mean) (15) | Korinth et al. (2007) ^a^
NIOSH rubber chemical cohort, U.S.A.^b^ | Exposed (post-shift)^e^: 40,830 ± 32,518 (46) Nonexposed (post-shift)^e^: 3,515 ± 6,036 (27)] | | Ward et al. (1996) (see also Stettler et al. (1992))
Workers in a TNT factory, China | Exposed^f^: 675 Control^f^: 386 | | Jones et al. (2005)

^a^ Air levels of ortho-toluidine higher among nonsmoking group, according to authors.

^b^ See also Section 3.

^c^ Smoking status not reported.

^d^ Reported as 287 ng/L and 432 ng/L. Conversion factor for normal hemoglobin levels in blood: 15 g Hb/dL (12–16 g Hb/dL [for females], 14–18 g Hb/dL [for males]) (CDC 2010).

^e^ Smokers and nonsmokers had similar values; combined group reported in table.

^f^ Median values estimated from graph and converted from pmol adduct/g Hb (1 pmol o-toluidine = 107.2 pg). Smoking status not reported.

## 1.4 Characterization of Exposure in the Workplace

ortho-Toluidine is synthesized from toluene by a two-step process (Bowers 2011; IARC 2010e) (see Figure 1-3 and Appendix C). Mononitration of toluene produces three isomers (ortho-, meta-, and para-) of nitrotoluene, which can be separated by distillation prior to reduction of the nitro- group to an amine. Reduction of ortho-nitrotoluene to ortho-toluidine can be accomplished by several methods, but the most common method currently is a continuous vapor-phase hydrogenation process with a catalyst such as Raney nickel, copper, molybdenum, tungsten, vanadium, noble metals, or various supported metals.

Figure 1-3

Chemical Synthesis of ortho-Toluidine from Toluene

Occupational exposure to ortho-toluidine can occur by inhalation or skin contact (IARC 2010e) during its production, or during its use in production of chemical intermediates for pesticides, of rubber chemicals, or of intermediates for dyes and pigments. As small amounts of ortho-toluidine are also used in laboratory work, medical and laboratory personnel are exposed to low air concentrations of ortho-toluidine (USEPA (1984), Kauppinen et al. (2003), as cited in IARC (2012)).

Evidence that ortho-toluidine is absorbed following occupational exposure via inhalation or skin contact comes from studies measuring ortho-toluidine in urine or as hemoglobin adducts in rubber industry workers and other industries which use ortho-toluidine (Brown et al. 1995; Jones et al. 2005; Korinth et al. 2007; Stettler et al. 1992) (see Section 2.1.2). Note that the OSHA PEL for ortho-toluidine is 5 ppm and the ACGIH TLV-TWA is 2 ppm, and both occupational exposure limits include a skin notation, which indicates potential significant contribution to overall exposure via the cutaneous route, including mucous membranes and eyes, by contact with vapors, liquids, and solids. Consideration of the decrease in ortho-toluidine air levels relative to the ACGIH TLV-TWA of 2 ppm (with skin notation) highlights the importance of dermal exposure in occupational settings.

Limited information is available on exposure to ortho-toluidine in the various industries where ortho-toluidine is used or produced. Most of the exposure information found is from the human cancer studies, and details on the exposure conditions of those individual studies is presented in Appendix C, which is provided as background information to interpret the epidemiological studies. Exposure levels across industries are presented in Table 1-5 and biomonitoring data were presented in Table 1-4. No information was found on levels of exposure to ortho-toluidine during production of the pesticide intermediates (such as 6-ethyl-ortho-toluidine or 4-chloro-ortho-toluidine). The highest levels of exposures (air) were reported from a study of workers at a chemical plant in the former Soviet Union where ortho-toluidine was produced via reduction of ortho-nitrotoluene. Concentrations of ortho-toluidine in the air were two- to sevenfold higher than the maximum permissible concentration for the USSR of 3 mg/m^3^ [0.7 ppm] (Khlebnikova et al. (1970), as cited in IARC (2012)). Dermal exposures also were reported (IARC 2012). Most of the air-monitoring data in the United States suggest that occupational exposure levels to ortho-toluidine are usually <1 ppm (e.g., up to 0.5 ppm in the dye and pigment industry) but may have been higher in the past.

Table 1-5 Exposure to ortho-Toluidine in Various Industries

Industry (Year) | TWA (Range), ppm^a^ | Number of Samples | Reference
ortho-Toluidine production - distillation and extraction processes | [5.7–6.5]^b^ | – | Khlebnikova et al. (1970) ^c^
Rubber chemical industry | [0.1]^d^ | 7 | Ward et al. (1996)
Dye and pigment industry - thioindigo production worker (1940) | <0.5 | – | Ott and Langner (1983)
OSHA sampling data (1985–6, 1988, 1997, 2001)^e^ | 0.06–0.11 | 26^f^ | OSHA (2011)

^a^ Values shown in brackets converted to ppm using conversion factor in Table 1-2.

^b^ Reported as 25–28.6 mg/m^3^.

^c^ As cited in IARC (2012).

^d^ Reported as 516 µg/m^3^.

^e^ OSHA Chemical Exposure Health Dataset.

^f^ Only 6 samples from 1 facility in the rubber industry had detectable levels.

The most detailed exposure information was found for the rubber chemical industry. Air monitoring data were available from both a NIOSH assessment of a rubber chemical manufacturing plant carried out in 1990 (Figure 1-4) and company data from three intervals covering the period from 1976 to 2004 (Figure 1-5) (Hanley et al. 2012). NIOSH TWA breathing zone air sampling data or company-collected data for the rubber chemicals department (i.e., antioxidant, accelerant, and recycle process, and maintenance workers) indicate that the geometric mean breathing zone concentrations for ortho-toluidine for antioxidant production workers and maintenance personnel were similar and approximately twice those for accelerant production. Exposure levels among rubber chemical workers have decreased over time from a high of 0.1 ppm (time period from 1976 to 1979) to <0.02 ppm (time period from 1995 to 2004). Data reported for the same operations, e.g., “Maintenance,” are higher for the results from the NIOSH survey compared with the company-reported data, but the time periods covered differ, and the NIOSH data were based on fewer samples for each process.

Figure 1-4

Air Monitoring Data (TWA Breathing Zone, Geometric Means) for ortho-Toluidine Collected by NIOSH in 1990 for Processes in the Rubber Chemicals Department

Figure 1-5

Air Monitoring Data (TWA Breathing Zone, Geometric Means) Collected by the Company by Department and Time Period

The continued use of ortho-toluidine in the rubber chemicals industry and for production of the herbicide intermediate and dye intermediates indicate that workers in the United States are currently exposed, although no current information is available on the number of workers in each industry. Data from the NIOSH National Occupational Exposure Survey (NOES), conducted between 1981 and 1983, estimated that about 30,000 workers, including approximately 15,500 women, were potentially exposed to ortho-toluidine during that time period (NIOSH 1990). (Note: The NOES database has not been updated since July 1, 1990, and NIOSH has not conducted any national surveys of occupational exposure since that time.)

NIOSH recommends that worker exposure to ortho-toluidine be minimized through the use of engineering controls, work practices, and personal protective equipment (NIOSH 1991).

## 1.5 Potential for Exposure from Other Sources: Cigarette Smoking, Medical and Consumer Products, and Food

ortho-Toluidine (and other arylamines) have been detected in the urine of non-occupationally exposed individuals in several studies (see Table 1-4); the sources proposed for the exposure underlying these levels include combustion products, passive smoking, dyestuffs in cosmetics and clothing (Riffelmann et al. 1995), and food (el-Bayoumy et al. 1986), but no data were identified to document contributions by any of these potential sources. ortho-Toluidine was released by acid hydrolysis from 11 of 12 urinary bladder tumor samples (8.72 ± 4.49 fmol/μg DNA) as well as from 13 of 46 urinary bladder epithelial tissue samples (0.24 ± 0.63) and from 10 of 46 urinary bladder submucosal tissue samples (0.27 ± 0.70) obtained from sudden death victims in Germany (Böhm et al. 2011) (see the footnote in Section 5.1.4 for further discussion of test methods used by Böhm et al. (2011)). The authors reported that the subjects had no known occupational exposure to aromatic amines and that smoking status had no significant effect on the adduct levels detected. ortho-Toluidine adducts to hemoglobin (Hb) were already detected in 25 patients before treatment with prilocaine as a local anesthetic (see below) (Gaber et al. 2007; IARC 2012). Several lines of evidence suggest that exposure to ortho-toluidine occurs for non-occupationally exposed individuals from sources such as cigarette smoking, medical products (e.g., the local anesthetic prilocaine), some consumer products (e.g., hair dyes), and possibly food.

ortho-Toluidine has been measured in mainstream cigarette smoke at 9 to 144 ng per cigarette (Stabbert et al. (2003), as cited in IARC (2012)). ortho-Toluidine concentrations in second-hand smoke have been reported to be approximately 20 times more than in first-hand smoke (Patrianakos and Hoffmann 1979). ortho-Toluidine urinary concentrations and hemoglobin adducts have generally been reported to be somewhat higher in non-occupationally exposed smokers than in non-smokers (el-Bayoumy et al. 1986; Riedel et al. 2006; Riffelmann et al. 1995), although in many studies the influence of smoking was weak (Kütting et al. 2009) (see Table 1-4). Among workers exposed to ortho-toluidine, there was little difference between exposure levels (urinary concentration or hemoglobin adducts) among workers that smoked compared with non-smoking workers (Korinth et al. 2007; Riffelmann et al. 1995; Ward et al. 1996).

Exposure to ortho-toluidine from medical products can occur from a product used for anesthesia. Prilocaine, a widely used local or topical anesthetic is required by U.S. Pharmacopeia standards to contain no more than 0.01% ortho-toluidine, but once in the body, prilocaine can be metabolized to release ortho-toluidine. Humans exposed to prilocaine excreted 0.75% of the dose as ortho-toluidine and 36.9% as hydroxylated ortho-toluidine (NTP 2000). The average amount of ortho-toluidine adducts to hemoglobin (Hb) increased 41-fold, from 0.54 ± 0.95 ng/g Hb before treatment to 22 ± 13.2 ng/g Hb at 24 hours after surgery in 25 patients who received prilocaine for local anesthesia (Gaber et al. 2007; IARC 2012). Information on sales of dental local anesthetics in the United States in the 11-year period from 1997 to 2008 indicate average sales of approximately 18 million cartridges of prilocaine per year (Garisto et al. 2010), and recommended doses range from 1 to 8 72-mg cartridges per dental procedure (DrugsArea.com 2007). No specific information on the number of people exposed to prilocaine annually in the United States was identified, but based on the sales figures, a relatively small percentage of the population could be treated with prilocaine (assuming one cartridge per person, no more than 6% of the population could be exposed). Based on the current U.S. population of 314 million, potential exposure to this source of ortho-toluidine could still affect an estimated 18,000,000 people. The actual percentage of people could be lower, depending on the use of multiple doses for individual dental patients, but that would result in increased exposure levels for those patients. Prilocaine is also present with lidocaine in a topical local anesthetic cream used to numb the skin for needle insertion or minor surgical procedures; although these products for both prescription and over-the-counter sales are widely advertised on the Internet, no sales or use data for this preparation were found.

Exposure to ortho-toluidine can potentially result from exposure to dyes in consumer products, including some hair dyes, other dyes, and tattoos. Akyüz and Ata (2008, as cited in IARC 2012) reported finding ortho-toluidine in 34 of 54 hair dyes tested in Turkey, at levels up to 1,547 μg/g. Hair dyes in Turkey were identified as available for sale on the Internet, but no information on the ortho-toluidine content of the dyes was identified (Alibaba.com 2013; Allbiz 2013). ortho-Toluidine was found in the fixative of a commercial hair-waving product at ng/g levels from a study in Sweden (Johansson et al. 2015). In the same study, hemoglobin adducts were reported to increase significantly with increasing numbers of hair waving treatments performed per week among non-smoking hairdressers, and a trend toward increasing concentrations with increased use of light-color permanent hair dye treatments was also found.

Currently, 11 ortho-toluidine-based dyes are listed in the Colour Index as having commercial products, ranging from 2 to 193 depending on the dye (Freeman 2012). Most of the manufacturing involving these dyes occurs outside the United States and Europe, mainly in China and India. Many current commercial organic pigments, including Pigment Red 95, Pigment Red 148, and Pigment Red 253, are derived from ortho-toluidine. Pigment Red 95, Pigment Red 148, and Pigment Red 253 require the product from the reaction of ortho-toluidine with beta-oxynaphthoic acid for their production. The ortho-toluidine-based colorant Pigment Yellow 14 (193 commercial product listings in the Colour Index) requires production of the ortho-toluidine-based precursor acetoacet-ortho-toluitide. No information on specific use of these dyes in the United States was identified, but they are available from a number of suppliers, primarily in China and India, and no U.S. import restrictions were found.

Recent information from the European Union (EC 2013a; 2013b) identified two tattoo inks containing 89 mg/kg and 120 mg/kg of ortho-toluidine. Since most tattoo inks are purchased abroad via the Internet or during tattoo conventions (Shubhangi et al. 2013), the inks represent a potential source of exposure to ortho-toluidine for the 21% of the U.S. population who reported having at least one tattoo in a 2012 poll (Harris Interactive 2012).

In a German survey of primary and secondary amines in the human environment, a number of foods were examined; <0.1 ppm of ortho-toluidine was detected in a sample of broken beans; however, it was not found in 9 other samples of preserved vegetables, or in more than 16 other foods tested (Neurath et al. (1977), as cited in HSDB (2011)). Also, aminotoluene (toluidine), isomer unspecified, was found in shelled peas at a concentration of 0.4 ppm, in red cabbage at a concentration of 0.2 ppm, in kale at a concentration of 1.1 ppm, in carrots at a concentration of 7.2 ppm, and in celery at a concentration of 1.1 ppm (NLM 2011). As cited in IARC (2012), Vitzthum et al. (1975) reported that ortho-toluidine has been detected as a volatile in black tea (IARC 2012). No information for ortho-toluidine was identified in the U.S. Food and Drug Administration’s Total Diet Study (TDS) for market baskets 1991–3 through 2003–4 collected between September 1991 and October 2003 (FDA 2006).

In summary, although exposure levels from all of these sources are lower relative to occupational exposures, almost everyone would be affected by exposure through food. In contrast, about 19% of U.S. adults smoked in 2010 (CDC 2012), and estimates for use of hair dye “indicate that more than one-third of women over age 18 and approximately 10% of men over age 40 use some type of hair dye” (Huncharek and Kupelnick 2005). Based on 2010 U.S. census data (Howden and Meyer 2011), approximately 43 million individuals or a little <15% of the U.S. population would be exposed to hair dyes of all types. As noted above, exposure to ortho-toluidine from the use of prilocaine as a dental anesthetic is estimated to occur to 6 percent or less of the U.S. population (estimated 18,000,000 people).

## 1.6 Potential for Environmental Exposure

People in the United States are potentially exposed to ortho-toluidine from the environment via releases into the atmosphere, as documented by TRI data (see Section 1.6.1), and data regarding people living close to emitting facilities (see Table 1-6). Occurrence data support these conclusions (see Section 1.6.2). In addition, ortho-toluidine hemoglobin adducts were found to be higher among children residing in cities compared with children residing in a largely rural environment in Germany suggesting the potential for environmental exposure because it is unlikely that food or personal products use differs in the three geographical areas. ortho-Toluidine hemoglobin adducts were lower in children from smoking homes compared with non-smoking homes.

Table 1-6 Demographic Data for Areas within 0.5 Miles and 1 Mile of the Top 5 ortho-Toluidine-emitting Facilities in 2010

City | State | ortho-Toluidine Air Emissions (Pounds) | Total Persons within 0.5 Miles | Total Persons within 1 Mile
Niagara Falls^a^ | NY | 3,491 | 763 | 4,428
Pasadena | TX | 673 | 0 | 0
Geismar | LA | 609 | 0 | 6
Pascagoula | MS | 139 | 0 | 13
Kingsport | TN | 111 | 137 | 2,942
Total | | 5,023 | 900 | 7,389

Sources: USEPA (2012a; 2012b).

^a^ This plant is the same one assessed by Hanley et al. (2012) for exposure to ortho-toluidine and aniline.

### 1.6.1 Release of ortho-Toluidine to the Environment

ortho-Toluidine’s production and use in the production of textile dyes or rubber vulcanization accelerators and antioxidants, and as an intermediate in organic synthesis results in its release to the environment through various waste streams (NLM 2011). According to the TRI, total reported on- and off-site release of ortho-toluidine was slightly over 6,600 pounds from 15 facilities in 2010 (USEPA 2012b). Releases to air accounted for 77.4% of total releases, disposal by underground injection for 19.6%, and releases to water for 3.0%. No releases were reported to either land or off-site disposal. Figure 1-6 shows a color-coded map of sites reporting on-site ortho-toluidine releases into the air, water, and ground to TRI in 2010 (NLM 2012b). The color of each circle indicates the amount of total on-site release for calendar year 2010. (See below for estimates of the numbers of individuals living near facilities reporting release of ortho-toluidine to the air.) Based on the visual depiction of ortho-toluidine releases in Figure 1-6, ortho-toluidine has been released at industrial facilities mostly in the northeast and southeast regions of the United States. The highest reported ortho-toluidine release is from a facility in Niagara Falls, NY, which is the site of the rubber chemical plant studied by NIOSH (see Section 1.4).

Figure 1-6

Map of Reported TRI On-site ortho-Toluidine Releases for 2010

The top 5 ortho-toluidine-emitting facilities released approximately 5,000 pounds of ortho-toluidine to the air, accounting for approximately 98% of total ortho-toluidine air emissions reported to TRI in 2010 (USEPA 2012b). Table 1-6 presents demographic data from EPA’s EJView website based on U.S. Census data for 2000 for areas within 0.5 miles and 1 mile of the top 10 ortho-toluidine-emitting facilities in 2010. Based on these data, approximately 1,400 people lived within 0.5 miles of these facilities, and 8,800 people within 1 mile of these facilities. These facilities are engaged in production of rubber chemicals, pesticide intermediates, dye intermediates, or ortho-toluidine. The numbers could be underestimates because census data are for residential populations and would not include workers who do not live within these boundaries. No data were identified for concentrations of ortho-toluidine in air near any of these sites.

Figure 1-7 shows a map of Superfund sites on the National Priorities List (NPL) where ortho-toluidine was listed as a site contaminant (NLM 2012b). Based on Figure 1-7, Superfund sites where ortho-toluidine was listed as a site contaminant also appear to be located primarily in the northeast and southeast United States.

Figure 1-7

Map of Superfund Sites at Which ortho-Toluidine Was Listed as a Site Contaminant

### 1.6.2 Fate and Occurrence

Environmental exposure to ortho-toluidine is possible based on its occurrence in water and sediment worldwide. However, no data for ortho-toluidine concentration levels in ambient air or soil have been identified. Table 1-7 presents concentration level data identified for ortho-toluidine in water and sediment. The highest levels occurred in sediment or water close to industrial areas.

Table 1-7 ortho-Toluidine Groundwater, Surface Water, and Sediment Concentration Levels

Location | Number of Samples/Frequency of Detection | Mean Conc. (Range), ppb | References^a^
Groundwater
Hoe Creek coal gasification project, Northeastern WY | 3 | – (0.06–9.2)^b^ | Stuermer et al. (1982)
Surface Water
Rhine River, Netherlands | 6% of samples | 0.03 (1.8 max) | Wegman and De Korte (1981)
Rhine River tributaries, Netherlands | 8% frequency of detection | – (0.07–0.2)^c^ | Wegman and De Korte (1981)
River Waal, Netherlands | Not reported | 0.7 (–) | Meijers and van der Leer (1976)
Japan, industrial areas between 1974 and 1976 | 8 out of 68 samples | 20 (–) | Kubota (1979)
Sediment
Japan, industrial areas between 1974 and 1976 | 27 out of 68 samples | 72 (–) | Kubota (1979)

– = no data available.

^a^ As cited in NLM (2011).

^b^ Combined concentration of 2- and 4-aminotoluene (ortho- and para-toluidine), sampled 15 months after completion of project.

^c^ Range of means.

## 1.7 Synthesis and Summary

Several lines of evidence indicate that a significant number of people living in the United States are exposed to ortho-toluidine. This evidence includes widespread use and imports of large amounts of ortho-toluidine (53 million pounds imported in 2013), and biological monitoring data demonstrating exposure in both occupationally and nonoccupationally exposed individuals and in both smokers and nonsmokers.

The highest exposure to ortho-toluidine occurs in the workplace; urinary exposure levels were over 26-fold higher among workers exposed to ortho-toluidine than among unexposed workers (Ward et al. 1996). Exposure via inhalation and dermal contact also can occur in the workplace through the production and use of ortho-toluidine in the chemical industry.

Exposure occurs through these occupational uses, but the presence of ortho-toluidine in urine and as hemoglobin adducts in individuals without known occupational exposure supports more widespread exposure. One source of this exposure is primary and second-hand tobacco smoking, but exposure from consumer products (e.g., hair dyes, tattoos, ortho-toluidine based dyes), dental products (e.g., prilocaine), and food is also possible. Although nonoccupational exposure levels are lower than occupational exposure levels, these exposures are common, indicating that more people living in the United States are potentially exposed to ortho-toluidine from these sources than occupationally. No direct evidence for exposure of the general population to ortho-toluidine from environmental sources was identified, but TRI data indicate that production- and use-related releases of ortho-toluidine have occurred at numerous industrial facilities in the United States, and a biological monitoring study in Europe reported that exposure levels in children varied with geographical residence (lower in a largely rural environment) suggesting the importance of environmental sources.