# Abbreviations

  ^1^H NMR: proton nuclear magnetic resonance
  4-AMP: 4-amino-3-methylphenol
  4-COT: 4-chloro-ortho-toluidine
  8-OH-dG: 8-hydroxydeoxyguanosine
  AAF: 2-acetylaminofluorene
  ACGIH: American Conference of Governmental Industrial Hygienists
  ADME: absorption, distribution, metabolism, and excretion
  ALL: acute lymphoblastic leukemia
  CA: chromosomal aberration
  CASRN: Chemical Abstracts Service registry number
  CDR: Chemical Data Reporting Rule
  CHO: Chinese hamster ovary
  CIN: chromosomal instability
  dA: deoxyadenosine
  DEN: diethylnitrosamine
  dG: deoxyguanosine
  DNA: deoxyribonucleic acid
  EG: ethylguanine
  EHOMO: energy of the highest occupied molecular orbital
  Endo III: endonuclease III
  EPA: Environmental Protection Agency
  FDA: Food and Drug Administration
  FU: follow-up
  G: guanine
  GC/MS: gas chromatography/mass spectroscopy
  GI: gastrointestinal
  GIS: Geographic Information System
  GM: geometric mean
  Hb: hemoglobin
  HDAC: histone deacetylase
  HEG: (2-hydroxyethyl) guanine
  HGPRT: hypoxanthine-guanine phosphoribosyl transferase
  HHE: Health Hazard Evaluation
  HIC: highest ineffective concentration
  HID: highest ineffective dose
  HPLC: high-performance liquid chromatography
  hr: hour
  HWE: healthy worker (hire or survival) effect
  I: inconclusive
  i.p.: intraperitoneal
  i.v.: intravenous
  IARC: International Agency for Research on Cancer
  ICD-9: International Classification of Diseases, Ninth Revision
  IDLH: immediately dangerous to life and health
  IUR: Inventory Update Rule
  JEM: job-exposure matrix
  kg: kilogram
  L: liter
  LEC: lowest effective concentration
  LED: lowest effective dose
  Log K_ow_: logarithm of octanol/water partition coefficient
  LOH: loss of heterozygosity
  m^3^: cubic meter
  MBT: 2-mercaptobenzothiazole
  MG: methylguanine
  mg: milligram
  mL: milliliter
  MN: micronucleus
  MS: mass spectrometry
  N.D.: not detected
  not determined
  NA: not applicable
  NAT1: N-acetyltransferase 1
  NAT2: N-acetyltransferase 2
  NCE: normochromatic erythrocyte
  NDMA: N-nitrosodimethylamine
  NHANES: National Health and Nutrition Examination Survey
  NIOSH: National Institute for Occupational Safety and Health
  NLM: National Library of Medicine
  NOES: National Occupational Exposure Survey
  NPL: National Priorities List
  NR: not reported
  none reported
  NS: not significant
  nt: nucleotides
  NT: not tested
  o-NT: o-nitrosotoluene
  OR: odds ratio
  OSHA: Occupational Safety and Health Administration
  OTM: olive tail moment
  PBN: phenyl-β-naphthylamine
  PCE: polychromatic erythrocyte
  PCNA: proliferating cell nuclear antigen
  PEL: permissible exposure limit
  PGST: placental glutathione S-transferase
  p.o.: per os (oral administration)
  ppm: parts per million
  QSAR: quantitative structure-activity relationship
  RBC: red blood cell
  RLV: Rauscher-leukemia virus
  ROS: reactive oxygen species
  RQ: reportable quantity
  RR: relative risk
  SA7: Simian Agent 7 adenovirus
  SAFE: significance analysis of function and expression
  SCE: sister-chromatid exchange
  SIC: Standard Industrial Classification
  SIR: standardized incidence ratio
  SMR: standardized mortality ratio
  SOCMI: synthetic organic chemical manufacturing industry
  SOD: superoxide dismutase
  SPA: solid phosphoric acid
  SRR: standardized rate ratio
  SSB: single strand break
  TDS: Total Diet Study
  TL: tail length
  TLC: thin-layer chromatography
  TLV-TWA: threshold limit value – time-weighted average
  TRI: Toxics Release Inventory
  TSCA: Toxic Substances and Recovery Act
  TSFE: time since first employment
  UDS: unscheduled DNA synthesis
  UK: United Kingdom
  WBC: white blood cell
  wt%: weight percent
  µg: microgram