# References

Ahmadzai AA, Trevisan J, Pang W, Patel II, Fullwood NJ, Bruce SW, Pant K, Carmichael PL, Scott AD, Martin FL. 2012. Classification of test agent-specific effects in the Syrian hamster embryo assay (pH 6.7) using infrared spectroscopy with computational analysis. Mutagenesis. 27(3):375–382. 10.1093/mutage/ges003 22362182
Akyüz M, Ata S. 2008. Determination of aromatic amines in hair dye and henna samples by ion-pair extraction and gas chromatography-mass spectrometry. J Pharm Biomed Anal. 47(1):68–80. 10.1016/j.jpba.2007.12.011 18280687
Alibaba.com. 2013. Alibaba.com product database. Alibaba.com. https://www.alibaba.com/?from_http=1 and search on “hair dye,” then narrow search by country, Turkey. [Accessed: June 4, 2013]
Allbiz. 2013. Allbiz product database. Allbiz. http://www.tr.all.biz/en/hair-dye-bgg1059300. [Accessed: May 31, 2013]
Amlacher E, Ziebarth D. 1979. Effectiveness in the carcinogenicity prescreening. A partial comparison of the bacterial mutagenicity test (Ames), the thymidine incorporation inhibiting screening system (Amlacher) and the promoting activity test (Danz). Arch Geschwulstforsch. 49(6):490–494. 543777
An T, Sun L, Li G, Wan S. 2010. Gas-phase photocatalytic degradation and detoxification of o-toluidine: Degradation mechanism and Salmonella mutagenicity assessment of mixed gaseous intermediates. J Mol Catal A Chem. 333(1-2):128–135. 10.1016/j.molcata.2010.10.009
Anders A, Zechel C, Schlatterer B, Groger H, Schmidt D, Smith A, Anders F. 1991. Genetic and molecular approach for breeding and use of laboratory fish for the detection of agents with carcinogenic and/or promoting activity. Bull Cancer. 78(5):415–433. 1878604
Ashby J, de Serres FJ, Draper M, Ishidate M Jr, Margolin BH, Matter BE, Shelby MD. 1985. Progress in Mutation Research. New York, NY: Elsevier Science Publishers; Evaluation of short-term tests for carcinogens. Report of the International Program on Chemical Safety Collaborative Study on In Vitro Assays.
Axelson O, Steenland K. 1988. Indirect methods of assessing the effects of tobacco use in occupational studies. Am J Ind Med. 13(1):105–118. 10.1002/ajim.4700130107 3344750
Baptista RJ. 2012. The faded rainbow: The rise and fall of the western dye industry 1856-2000. http://www.colorantshistory.org/files/Faded_Rainbow_Article_April_21_2012.pdf.
Bardelli A, Cahill DP, Lederer G, Speicher MR, Kinzler KW, Vogelstein B, Lengauer C. 2001. Carcinogen-specific induction of genetic instability. Proc Natl Acad Sci USA. 98(10):5770–5775. 10.1073/pnas.081082898 11296254
Barrett JC, Lamb PW. 1985. Tests with the Syrian hamster embryo cell transformatin assay. Prog Mutat Res. 5:623–628.
Beland FA, Beranek DT, Dooley KL, Heflich RH, Kadlubar FF. 1983. Arylamine-DNA adducts in vitro and in vivo: Their role in bacterial mutagenesis and urinary bladder carcinogenesis. Environ Health Perspect. 49:125–134. 10.1289/ehp.8349125 6339219
Beland FA, Kadlubar FF. 1985. Formation and persistence of arylamine DNA adducts in vivo. Environ Health Perspect. 62:19–30. 10.1289/ehp.856219 4085422
Beland FA, Melchior WB Jr, Mourato LL, Santos MA, Marques MM. 1997. Arylamine-DNA adduct conformation in relation to mutagenesis. Mutat Res. 376(1-2):13–19. 10.1016/S0027-5107(97)00020-1 9202733
Benigni R, Giuliani A, Franke R, Gruska A. 2000. Quantitative structure-activity relationships of mutagenic and carcinogenic aromatic amines. Chem Rev. 100(10):3697–3714. 10.1021/cr9901079 11749325
Benigni R, Passerini L. 2002. Carcinogenicity of the aromatic amines: From structure-activity relationships to mechanisms of action and risk assessment. Mutat Res. 511(3):191–206. 10.1016/S1383-5742(02)00008-X 12088717
Bernard S. 2012. Stanley Bernard, Drexel Chemical Company, letter to the U.S. House of Representatives. June 19, 2012.
Beyerbach A, Farmer PB, Sabbioni G. 1996. Synthesis and analysis of DNA adducts of arylamines. Biomarkers. 1(1):9–20. 10.3109/13547509609079342 23888889
Birner G, Neumann HG. 1988. Biomonitoring of aromatic amines II: Hemoglobin binding of some monocyclic aromatic amines. Arch Toxicol. 62(2-3):110–115. 10.1007/BF00570128 3196145
Bitsch A, Klöhn PC, Hadjiolov N, Bergmann O, Neumann HG. 1999. New insights into carcinogenesis of the classical model arylamine 2-acetylaminofluorene. Cancer Lett. 143(2):223–227. 10.1016/S0304-3835(99)00129-9 10503908
Böhm F, Schmid D, Denzinger S, Wieland WF, Richter E. 2011. DNA adducts of ortho-toluidine in human bladder. Biomarkers. 16(2):120–128. 10.3109/1354750X.2010.534556 21117897
Boorman GA, Wilson J, van Zwieten MJ, Eustis SL. 1990. Chapter 19: Mammary Gland. In: Boorman GA, Eustis SL, M.R E, Montgomery Jr CA, MacKenzie WF, editors. Pathology of the Fischer Rat. San Diego, CA: Academic Press, Inc. p. 295-312.
Bowers JS. 2011. Toluidines. In: Ullman's Encyclopedia of Industrial Chemistry. Weinheim: Wiley-VCH Velrag GmbH & Co KGaA. p. 119-126.
Branco PS, Antunes AM, Marques MM, Chiarelli MP, Lobo AM, Prabhakar S. 1999. New syntheses of DNA adducts from methylated anilines present in tobacco smoke. Chem Res Toxicol. 12(12):1223–1233. 10.1021/tx9901229 10604872
Branner B, Kutzer C, Zwickenpflug W, Scherer G, Heller WD, Richter E. 1998. Haemoglobin adducts from aromatic amines and tobacco-specific nitrosamines in pregnant smoking and non-smoking women. Biomarkers. 3(1):35–47. 10.1080/135475098231354 23899255
Brauers A, Manegold E, Buettner R, Baron JM, Merk HF, Jakse G. 2000. Cytochrome P450 isoenzyme mRNA expression pattern in human urinary bladder malignancies and normal urothelium. Cancer Detect Prev. 24(4):356–363. 11059566
Breivik J, Gaudernack G. 1999. Genomic instability, DNA methylation, and natural selection in colorectal carcinogenesis. Semin Cancer Biol. 9(4):245–254. 10.1006/scbi.1999.0123 10448112
Brennan RJ, Schiestl RH. 1999. The aromatic amine carcinogens o-toluidine and o-anisidine induce free radicals and intrachromosomal recombination in Saccharomyces cerevisiae. Mutat Res. 430(1):37–45. 10.1016/S0027-5107(99)00118-9 10592316
Brock WJ, Hundley SG, Lieder PH. 1990. Hepatic macromolecular binding and tissue distribution of ortho- and para-toluidine in rats. Toxicol Lett. 54(2-3):317–325. 10.1016/0378-4274(90)90199-V 1701932
Brown KK, Teass AW, Simon S, Ward EM. 1995. A biological monitoring method for o-toluidine and aniline in urine using high performance liquid chromatography with electrochemical detection. Appl Occup Environ Hyg. 10(6):557–565. 10.1080/1047322X.1995.10389074
Bryant MS, Vineis P, Skipper PL, Tannenbaum SR. 1988. Hemoglobin adducts of aromatic amines: Associations with smoking status and type of tobacco. Proc Natl Acad Sci USA. 85(24):9788–9791. 10.1073/pnas.85.24.9788 3200858
Cain JC, Thorpe JF. 1905. The synthetic dyestuffs and the intermediate products from which they are derived. London, UK: Charles Griffin and Company, Ltd.
Carreón T, Hein MJ, Hanley KW, Viet SM, Ruder AM. 2014. Bladder cancer incidence among workers exposed to o-toluidine, aniline and nitrobenzene at a rubber chemical manufacturing plant. Occup Environ Med. 71(3):175–182. 10.1136/oemed-2013-101873 24368697
Carreón T, Hein MJ, Viet SM, Hanley KW, Ruder AM, Ward EM. 2010. Increased bladder cancer risk among workers exposed to o-toluidine and aniline: A reanalysis. Occup Environ Med. 67(5):348–350. 10.1136/oem.2009.051136 19884651
Case RA, Hosker ME, Mc DD, Pearson JT. 1954. Tumours of the urinary bladder in workmen engaged in the manufacture and use of certain dyestuff intermediates in the British chemical industry. I. The role of aniline, benzidine, alpha-naphthylamine, and beta-naphthylamine. Br J Ind Med. 11(2):75–104. 10.1136/oem.11.2.75 13149741
Case RA, Pearson JT. 1954. Tumours of the urinary bladder in workmen engaged in the manufacture and use of certain dyestuff intermediates in the British chemical industry. II. Further consideration of the role of aniline and of the manufacture of auramine and magenta (fuchsine) as possible causative agents. Br J Ind Med. 11(3):213–216. 10.1136/oem.11.3.213 13182161
Castelao JE, Yuan JM, Skipper PL, Tannenbaum SR, Gago-Dominguez M, Crowder JS, Ross RK, Yu MC. 2001. Gender- and smoking-related bladder cancer risk. J Natl Cancer Inst. 93(7):538–545. 10.1093/jnci/93.7.538 11287448
Castro-Jiménez MÁ, Orozco-Vargas LC. 2011. Parental exposure to carcinogens and risk for childhood acute lymphoblastic leukemia, Colombia, 2000-2005. Prev Chronic Dis. 8(5):A106. 21843409
Centers for Disease Control and Prevention (CDC). 2010. Training and education - Treatment & management monitoring treatment. Atlanta, GA: Centers for Disease Control and Prevention. https://www.cdc.gov/ncbddd/hemochromatosis/training/treatment/monitoring_treatment.html.
Centers for Disease Control and Prevention (CDC). 2012. Fast facts: Smoking and tobacco use. Atlanta, GA: Centers for Disease Control and Prevention. https://www.cdc.gov/tobacco/data_statistics/fact_sheets/fast_facts/. [Accessed: February 21, 2013]
Cesarone CF, Bolognesi C, Santi L. 1982. Evaluation of damage to DNA after in vivo exposure to different classes of chemicals. Arch Toxicol. 5:355–359. 10.1007/978-3-642-68511-8_66
Cheever KL, DeBord DG, Swearengin TF, Booth-Jones AD. 1992. ortho-Toluidine blood protein adducts: HPLC analysis with fluorescence detection after a single dose in the adult male rat. Fundam Appl Toxicol. 18(4):522–531. 10.1016/0272-0590(92)90111-T 1526364
Cheever KL, Richards DE, Plotnick HB. 1980. Metabolism of ortho-, meta-, and para-toluidine in the adult male rat. Toxicol Appl Pharmacol. 56(3):361–369. 10.1016/0041-008X(80)90069-1 7222020
Chung KT, Fulk GE, Andrews AW. 1981. Mutagenicity testing of some commonly used dyes. Appl Environ Microbiol. 42(4):641–648. 10.1128/aem.42.4.641-648.1981 7039509
Ciccoli L, Ferrali M, Rossi V, Signorini C, Alessandrini C, Comporti M. 1999. Hemolytic drugs aniline and dapsone induce iron release in erythrocytes and increase the free iron pool in spleen and liver. Toxicol Lett. 110(1-2):57–66. 10.1016/S0378-4274(99)00138-1 10593595
Collins JJ, Strauss ME, Riordan SG. 1999. Mortalities of workers at the Nitro plant with exposure to 2-mercaptobenzothialzole. Occup Environ Med. 56(10):667–671. 10.1136/oem.56.10.667 10658544
Conso F, Pontal P. 1982. [Amino-tumors of the bladder. Possible role of industrial exposure to toluidine and aminoazotoluene]. Arch Mal Prof. 43(4):307–310.
SRI Consulting. 2012. Directory of chemical producers. Menlo Park, CA: SRI Consulting. Database edition. [Accessed: January 9, 2012]
Danford N. 1991. The genetic toxicology of ortho-toluidine. Mutat Res. 258(3):207–236. 10.1016/0165-1110(91)90010-S 1719402
Daniel MR, Dehnel JM. 1981. Cell transformation test with baby hamsetr kidney cells. In: de Serres FJ, Ashby J, editors. Evaluation of Short-term Tests for Carcinogens. New York, NY: Elsevier North Holland, Inc.; p. 626–637.
de Serres FJ, Ashby J. 1981. Progress in Mutation Research. New York, NY: Elsevier North Holland, Inc.; Evaluation of short-term tests for carcinogens; p. 813.
DeBord DG, Swearengin TF, Cheever KL, Booth-Jones AD, Wissinger LA. 1992. Binding characteristics of ortho-toluidine to rat hemoglobin and albumin. Arch Toxicol. 66(4):231–236. 10.1007/BF02307167 1514920
DeBruin LS, Pawliszyn JB, Josephy PD. 1999. Detection of monocyclic aromatic amines, possible mammary carcinogens, in human milk. Chem Res Toxicol. 12(1):78–82. 10.1021/tx980168m 9894021
Decarli A, Peto J, Piolatto G, La Vecchia C. 1985. Bladder cancer mortality of workers exposed to aromatic amines: Analysis of models of carcinogenesis. Br J Cancer. 51(5):707–712. 10.1038/bjc.1985.106 3994914
Delclos KB, Kadlubar FF. 1997. Carcinogenic aromatic amines and amides. In: Bowden GT, Fischer SM, editors. Comprehensive Toxicology. New York, NY: Elsevier Science; p. 141–170.
Díaz Gómez MI, Fanelli SL, Delgado de Layño AM, Castro JA, Castro GD. 2006. Liver nuclear and microsomal CYP2E1-mediated metabolism of xenobiotics in rats chronically drinking an alcohol-containing liquid diet. Toxicol Ind Health. 22(9):367–374. 10.1177/0748233706070982 17533807
DrugsArea.com. 2007. Prilocaine. DrugsArea.com. http://drugsarea.com/Dets-Drugs/Prilocainepd.html. [Accessed: February 22, 2013]
Duan JD, Jeffrey AM, Williams GM. 2008. Assessment of the medicines lidocaine, prilocaine, and their metabolites, 2,6-dimethylaniline and 2-methylaniline, for DNA adduct formation in rat tissues. Drug Metab Dispos. 36(8):1470–1475. 10.1124/dmd.107.019950 18490435
Ekman B, Strömbeck JP. 1947. Demonstration of tumorigenic decomposition products of 2, 3-azotoluene. Acta Physiol Scand. 14(1-2):43–50. 10.1111/j.1748-1716.1947.tb00440.x 20273356
Ekman B, Strömbeck JP. 1949. The effect of some splitproducts of 2,3-azotoluene on the urinary bladder in th erat and their excretion on various diets. Acta Pathol Microbiol Scand. 26(3):447–471. 10.1111/j.1699-0463.1949.tb00747.x
el-Bayoumy K, Donahue JM, Hecht SS, Hoffmann D. 1986. Identification and quantitative determination of aniline and toluidines in human urine. Cancer Res. 46(12 Pt 1):6064–6067. 3779628
English JC, Bhat VS, Ball GL, McLellan CJ. 2012. Establishing a total allowable concentration of o-toluidine in drinking water incorporating early lifestage exposure and susceptibility. Regul Toxicol Pharmacol. 64(2):269–284. 10.1016/j.yrtph.2012.08.011 22940434
European Commission (EC). 2013a. Tattoo ink - Eternal ink nuclear green. European Commission. http://unsafeproducts.eu/2013/02/08/tattoo-ink-eternal-ink-nuclear-green/. [Accessed: December 9, 2013]
European Commission (EC). 2013b. Tattoo ink - Lightning yellow. European Commission. http://unsafeproducts.eu/2012/11/30/tattoo-ink-lightning-yellow/. [Accessed: December 9, 2013]
Eyer P. 1983. The red cell as a sensitive target for activated toxic arylamines. Arch Toxicol Suppl. 6:3–12. 10.1007/978-3-642-69083-9_1 6578736
Fernandez M, Gauthier L, Jaylet A. 1989. Use of newt larvae for in vivo genotoxicity testing of water: Results on 19 compounds evaluated by the micronucleus test. Mutagenesis. 4(1):17–26. 10.1093/mutage/4.1.17 2654548
U.S. Food and Drug Aministration (FDA). 2006. U.S. Food and Drug Administration - Total diet study market baskets 1991-3 through 2003-4. College Park, MD: U.S. Food and Drug Aministration.
Fowler P, Smith K, Young J, Jeffrey L, Kirkland D, Pfuhler S, Carmichael P. 2012. Reduction of misleading (“false”) positive results in mammalian cell genotoxicity assays. I. Choice of cell type. Mutat Res. 742(1-2):11–25. 10.1016/j.mrgentox.2011.10.014 22138618
Franke R, Gruska A, Bossa C, Benigni R. 2010. QSARs of aromatic amines: Identification of potent carcinogens. Mutat Res. 691(1-2):27–40. 10.1016/j.mrfmmm.2010.06.009 20600167
Franke R, Gruska A, Giuliani A, Benigni R. 2001. Prediction of rodent carcinogenicity of aromatic amines: A quantitative structure-activity relationships model. Carcinogenesis. 22(9):1561–1571. 10.1093/carcin/22.9.1561 11532881
Freeman HS. 2012. Use of o-toluidine in the manufacture of dyes and on the potential for exposure to other chemicals in the processes involving o-toluidine. Durham, NC: Intergrated Laboratory Systems, Inc.
Freudenthal RI, Stephens E, Anderson DP. 1999. Determining the potential of aromatic animes to induce cancer of the urinary bladder. Int J Toxicol. 18:353–359. 10.1080/109158199225260
Frith CH, Greenman DL, Cohen SM. 1994. Urinary bladder carcinogenesis in the rodent. In: Waalkes MP, Ward JM, editors. Carcinogenesis. New York, NY: Raven Press, Ltd. p; p. 161–197.
Gaber K, Harreus UA, Matthias C, Kleinsasser NH, Richter E. 2007. Hemoglobin adducts of the human bladder carcinogen o-toluidine after treatment with the local anesthetic prilocaine. Toxicology. 229(1-2):157–164. 10.1016/j.tox.2006.10.012 17129655
Gadupudi GS, Chung KT. 2011. Comparative genotoxicity of 3-hydroxyanthranilic acid and anthranilic acid in the presence of a metal cofactor Cu (II) in vitro. Mutat Res. 726(2):200–208. 10.1016/j.mrgentox.2011.09.012 22015263
Gan J, Skipper PL, Gago-Dominguez M, Arakawa K, Ross RK, Yu MC, Tannenbaum SR. 2004. Alkylaniline-hemoglobin adducts and risk of non-smoking-related bladder cancer. J Natl Cancer Inst. 96(19):1425–1431. 10.1093/jnci/djh274 15467031
Gan J, Skipper PL, Tannenbaum SR. 2001. Oxidation of 2,6-dimethylaniline by recombinant human cytochrome P450s and human liver microsomes. Chem Res Toxicol. 14(6):672–677. 10.1021/tx000181i 11409937
Garberg P, Åkerblom EL, Bolcsfoldi G. 1988. Evaluation of a genotoxicity test measuring DNA-strand breaks in mouse lymphoma cells by alkaline unwinding and hydroxyapatite elution. Mutat Res. 203(3):155–176. 10.1016/0165-1161(88)90101-X 2836728
Garisto GA, Gaffen AS, Lawrence HP, Tenenbaum HC, Haas DA. 2010. Occurrence of paresthesia after dental local anesthetic administration in the United States. J Am Dent Assoc. 141(7):836–844. 10.14219/jada.archive.2010.0281 20592403
Genin VA, Pliss GB, Pylev LN, Shabad LM. 1978. [Prevention of occupational urinary bladder tumours in the manufacture of toluidines]. Gigiena Truda i Professional’nye Zabolevaniya. 7:10–15.
Gupta RL, Gupta AK, Pathak DP, Juneja TR. 1987. Mutagenic studies of ortho-toluidine and its potential metabolites. Indian J Exp Biol. 25(9):618–622. 3449450
Gupta RL, Kaur IP, Gupta AK, Pathak DP, Juneja TR. 1989. Effect of norharman on the mutagenicity of toluidine metabolites. Toxicol Lett. 48(1):75–81. 10.1016/0378-4274(89)90188-4 2665189
Hada N, Totsuka Y, Enya T, Tsurumaki K, Nakazawa M, Kawahara N, Murakami Y, Yokoyama Y, Sugimura T, Wakabayashi K. 2001. Structures of mutagens produced by the co-mutagen norharman with o- and m-toluidine isomers. Mutat Res. 493(1-2):115–126. 10.1016/S1383-5718(01)00168-1 11516721
Haglund J, Henderson AP, Golding BT, Tornqvist M. 2002. Evidence for phosphate adducts in DNA from mice treated with 4-(N-Methyl-N-nitrosamino)-1-(3-pyridyl)-1-butanone (NNK). Chem Res Toxicol. 15(6):773–779. 10.1021/tx015542o 12067244
Hanley KW, Viet SM, Hein MJ, Carreon T, Ruder AM. 2012. Exposure to o-toluidine, aniline, and nitrobenzene in a rubber chemical manufacturing plant: A retrospective exposure assessment update. J Occup Environ Hyg. 9(8):478–490. 10.1080/15459624.2012.693836 22708702
Harris Interactive. 2012. One in Five U.S. Adults now has a tattoo. Harris Interactive. http://www.harrisinteractive.com/NewsRoom/HarrisPolls/tabid/447/mid/1508/articleId/970/ctl/ReadCustom%20Default/Default.aspx. [Accessed: January 28, 2014]
Hatch GG, Anderson TM. 1985. Assays for enhanced DNA viral transformation of primary Syrian hamster embryo (SHE) cells. Prog Mutat Res. 5:629–638.
Hecht SS, El-Bayoumy K, Rivenson A, Fiala E. 1982. Comparative carcinogenicity of o-toluidine hydrochloride and o-nitrosotoluene in F-344 rats. Cancer Lett. 16(1):103–108. 10.1016/0304-3835(82)90097-0 7116337
Hecht SS, El-Bayoumy K, Rivenson A, Fiala ES. 1983. Bioassay for carcinogenicity of 3,2′-dimethyl-4-nitrosobiphenyl, o-nitrosotoluene, nitrosobenzene and the corresponding amines in Syrian golden hamsters. Cancer Lett. 20(3):349–354. 10.1016/0304-3835(83)90034-4 6627231
Hecht SS, El-Bayoumy K, Tulley L, LaVoie E. 1979. Structure-mutagenicity relationships of N-oxidized derivatives of aniline, o-toluidine, 2′-methyl-4-aminobiphenyl, and 3,2′-dimethyl-4-aminobiphenyl. J Med Chem. 22(8):981–987. 10.1021/jm00194a019 385878
Hein DW. 1988 a. Acetylator genotype and arylamine-induced carcinogenesis. Biochim Biophys Acta. 948(1):37–66. 3293663
Hein DW. 1988 b. Genetic polymorphism and cancer susceptibility: Evidence concerning acetyltransferases and cancer of the urinary bladder. BioEssays. 9(6):200–204. 10.1002/bies.950090605 3072000
Hein DW. 2009. N-acetyltransferase SNPs: Emerging concepts serve as a paradigm for understanding complexities of personalized medicine. Expert Opin Drug Metab Toxicol. 5(4):353–366. 10.1517/17425250902877698 19379125
Hein DW, Doll MA, Rustan TD, Gray K, Feng Y, Ferguson RJ, Grant DM. 1993. Metabolic activation and deactivation of arylamine carcinogens by recombinant human NAT1 and polymorphic NAT2 acetyltransferases. Carcinogenesis. 14(8):1633–1638. 10.1093/carcin/14.8.1633 8353847
Higuchi R, Fukami T, Nakajima M, Yokoi T. 2013. Prilocaine- and lidocaine-induced methemoglobinemia is caused by human carboxylesterase-, CYP2E1-, and CYP3A4-mediated metabolic activation. Drug Metab Dispos. 41(6):1220–1230. 10.1124/dmd.113.051714 23530020
Hill AB. 1965. The environment and disease: Association or causation? Proc R Soc Med. 58:295–300. 10.1177/003591576505800503 14283879
Hjelm M. 1965. Age dependency and cause of prilocaine-induced methaemoglobaemiae. Acta Anaesthesiol Scand. 9 Suppl 16:171–174. 10.1111/j.1399-6576.1965.tb00537.x
Höglund M, Säll T, Heim S, Mitelman F, Mandahl N, Fadl-Elmula I. 2001. Identification of cytogenetic subgroups and karyotypic pathways in transitional cell carcinoma. Cancer Res. 61(22):8241–8246. 11719456
Howden LM, Meyer JA. 2011. Age and sex composition: 2010. Washington, D.C.: U.S. Census Bureau.
Howe JR. 1977. Is there a cancer risk in the laboratory use of magenta and related dyes? Lab Pract. 26:87–91.
Huncharek M, Kupelnick B. 2005. Personal use of hair dyes and the risk of bladder cancer: Results of a meta-analysis. Public Health Rep. 120(1):31–38. 10.1177/003335490512000107 15736329
International Agency for Research on Cancer (IARC). 1987. ortho-Toluidine. In: Overall Evaluations of Carcinogenicity. Lyon, France: International Agency for Research on Cancer. p. 362.
International Agency for Research on Cancer (IARC). 2000. ortho-Toluidine. In: Some Industrial Chemicals. Lyon, France: International Agency for Research on Cancer. p. 267-322.
International Agency for Research on Cancer (IARC). 2010 a. Some Aromatic Amines, Organic Dyes, and Related Exposures. Lyon, France: International Agency for Research on Cancer. p; 2-Naphthylamine; p. 369–405.
International Agency for Research on Cancer (IARC). 2010 b. Some Aromatic Amines, Organic Dyes, and Related Exposures. Lyon, France: International Agency for Research on Cancer. p; 4-Aminobiphenyl; p. 71–109.
International Agency for Research on Cancer (IARC). 2010 c. Some Aromatic Amines, Organic Dyes, and Related Exposures. Lyon, France: International Agency for Research on Cancer; 4-Chloro-ortho-toluidine; p. 471–498.
International Agency for Research on Cancer (IARC). 2010 d. Some Aromatic Amines, Organic Dyes, and Related Exposures. Lyon, France: International Agency for Research on Cancer; General discussion of common mechanisms for aromatic amines; p. 41–54.
International Agency for Research on Cancer (IARC). 2010e. ortho-Toluidine. In: Some Aromatic Amines, Organic Dyes, and Related Exposures. Lyon, France: International Agency for Research on Cancer. p. 395-439.
International Agency for Research on Cancer (IARC). 2012. ortho-Toluidine. In: A Review of Human Carcinogens: Chemical Agents and Related Occupations. Lyon, France: International Agency for Research on Cancer. p. 8.
International Programme on Chemical Safety (IPCS). 1998. Concise international chemical assessment document 7: o-Toluidine. Geneva, Switzerland: World Health Organization.
Jodynis-Liebert J, Matuszewska A. 1999. Effect of toluidines and dinitrotoluenes on caffeine metabolic ratio in rat. Toxicol Lett. 104(1-2):159–165. 10.1016/S0378-4274(98)00346-4 10048762
Johansson GM, Jönsson BA, Axmon A, Lindh CH, Lind ML, Gustavsson M, Broberg K, Boman A, Meding B, Lidén C, et al. 2015. Exposure of hairdressers to ortho- and meta-toluidine in hair dyes. Occup Environ Med. 72(1):57–63. 10.1136/oemed-2013-101960 24912758
Jones CR, Liu YY, Sepai O, Yan H, Sabbioni G. 2005. Hemoglobin adducts in workers exposed to nitrotoluenes. Carcinogenesis. 26(1):133–143. 10.1093/carcin/bgh286 15471893
Jones CR, Sabbioni G. 2003. Identification of DNA adducts using HPLC/MS/MS following in vitro and in vivo experiments with arylamines and nitroarenes. Chem Res Toxicol. 16(10):1251–1263. 10.1021/tx020064i 14565767
Kadlubar FF, Badawi AF. 1995. Genetic susceptibility and carcinogen-DNA adduct formation in human urinary bladder carcinogenesis. Toxicol Lett. 82-83:627–632. 10.1016/0378-4274(95)03507-9 8597119
Kadlubar FF, Dooley KL, Teitel CH, Roberts DW, Benson RW, Butler MA, Bailey JR, Young JF, Skipper PW, Tannenbaum SR. 1991. Frequency of urination and its effects on metabolism, pharmacokinetics, blood hemoglobin adduct formation, and liver and urinary bladder DNA adduct levels in beagle dogs given the carcinogen 4-aminobiphenyl. Cancer Res. 51(16):4371–4377. 1868460
Kato R, Yamazoe Y. 1994. Metabolic activation of N-hydroxylated metabolites of carcinogenic and mutagenic arylamines and arylamides by esterification. Drug Metab Rev. 26(1-2):413–429. 10.3109/03602539409029806 8082577
Kauppinen T, Pukkala E, Saalo A, Sasco AJ. 2003. Exposure to chemical carcinogens and risk of cancer among Finnish laboratory workers. Am J Ind Med. 44(4):343–350. 10.1002/ajim.10278 14502761
Kawanishi S, Hiraku Y, Murata M, Oikawa S. 2002. The role of metals in site-specific DNA damage with reference to carcinogenesis. Free Radic Biol Med. 32(9):822–832. 10.1016/S0891-5849(02)00779-7 11978484
Kerckaert GA, LeBoeuf RA, Isfort RJ. 1998. Assessing the predictiveness of the Syrian hamster embryo cell transformation assay for determining the rodent carcinogenic potential of single ring aromatic/nitroaromatic amine compounds. Toxicol Sci. 41(2):189–197. 10.1093/toxsci/41.2.189 9520355
Khan MF, Boor PJ, Gu Y, Alcock NW, Ansari GA. 1997. Oxidative stress in the splenotoxicity of aniline. Fundam Appl Toxicol. 35(1):22–30. 10.1006/faat.1996.2259 9024670
Khlebnikova MI, Gladkova EV, Kurenko LT, Pshenitsyn AV, Shalin BM. 1970. [Problems of industrial hygiene and health status of workers engaged in the production of o-toluidine]. Gigiena Truda i Professional’nye Zabolevaniya. 14:7–10.
Korinth G, Luersen L, Schaller KH, Angerer J, Drexler H. 2008. Enhancement of percutaneous penetration of aniline and o-toluidine in vitro using skin barrier creams. Toxicol In Vitro. 22(3):812–818. 10.1016/j.tiv.2007.11.006 18155878
Korinth G, Weiss T, Penkert S, Schaller KH, Angerer J, Drexler H. 2007. Percutaneous absorption of aromatic amines in rubber industry workers: Impact of impaired skin and skin barrier creams. Occup Environ Med. 64(6):366–372. 10.1136/oem.2006.027755 17182646
Kubota Y. 1979. Experience with the chemical substances control law in Japan. Ecotoxicol Environ Saf. 3(3):256–268. 10.1016/0147-6513(79)90016-2 499030
Kulkarni B, Fiala ES, Weisburger JH. 1983. Estimation of N-hydroxy-o-toluidine, a urinary metabolite of o-toluidine and o-nitrosotoluene, by high performance liquid chromatography with electrochemical detection. Carcinogenesis. 4(10):1275–1279. 10.1093/carcin/4.10.1275 6616755
Kütting B, Göen T, Schwegler U, Fromme H, Uter W, Angerer J, Drexler H. 2009. Monoarylamines in the general population—a cross-sectional population-based study including 1004 Bavarian subjects. Int J Hyg Environ Health. 212(3):298–309. 10.1016/j.ijheh.2008.07.004 18789761
Lao Y, Yu N, Kassie F, Villalta PW, Hecht SS. 2007 a. Analysis of pyridyloxobutyl DNA adducts in F344 rats chronically treated with (R)- and (S)-N′-nitrosonornicotine. Chem Res Toxicol. 20(2):246–256. 10.1021/tx060208j 17305408
Lao Y, Yu N, Kassie F, Villalta PW, Hecht SS. 2007 b. Formation and accumulation of pyridyloxobutyl DNA adducts in F344 rats chronically treated with 4-(methylnitrosamino)-1-(3-pyridyl)-1-butanone and enantiomers of its metabolite, 4-(methylnitrosamino)-1-(3-pyridyl)-1-butanol. Chem Res Toxicol. 20(2):235–245. 10.1021/tx060207r 17305407
Lawrence N, McGregor DB. 1985. Assays for the induction of morphological transformation in C3H/10T 1/2 cells in culture with and without S9-mediated metabolic activation. Prog Mutat Res. 5:651–658.
Leslie C, Reidy GF, Murray M, Stacey NH. 1988. Induction of xenobiotic biotransformation by the insecticide chlordimeform, a metabolite 4-chloro-o-toluidine and a structurally related chemical o-toluidine. Biochem Pharmacol. 37(13):2529–2535. 10.1016/0006-2952(88)90242-0 3390215
Lewalter J, Korallus U. 1985. Blood protein conjugates and acetylation of aromatic amines. New findings on biological monitoring. Int Arch Occup Environ Health. 56(3):179–196. 10.1007/BF00396596 4066048
Lindenblatt N, Belusa L, Tiefenbach B, Schareck W, Olbrisch RR. 2004. Prilocaine plasma levels and methemoglobinemia in patients undergoing tumescent liposuction involving less than 2,000 ml. Aesthetic Plast Surg. 28(6):435–440. 10.1007/s00266-004-0009-5 15870963
Lindner D, Smith S, Leroy CM, Tricker AR. 2011. Comparison of exposure to selected cigarette smoke constituents in adult smokers and nonsmokers in a European, multicenter, observational study. Cancer Epidemiol Biomarkers Prev. 20(7):1524–1536. 10.1158/1055-9965.EPI-10-1186 21613391
Lower GM Jr, Bryan GT. 1973. Enzymatic N-acetylation of carcinogenic aromatic amines by liver cytosol of species displaying different organ susceptibilities. Biochem Pharmacol. 22(13):1581–1588. 10.1016/0006-2952(73)90024-5 4729805
Lüersen L, Wellner T, Koch HM, Angerer J, Drexler H, Korinth G. 2006. Penetration of β-naphthylamine and o-toluidine through human skin in vitro. Arch Toxicol. 80(10):644–646. 10.1007/s00204-006-0095-z 16596380
Maeshima H, Ohno K, Nakano S, Yamada T. 2010. Validation of an in vitro screening test for predicting the tumor promoting potential of chemicals based on gene expression. Toxicol In Vitro. 24(3):995–1001. 10.1016/j.tiv.2009.12.013 20025956
Maire MA, Pant K, Poth A, Schwind KR, Rast C, Bruce SW, Sly JE, Kunz-Bohnenberger S, Kunkelmann T, Engelhardt G, et al. 2012. Prevalidation study of the Syrian hamster embryo (SHE) cell transformation assay at pH 7.0 for assessment of carcinogenic potential of chemicals. Mutat Res. 744(1):64–75. 10.1016/j.mrgentox.2011.12.007 22227405
Markowitz SB, Levin K. 2004. Continued epidemic of bladder cancer in workers exposed to ortho-toluidine in a chemical factory. J Occup Environ Med. 46(2):154–160. 10.1097/01.jom.0000111602.76443.15 14767218
Marques MM, Mourato LL, Amorim MT, Santos MA, Melchior WB Jr, Beland FA. 1997. Effect of substitution site upon the oxidation potentials of alkylanilines, the mutagenicities of N-hydroxyalkylanilines, and the conformations of alkylaniline-DNA adducts. Chem Res Toxicol. 10(11):1266–1274. 10.1021/tx970104w 9403181
Marques MM, Mourato LL, Santos MA, Beland FA. 1996. Synthesis, characterization, and conformational analysis of DNA adducts from methylated anilines present in tobacco smoke. Chem Res Toxicol. 9(1):99–108. 10.1021/tx950044z 8924623
Martin FL, Cole KJ, Harvey D, Weaver G, Williams JA, Millar BC, Phillips DH, Grover PL. 2000 a. DNA damage in human breast milk cells and its induction by ‘early’ and ‘late’ milk extracts. Carcinogenesis. 21(4):799–804. 10.1093/carcin/21.4.799 10753218
Martin FL, Cole KJ, Williams JA, Millar BC, Harvey D, Weaver G, Grover PL, Phillips DH. 2000 b. Activation of genotoxins to DNA-damaging species in exfoliated breast milk cells. Mutat Res. 470(2):115–124. 10.1016/S1383-5742(00)00046-6 11027965
Matthews EJ, DelBalzo T, Rundell JO. 1985. Assays for morphological transformation and mutation to ouabain resistance of Balb / c-3T3 cells in culture. Prog Mutat Res. 5:639–650.
McFee AF, Jauhar PP, Lowe KW, MacGregor JT, Wehr CM. 1989. Assays of three carcinogen/non-carcinogen chemical pairs for in vivo induction of chromosome aberrations, sister chromatid exchanges and micronuclei. Environ Mol Mutagen. 14(4):207–220. 10.1002/em.2850140402 2583129
Meijers AP, van der Leer RC. 1976. The occurrence of organic micropollutants in the River Rhine and the River Maas in 1974. Water Res. 10:597–604. 10.1016/0043-1354(76)90140-8
Michaels D. 1988. Waiting for the body count: Corporate decision making and bladder cancer in the U. S. dye industry. Med Anthropol Q. 2(3):215–232. 10.1525/maq.1988.2.3.02a00030
Mori M, Totsuka Y, Fukutome K, Yoshida T, Sugimura T, Wakabayashi K. 1996. Formation of DNA adducts by the co-mutagen norharman with aromatic amines. Carcinogenesis. 17(7):1499–1503. 10.1093/carcin/17.7.1499 8706255
Morris PJT, Travis AS. 1992. A history of the international dyestuff industry. Am Dyest Report. 81(11):49.
Murata M, Kawanishi S. 2011. Mechanisms of oxidative DNA damage induced by carcinogenic arylamines. Front Biosci. 16:1132–1143. 10.2741/3739 21196222
Nagao M, Takahashi Y. 1981. Mutagenic activity of 42 coded compounds in the Salmonella/microsome assay. In: de Serres FJ, Ashby J, editors. Evaluation of Short-Term Tests for Carcinogens. New York: Elsevier; p. 302–313.
Nagao M, Yahagi T, Sugimura T. 1978. Differences in effects of norharman with various classes of chemical mutagens and amounts of S-9. Biochem Biophys Res Commun. 83(2):373–378. 10.1016/0006-291X(78)91000-8 358980
National Cancer Institute (NCI). 1979. Bioassay of o-toluidine hydrochloride for possible carcinogenicity (CAS No. 636-21-5). Bethesda, MD: United States Department of Health and Human Services, National Institutes of Health, National Cancer Institute. DHEW Publication No. (NIH) 79-1709.
National Institute for Occupational Safety and Health (NIOSH). 1990. National Occupational and Hazard Survey (1981-1983). National Institute for Occupational Safety and Health. https://www.cdc.gov/noes/noes4/73470sco.html, https://www.cdc.gov/noes/noes4/x8305sco.html. [Last updated: July 1, 1990]
National Institute for Occupational Safety and Health (NIOSH). 1991. Preventing bladder cancer from exposure to o-toluidine and aniline. Am Ind Hyg Assoc J. 52(5):A260, A262.
National Library of Medicine (NLM). 2005. Hazardous Substances Data Bank. 2-Methylaniline hydrochloride. National Library of Medicine. http://toxnet.nlm.nih.gov/cgi-bin/sis/htmlgen?HSDB and search on CAS number or compound name. [Accessed: January 19, 2011]
National Library of Medicine (NLM). 2011. Hazardous Substances Data Bank. 2-Aminotoluene. National Library of Medicine. http://toxnet.nlm.nih.gov/cgi-bin/sis/htmlgen?HSDB and search on CAS number or compound name. [Accessed: January 19, 2011]
National Library of Medicine (NLM). 2012a. ChemIDplus advanced. National Library of Medicine. http://chem.sis.nlm.nih.gov/chemidplus/chemidheavy.jsp and select Registry Number and search on CAS number. [Accessed: May 31, 2012]
National Library of Medicine (NLM). 2012b. TOXMAP: Environmental health e-maps. National Institutes of Health, National Library of Medicine. http://toxmap.nlm.nih.gov/toxmap/main/index.jsp and search o-toluidine. [Accessed: May 31, 2012]
National Toxicology Program (NTP). 1996. NTP technical report on comparative toxicity and carcinogenicity studies of o-nitrotoluene and o-toluidine hydrochloride (CAS Nos. 88-72-2 and 636-21-5) administered in feed to male F344/N rats. Research Triangle Park, NC: United States Department of Health and Human Services, Public Health Service, National Institutes of Health. NIH Publication No. 96-3936.
National Toxicology Program (NTP). 2000. Local anesthetics that metabolize to 2,6-xylidine or o-toluidine. Final review of toxicological literature. Research Triangle Park, NC: United States Department of Health and Human Services, Public Health Service, National Institutes of Health.
National Toxicology Program (NTP). 2011a. o-Toluidine and its Hydrochloride. In: Report on Carcinogens. 12th ed. Research Triangle Park, NC: United States Department of Health and Human Services, Public Health Service, National Institutes of Health. p. 416-418.
National Toxicology Program (NTP). 2011b. p-Chloro-o-toluidine and its Hydrochloride. In: Report on Carcinogens. 12th ed. Research Triangle Park, NC: United States Department of Health and Human Services, Public Health Service, National Institutes of Health. p. 104-105.
Neal SB, Probst GS. 1983. Chemically-induced sister-chromatid exchange in vivo in bone marrow of Chinese hamsters. An evaluation of 24 compounds. Mutat Res. 113(1):33–43. 10.1016/0165-1161(83)90239-X 6828042
Nesnow S, Curtis G, Garland H. 1985. Tests with the C3H/10T 1/2 clone 8 morphological transformation bioassay. Prog Mutat Res. 5:659–664.
Neumann HG. 1986. The role of DNA damage in chemical carcinogenesis of aromatic amines. J Cancer Res Clin Oncol. 112(2):100–106. 10.1007/BF00404390 3533949
Neumann HG. 2007. Aromatic amines in experimental cancer research: Tissue-specific effects, an old problem and new solutions. Crit Rev Toxicol. 37(3):211–236. 10.1080/10408440601028603 17453932
Neurath GB, Dünger M, Pein FG, Ambrosius D, Schreiber O. 1977. Primary and secondary amines in the human environment. Food Cosmet Toxicol. 15(4):275–282. 10.1016/S0015-6264(77)80197-1 590888
Nishigaki R, Totsuka Y, Kataoka H, Ushiyama H, Goto S, Akasu T, Watanabe T, Sugimura T, Wakabayashi K. 2007. Detection of aminophenylnorharman, a possible endogenous mutagenic and carcinogenic compound, in human urine samples. Cancer Epidemiol Biomarkers Prev. 16(1):151–156. 10.1158/1055-9965.EPI-06-0052 17220344
Occupational Safety and Health Administration (OSHA). 2011. Chemical exposure health data. Washington, D.C.: United States Department of Labor; [cited 2013 Jun 11].
Oda Y, Totsuka Y, Wakabayashi K, Guengerich FP, Shimada T. 2006. Activation of aminophenylnorharman, aminomethylphenylnorharman and aminophenylharman to genotoxic metabolites by human N-acetyltransferases and cytochrome P450 enzymes expressed in Salmonella typhimurium umu tester strains. Mutagenesis. 21(6):411–416. 10.1093/mutage/gel047 17067997
Oda Y, Yamazaki H, Shimada T. 1999. Role of human N-acetyltransferases, NAT1 or NAT2, in genotoxicity of nitroarenes and aromatic amines in Salmonella typhimurium NM6001 and NM6002. Carcinogenesis. 20(6):1079–1083. 10.1093/carcin/20.6.1079 10357791
Oda Y, Yamazaki H, Watanabe M, Nohmi T, Shimada T. 1995. Development of high sensitive umu test system: Rapid detection of genotoxicity of promutagenic aromatic amines by Salmonella typhimurium strain NM2009 possessing high O-acetyltransferase activity. Mutat Res. 334(2):145–156. 10.1016/0165-1161(95)90005-5 7885366
Oettel H, Thiess AM, Uhl C. 1968. [Contribution to the problem of occupational lung cancers. Long-term observations from the BASF. First report]. Zentralbl Arbeitsmed. 18(10):291–303. 5731005
Ohkuma Y, Hiraku Y, Oikawa S, Yamashita N, Murata M, Kawanishi S. 1999. Distinct mechanisms of oxidative DNA damage by two metabolites of carcinogenic o-toluidine. Arch Biochem Biophys. 372(1):97–106. 10.1006/abbi.1999.1461 10562421
Ott MG, Langner RR. 1983. A mortality survey of men engaged in the manufacture of organic dyes. J Occup Med. 25(10):763–768. 10.1097/00043764-198310000-00018 6631562
Pant K, Bruce SW, Sly JE, Kunkelmann T, Kunz-Bohnenberger S, Poth A, Engelhardt G, Schulz M, Schwind KR. 2012. Prevalidation study of the Syrian hamster embryo (SHE) cell transformation assay at pH 6.7 for assessment of carcinogenic potential of chemicals. Mutat Res. 744(1):54–63. 10.1016/j.mrgentox.2011.12.005 22178964
Patrianakos C, Hoffmann D. 1979. Chemical studies on tobacco smoke LXIV. On the analysis of aromatic amines in cigarette smoke. J Anal Toxicol. 3:150–154. 10.1093/jat/3.4.150
Phillips JL, Richardson IC. 2006. Aneuploidy in bladder cancers: The utility of fluorescent in situ hybridization in clinical practice. BJU Int. 98(1):33–37. 10.1111/j.1464-410X.2006.06189.x 16831139
Piolatto G, Negri E, La Vecchia C, Pira E, Decarli A, Peto J. 1991. Bladder cancer mortality of workers exposed to aromatic amines: An updated analysis. Br J Cancer. 63(3):457–459. 10.1038/bjc.1991.106 2003988
Pira E, Piolatto G, Negri E, Romano C, Boffetta P, Lipworth L, McLaughlin JK, La Vecchia C. 2010. Bladder cancer mortality of workers exposed to aromatic amines: A 58-year follow-up. J Natl Cancer Inst. 102(14):1096–1099. 10.1093/jnci/djq214 20548022
Pliss GB. 2004. [Experimental study of ortho-toluidine carcinogenicity]. Vopr Onkol. 50(5):567–571. 15715098
Poirier MC, Fullerton NF, Smith BA, Beland FA. 1995. DNA adduct formation and tumorigenesis in mice during the chronic administration of 4-aminobiphenyl at multiple dose levels. Carcinogenesis. 16(12):2917–2921. 10.1093/carcin/16.12.2917 8603464
Prince MM, Ward EM, Ruder AM, Salvan A, Roberts DR. 2000. Mortality among rubber chemical manufacturing workers. Am J Ind Med. 37(6):590–598. 10.1002/(SICI)1097-0274(200006)37:6<590::AID-AJIM3>3.0.CO;2-8 10797502
Richardson K, Band PR, Astrakianakis G, Le ND. 2007. Male bladder cancer risk and occupational exposure according to a job-exposure matrix-a case-control study in British Columbia, Canada. Scand J Work Environ Health. 33(6):454–464. 10.5271/sjweh.1169 18327514
Richter E, Branner B. 2002. Biomonitoring of exposure to aromatic amines: Haemoglobin adducts in humans. J Chromatogr B Analyt Technol Biomed Life Sci. 778(1-2):49–62. 10.1016/S0378-4347(01)00466-2 12376116
Richter E, Rosler S, Scherer G, Gostomzyk JG, Grubl A, Kramer U, Behrendt H. 2001. Haemoglobin adducts from aromatic amines in children in relation to area of residence and exposure to environmental tobacco smoke. Int Arch Occup Environ Health. 74(6):421–428. 10.1007/s004200100243 11563605
Riedel K, Scherer G, Engl J, Hagedorn HW, Tricker AR. 2006. Determination of three carcinogenic aromatic amines in urine of smokers and nonsmokers. J Anal Toxicol. 30(3):187–195. 10.1093/jat/30.3.187 16803653
Riffelmann M, Muller G, Schmieding W, Popp W, Norpoth K. 1995. Biomonitoring of urinary aromatic amines and arylamine hemoglobin adducts in exposed workers and nonexposed control persons. Int Arch Occup Environ Health. 68(1):36–43. 10.1007/BF01831631 8847111
Robbiano L, Carrozzino R, Bacigalupo M, Corbu C, Brambilla G. 2002. Correlation between induction of DNA fragmentation in urinary bladder cells from rats and humans and tissue-specific carcinogenic activity. Toxicology. 179(1-2):115–128. 10.1016/S0300-483X(02)00354-2 12204548
Rubino GF, Scansetti G, Piolatto G, Pira E. 1982. The carcinogenic effect of aromatic amines: An epidemiological study on the role of o-toluidine and 4,4′-methylene bis (2-methylaniline) in inducing bladder cancer in man. Environ Res. 27(2):241–254. 10.1016/0013-9351(82)90079-2 7084156
Ruder AM, Ward EM, Roberts DR, Teass AW, Brown KK, Fingerhut MA, Stettler LE. 1992. Response of the National Institute for Occupational Safety and Health to an occupational health risk from exposure to ortho-toluidine and aniline. Scand J Work Environ Health. 18 Suppl 2:82–84. 1514097
Sabbioni G. 1992. Hemoglobin binding of monocyclic aromatic amines: Molecular dosimetry and quantitative structure activity relationships for the N-oxidation. Chem Biol Interact. 81(1-2):91–117. 10.1016/0009-2797(92)90029-K 1730150
Sabbioni G, Sepai O. 1995. Comparison of hemoglobin binding, mutagenicity, and carcinogenicity of arylamines and nitroarenes. Chimia (Aarau). 49(10):374–380. 10.2533/chimia.1995.374
Sakai A, Sasaki K, Muramatsu D, Arai S, Endou N, Kuroda S, Hayashi K, Lim YM, Yamazaki S, Umeda M, et al. 2010. A Bhas 42 cell transformation assay on 98 chemicals: The characteristics and performance for the prediction of chemical carcinogenicity. Mutat Res. 702(1):100–122. 10.1016/j.mrgentox.2010.07.007 20656056
Salamone MF, Heddle JA, Katz M. 1981. Chapter 66, Mutagenic activity of 41 compounds in the in vivo micronucleus assay. In: de Serres FJ, Ashby J, editors. Evaluation of Short-Term Tests for Carcinogens. New York, NY: Elsevier North Holland, Inc.; p. 686–697.
Saletta F, Matullo G, Manuguerra M, Arena S, Bardelli A, Vineis P. 2007. Exposure to the tobacco smoke constituent 4-aminobiphenyl induces chromosomal instability in human cancer cells. Cancer Res. 67(15):7088–7094. 10.1158/0008-5472.CAN-06-4420 17671175
Sandberg AA. 2002. Cytogenetics and molecular genetics of bladder cancer: A personal view. Am J Med Genet. 115(3):173–182. 10.1002/ajmg.10693 12407698
Sanner T, Rivedal E. 1985. Tests with the Syrian hamster embryo (SHE) cell transformation assay. Prog Mutat Res. 5:665–671.
Seiler JP. 1977. Inhibition of testicular DNA synthesis by chemical mutagens and carcinogens. Preliminary results in the validation of a novel short term test. Mutat Res. 46(4):305–310. 10.1016/0165-1161(77)90007-3 895760
Sekihashi K, Yamamoto A, Matsumura Y, Ueno S, Watanabe-Akanuma M, Kassie F, Knasmuller S, Tsuda S, Sasaki YF. 2002. Comparative investigation of multiple organs of mice and rats in the comet assay. Mutat Res. 517(1-2):53–75. 10.1016/S1383-5718(02)00034-7 12034309
Seyler TH, Reyes LR, Bernert JT. 2010. Analysis of 4-aminobiphenyl hemoglobin adducts in smokers and nonsmokers by pseudo capillary on-column gas chromatography- tandem mass spectrometry. J Anal Toxicol. 34(6):304–311. 10.1093/jat/34.6.304 20663282
Shibutani S, Takeshita M, Grollman AP. 1991. Insertion of specific bases during DNA synthesis past the oxidation-damaged base 8-oxodG. Nature. 349(6308):431–434. 10.1038/349431a0 1992344
Short CR, King C, Sistrunk PW, Kerr KM. 1983. Subacute toxicity of several ring-substituted dialkylanilines in the rat. Fundam Appl Toxicol. 3(4):285–292. 10.1016/S0272-0590(83)80141-9 6628890
Shubhangi K, Alka D, Neha U, Kumar MR, Shalini G. 2013. Cancer risk in tattoos: A review. IOSR-JDMS. 5(1):62–64. 10.9790/0853-0516264
Sinks T, Lushniak B, Haussler BJ, Sniezek J, Deng JF, Roper P, Dill P, Coates R. 1992. Renal cell cancer among paperboard printing workers. Epidemiology. 3(6):483–489. 10.1097/00001648-199211000-00004 1420513
Skipper PL, Kim MY, Sun HL, Wogan GN, Tannenbaum SR. 2010. Monocyclic aromatic amines as potential human carcinogens: Old is new again. Carcinogenesis. 31(1):50–58. 10.1093/carcin/bgp267 19887514
Skipper PL, Tannenbaum SR. 1994. Molecular dosimetry of aromatic amines in human populations. Environ Health Perspect. 102 Suppl 6:17–21. 7889842
Smarte.org. 2008. Understanding units of measurement. http://www.smarte.org/smarte/resource/sn-units-of-measure.xml.
Son OS, Everett DW, Fiala ES. 1980. Metabolism of o-[methyl-14C]toluidine in the F344 rat. Xenobiotica. 10(7-8):457–468. 10.3109/00498258009033781 7445517
Sorahan T. 2008. Bladder cancer risks in workers manufacturing chemicals for the rubber industry. Occup Med (Lond). 58(7):496–501. 10.1093/occmed/kqn104 18725381
Sorahan T, Hamilton L, Jackson JR. 2000. A further cohort study of workers employed at a factory manufacturing chemicals for the rubber industry, with special reference to the chemicals 2-mercaptobenzothiazole (MBT), aniline, phenyl-β-naphthylamine and o-toluidine. Occup Environ Med. 57(2):106–115. 10.1136/oem.57.2.106 10711278
Sorahan T, Pope D. 1993. Mortality study of workers employed at a plant manufacturing chemicals for the rubber industry: 1955-86. Br J Ind Med. 50(11):998–1002. 10.1136/oem.50.11.998 8280636
Stabbert R, Schäfer KH, Biefel C, Rustemeier K. 2003. Analysis of aromatic amines in cigarette smoke. Rapid Commun Mass Spectrom. 17(18):2125–2132. 10.1002/rcm.1161 12955743
Stasik MJ. 1988. Carcinomas of the urinary bladder in a 4-chloro-o-toluidine cohort. Int Arch Occup Environ Health. 60(1):21–24. 10.1007/BF00409374 3350600
Stasik MJ, Lange HL, Schuckmann F. 1985. A retrospective mortality study of 4-chloro-2-methylaniline workers. Paper presented at the MEDICHEM symposium, Bahia, Brasil.
Stettler LE, Savage RE, Brown KK, Cheever KL, Weigel WW, DeBord DG, Teass AW, Dankovic D, Ward EM. 1992. Biological monitoring for occupational exposures to ortho-toluidine and aniline. Scand J Work Environ Health. 18 Suppl 2:78–81. 1514095
Stiborová M, Mikšanová M, Šulc M, Rýdlová H, Schmeiser HH, Frei E. 2005. Identification of a genotoxic mechanism for the carcinogenicity of the environmental pollutant and suspected human carcinogen o-anisidine. Int J Cancer. 116(5):667–678. 10.1002/ijc.21122 15828049
Stillwell WG, Bryant MS, Wishnok JS. 1987. GC/MS analysis of biologically important aromatic amines. Application to human dosimetry. Biomed Environ Mass Spectrom. 14(5):221–227. 10.1002/bms.1200140505 2955825
Strömbeck JP. 1946. Azotoluene bladder tumours in rats. J Pathol Bacteriol. 58:275–278. 10.1002/path.1700580216 20996429
Stuermer DH, Ng DJ, Morris CJ. 1982. Organic contaminants in groundwater near an underground coal gasification site in northeastern Wyoming. Environ Sci Technol. 16(9):582–587. 10.1021/es00103a009 22284199
Styles JA. 1981. Activity of 42 coded compounds in the BHK-21 cell transformation test. Prog Mutat Res. 1:638–646.
Sugimura T, Nagao M, Wakabayashi K. 1982. Metabolic aspects of the comutagenic action of norharman. Adv Exp Med Biol. 136B:1011–1025. 7046384
Suk WA, Humphreys JE. 1985. Assay for the carcinogenicity of chemical agents using enhancement of anchorage-independent survival of retrovirus-infected Fischer rat embryo cells. Prog Mutat Res. 5:673–683.
Suzuki H, Ikeda N, Kobayashi K, Terashima Y, Shimada Y, Suzuki T, Hagiwara T, Hatakeyama S, Nagaoka K, Yoshida J, et al. 2005. Evaluation of liver and peripheral blood micronucleus assays with 9 chemicals using young rats. A study by the Collaborative Study Group for the Micronucleus Test (CSGMT)/Japanese Environmental Mutagen Society (JEMS)-Mammalian Mutagenicity Study Group (MMS). Mutat Res. 583(2):133–145. 10.1016/j.mrgentox.2005.03.012 15899588
Takayama S, Hasegawa H, Ohgaki H. 1989. Combination effects of forty carcinogens administered at low doses to male rats. Jpn J Cancer Res. 80(8):732–736. 10.1111/j.1349-7006.1989.tb01706.x 2511179
Talaska G. 2003. Aromatic amines and human urinary bladder cancer: Exposure sources and epidemiology. J Environ Sci Health C Environ Carcinog Ecotoxicol Rev. 21(1):29–43. 10.1081/GNC-120021372 12826031
Talaska G, Au WW, Ward JB Jr, Randerath K, Legator MS. 1987. The correlation between DNA adducts and chromosomal aberrations in the target organ of benzidine exposed, partially-hepatectomized mice. Carcinogenesis. 8(12):1899–1905. 10.1093/carcin/8.12.1899 3677313
Talaska G, Schamer M, Skipper P, Tannenbaum S, Caporaso N, Unruh L, Kadlubar FF, Bartsch H, Malaveille C, Vineis P. 1991. Detection of carcinogen-DNA adducts in exfoliated urothelial cells of cigarette smokers: Association with smoking, hemoglobin adducts, and urinary mutagenicity. Cancer Epidemiol Biomarkers Prev. 1(1):61–66. 1845172
Tanaka N, Bohnenberger S, Kunkelmann T, Munaro B, Ponti J, Poth A, Sabbioni E, Sakai A, Salovaara S, Sasaki K, et al. 2012. Prevalidation study of the BALB/c 3T3 cell transformation assay for assessment of carcinogenic potential of chemicals. Mutat Res. 744(1):20–29. 10.1016/j.mrgentox.2011.12.008 22198331
Teass AW, DeBord DG, Brown KK, Cheever KL, Stettler LE, Savage RE, Weigel WW, Dankovic D, Ward E. 1993. Biological monitoring for occupational exposures to o-toluidine and aniline. Int Arch Occup Environ Health. 65(1) Suppl:S115–S118. 10.1007/BF00381320 8406905
Topham JC. 1980. Do induced sperm-head abnormalities in mice specifically identify mammalian mutagens rather than carcinogens? Mutat Res. 74(5):379–387. 10.1016/0165-1161(80)90195-8 7207475
Topham JC. 1981. Chapter 70, Evaluation of some chemicals by the sperm morphology assay. In: de Serres FJ, Ashby J, editors. Evaluation of Short-Term Tests for Carcinogens. New York, NY: Elsevier North Holland, Inc.; p. 718–720.
Tsuchimoto T, Matter BE. 1981. Chapter 68, Activity of coded compounds in the micronucleus test. In: de Serres FJ, Ashby J, editors. Evaluation of Short-Term Tests for Carcinogens. New York, NY: Elsevier North Holland, Inc.; p. 705–711.
Uebelin F, Pletscher A. 1954. [Etiology and prophylaxis of commercial tumors in the textile industry]. Schweiz Med Wochenschr. 84(32):917–920. 13205162
Umeda M, Tanaka K, Ono T. 1989. Promotional effect of lithocholic acid and 3-hydroxyanthranilic acid on transformation of X-ray-initiated BALB/3T3 cells. Carcinogenesis. 10(9):1665–1668. 10.1093/carcin/10.9.1665 2766458
United Nations Environment Program Chemicals (UNEP). 2004. Screening information dataset: o-Toluidine (CAS No. 95-53-4). UNEP Chemicals. http://www.chem.unep.ch/irptc/sids/OECDSIDS/sidspub.html and search by chemical name.
United States International Trade Commission (USITC). 2012. USITC interactive tariff and trade dataweb. United States International Trade Commission. https://dataweb.usitc.gov/scripts/user_set.asp and search on HTS no. 292143. [Accessed: November 28, 2012]
University of Akron. 2012a. The chemical database. 2-Methylaniline hydrochloride. The Department of Chemistry at the University of Akron. http://ull.chemistry.uakron.edu/erd and search on CAS number. [Accessed: October 26, 2012]
University of Akron. 2012b. The chemical database. o-Toluidine. The Department of Chemistry at the University of Akron. http://ull.chemistry.uakron.edu/erd and search on CAS number. [Accessed: May 31, 2012]
U.S. Environmental Protection Agency (USEPA). 1984. Chemical Hazard Information Profile (CHIP): ortho-Toluidine; ortho-toluidine hydrochloride. Washington, D.C.: Office of Pesticide Programs and Toxic Substances.
U.S. Environmental Protection Agency (USEPA). 1994. Intergrated risk information system. Aniline. Washington, DC: U.S. Environmental Protection Agency. https://www.epa.gov/iris/subst/0350.htm. [Accessed: June 26, 2012]
U.S. Environmental Protection Agency (USEPA). 2012a. Inventory Update Reporting (IUR). Washington, DC: U.S. Environmental Protection Agency. https://www.epa.gov/iur/tools/data/index.html and search by CAS no.
U.S. Environmental Protection Agency (USEPA). 2012b. TRI explorer chemical report. U.S. Environmental Protection Agency. https://www.epa.gov/triexplorer and select o-Toluidine and o-Toluidine Hydrochloride. [Accessed: November 28, 2012]
U.S. Environmental Protection Agency (USEPA). 2013a. Non-confidential 2006 IUR records by chemical, including manufacturing, processing and use information. U.S. Environmental Protection Agency. https://cfpub.epa.gov/iursearch/ and search by CAS no. [Accessed: May 17, 2013]
U.S. Environmental Protection Agency (USEPA). 2013b. Pesticides Chemical Search. U.S. Environmental Protection Agency. https://iaspub.epa.gov/apex/pesticides/f?p=chemicalsearch:1. [Accessed: February 22, 2013]
Veys CA. 1996. Bladder cancer in rubber workers: A phenyl beta-naphthylamine (PBNA) exposed workforce. Prog Rubber Plastics Tech. 12(4):258–273.
Viet SM, Hanley KW, Carreon-Valencia T, Ruder AM. 2009. Assessment of exposure to o-toluidine and other aromatic amines in a rubber chemical manufacturing plant. NIOSH 2009 Feb IWSB Report #73.08.
Vitzthum OG, Werkhoff P, Hubert P. 1975. New volatile constituents of black tea aroma. J Agric Food Chem. 23:999–1003. 10.1021/jf60201a032
Ward E, Carpenter A, Markowitz S, Roberts D, Halperin W. 1991. Excess number of bladder cancers in workers exposed to ortho-toluidine and aniline. J Natl Cancer Inst. 83(7):501–506. 10.1093/jnci/83.7.501 2005633
Ward E, Roberts D, Dankovic D, Flesch J, Reed L, Fajen J. 1994. Response to “A re-examination of the cause of excess bladder cancers in chemical plant workers”. J Natl Cancer Inst. 86(1):60–62. 10.1093/jnci/86.1.60
Ward EM. 1997. Monitoring of aromatic amine exposures in workers at a chemical plant with a known bladder cancer excess - response. J Natl Cancer Inst. 89(10):735. 10.1093/jnci/89.10.735
Ward EM, Sabbioni G, DeBord DG, Teass AW, Brown KK, Talaska GG, Roberts DR, Ruder AM, Streicher RP. 1996. Monitoring of aromatic amine exposures in workers at a chemical plant with a known bladder cancer excess. J Natl Cancer Inst. 88(15):1046–1052. 10.1093/jnci/88.15.1046 8683635
Watanabe C, Egami T, Midorikawa K, Hiraku Y, Oikawa S, Kawanishi S, Murata M. 2010. DNA damage and estrogenic activity induced by the environmental pollutant 2-nitrotoluene and its metabolite. Environ Health Prev Med. 15(5):319–326. 10.1007/s12199-010-0146-1 21432561
Wegman RCC, De Korte GAL. 1981. Aromatic amines in surface waters of the Netherlands. Water Res. 15:391–394. 10.1016/0043-1354(81)90045-2
Weisburger EK, Russfield AB, Homburger F, Weisburger JH, Boger E, Van Dongen CG, Chu KC. 1978. Testing of twenty-one environmental aromatic amines or derivatives for long-term toxicity or carcinogenicity. J Environ Pathol Toxicol. 2(2):325–356. 84039
Wellner T, Luersen L, Schaller KH, Angerer J, Drexler H, Korinth G. 2008. Percutaneous absorption of aromatic amines - a contribution for human health risk assessment. Food Chem Toxicol. 46(6):1960–1968. 10.1016/j.fct.2008.01.036 18343009
Williamson MP, Elder PA, Knowles MA. 1994. The spectrum of TP53 mutations in bladder carcinoma. Genes Chromosomes Cancer. 9(2):108–118. 10.1002/gcc.2870090206 7513540
Windmill KF, McKinnon RA, Zhu X, Gaedigk A, Grant DM, McManus ME. 1997. The role of xenobiotic metabolizing enzymes in arylamine toxicity and carcinogenesis: Functional and localization studies. Mutat Res. 376(1-2):153–160. 10.1016/S0027-5107(97)00038-9 9202751
Woo YT, Lai DY. 2004. Aromatic amino and nitro–amino compounds and their halogenated derivatives. In: Bingham E, Cohrssen B, Powell CH, editors. Patty's Toxicology. John Wiley & Sons, Inc. 10.1002/0471435139.tox058
Yu MC, Skipper PL, Tannenbaum SR, Chan KK, Ross RK. 2002. Arylamine exposures and bladder cancer risk. Mutat Res. 506-507:21–28. 10.1016/S0027-5107(02)00148-3 12351141
Zdzienicka MZ, de Kok AJ, Simons JWIM. 1985. Assays for the induction of cell transformation in Chinese hamster ovary (CHO) cells and in Syrian hamster embryo (SHE) cells. Prog Mutat Res. 5:685–688.
Zhang N, Liu L, Liu F, Wagner CR, Hanna PE, Walters KJ. 2006. NMR-based model reveals the structural determinants of mammalian arylamine N-acetyltransferase substrate specificity. J Mol Biol. 363(1):188–200. 10.1016/j.jmb.2006.08.026 16959263