# Introduction and Methods

ortho-Toluidine (ortho-methylaniline, CASRN 95-53-4) is a synthetic chemical that is currently used in the United States in the manufacture of rubber chemicals, of a chemical intermediate for herbicides, of dye intermediates, and of the local anesthetic prilocaine. ortho-Toluidine has been listed in the Report on Carcinogens (RoC) as reasonably anticipated to be a human carcinogen since 1983 based on sufficient evidence of carcinogenicity from studies in experimental animals. Since that time, several cancer studies in humans have been published in the peer-reviewed literature, and the International Agency for Research on Cancer (2010, 2012) has concluded that ortho-toluidine is carcinogenic to humans (Group 1). ortho-Toluidine has been selected as a candidate substance for review for possible change in listing status in the RoC based on evidence of current U.S. exposure and an adequate database of cancer studies.

## Monograph Contents

This RoC monograph on ortho-toluidine reviewed the relevant scientific information and assesses its quality, applied the RoC listing criteria to the scientific information, and recommends an RoC listing status for ortho-toluidine. The monograph for ortho-toluidine provides information on the following topics: human exposure and chemical properties (Section 1), disposition and toxicokinetics (Section 2), cancer studies in humans (Section 3), cancer studies in experimental animals (Section 4), and mechanistic data and other related effects (Section 5), including studies of genetic toxicology and potential mechanisms of carcinogenicity, relevant toxicological effects. The information in Section 6 is a synthesis of Sections 2 through 5.

The scientific information reviewed in Sections 2 through 5 must come from publicly available, peer-reviewed sources. Information in Section 1, including chemical and physical properties, analytical methods, production, use, and occurrence, may come from publicly available, peer-reviewed or non-peer-reviewed sources.

## Process for Preparation of the Cancer Evaluation Component

The process for preparing the cancer evaluation component of the monograph included approaches for obtaining public and scientific input and using systematic methods (e.g., standardized methods for identifying the literature (see Appendix A), inclusion/exclusion criteria, extraction of data and evaluation of study quality using specific guidelines, and assessment of the level of evidence for carcinogenicity using established criteria).

The Office of the RoC (ORoC) followed the approaches outlined in the concept document, which discusses the scientific issues and questions relevant to the evaluation of ortho-toluidine carcinogenicity, the scope and focus of the monograph, and the approaches to obtain scientific and public input to address the key scientific questions and issues, for preparing the cancer evaluation component of the draft monograph. The ORoC presented the draft concept document for ortho-toluidine to the NTP Board of Scientific Counselors (BSC) at the June 21–22, 2012 meeting that provided opportunity for written and oral public comments and is available on the RoC website (https://ntp.niehs.nih.gov/go/37898), after which the concept was finalized and ortho-toluidine was approved by the NTP Director as a candidate substance for review.

### Key Scientific Questions and Issues Relevant for the Cancer Evaluation

The carcinogenicity of ortho-toluidine in experimental animals has been well established since the early 1980s, and no new data were identified to challenge these conclusions or to suggest that the findings in experimental animals are not relevant to humans. The monograph assesses the cancer studies in experimental animals that were not part of the original listing. The key questions and issues in the re-review of ortho-toluidine concern the evaluation of human cancer studies and mechanistic data.

#### Questions Related to the Evaluation of Human Cancer Studies

- What is the level of evidence (sufficient, limited, or inadequate) for the carcinogenicity of ortho-toluidine from studies in humans? What are the tissue sites?
- What are the major potential confounders (i.e., co-exposures) for evaluating urinary bladder cancer risk in these studies?
- Can any association between urinary bladder cancer and exposure to ortho-toluidine be explained by exposure to these co-exposures or other risk factors for urinary bladder cancer?

#### Questions Related to the Evaluation of Toxicological and Mechanistic Data

- What are the tumor sites that contribute to the sufficient evidence in experimental animals? Do the cancer studies in experimental animals published since the original listing provide additional information on the tumor sites?
- What are the potential mechanisms by which ortho-toluidine may cause cancer?
  - Is there evidence that these mechanisms occur in humans? Is there evidence to support biological plausibility for cancers of the liver in experimental animals and humans?

### Approach for Obtaining Scientific and Public Input

Additional scientific input from experts was obtained for exposure, human cancer studies, and disposition and toxicokinetics of ortho-toluidine. (Technical advisors are identified on the “CONTRIBUTORS” page.)

Public comments on scientific issues were requested at several times prior to the development of the draft RoC monograph, including the request for information on the nomination, and the request for comment on the draft concept document, which outlined the rationale and approach for conducting the scientific review. In addition, NTP posted its protocol for reviewing the human cancer studies for public input on the ORoC webpage for ortho-toluidine (available at https://ntp.niehs.nih.gov/go/37898) several months prior to the release of the draft monograph. Public comment on ortho-toluidine is available at https://ntp.niehs.nih.gov/go/37663.

### Methods for Writing the Cancer Evaluation Component of the Monograph

The procedures by which relevant literature was identified, data were systematically extracted and summarized, and the draft monograph was written, together with the processes for scientific review, quality assurance, and assessment and synthesis of data, are described below.

The preparation of the RoC monograph for ortho-toluidine began with development of a literature search strategy to obtain information relevant to the topics listed above for Sections 1 through 5 using search terms developed in collaboration with a reference librarian (see Appendix A for a detailed description of the literature search strategy). The citations (N = 2,755) identified from these searches were uploaded to a web-based systematic review software for evaluation by two separate reviewers using inclusion/exclusion criteria, and 278 references were selected for final inclusion in the draft monograph using these criteria. Studies identified from the literature searches but excluded from the review include publications on chemicals other than ortho-toluidine (or relevant structurally related compounds such as ortho-toluidine metabolites and analogues), and studies involving exposure to ortho-toluidine that reported results for topics not covered in this monograph (see Monograph Contents).

Information for the exposure, relevant cancer, and mechanistic sections was systematically extracted in tabular format and/or summarized in the text, following specific procedures developed by ORoC, from studies selected for inclusion in the monograph. All sections of the monograph underwent scientific review and quality assurance (QA) (i.e., assuring that all the relevant data and factual information extracted from the publications have been reported accurately) by a separate reviewer. Any discrepancies between the writer and the reviewer were resolved by mutual discussion in reference to the original data source.

Strengths, weaknesses, and study quality of the cancer studies for ortho-toluidine in humans (see Appendix D) or experimental animals (see Appendix E) were assessed based on a series of a priori questions. For the human cancer studies, these questions and the guidelines for answering the questions were available in the protocol (https://ntp.niehs.nih.gov/NTP/roc/thirteenth/Protocols/ortho-ToluidineProtocol_508.pdf), which also outlines the approach for evaluating potential confounding from occupational co-exposures or other lifestyle factors. Relevant genotoxicity and mechanistic studies were also assessed for their strengths and weaknesses.

Human exposure information was assessed to determine whether the evidence indicates that a significant number of persons residing in the United States are exposed to ortho-toluidine (see Foreword for information regarding the congressional mandate for the RoC). However, for many substances, this information is not available, and typically, U.S. exposure can be inferred from data on use, production volume, occupational monitoring, environmental occurrence, estimated daily intake, and biomonitoring. Because cancer has a long latency period, past exposure is also considered in the assessment.

RoC listing criteria (see text box) were applied to the available database of carcinogenicity data to assess the level of evidence (sufficient, limited, or inadequate) for the carcinogenicity of ortho-toluidine from studies in humans and the level of evidence (sufficient, not sufficient) from studies in experimental animals. The approach for synthesizing the evidence across studies and reaching a level of evidence conclusion was outlined in the protocol. The initial conclusions do not integrate the human cancer, experimental cancer, and mechanistic data. The evaluation of the mechanistic data included a complete discussion and assessment of the strength of evidence for potential modes of action for ortho-toluidine-induced neoplasia, including metabolic activation, cytotoxicity, genetic-related effects, and epigenetic effects. The RoC listing criteria were then applied to the body of knowledge (cancer studies in humans and experimental animals and mechanistic data) for ortho-toluidine to reach a listing recommendation.

RoC Listing Criteria

##### Known To Be Human Carcinogen:

There is sufficient evidence of carcinogenicity from studies in humans*, which indicates a causal relationship between exposure to the agent, substance, or mixture, and human cancer.

##### Reasonably Anticipated To Be Human Carcinogen:

There is limited evidence of carcinogenicity from studies in humans*, which indicates that causal interpretation is credible, but that alternative explanations, such as chance, bias, or confounding factors, could not adequately be excluded, OR

there is sufficient evidence of carcinogenicity from studies in experimental animals, which indicates there is an increased incidence of malignant and/or a combination of malignant and benign tumors (1) in multiple species or at multiple tissue sites, or (2) by multiple routes of exposure, or (3) to an unusual degree with regard to incidence, site, or type of tumor, or age at onset, OR

there is less than sufficient evidence of carcinogenicity in humans or laboratory animals; however, the agent, substance, or mixture belongs to a well-defined, structurally related class of substances whose members are listed in a previous Report on Carcinogens as either known to be a human carcinogen or reasonably anticipated to be a human carcinogen, or there is convincing relevant information that the agent acts through mechanisms indicating it would likely cause cancer in humans.

Conclusions regarding carcinogenicity in humans or experimental animals are based on scientific judgment, with consideration given to all relevant information. Relevant information includes, but is not limited to, dose response, route of exposure, chemical structure, metabolism, pharmacokinetics, sensitive sub-populations, genetic effects, or other data relating to mechanism of action or factors that may be unique to a given substance. For example, there may be substances for which there is evidence of carcinogenicity in laboratory animals, but there are compelling data indicating that the agent acts through mechanisms which do not operate in humans and would therefore not reasonably be anticipated to cause cancer in humans.

*This evidence can include traditional cancer epidemiology studies, data from clinical studies, and/or data derived from the study of tissues or cells from humans exposed to the substance in question that can be useful for evaluating whether a relevant cancer mechanism is operating in people.

## Preparation of the RoC

As mentioned in “Monograph Contents,” the substance profile for ortho-toluidine contains the NTP’s listing recommendation proposed for the RoC, a summary of the scientific evidence considered key to reaching that decision, and data on properties, use, production, exposure, and Federal regulations and guidelines to reduce exposure to ortho-toluidine. NTP submits the substance profiles for ortho-toluidine and other newly reviewed candidate substances with recommended listing status to the NTP Executive Committee for consultation and then to the Secretary of HHS for review and approval. Upon their approval by the Secretary, the next Edition of the RoC is prepared in electronic format, transmitted to Congress, and published on the RoC website for the public (for more information on the Process for Preparation of the RoC, see https://ntp.niehs.nih.gov/go/rocprocess).