# Appendix F Data Tables for Genotoxicity and Other Relevant Data

The 14 tables on the following pages contain data discussed in the “Mechanisms and Other Relevant Effects” section.

Genotoxicity data are reported for in vitro studies of ortho-toluidine mutagenicity in bacteria and yeast (Table F-1), co-mutagenic effects of ortho-toluidine and norharman in bacteria (Table F-2), genetic effects of ortho-toluidine in non-mammalian eukaryotes (Table F-3), in vitro genotoxicity studies of ortho-toluidine in mammalian cells (Table F-4), cell transformation studies of ortho-toluidine in rodent cells (Table F-5), DNA adducts from ortho-toluidine exposure in vivo (Table F-6), ortho-toluidine-releasing DNA adducts in bladder tissue from cancer patients and sudden death victims (Table F-7), genotoxicity effects of ortho-toluidine in vivo (Table F-8), mutagenicity of ortho-toluidine metabolites (Table F-9), hemoglobin and albumin adducts formed in vitro and in vivo (Table F-10).

Table F-1 Genetic Effects of ortho-Toluidine in Bacteria

Bacteria Strains | Endpoint | Res.^a^ − S9 | Res.^a^ + S9 | HID (μg/Plate)^b^ | LED (μg/Plate)^b^ | Comments
S. typhimurium TA92 TA100 TA102 TA1535 G46 | Reverse mutation (base pair: plate incorporation, pre-incubation, or fluctuation method) | 0/1 0/26 0/2 0/17 0/1 | 0/1 5/26 0/2 0/18 0/1 | 2,000 10,000 10,000 10,000 1,000 μg/mL | 100 μg/mL | TA100 positive in one study with 30% hamster S9 but negative with rat S9. Two positive studies with rat S9 (30%) and one positive study with the fluctuation test with rat S9. Most recent study (An et al. 2010) reported weak positive response in TA100 with rat S9 (concentration not specified) at 2,000 to 4,000 μg/plate
S. typhimurium TA97 TA98 TA1537 TA1538 C3076 D3052 | Reverse mutation (frameshift: plate incorporation, pre-incubation, or fluctuation method) | 0/3 0/25 0/16 0/15 0/1 0/1 | 0/3 2/26 0/16 2/16 0/1 0/1 | 10,000 10,000 10,000 10,000 1,000 μg/mL 1,000 μg/mL | 1.3 μg/mL 10 μg/mL | One positive study with TA98 required 30% rat S9. The other positive study with TA98 required phenobarbitol-induced rat S9. One positive study with TA1538 used the fluctuation test and a mixed-induced S9 (phenobarbitone + β-naphthoflavone) and the other positive study used the standard plate incorporation method and Aroclor-induced rat S9.
S. typhimurium TA98 TA100 | Reverse mutation (host-mediated assay) | 0/1 0/1 | 1/1 0/1 | 1,000 1,000 | 500 | Urine extracts from rats administered 300 mg/kg o-toluidine was mutagenic in TA98 with 30% hamster S9.
S. typhimurium BA13 TM677 | Forward mutation arabinose resistance 8-azaguanine resistance | NT 0/1 | 1/1 0/2 | 965 500 | 480 | BA13 positive only with 30% rat S9, negative with 10% rat S9 at 965 μg/plate. TM677 studies used standard protocols with Aroclor or phenobarbitol induced rat liver S9.
S. typhimurium TA1535/pSK102 | Prophage induction, SOS repair, DNA strand breaks or cross-links | 0/1 | 0/1 | 1,670 | – | –
E. coli WP2 uvrA | Reverse mutation | 0/5 | 1/5 | 1,000 | 50 μg/mL | Positive in one study with 10% rat S9 but negative in four other studies.
E. coli EMT-1,-2,-3,-4 | Zorotest lambda prophage, gal gene expression | 0/1 | 0/1 | 5,000 | – | –
E. coli JC2921 JC5519 | rec assay (growth inhibition) | 0/1 0/1 | 1/1 1/1 | NR | NR | Negative in four other DNA repair deficient strains (JC7623, 7689, 8471, and 9238).
E. coli rec strains | Differential toxicity | 1/3 | 0/2 | 2,500 | 20 μL/disc | Positive result was not confirmed in repeat studies in two different labs.
E. coli W3110 (pol A^+^) P3478 (pol A^−^) | Differential toxicity (liquid suspension) | 0/1 | 0/1 | 250 | – | No difference in survival in the polymerase deficient strain compared to the wild-type strain.
E. coli 58-161 envA C600 | Prophage lambda induction, SOS repair | NT | 1/1 | – | 2,500 | Tested with metabolic activation only. Chemical-induced induction was 25-fold greater than spontaneous induction.
B. subtilis H17 rec^+^ M45 rec^−^ | rec assay (DNA damage) | 1/1 | 1/1 | – | NR | Only one study conducted. Used the more sensitive spore method rather than vegetative cells. Only reported the maximum dose tested (20 μL/disc). Rat and yellowtail fish S9 used.

Sources: An et al. (2010); Danford (1991); IARC (2010e).

HID = highest ineffective dose; LED = lowest effective dose; NR = not reported; NT = not tested; Res. = Results.

^a^ Number of positive studies/number of studies reviewed.

^b^ HIDs are the same value with or without S9. Since no studies were positive without S9, the LEDs values apply only to the few positive studies with S9.

Table F-2 Co-mutagenic Effects of ortho-Toluidine and Norharman in Bacteria

Bacteria Strains | Endpoint | Results^a^ − Norharman (HID/LED μg/mL) | Results^a^ + Norharman (HID/LED μg/mL) | Reference
S. typhimurium TA98 TA100 | Reverse mutation (plate incorporation) | − (100) − (100) | + (20) + (20) | Nagao et al. (1978) (cited in Danford (1991))
S. typhimurium TA98 TA100 TA1537 | Reverse mutation (plate incorporation) | − (500) − (500) − (500) | + (25) + (25) + (25) | Nagao and Takahashi (1981) (cited in Danford (1991))
S. typhimurium TA98 | Reverse mutation (pre-incubation) | − (25) | + (25) | Nagao et al. (1978) (cited in Danford (1991))
S. typhimurium TA98 TA100 TA1535 TA1538 | Reverse mutation (pre-incubation) | − (100) − (100) − (100) − (100) | + (20) − (100) − (100) + (20) | Sugimura et al. (1982) (cited in Danford (1991))
S. typhimurium TA98 | Reverse mutation (pre-incubation) | − (100) | + (100) | Mori et al. (1996)
S. typhimurium TA98 | DNA adducts | − (4 mg) | + (4 mg) | Mori et al. (1996)
S. typhimurium YG1024 | DNA adducts | − (4 mg) | + (4 mg) | Hada et al. (2001)

− = negative; + = positive; HID = highest ineffective dose; LED = lowest effective dose.

^a^ All positive responses occurred with metabolic activation.

Table F-3 Genetic Effects of ortho-Toluidine in Non-mammalian Eukaryotes

Test System | Endpoint | Results^a^ − S9 | Results^a^ + S9 | HID (μg/mL) | LED (μg/mL)
Aspergillus nidulans | Forward mutation | 0/1 | NT | 504 | –
Aspergillus nidulans | Genetic crossing-over | 0/1 | NT | 2,520 | –
Saccharomyces cerevisiae | Differential toxicity | 1/2 | 1/2 | 1,000 | 300
Saccharomyces cerevisiae | Gene conversion | 1/8 | 2/8 | 2,000 | 50
Saccharomyces cerevisiae | Mutations | 2/8 | 1/7 | 2,500 | 378
Saccharomyces cerevisiae | Deletion assay | 2/2 | 1/1 | – | 1,000
Saccharomyces cerevisiae | Interchromosomal recombination | 0/2 | 0/2 | 8,000 | –
Saccharomyces cerevisiae | Aneuploidy | 2/3 | 2/2 | 1.5 μL/mL | 50
Schizosaccharomyces pombe | Forward mutation | 0/1 | 0/1 | 1,920 | –
Drosophila melanogaster | Somatic mutation and recombination | 5/6 | | 2 mM (feed) | 0.94 mM (feed)

Sources: Danford (1991); IARC (2010e), Brennan and Schiestl (1999).

HID = highest ineffective dose; LED = lowest effective dose; NT = not tested.

^a^ Number of positive studies/number of studies reviewed.

Table F-4 In Vitro Genetic Toxicology Studies in Mammalian Cells

Endpoint | Cell Type (Assay) | Results^a^ −S9 No. Studies | LED (μg/mL) | HID (μg/mL) | Results^a^ +S9 No. Studies | LED (μg/mL) | HID (μg/mL)
Human cells
DNA damage/strand breaks | MCL-5^b^ (comet assay) | 1/1 | 454 | – | – | – | –
DNA damage/strand breaks | Exfoliated milk cells^b^ (comet assay) | 1/1 | [91] | – | – | – | –
DNA damage/strand breaks | Urinary bladder mucosa^b^ (comet assay) | 1/1 | [1,714] | – | – | – | –
Unscheduled DNA synthesis | HeLa cells | 0/3 | – | 1,000 | 3/3 | 25 | –
Gene mutations | TK6 lymphoblasts (TK) | 0/1 | – | 750 | 1/1 | 450 | –
Gene mutations | AHH-1 lymphoblasts^b^ (HGPRT) | 1/1 | 300 | – | – | – | –
Sister chromatid exchange | Lymphocytes | 1/2^c^ | [21.4] | – | 0/1 | – | 600
Micronucleus | Lymphocytes | 1/1 | [214] | – | 0/1 | – | [960]
Rodent cells
DNA damage/strand breaks | Rat hepatocytes^b^ (alkaline elution) | 1/1 | 319 | – | – | – | –
DNA damage/strand breaks | Rat urinary bladder mucosa^b^ (comet assay) | 1/1 | [857] | – | – | – | –
DNA damage/strand breaks | Chinese hamster ovary (CHO) (alkaline sucrose gradient) | 1/2 | 4,280 | 5,360 | 2/2 | 2,140 | –
Unscheduled DNA synthesis | Rat hepatocytes^b^ | 1/6 | 107 | 53.5 | – | – | –
Unscheduled DNA synthesis | Syrian golden hamster hepatocytes^b^ | 0/2 | – | 10.7 | – | – | –
Gene mutations | CHO (Hprt, ouabain resistance) | 0/1 | – | 500 | ?/1 | – | –
Gene mutations | Chinese hamster lung (CHL) V79 (Hprt, ouabain resistance) | 1/4 | 500 | 2,000 | 0/4 | – | 1,000
Gene mutations | Mouse lymphoma L5178Y (Tk) | 2/6 | 10 | 1,004 | 0/5 | – | 1,004
Gene mutations | Mouse lymphoma L5178Y (Hprt) | 1/2 | 200 | 1,300 | 1/2 | 200 | 1,300
Gene mutations | L5178Y (ouabain resistance) | 0/2 | – | 1,004 | 0/2 | – | 1,004
Gene mutations | Mouse BALB/c 3T3 (ouabain resistance) | – | – | – | 1/1 | 250 | –
Sister chromatid exchange | CHO | 3/5 | 300 | [2,140] | 1/5 | ? | [2,140]
Sister chromatid exchange | CHL | 1/1 | 268 | – | 1/1 | 268 | –
Sister chromatid exchange | Rat liver epithelial cells (RL_4_)^b^ | 1/1 | 21.8 | – | – | – | –
Sister chromatid exchange | CHO (plasma from exposed rats) | 1/1 | 400^d^ | – | – | – | –
Chromosomal aberrations | Chinese hamster liver fibroblasts (CH1-L)^b^ | 1/1 | 12 | – | – | – | –
Chromosomal aberrations | CHO | 1/3 | 500 | [2,140] | 2/3 | 250 | [2,140]
Chromosomal aberrations | CHL | 0/1 | – | 1,500 | 1/1 | 1,000 | –
Chromosomal aberrations | RL_4_^b^ | 1/1 | 700 | – | – | – | –
Micronucleus | CHO | 0/1 | – | [4,286] | 0/1 | – | [4,286]
Micronucleus | Syrian hamster embryo (SHE) | 1/1 | NR | – | – | – | –
Aneuploidy/polyploidy^e^ | CH1-L^b^ | 1/1 | 60 | – | – | – | –
Aneuploidy/polyploidy^e^ | CHL | 1/1 | 1,000 | – | 0/1 | – | 1,500
Aneuploidy/polyploidy^e^ | RL_4_^b^ | 0/1 | – | 700 | – | – | –
Mitotic spindle | CH1-L^b^ | 0/1 | – | 120 | – | – | –
Inhibition cellular communication | CHL V79^b^ | 2/3 | 5 | 535 | – | – | –

Sources: Danford (1991); IARC (2010e); Martin (2000a; 2000b) (DNA damage in human exfoliated milk cells), Robbiano et al. (2002) (DNA damage in human bladder mucosa and rat bladder mucosa cells).

[ ] Indicates data provided by original author (e.g., as molarity) was converted to µg/ml for ease of comparison.

HID = highest ineffective dose; LED = lowest effective dose; NR = not reported; ? = inconclusive.

^a^ Number of positive studies/number of studies reviewed.

^b^ Cells with an intrinsic metabolizing system; no testing +S9.

^c^ One test was positive and the other was inconclusive.

^d^ In vivo metabolism: CHO cells exposed to plasma from rats treated with 400 mg/kg ortho-toluidine.

^e^ All studies examined 100 metaphases with 2 to 3 replicates/dose and compared results to negative and positive controls.

Table F-5 Cell Transformation Studies of ortho-Toluidine in Rodent Cells

Cell Type | Results −S9 | Results +S9 | HID (μg/mL) | LED (μg/mL) | Reference
Mouse BALB/c 3T3 | − | NT | 2 | | Maeshima et al. (2010)
Mouse BALB/c 3T3 | +^a^ | NT | | 800 | Tanaka et al. (2012)
Mouse BALB/c 3T3 | − | + | 330 | 150 | Matthews et al. (1985)
Mouse Bhas 42^b^ initiation assay promotion assay | − + | NT NT | 800 | 300 | Sakai et al. (2010)
Syrian hamster embryo (SHE) cells^c^ | + | NT | | 50 | Ahmadzai et al. (2012)
Syrian hamster embryo (SHE) cells^c^ | +^d^ | NT | | 40 | Pant et al. (2012)
Syrian hamster embryo (SHE) cells^c^ | + | NT | | 20–600^e^ | Maire et al. (2012)
Syrian hamster embryo (SHE) cells^c^ | + | NT | | 1 | Barrett and Lamb (1985)
Syrian hamster embryo (SHE) cells^c^ | + | NT | | 100 | Sanner and Rivedal (1985)
Syrian hamster embryo (SHE) cells^c^ | + | NT | | 750 | Kerckaert et al. (1998)
SHE-SA7^c^ | (+) | NT | | 965 | Hatch and Anderson (1985)
Mouse C3H/10T1/2 | − | (+) | | 600 | Lawrence and McGregor (1985)
Mouse C3H/10T1/2 | + | NT | | 500 | Nesnow et al. (1985)
Chinese hamster ovary cells | − | − | 500 | | Zdzienicka et al. (1985)
Baby hamster kidney (BHK-21) cells | + | + | | 362 | Daniel and Dehnel (1981)
Baby hamster kidney (BHK-21) cells | NT | + | | 250 | Styles (1981)
RLV/F344 rat embryo cells^c^ | (+) | NT | | 10 | Suk and Humphreys (1985)

− = negative; + = positive; (+) = weak positive; HID = highest ineffective dose; LED = lowest effective dose; NT = not tested; RLV = Rauscher-leukemia virus; SA7 = Simian Agent 7 adenovirus.

^a^ Tested in three labs: initial results were positive in 2 labs and negative in another although the number of foci was increased at the highest dose. Retest was clearly positive.

^b^ BALB/c 3T3 clone transfected with an oncogenic murine ras gene (v-Ha-ras).

^c^ Cells with an intrinsic metabolizing system.

^d^ Tested in three labs: initial result in one lab was inconclusive due to cytotoxicity. Retest at lower concentration was positive.

^e^ Tested positive in four labs but different LEDs in each lab.

Table F-6 DNA Adducts from ortho-Toluidine Exposure In Vivo

Reference | Sex:Species (No./Group) | Tissue | Exp. Route^a^ | Dose or HID/LED (mg/kg) | Results | Evaluation: Comments
Brock et al. (1990) | M:Crl:CD rats (4–5) | Liver | gavage | 500 | <1 pmol/µg | Positive: binding peaked at 24 hr. Levels were lower than measured with para-toluidine (see Section 5.2.2), specific adduct was not identified
Jones and Sabbioni (2003) | F:Wistar rats (2) | Liver | Gavage | ~54^b^ | Possible dG adduct | Negative: tentatively identified dG adduct determined to be false positive. Detection limit: <3.1/10^8^ bases
Duan et al. (2008) | M:F344 rats (3) | liver nose bladder WBCs | gavage (1 or 7 daily doses) | 54 54 322 322 | 1.2/10^7^ nt 0.55/10^7^ nt ND ND | Positive: liver and nasal mucosa, single and multiple doses, specific adducts were not identified Negative: urinary bladder and WBCs Detection limit: ~1/10^8^ bases

Exp. = Exposure; HID = highest ineffective dose; LED = lowest effective dose; ND = not detected; nt = nucleotides; WBCs = white blood cells.

^a^ Single dose unless otherwise noted.

^b^ Administered 0.5 mM/kg = ~54 mg/kg.

Table F-7 ortho-Toluidine-releasing DNA Adducts (fmol/μg DNA ± S.D.) in Bladder Tissue from Cancer Patients (CP) and Sudden Death Victims (SDV)^a^

Group | CP | | | SDV
Group | (N) | Epithelial | Submucosal | (N) | Bladder Tumor
Non-smokers | 27 | 0.136 ± 0.280 | 0.292 ± 0.784 | 7 | 10.580 ± 3.055***
Smokers | 19 | 0.378 ± 0.910 | 0.232 ± 0.571 | 5 | 6.120 ± 5.193*
All | 46 | 0.236 ± 0.625 | 0.267 ± 0.697 | 12 | 8.722 ± 4.491***

* p < 0.05; ***p < 0.001 (Mann-Whitney test; compared to bladder tissue from sudden death victims).

Source: Böhm et al. (2011).

^a^ Direct evidence for covalent binding of ortho-toluidine with DNA was not provided by the authors.

Table F-8 Genotoxic Effects of ortho-Toluidine In Vivo

Reference | Test System (Time after Dosing hr) | Sex:Species (No./Group) | Tissue | Exp. Route^a^ | Dose or HID/LED (mg/kg) | Results | Evaluation:Comments
Cesarone et al. (1982) | DNA SSB (4) | M: Swiss CD1 mice (8) | liver kidney | i.p. | 0 100 0 100 | 21 × 10^-3^/mL^b^ 63 × 10^-3^ 22 × 10^-3^ 51 × 10^-3^ | Positive Results reported as mean elution rate (see footnote).
Robbiano et al. (2002) | DNA damage (20) | M: Sprague-Dawley rats (3) | bladder kidney liver | gavage | ¼ LD_50_^c^ ½ LD_50_ ½ LD_50_ ½ LD_50_ | ~7.4* 9.7* ~1 ~1 | Positive (bladder) Negative (kidney and liver) Comet assay. Results reported as the ratio of treated/control tail moment.
Sekihashi et al. (2002) | DNA damage (3, 8, 24) | M: ddY mice (4) | stomach colon liver kidney bladder lung brain bone marrow | gavage | 600 (½ LD_50_) | [underlined: Sampling time (h)] [underlined: 0] [underlined: 3] [underlined: 8] [underlined: 24] 5.8 12.0 12.6 5.0 2.8 6.2 4.3 4.8 2.4 2.2 8.5 3.5 2.0 5.0 6.6 2.2 5.1 16.7 21.5 9.9 2.2 17.1 12.3 2.8 0.9 7.3 9.2 1.2 0.8 1.9 3.8 1.8 | Positive (Bold) stomach (3** & 8*** h), liver (8* h), bladder (3** & 8*** h), lung (3*** & ***8 h), brain (8* h) Untreated animals as negative controls DNA migration (µm) = length of whole comet – diameter of comet head 50 nuclei measured/organ/animal
Sekihashi et al. (2002) | DNA damage (3, 8, 24) | M: Wistar rats (4) | stomach colon liver kidney bladder lung brain bone marrow | gavage | 600 (½ LD_50_) | [underlined: Sampling time (h)] [underlined: 0] [underlined: 3] [underlined: 8] [underlined: 24] 13.0 15.0 30.6 27.4 10.7 15.1 20.0 22.7 1.8 2.3 5.4 2.4 2.8 23.7 15.4 7.9 8.0 13.1 17.7 16.9 2.4 6.7 4.4 3.4 1.8 2.7 1.0 1.8 1.6 1.2 0.5 1.0 | Positive (bold) stomach (8* & 24* h), colon (24* h), kidney (3** h), bladder (8* h) Untreated animals as negative controls DNA migration (µm) = length of whole comet – diameter of comet head 50 nuclei measured/organ/animal
Neal and Probst (1983) | SCE (18) | F: Chinese hamsters (3) | bone marrow | i.p. or gavage^d^ | 0 100 200 300 | 4.1 ± 1.3 4.5 ± 1.6 5.6 ± 2.0* 5.6 ± 2.1* | Weak positive 25 metaphases/animal were scored (SCE/metaphase).
McFee et al. (1989) | SCE (23) | M: B6C3F_1_ mice (4) | bone marrow | i.p. | 0 150 300 600 Trend | 3.3 ± 0.21 4.5 ± 0.28 6.1 ± 0.69 6.5 ± 0.35* p = 0.0001 | Positive 2nd trial conducted at 450 and 600 mg/kg. Significant at 450 but not at 600. 25 metaphases/animal scored. Pronounced sedation occurred at doses >300 mg/kg.
McFee et al. (1989) | CA (17) | M: B6C3F_1_ mice (7–8) | bone marrow | i.p. | 0 150 300 600 Trend | 1.5 ± 0.69 0.75 ± 0.37 1.1 ± 0.60 0.57 ± 0.37 p = −0.14 | Negative 50 metaphases/animal scored. Results represent % aberrant cells.
McFee et al. (1989) | MN (24, 48, 72) | M: B6C3F_1_ mice (8) | bone marrow | i.p. | 0 75 150 300 Trend | 2.16–2.65 0.56–2.39 1.57–2.28 2.00–3.02 p = 0.15–0.31 | Negative Data are the mean MN/1000 PCEs scored. Considerable fluctuation in percentage of PCEs observed but no apparent pattern. Values shown indicate range from 24 to 72 hrs.
Salamone et al. (1981) | MN (30, 48, 72, 96) | M: B6C3F_1_ mice (5) | bone marrow | i.p. | 270 × 2 169 337 | 1 (72 hr) 5 (30 hr) 2 (72 hr) | Negative Data are the sum of MN/500 PCEs/mouse for 4 to 5 mice at peak sampling time. Multiple sampling times used to increase sensitivity. Phase 1 mice received 2 injections (24 hr apart) at 80% LD_50_ and sampled at 48, 72, and 96 hr. Phase 2 mice received single injection at 50% or 100% LD_50_ and sampled at 30, 48, and 72 hr). LD_50_ = 0.338 mL/kg or about 337.3 mg/kg.
Tsuchimoto and Matter (1981) | MN (6) | M/F: CD-1 mice (4) | bone marrow | i.p. | 0 40 × 2 80 × 2 160 × 2 | 0.08 (0.07–0.13) 0.08 (0.0–0.13) 0.05 (0.0–0.13) 0.15 (0.0–0.27) | Negative Two doses given 24 hr apart. Mice were killed 6 hr after the second dose. Data are the mean % micronucleated PCEs and range (1,500 PCEs scored/animal).
Suzuki et al. (2005) | MN (3–5 days) | M: F344 or SD rats^d^ (4) | liver | i.p. or gavage^d^ | [underlined: Lab 1] 0 300 600 [underlined: Lab 2] 0 300 600 | 0.05 0.1–0.11 0.01–0.06 0.04 0.04–0.08 0.01–0.04 | Negative Data are the mean % micronucleated hepatocytes (2,000 hepatocytes scored/animal) and range over sampling times (3 to 5 days) Experiments conducted independently in two laboratories.
Suzuki et al. (2005) | MN (2 days) | M: F344 or SD rats^d^ (4) | Blood | i.p. or gavage^d^ | [underlined: Lab 1] 0 300 600 [underlined: Lab 2] 0 300 600 | 0.08 ± 0.06 0.25 ± 0.11* 0.36 ± 0.09** 0.21 ± 0.06 0.19 ± 0.03 0.46 ± 0.11** | Positive Data are mean % micronucleated reticulocytes (2,000 scored/animal on day 2) ± S.D.
Fernandez et al. (1989) | MN (12 days) | Newt larvae (15) | RBCs | Tank water | 0 ppm 4 ppm 20 ppm 40 ppm | 5.3 (87) 9.3 (140) 13.1 (197)* 27.2 (408)* | Positive Results are mean frequencies of micronucleated RBCs/1,000 cells (total no. cells with MN).
Topham (1980) | Transmissible genetic damage: abnormal sperm morphology (5 wk) | M: (CBA × BALB/c)F_1_ mice (5) | Sperm | i.p. | 400 × 5 | Small increase at high doses | Negative Dose range 50 to 500 mg/kg, 500 mg/kg dose was toxic, repeat studies did not confirm original observation. All tests included positive controls.
Topham (1981) | Transmissible genetic damage: abnormal sperm morphology (5 wk) | M: (CBA × BALB/c)F_1_ mice (5) | Sperm | i.p. | 100 × 5 250 × 5 | 1.4% increase 1.7% increase | Inconclusive: Increase was statistically significant compared to controls but did not fulfill all criteria for a positive response (i.e., response was < double the response in negative controls). Dose range 50 to 500 mg/kg, 500 mg/kg dose was lethal. At least 250 sperm examined. All tests included positive controls.
Amlacher and Ziebarth (1979) (cited in Danford (1991)) | DNA synthesis inhibition. | ?: suckling mouse | Kidney | i.p. or intra-gastric | 15%–30% of LD_50_ | No effect | Negative Measured as mean decrease of silver grains on autoradiograph per 150 renal cell nuclei compared to nuclei of untreated controls. Few details provided in original reference or in Danford (1991).
Seiler (1977) | DNA synthesis inhibition | M: Mouse (3–4) | Testes | gavage | 200 | 75%* | Positive Results reported as % of tritiated thymidine incorporation compared to concurrent controls. Only one dose tested.

* p < 0.05 compared with controls; **p < 0.01 compared with controls.

CA = chromosomal aberration; Exp. = Exposure; HID = highest ineffective dose; i.p. = intraperitoneal; LED = lowest effective dose; MN = micronucleus; PCEs = polychromatic erythrocytes; RBCs = red blood cells; SCE = sister chromatid exchange; SSB = single strand breaks.

^a^ Single dose unless otherwise noted.

^b^ Values represent the elution rate (K) where K = ln (DNA% retained on filter)/eluted volume.

^c^ LD_50_ value was not reported, HSDB (2011) reported rat oral LD_50_ of 750 mg/kg, NTP (1996) reported values of 900 to 2,951 mg/kg.

^d^ Authors tested multiple chemicals but did not provide further detail.

Table F-9 Mutagenicity of ortho-Toluidine Metabolites in Salmonella Strains

Metabolite | TA100 (−S9) | TA100 (+S9) | TA1535 (−S9) | TA1535 (+S9) | TA98 (−S9) | TA98 (+S9) | HID/LED (μM/plate)
N-Hydroxy-o-toluidine | − | + | − | + | − | − | 0.5/1
o-Nitrosotoluene | − | + | − | + | − | − | 0.5/1
N-Acetyl-o-toluidine | − | − | NT | NT | − | − | 10
N-Acetyl-N-hydroxy-o-toluidine | − | − | + | − | − | + | 5/10
N-Acetoxy-N-acetyl-o-toluidine | − | − | NT | NT | − | − | 10
2-Hydroxy-6-methyl-acetanilide^a^ | − | − | NT | NT | − | − | 10^c^
o-Azoxytoluene | − | − | NT | NT | − | − | 10^c^
o-Azotoluene | − | − | NT | NT | − | − | 10^c^
Anthranilic acid^b^ | − | − | − | − | − | − | 5,000 μg/ plate

Sources: Chung et al. (1981); Gadupudi and Chung (2011); Gupta et al. (1987); Hecht et al. (1979).

HID/LED = highest ineffective dose/lowest effective dose; − = negative; + = positive; NT = not tested.

^a^ N-acetyl-2-amino-meta-cresol.

^b^ Also tested negative in S. typhimurium strains TA1537, TA1538, and TA102.

^c^ Tested doses not explicitly stated; HID inferred from highest doses tested with other negative compounds.

Table F-10 Hemoglobin and Albumin Adducts Formed In Vitro and In Vivo

Reference | Exposure Conditions Route of Exposure o-Toluidine Concentration Time of Sacrifice | Protein | Adduct Detection | Results | Comments
In vitro (protein)
Stettler et al. (1992) | 130 nmol rat liver microsomes and cofactors 10 to 60 minutes | Albumin (rat or human) | Radioactivity | No appreciable binding | Authors state that conditions may not have been optimal
Stettler et al. (1992) | 130 nmol rat liver microsomes and cofactors 10 to 60 minutes | Hb | Radioactivity | 8–9 ng/mg Hb | Microsomes prepared from phenobarbital-induced animals increased o-toluidine binding 1.5-fold (27.2 ng/mg) compared to control microsomes (16.2 ng)
In vivo studies
Birner and Neumann (1988) | B6C3F_1_ mice (female) Gavage 0.47 to 0.6 mmol/kg 24 hr sacrifice | Hb | Base hydrolysis GC | HBI = 2.1 ± 0.4 | –
Birner and Neumann (1988) | Wistar rats (female) Gavage 0.47 to 0.6 mmol/kg 24 hr sacrifice | Hb | Base hydrolysis GC | HBI = 4.0 ± 0.65 | –
DeBord et al. (1992) | Sprague-Dawley rats (male) i.p.: Dose effect study: 10, 20, 40, 50, or 100 mg/kg bw 4 hr sacrifice Time course study: 50 mg/kg, 2–72 hr sacrifice; 100 mg/kg, 4 hr–28 d sacrifice p.o. 100 mg/kg 24 hr sacrifice | Hb | Radioactivity | Dose effect study: Highest level (23.0 ± 5.1 ng/mg Hb) at highest dose (100 mg/kg) HBI = 51.8 Time course study (50 mg/kg): Highest level (14.2 ± 2.6 ng/mg Hb) at 24 hr p.o. 10.0 ± 0.8 ng/mg Hb | Hb peak at 24 hr in both time course studies Radioactivity still available at 28 days Half-life 12.3 days Pretreatment with phenobarbital (PB) or [3-naphthoflavone Increased binding in PB-induced animals considered not statistically significant; large rat to rat variability in the treatment group Due to high variability of findings, study considered inadequate to determine role of metabolic activation.
DeBord et al. (1992) | Sprague-Dawley rats (male) i.p. Same design as Hb study for dose effect and time course (albumin not analyzed in p.o. animals) | Albumin | Radioactivity | Dose effect: Highest level (32 ng/mg albumin) at highest dose (100 mg/kg) Time course study (50 mg/kg): Highest level (15.6 ng/mg Hb) at 4 hr | Albumin peak at 4 hr in both time course studies No radioactivity at 72 hr (50 mg/kg) or 14 d (100 mg/kg) Half-life = 2.6 d
Stettler et al. (1992) | Sprague-Dawley rats (male)^a^ i.p. 110, 20, 40, 50 100 mg/kg 4 hr | Hb | Base hydrolysis Radioactivity/ HPLC or GC | Dose-related response | Higher doses: decreased in the percent of bound o-toluidine that could be hydrolyzed suggesting other adducts are formed that are not susceptible to base-hydrolysis
Cheever et al. (1992) | Sprague-Dawley rats (male) Route of exposure study: 50 mg/kg/wt i.p. and po 4 hr sacrifice Time course studies: 50 mg/kg i.p. up to 72 hr; 100 mg/kg i.p. up to 28 d Dose effect study: 10 to 100 mg/kg bw i.p. 4 hr | Hb | Base hydrolysis Thin layer chromatography/ HPLC or GC-MS | Route of exposure study: i.p. 3.5 ± 1.6 ng/mg Hb p.o. 0.4 ± 0.6 ng/mg Hb Time course studies 50 mg/kg: Highest level (3.7 ± 0.5 ng/mg Hb) at 24 hr; 100 mg/kg: adducts detected up to 28 d Dose Effect study Highest level (7.5 ± 0.9 ng/mg Hb) at 100 mg/kg | Half-life = 11 day (following single i.p. dose of 100 mg/kg)
Cheever et al. (1992) | Sprague-Dawley rats (male) Same design as Hb study | Albumin | Base hydrolysis Thin layer chromatography/ HPLC or GC-MS | Time course study: (50 mg/kg): Highest level (2.5 ng/mg albumin) at 4 hr | Not detected at 24 hr

HBI = hemoglobin binding index = (mmol bound/mmol Hb)/mmol dose/kg body wt; Hb = hemoglobin.

^a^ Species and sex not clear, but male Sprague-Dawley specified as being used for the preparation of the phenobarbital-induced microsomes.