# Appendix E Assessment of the Quality of the Individual Animal Cancer Studies on Exposure to ortho-Toluidine

Seven publications, reporting on eleven studies, were identified that were either long-term carcinogenicity studies or reported neoplastic lesions in experimental animals exposed to ortho-toluidine (See Section 4, Cancer studies in Experimental Animals). Each of these primary studies was systematically evaluated in a two-step process by first evaluating whether the level of detail reported for key elements of study design, experimental procedures, and carcinogenesis endpoints was adequate for evaluating its quality and interpreting its results. Studies that were adequately reported were further evaluated for concerns for study quality that might negatively impact the ability to assess carcinogenicity. Those studies with adequate reporting and that did not have major concerns of study quality are included in the cancer assessment described in Section 4, Cancer Studies in Experimental Animals.

## E.1 Adequacy of Reporting for ortho-Toluidine Studies

The reporting quality of key elements for two of the eleven studies was considered to be inadequate for cancer evaluation: a study in mice exposed to ortho-toluidine by subcutaneous injection (Pliss 2004) and a tumor initiation study in genetically altered fish (Anders et al. 1991). In the study in mice, the total number of animals exposed, and the duration period were not clearly defined; the authors noted that some deaths occurred in the exposed animals, and more animals were added later, but did not provide any details on the cause of death, the exposure duration of the animals that died, and the timing of the addition of new mice to the study.

There is no reference to validation or standardization of this fish model for cancer detection. The almost complete lack of description of study design, study validation, and data analysis makes this study inadequate for evaluation of carcinogenicity. The reporting is inadequate for details such as the tumor incidence of untreated fish, necropsy procedures, the sex used, dose selection rationale or toxicities, duration of observation, and purity of chemical.

## E.2 Study Quality Assessment

Table E-1 (rats) and Table E-2 (other animals) report the assessment of nine studies that were considered to have adequate reporting quality, including feeding studies in rats (Hecht et al. 1982; NCI 1979; NTP 1996; Weisburger et al. 1978), mice (NCI 1979; Weisburger et al. 1978) dogs (Pliss 2004) and subcutaneous injection studies in hamsters (Hecht et al. 1983) and rats (Pliss 2004). Study quality was assessed using questions related to the following study performance elements: substance characterization, animal husbandry, study design, endpoint assessment, and data interpretation. In most cases, each question inquires whether there are concerns (minimal, some, major, unknown, i.e., no information reported) that the quality of a specific study element is adequate for attributing any neoplastic endpoints to exposure to ortho-toluidine. In general, the ranking of the concerns for the study elements is based on how far each study element deviates from the ideal (see below).

The assessment of the overall quality of a study is based on consideration of the individual elements and how they impact the usefulness of that study in assessing carcinogenicity. Studies that were given the most weight in the evaluation (e.g., those with no or minimal concerns in key elements) are those with the characteristics listed below.

- Use a chemical that is representative of the candidate substance (in terms of purity and stability) so that any observed effects can be attributed to the candidate substance.
- No evidence of poor animal husbandry conditions (such as high mortality due to infection). Often information on animal husbandry conditions is not known and while this information is desirable, it is not a requirement.
- Exposure of animals to high enough doses (resulting in tolerable toxicities) for a sufficiently long duration (approaching the lifetime of the animal), but not to a dose that limits survival over the exposure period. The use of more than one dose level is ideal but is not a requirement.
- Have an appropriate comparison group (e.g., ideally unexposed, sham treated concurrent controls). The absence of an appropriate control group, by itself, is sufficient for judging a study to be inadequate for cancer evaluation.
- Have adequate statistical power to detect an effect, which is based on the number of animals used in a study, the incidence of tumors in control vs. treated group, and the rarity of the tumor.
- Perform full necropsies and histopathological examinations on all tissues. Ideally, animals are exposed to multiple doses that allow for statistical comparisons to the control group and dose-response analysis.

An ideal study would have the following characteristics, which are related to interpreting the study. In general, with the exception of route of exposure, these do not contribute as much weight to the overall evaluation of the study as the characteristics related to the validity of the study discussed above.

- The use of an exposure route comparable to human exposure.
- The use of animal model that is sensitive for detecting tumors and does not have high background rates for the observed tumors. Studies in both sexes are more informative than those testing only one sex. Often this information is not available.
- Availability of historical control data, which can be helpful in assessing the significance of a finding, especially in the case of rare tumors, lower powered studies, or assessment of background tumor incidences. Rare tumors will be considered in the assessment even if their incidences do not reach significance.
- Appropriate reporting of incidence data and statistical methods. If statistical tests are not reported, the study should at a minimum present incidence data for specific tumors so that statistical tests can be run.

Studies having elements that are judged to have some or major concerns may still be considered in the evaluation or can be considered to provide support to the more informative studies. It should also be noted that some concerns about a study element (such as inadequate observation and exposure period and statistical power) would decrease the sensitivity of a study to detect an effect; however, if despite these limitations positive findings were described, these studies would inform a cancer assessment. In contrast, other concerns (poor purity of the chemical) may lead to false positive or false negative results, and thus in general, studies having major concerns are considered to be inadequate for cancer evaluation.

Table E-1 Assessment of the Quality of Cancer Studies in Rats

| Weisburger et al. (1978) | NCI (1979) | Hecht et al. (1982) | NTP (1996) | Pliss (2004)
Substance characterization
Are there concerns that the purity solubility and stability of the chemical are not adequate for attributing any neoplastic effects to the substance? | Concerns: minimal Tested for purity, but only a non-specific purity was reported as 97% to 99% for most chemicals. Stability was only tested for 3 days and results were not reported. | Concerns: minimal Purity was tested and found to be >99%. Stability testing was not reported. | Concerns: minimal Reported as purified by recrystallization and melting point determination. No stability tests were reported. | Concerns: minimal Purity (100%) and stability in feed tested. | Concerns: minimal Purity reported as >99.7% with 0.2% p-toluidine as a contaminant. No stability tests were reported.
Animal husbandry
Are there concerns that the quality of the animal husbandry (e.g., care, diet, maintenance, and disease surveillance) is not adequate for attributing any neoplastic effects to the substance? | Few details were reported. | Concerns: minimal | Concerns: some No information on disease surveillance. Housing, diet described. | Concerns: minimal Studies done under U.S. FDA Good Laboratory Practice regulations; subclinical disease surveillance performed. | Minimal information on housing reported. No other information reported.
Study design
Are there concerns that the study design did not include randomization of animals to dose groups and blinding of dose groups? | No information reported | No information reported | No information reported | Concerns: minimal Animals were distributed randomly into groups of approximately equal initial mean body wts. | No information reported
Are there concerns that the dosing regimen (dose selection and dose groups, or other factors) is either not adequate for detecting a neoplastic effect (if present) or for attributing any tumor effects to the substance? | Concerns: minimal Two dose levels were tested and were based on the “maximum tolerated dose” of a 30-day study. Results of the 30-day study were not reported. Initial doses caused >10% body weight loss and were decreased after 3 months. | Concerns: minimal Two dose levels were tested and were based on the “MTD” of a 7-week study. These dose levels did not significantly decrease survival. | Concerns: minimal Only one exposed dose level tested; dose was toxic based on decreased survival after 88 wk (20% survival) compared to untreated controls (60% survival). Survival in control and treated groups comparable through week 68 of study. | Concerns: minimal One dose level tested, dose was toxic based on decreased of body weight gain (up to 27%) in the exposed group. | Concerns: some Only one dose level (30 mg, s.c.) tested, reported as “maximally tolerated dose;” however, no other information was provided
Are there concerns that the study duration (exposure and observation) is not adequate to detect a neoplastic effect, if present? | Concerns: minimal Exposure occurred for 18 months and observation was for 2 years. | Concerns: minimal Exposure and observation occurred for two years. | Concerns: minimal The exposure (73 wk) and observation duration (93 wk) were adequate although do not quite meet the ideal conditions of close to lifetime exposure. | Concerns: major Exposure (13 wk) and observation (26 wk) durations were short, only one dose level. | Concerns: minimum Study duration 2 years
Are there concerns that the concurrent control group was not adequate for evaluating the study? | Concerns: minimal A single group control and pooled control were used. | Concerns: minimal A concurrent control group was used that had less, but still sufficient numbers of, mice (20/sex) than the exposed groups (50/sex). | Concerns: minimal | Concerns: minimal | Concerns: minimal
Are there concerns that the study does not have adequate statistical power (number of animals per exposure and control group) to detect a neoplastic effect, if present? | Concerns: some 25 animals/exposed group and untreated control group, though a pooled control group had 111 animals. | Concerns: minimal | Concerns: minimal 30 males/exposed group. Some concern for rare tumors. | Concerns: some 20 animals/exposed group in the exposed groups; 10 animals in untreated control group. | Concern: some 25 animals/exposed group and untreated controls.
Endpoint assessment
Are there concerns that the assessment of study outcome (gross and microscopic tissue analysis) was not done blind? | No information reported | No information reported | No information reported | No information reported | No information reported
Are there concerns that the methods to access tumor outcome and the pathology procedures (necropsy, histology, or diagnosis) are not adequate for attributing the effects? | Concerns: minimal Complete necropsies and histological examinations were done on all major organs and gross lesions of animals that died after the first 6 months. | Concerns: minimal Complete necropsies and histological examinations were done on all major organs and gross lesions. | Concerns: minimal Complete necropsies and histological examinations were done on all major organs and gross lesions. | Concerns: minimal Complete necropsies and histological examinations were done on all organs and confirmed by an independent pathology laboratory. | Concerns: some Necropsies and histology were performed; however, it is unclear whether all major organ systems were examined.
Data interpretation
Are there concerns that survival-related effects could affect attributing the study findings to exposure? | Concerns: minimal No treatment related survival effects. | Concerns: some Decrease in survival at the high-dose group in both sexes. The study of males was stopped three weeks early because of low survival. | Concerns: some Survival was decreased to 20% in the exposed group compared with 60% in the untreated controls; however, survival did not sharply decrease until 18 months exposure. | Concerns: minimal No treatment related survival effects | Concerns: some Authors state that 30 animals (presumably of the 50 males and females combined) were available after 19.5 months and that 38 of 50 controls survived until 23 months
Are there concerns that the route of exposure is not adequate for evaluating the potential for human carcinogenicity? | Concerns: minimal Feeding | Concerns: minimal Feeding | Concerns: minimal Feeding | Concerns: minimal Feeding | Concerns: some Subcutaneous exposure
Are there concerns about the animal model (source, species, strain, or sex) that could affect study interpretation? | Concerns: some Only males were tested. | Concerns: minimal | Concerns: minimal Only male Fischer 344 rats were tested; concerns would be if no effects were observed. | Concerns: minimal Only male Fischer 344/N rats were tested; concern would be if no effects were observed. | Concerns: some An unspecified strain of male and female rats from an unreported source were tested.
Are historical control data reported? If not, this would be a concern for rare tumors, or tumors with high background. | No | Yes | No | No | No
Are there concerns that reporting of the data and statistical analyses are inadequate for evaluating the results? | Concerns: minimal | Concerns: minimal | Concerns: some Authors used chi-squared method to test for statistical significance, but no evidence that analyses were on o-tol exposed vs. control animals. Incidence data was available to perform pairwise comparisons using Fisher exact test. | Concerns: minimal | Concerns: major Data were not presented in a format that would allow for statistical analyses. All tumors combined for statistical analyses; no comparison of tumor burden to controls.
Overall assessment of study quality and utility for cancer assessment
Does this study have utility for cancer assessment? What is the overall level of concern for the quality of the study, and how would any concerns affect its interpretation? | Yes, minimal concerns in most key elements | Yes, minimal concerns in most key elements; | Yes, minimal concerns in most key elements | Positive findings (such as neoplasia, pre-neoplastic lesions), yes, minimal concerns Negative findings, no, major concerns Insufficient exposure and observation duration period. | Yes, some concerns: Most of the concerns would affect negative findings: one dose level, limited statistical power, uncertainty of completeness of necropsies

Table E-2 Assessment of the Quality of Cancer Studies in Other Experimental Animals: Mice, Hamsters, and Dogs

| Weisburger et al. (1978) | NCI (1979) | Hecht et al. (1983) (Hamsters) | Pliss (2004) (Dogs)
Substance characterization
Are there concerns that the purity solubility and stability of the chemical are not adequate for attributing any neoplastic effects to the substance? | Concerns: minimal Tested for purity, but only a non-specific purity was reported as 97% to 99% for most chemicals. Stability was only tested for 3 days and results were not reported. | Concerns: minimal Purity was tested and found to be >99%. Stability testing was not reported. | Concerns: minimal Reported as “pure” as determined by gas and thin layer chromatography; no stability tests were reported. | Concerns: minimal Purity reported as >99.7% with 0.2% p-toluidine as a contaminant. No stability tests were reported.
Animal husbandry
Are there concerns that the quality of the animal husbandry (e.g., care, diet, maintenance, and disease surveillance) is not adequate for attributing any neoplastic effects to the substance? | Few details were reported. | Concerns: minimal | Concerns: some No information on disease surveillance. Housing, diet described. | Minimal information on housing reported. No other information reported.
Study design
Are there concerns that the study design did not include randomization of animals to dose groups and blinding of dose groups? | No information reported | No information reported | No information reported | No information reported
Are there concerns that the dosing regimen (dose selection and dose groups, or other factors) is either not adequate for detecting a neoplastic effect (if present) or for attributing any tumor effects to the substance? | Concerns: minimal Two dose levels were tested and were based on the “maximum tolerated dose” of a 30-day study. Results of the 30-day study were not reported. Initial doses caused >10% body weight loss and were decreased after 3 months. | Concerns: minimal Two dose levels were tested and were based on the “MTD” of a 7-week study. These dose levels did not significantly decrease survival. | Concerns: minimal Only one dose level tested, dose was toxic based on decreased survival in the exposed group compared to control group. | Concerns: some Maximum tolerated dose exceeded (125 mg/kg, s.c.) in the first month; route of exposure changed to gelatin capsules by mouth for first month followed by gavage. No further lethal toxicities. Only one dose group (125 mg/kg) was tested.
Are there concerns that the study duration (exposure and observation) is not adequate to detect a neoplastic effect, if present? | Concerns: minimal Exposure occurred for 18 months and observation was for 21 months. | Concerns: minimal Exposure and observation occurred for two years. | Concerns: some The duration of exposure (52 wk) was short at 52 wk, observation duration (87 wk) was adequate although does not quite meet ideal condition (lifetime 2.5–3 yr). | Concerns: minimal Exposed close to lifespan (9 years)
Are there concerns that the concurrent control group was not adequate for evaluating the study? | Concerns: minimal A single group control and pooled control were used. | Concerns: minimal A concurrent control group was used that had less, but still sufficient numbers of, mice (20/sex) than the exposed groups (50/sex). | Concerns: minimal | Concerns: major No untreated control group was tested
Are there concerns that the study does not have adequate statistical power (number of animals per exposure and control group) to detect a neoplastic effect, if present? | Concerns: some 25 animals/sex/exposed group and untreated control group, though a pooled control group had 99 males and 102 females. | Concerns: minimal | Concerns: some 15 animals/group/sex | Concerns: major Only 3 dogs were exposed for more than 3 years
Endpoint assessment
Are there concerns that the assessment of study outcome (gross and microscopic tissue analysis) was not done blind? | No information reported | No information reported | No information reported | No information reported
Are there concerns that the methods to access tumor outcome and the pathology procedures (necropsy, histology, or diagnosis) are not adequate for attributing the effects? | Concerns: minimal Complete necropsies and histological examinations were done on all major organs and gross lesions of animals that died after the first 6 months. | Concerns: minimal Complete necropsies and histological examinations were done on all major organs and gross lesions. | Concerns: minimal Complete necropsies and histological examinations were done on all major organs and gross lesions. | Concerns: some Necropsies and histology were performed; however, it is unclear whether all major organ systems were examined.
Data interpretation
Are there concerns that survival-related effects could affect attributing the study findings to exposure? | Concerns: minimal No treatment related survival effects. | Concerns: minimal No treatment related survival effects. | Concerns: some Mean survival time (wk) was decreased in the exposed groups compared to the untreated controls (males 61.3 vs. 75.5; and females 57.8 vs. 68.7); may have decreased sensitivity for late occurring neoplasms. | Concerns: some Authors state that 2 of the 5 dogs died within a month after exposure, a 3rd dog died after ~3 yr.
Are there concerns that the route of exposure is not adequate for evaluating the potential for human carcinogenicity? | Concerns: minimal Feeding | Concerns: minimal Feeding | Concerns: some Subcutaneous exposure | Concerns: minimal Feeding/gavage
Are there concerns about the animal model (source, species, strain, or sex) that could affect study interpretation? | Concerns: minimal | Concerns: minimal | Concerns: minimal Both sexes of Syrian Golden hamsters were tested. | Concerns: minimal Dog considered to be a sensitive model human urinary bladder cancer.
Are historical control data reported? If not, this would be a concern for rare tumors, or tumors with high background. | No | Yes | No | No
Are there concerns that reporting of the data and statistical analyses are inadequate for evaluating the results? | Concerns: minimal | Concerns: minimal | Concerns: major Incidence data and statistical analyses were not reported. Stated that the incidence was not significantly different from control group. | Concerns: major Insufficient data to evaluate results
Overall assessment of study quality and utility for cancer assessment
Does this study have utility for cancer assessment? What is the overall level of concern for the quality of the study, and how would any concerns affect its interpretation? | Yes, minimal concerns in most key elements | Yes, minimal concerns in most key elements | Yes, some concerns in key elements. Most of the concerns would affect negative findings: short duration of exposure and observation; only one dose, limited statistical power | No, major concerns with key elements The lack of concurrent controls prevents attributing any tumor findings to exposure.